# Summary

1,4-Dichlorobenzene (1,4-DCB) is a chlorinated aromatic hydrocarbon that is used in various industrial and household applications, including as a fumigant for moth control, a deodorizer in urinal cakes, and an air freshener in domestic and public settings. These studies used a transcriptomic approach and standard toxicological endpoints to estimate the in vivo biological potency of 1,4-DCB. The data from these studies are intended to support risk assessment and establishment of acceptable exposure levels of 1,4-DCB in environmental and occupational settings.

In rats exposed to 1,4-DCB, the most sensitive apical endpoint was an increase in relative liver weight with a calculated benchmark dose (benchmark dose lower confidence limit)—BMD (BMD_L_)—of 191.4 (127.6) ppm. Increases in relative left kidney weight and absolute liver weight were the next most sensitive apical endpoint changes observed with BMDs (BMD_L_s) of 219.2 (89.4) and 245.5 (163.4) ppm, respectively. In mice exposed to 1,4-DCB, the most sensitive apical endpoint was a decrease in albumin/globulin ratio with a BMD (BMD_L_) of 15.1 (2.2) ppm. The next most sensitive apical endpoints observed were increases in relative liver weight and cholesterol concentration with BMDs (BMD_L_s) of 70.2 (47.4) and 71.0 (43.1) ppm, respectively.

In the heart, transcriptional changes at the gene set level were calculated to occur at a BMD (BMD_L_) as low as 141.4 (55.9) ppm, corresponding to cell cycle phase transition (GO:0044770) and mitotic cell cycle phase transition (GO:0044772), and as low as 91.0 (25.1) ppm in mice, corresponding to organic hydroxy compound biosynthetic process (GO:1901617). The most sensitive heart genes for which a reliable BMD could be determined were Lck, with a BMD (BMD_L_) of 31.7 (6.0) ppm, in rats and Krt18, with a BMD (BMD_L_) of 0.6 (0.1) ppm, in mice.

In the kidney, transcriptional changes at the gene set level were calculated to occur at a BMD (BMD_L_) as low as 121.0 (42.2) ppm in rats, corresponding to cell cycle phase transition (GO:0044770) and mitotic cell cycle phase transition (GO:0044772), and as low as 16.9 (2.0) ppm in mice, corresponding to circadian rhythm (GO:0007623). The most sensitive kidney gene in rats for which a reliable BMD could be determined was Srebf1 with a BMD (BMD_L_) of 31.8 (7.8) ppm. The most sensitive kidney gene in mice for which a reliable BMD could be determined was Chn1 with a BMD (BMD_L_) of 5.4 (0.9) ppm.

In the liver, transcriptional changes at the gene set level were calculated to occur at a BMD (BMD_L_) as low as 87.6 (59.6) ppm in rats, corresponding to xenobiotic metabolic process (GO:0006805), and as low as 6.3 (0.9) ppm in mice, corresponding to regulation of chromosome segregation (GO:0051983), positive regulation of cell cycle phase transition (GO:1901989), and positive regulation of mitotic cell cycle phase transition (GO:1901992). The most sensitive liver genes for which a reliable BMD could be determined were Cyp2b2 in rats and Cdc20 in mice with BMDs (BMD_L_s) of 48.4 (25.0) and 5.6 (0.7) ppm, respectively.

In the lung, transcriptional changes at the gene set level were calculated to occur at a BMD (BMD_L_) as low as 208.6 (55.4) ppm in rats, corresponding to chromosome segregation (GO:0007059), and as low as 1.4 (0.5) ppm in mice, corresponding to DNA replication (GO:0006260). One lung gene in mice had a BMD estimate below the lower limit of extrapolation (<0.333 ppm). The most sensitive lung genes for which a reliable BMD could be determined were Ddit4, with a BMD (BMD_L_) of 92.8 (13.6) ppm, in rats and Dtl and Ccna1 in mice, with BMDs (BMD_L_s) of 0.6 (0.2) and 0.6 (0.3) ppm, respectively.

In the ovary, transcriptional changes at the gene set level were calculated to occur at a BMD (BMD_L_) as low as 223.1 (90.9) ppm in rats, corresponding to ameboidal-type cell migration (GO:0001667). There were no active GO terms (i.e., no gene expression response at the gene set level) in mice exposed to 1,4-DCB. The most sensitive ovary genes for which a reliable BMD could be determined were Fosl1 in rats and Cyp2a4 in mice with BMDs (BMD_L_s) of 127.2 (22.7) and 48.8 (14.5) ppm, respectively.

Under the conditions of this short-term transcriptomic study in female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6D2F1/Crl mice, the most sensitive point of departure with a reliable estimate in rats was a transcriptional change in a heart gene, Lck, with a BMD (BMD_L_) of 31.7 (6.0) ppm. Apical endpoints and transcriptional changes at the gene set level provided potency estimates slightly higher than Lck. In mice, the most sensitive point of departure with a reliable estimate was a transcriptional change in a heart gene, Krt18, and two lung genes, Dtl and Ccna1, with BMDs (BMD_L_s) of 0.6 (0.1), 0.6 (0.2), and 0.6 (0.3) ppm, respectively. Transcriptional changes at the gene set level provided potency estimates slightly higher than Krt18, Dtl, and Ccna1 and apical endpoints provided potency estimates higher than Krt18, Dtl, and Ccna1.