# Results

## Apical Endpoint Analysis

### Animal Condition, Body Weights, and Organ Weights

#### Rats

One internal concentration assessment animal in the 800 ppm group was found dead on study day 4. All core rats exposed to 1,4-dichlorobenzene (1,4-DCB) survived to the end of the study. In the 800 ppm group, all core rats began exhibiting piloerection, bilateral dilated pupil, and moderate tremors on study day 0, with two of the rats also noted with lacrimation post exposure, one each on study days 1 and 3 (Appendix G). No significant change in terminal body weight was observed with exposure to 1,4-DCB (Table 2).

Table 2 Summary of Body Weights and Body Weight Gain of Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Endpoint^a,b^ | 0 ppm | 1 ppm | 10 ppm | 50 ppm | 150 ppm | 400 ppm | 800 ppm | BMD_1Std_ (ppm) | BMD_L1Std_ (ppm)
Rats
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Body Weight
Study Day
0 | 190.0 ± 3.8 | 186.5 ± 4.0 | 188.0 ± 4.9 | 193.5 ± 4.7 | 193.5 ± 4.6 | 190.1 ± 2.8 | 186.9 ± 1.9 | ND | ND
5 | 197.3 ± 4.0 | 188.6 ± 5.2 | 193.5 ± 5.4 | 196.6 ± 3.0 | 192.5 ± 5.8 | 189.5 ± 2.7 | 193.0 ± 2.6 | ND | ND
Body Weight Gain
Study Day Interval
0–5 | 7.3 ± 0.9 | 2.1 ± 1.9 | 5.5 ± 0.7 | 3.1 ± 2.0 | −1.0 ± 4.1** | −0.6 ± 1.5* | 6.1 ± 1.5 | ND | ND
Mice
n | 10 | 5 | 5 | 5 | 5 | 5 | NA | NA | NA
Body Weight
Study Day
0 | 18.3 ± 0.4 | 18.0 ± 0.3 | 18.5 ± 0.5 | 17.9 ± 0.4 | 18.4 ± 0.3 | 18.5 ± 0.4 | NA | ND | ND
5 | 18.4 ± 0.4 | 18.4 ± 0.3 | 18.7 ± 0.5 | 18.5 ± 0.3 | 19.0 ± 0.3 | 19.3 ± 0.6 | NA | ND | ND
Body Weight Gain
Study Day Interval
0–5 | 0.1 ± 0.1** | 0.4 ± 0.1 | 0.2 ± 0.4 | 0.6 ± 0.3 | 0.7 ± 0.1* | 0.8 ± 0.2* | NA | NVM | NVM

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm group. Statistical significance for the 0 ppm group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to 1 standard deviation from the mean; NA = not applicable; ND = not determined; NVM = nonviable model.

^a^ Data are displayed as mean ± standard error of the mean; body weight data are presented in grams.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

At study termination, absolute and relative left kidney weights were significantly increased in the ≥400 ppm groups with benchmark doses (benchmark dose lower confidence limits)—BMDs (BMD_L_s)—of 259.8 (93.3) and 219.2 (89.4) ppm, respectively (Table 3). There was also a significant increase in relative right kidney weight at 400 ppm; a BMD (BMD_L_) was not determined for increased relative right kidney weight because no viable model was available. A significant increase in absolute and relative liver weights occurred in the ≥400 ppm groups with BMDs (BMD_L_s) of 245.5 (163.4) and 191.4 (127.6) ppm, respectively. The organ weights mentioned above all exhibited positive trends. The BMDs for all organ weights were reviewed by a subject matter expert for anomalous modeling results (i.e., when the traditional statistics are notably different from the calculated BMD values). Significant trend and pairwise comparisons were not observed in absolute right kidney weight or absolute or relative heart or lung weights (Appendix G).

Table 3 Summary of Select Organ Weights of Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Endpoint^a,b,c^ | 0 ppm | 1 ppm | 10 ppm | 50 ppm | 150 ppm | 400 ppm | 800 ppm | BMD_1Std_ (ppm) | BMD_L1Std_ (ppm)
Rats
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Terminal Body Wt. (g) | 197.3 ± 4.0 | 188.6 ± 5.2 | 193.5 ± 5.4 | 196.6 ± 3.0 | 192.5 ± 5.8 | 189.5 ± 2.7 | 193.0 ± 2.6 | ND | ND
Left Kidney
Absolute (g) | 0.62 ± 0.01** | 0.62 ± 0.02 | 0.62 ± 0.02 | 0.62 ± 0.01 | 0.63 ± 0.02 | 0.67 ± 0.00* | 0.68 ± 0.03* | 259.8 | 93.3
Relative (mg/g)^d^ | 3.14 ± 0.06** | 3.29 ± 0.08 | 3.20 ± 0.09 | 3.15 ± 0.05 | 3.27 ± 0.11 | 3.53 ± 0.05** | 3.52 ± 0.15** | 219.2 | 89.4
Right Kidney
Relative (mg/g) | 3.22 ± 0.06* | 3.39 ± 0.08 | 3.35 ± 0.07 | 3.23 ± 0.06 | 3.38 ± 0.13 | 3.62 ± 0.09** | 3.47 ± 0.13 | NVM | NVM
Liver
Absolute (g) | 7.40 ± 0.18** | 7.29 ± 0.33 | 7.25 ± 0.25 | 7.73 ± 0.13 | 7.43 ± 0.29 | 8.68 ± 0.27** | 11.50 ± 0.40** | 245.5 | 163.4
Relative (mg/g) | 37.51 ± 0.75** | 38.60 ± 0.90 | 37.46 ± 0.77 | 39.38 ± 0.97 | 38.54 ± 0.60 | 45.81 ± 1.42** | 59.64 ± 2.21** | 191.4 | 127.6
Mice
n | 10 | 5 | 5 | 5 | 5 | 5 | NA | NA | NA
Terminal Body Wt. (g) | 18.4 ± 0.4 | 18.4 ± 0.3 | 18.7 ± 0.5 | 18.5 ± 0.3 | 19.0 ± 0.3 | 19.3 ± 0.6 | NA | ND | ND
Liver
Absolute (g) | 0.87 ± 0.02** | 0.92 ± 0.03 | 0.88 ± 0.04 | 0.92 ± 0.04 | 1.08 ± 0.03** | 1.65 ± 0.04** | NA | 83.7 | 59.2
Relative (mg/g) | 47.44 ± 0.80** | 49.78 ± 1.57 | 47.02 ± 1.17 | 49.55 ± 2.32 | 56.92 ± 0.88** | 85.72 ± 1.11** | NA | 70.2 | 47.4

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm group. Statistical significance for the 0 ppm group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to 1 standard deviation from the mean; NA = not applicable; ND = not determined; NVM = nonviable model.

^a^ Descriptions of organ weight endpoints and changes are provided in Appendix F.

^b^ Data are displayed as mean ± standard error of the mean.

^c^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^ Relative organ weights (organ weight-to-body weight ratios) are given as mg organ weight/g body weight.

#### Mice

One internal concentration assessment animal in the 50 ppm group was found dead on study day 2. All core mice exposed to 1,4-DCB survived to the end of the study with no adverse clinical observations noted (Appendix G). There were no significant changes in terminal body weight in core mice exposed to 1,4-DCB (Table 2).

At study termination, absolute and relative liver weights were significantly increased in the ≥150 ppm groups with both endpoints exhibiting a positive trend. The BMDs (BMD_L_s) for increased absolute and relative liver weights were 83.7 (59.2) and 70.2 (47.4) ppm, respectively (Table 3). Significant trend and pairwise comparisons were not observed in absolute or relative left or right kidney weights or absolute or relative heart or lung weights (Appendix G).

### Clinical Pathology

#### Rats

At study termination, the reticulocyte count had a positive trend with a significant increase at 800 ppm; the BMD (BMD_L_) was 437.0 (307.0) ppm (Table 4). Sorbitol dehydrogenase (SDH) activity and triglyceride concentration had positive trends with significant increases in the 800 ppm group (Table 5). The BMD (BMD_L_) for increased triglycerides was 489.4 (332.3) ppm, whereas a BMD (BMD_L_) for SDH was not determined because no viable model was available. Cholesterol concentration had a positive trend with significant increases in the 400 and 800 ppm groups; the BMD (BMD_L_) was 259.4 (126.2) ppm.

Table 4 Summary of Select Hematology Data for Female Rats Exposed to 1,4-Dichlorobenzene for Five Days

Endpoint^a,b^ | 0 ppm | 1 ppm | 10 ppm | 50 ppm | 150 ppm | 400 ppm | 800 ppm | BMD_1Std_ (ppm) | BMD_L1Std_ (ppm)
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Reticulocytes (10^6^/µL) | 0.2350 ± 0.0071** | 0.2148 ± 0.0098 | 0.2385 ± 0.0093 | 0.2546 ± 0.0081 | 0.2214 ± 0.0166 | 0.2436 ± 0.0112 | 0.3177 ± 0.0137** | 437.0 | 307.0

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm group. Statistical significance for the 0 ppm group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to 1 standard deviation from the mean; NA = not applicable.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

Table 5 Summary of Select Clinical Chemistry Data for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Endpoint^a,b,c^ | 0 ppm | 1 ppm | 10 ppm | 50 ppm | 150 ppm | 400 ppm | 800 ppm | BMD_1Std_ (ppm) | BMD_L1Std_ (ppm)
Rats
Sorbitol Dehydrogenase (IU/L) | 10.2 ± 0.6* (10) | 13.1 ± 3.1 (5) | 9.7 ± 0.6 (5) | 9.4 ± 1.3 (5) | 10.6 ± 2.6 (5) | 40.4 ± 23.7 (5) | 23.6 ± 1.5* (5) | NVM | NVM
Triglycerides (mg/dL) | 54.9 ± 3.6** (10) | 75.6 ± 5.2 (5) | 69.0 ± 7.1 (5) | 73.6 ± 9.4 (5) | 62.2 ± 8.1 (5) | 70.0 ± 6.4 (5) | ^112.8 ±^ 10.4** (5) | 489.4 | 332.3
Cholesterol (mg/dL) | 91.7 ± 4.2** (10) | 92.4 ± 2.2 (5) | 96.0 ± 6.5 (5) | 99.0 ± 8.1 (5) | 105.2 ± 4.3 (5) | 111.0 ± 4.6* (5) | 143.2 ± 5.3** (5) | 259.4 | 126.2
Mice
A/G Ratio | 2.94 ± 0.11** (3) | 2.86 (1) | 2.78 ± 0.03 (2) | –^d^ | 2.59 (1) | 2.26 ± 0.02* (2) | NA | 15.1 | 2.2
Cholesterol (mg/dL) | 124.3 ± 3.6** (8) | 113.7 ± 5.2 (3) | 117.7 ± 2.7 (3) | 126.5 ± 9.0 (4) | 159.3 ± 4.4* (4) | 269.3 ± 15.1* (3) | NA | 71.0 | 43.1

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm group. Statistical significance for the 0 ppm group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to 1 standard deviation from the mean; NA = not applicable; NVM = nonviable model; A/G ratio = albumin/globulin ratio.

^a^ Data are displayed as mean ± standard error of the mean (number of animals).

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests. Data with sample size of one were included in the trend test but excluded from the pairwise test.

^c^ Clinical chemistry data not reported were removed as outliers or were due to preanalytical or analytical conditions or errors, including but not limited to below linearity, short sample, quantity not sufficient, or extreme hemolysis.

^d^ No data were available due to insufficient volume available for analysis.

#### Mice

Because of serum volume limitations (i.e., quantity not sufficient), some pairwise statistical comparisons across different exposure groups and involving different parameters (Appendix G) were underpowered and may not accurately reflect the existence of “no effect.”

The albumin/globulin (A/G) ratio had a negative trend with a significant decrease in the 400 ppm group (Table 5); the decrease was driven by a (nonsignificant) increase in globulin concentration (Appendix G). The BMD (BMD_L_) for decreased A/G ratio was 15.1 (2.2) ppm. Cholesterol concentration had a positive trend with significant increases in the 150 and 400 ppm groups; the BMD (BMD_L_) was 71.0 (43.1) ppm.

### Apical Endpoint Benchmark Dose Summary

A summary of the calculated BMDs for each toxicological endpoint, by species, is provided in Table 6. The endpoint-specific lowest-observed-effect level (LOEL) and no-observed-effect level (NOEL) are included and could be informative for endpoints that lack a calculated BMD either because no viable model was available or because the estimated BMD was below the lower limit of extrapolation (<0.333 ppm).

Table 6 BMD, BMD_L_, LOEL, and NOEL Summary for Apical Endpoints, Sorted by BMD or LOEL from Low to High for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Endpoint | BMD_1Std_ (ppm) | BMD_L1Std_ (ppm) | LOEL (ppm)^a^ | NOEL (ppm) | Direction of Change
Rats
Relative Liver Weight | 191.4 | 127.6 | 400 | 150 | UP
Relative Left Kidney Weight | 219.2 | 89.4 | 400 | 150 | UP
Absolute Liver Weight | 245.5 | 163.4 | 400 | 150 | UP
Cholesterol | 259.4 | 126.2 | 400 | 150 | UP
Absolute Left Kidney Weight | 259.8 | 93.3 | 400 | 150 | UP
Reticulocytes | 437.0 | 307.0 | 800 | 400 | UP
Triglycerides | 489.4 | 332.3 | 800 | 400 | UP
Relative Right Kidney Weight | NVM | NVM | 400 | 150 | UP
Sorbitol Dehydrogenase | NVM | NVM | 800 | 400 | UP
Mice
A/G Ratio | 15.1 | 2.2 | 400 | 150 | DOWN
Relative Liver Weight | 70.2 | 47.4 | 150 | 50 | UP
Cholesterol | 71.0 | 43.1 | 150 | 50 | UP
Absolute Liver Weight | 83.7 | 59.2 | 150 | 50 | UP
Body Weight Gain | NVM | NVM | 150 | 50 | UP

BMD = benchmark dose; BMD_L_ = benchmark dose lower confidence limit; LOEL = lowest-observed-effect level; NOEL = no-observed-effect level; BMD_1Std_ = benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to 1 standard deviation from the mean; NVM = no viable model; A/G ratio = albumin/globulin ratio.

^a^ Values in bold text indicate the LOEL of endpoints for which a BMD could not be calculated.

## Gene Set Benchmark Dose Analysis

Chemical-induced alterations in heart, kidney, liver, lung, and ovary gene transcript expression were examined to determine those gene sets most sensitive to 1,4-DCB exposure. To that end, BMD analysis of transcripts and gene sets (Gene Ontology [GO] biological process) was conducted to determine the potency of the chemical to elicit gene expression changes in the heart, kidney, liver, lung, and ovary. This analysis used transcript-level BMD data to assess an aggregate score of gene set potency (5th percentile of transcript BMDs) and enrichment.

The “active” gene sets with the lowest 5th percentile BMD values are shown in the heart (Table 7), kidney (Table 8), liver (Table 9), lung (Table 10), and ovary (Table 11), with a summary of the top gene set per tissue based on lowest BMD 5th percentile provided in Table 12. No gene sets had estimated 5th percentile BMD values <0.333 ppm. The gene sets shown in Table 7 to Table 11 should be interpreted with caution from the standpoint of the underlying biological mechanism and any relationship to toxicity or toxic agents referenced in the GO term definitions. The data primarily should be considered as a metric of potency for chemical-induced transcriptional changes (i.e., a concerted biological change) that could serve as a surrogate of estimated biological potency and, by extension, toxicological potency when more definitive toxicological data are unavailable.

Table 7 Top 10 Heart Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Category Name^a,b^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^c^ | Genes with Changed Direction Up/Down
Rats
GO:0044770 cell cycle phase transition | 5/58 (8.6%) | 141.4 (55.9–292.9) | 0/5
GO:0044772 mitotic cell cycle phase transition | 5/52 (9.6%) | 141.4 (55.9–292.9) | 0/5
GO:0051301 cell division | 6/84 (7.1%) | 181.5 (65.8–517.4) | 0/6
GO:0007049 cell cycle | 4/45 (8.9%) | 192.5 (68.7–382.0) | 0/4
GO:0000226 microtubule cytoskeleton organization | 4/80 (5.0%) | 197.5 (80.5–710.7) | 0/4
GO:0007059 chromosome segregation | 4/41 (9.8%) | 202.9 (85.1–551.4) | 0/4
GO:1903047 mitotic cell cycle process | 11/149 (7.4%) | 242.4 (96.3–435.9) | 0/11
GO:0022402 cell cycle process | 12/194 (6.2%) | 282.0 (108.6–1,328.0) | 0/12
GO:0019730 antimicrobial humoral response | 5/43 (11.6%) | 333.8 (156.8–476.7) | 2/3
GO:0006959 humoral immune response | 5/80 (6.3%) | 347.4 (174.4–695.6) | 2/3
Mice
GO:1901617 organic hydroxy compound biosynthetic process | 3/52 (5.8%) | 91.0 (25.1–495.5) | 3/0
GO:0007623 circadian rhythm | 3/49 (6.1%) | 139.5 (37.4–273.5) | 2/1
GO:0030595 leukocyte chemotaxis | 3/49 (6.1%) | 178.4 (91.9–411.5) | 3/0
GO:0097529 myeloid leukocyte migration | 3/51 (5.9%) | 178.4 (91.9–411.5) | 3/0

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology.

^a^ Active genes and GO biological process definitions are available in Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ Only four heart GO biological process gene sets were active in mice.

^c^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

Table 8 Top 10 Kidney Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Genes with Changed Direction Up/Down
Rats
GO:0044770 cell cycle phase transition | 4/58 (6.9%) | 121.0 (42.2–652.8) | 1/3
GO:0044772 mitotic cell cycle phase transition | 4/52 (7.7%) | 121.0 (42.2–652.8) | 1/3
GO:0001822 kidney development | 6/57 (10.5%) | 197.7 (91.7–305.6) | 5/1
GO:0019218 regulation of steroid metabolic process | 5/49 (10.2%) | 224.1 (73.8–NC) | 4/1
GO:0030324 lung development | 4/45 (8.9%) | 224.1 (73.8–NC) | 3/1
GO:0006694 steroid biosynthetic process | 6/54 (11.1%) | 225.9 (89.2–NC) | 4/2
GO:0008203 cholesterol metabolic process | 5/54 (9.3%) | 225.9 (89.2–NC) | 3/2
GO:0016125 sterol metabolic process | 5/56 (8.9%) | 225.9 (89.2–NC) | 3/2
GO:0046165 alcohol biosynthetic process | 6/42 (14.3%) | 225.9 (89.2–NC) | 5/1
GO:0001676 long-chain fatty acid metabolic process | 5/55 (9.1%) | 226.7 (96.8–365.3) | 5/0
Mice
GO:0007623 circadian rhythm | 5/49 (10.2%) | 16.9 (2.0–793.4) | 3/2
GO:0015850 organic hydroxy compound transport | 4/58 (6.9%) | 17.6 (3.9–778.1) | 3/1
GO:0006869 lipid transport | 5/77 (6.5%) | 22.5 (5.6–84.1) | 4/1
GO:0010565 regulation of cellular ketone metabolic process | 3/56 (5.4%) | 107.2 (74.6–880.6) | 3/0
GO:0006805 xenobiotic metabolic process | 6/56 (10.7%) | 108.3 (48.2–389.5) | 6/0
GO:0015718 monocarboxylic acid transport | 3/52 (5.8%) | 112.1 (76.4–186.6) | 2/1
GO:0048511 rhythmic process | 6/89 (6.7%) | 129.9 (83.8–241.2) | 4/2
GO:0033559 unsaturated fatty acid metabolic process | 5/40 (12.5%) | 136.9 (55.1–282.5) | 5/0
GO:0006631 fatty acid metabolic process | 8/117 (6.8%) | 139.4 (60.5–491.7) | 8/0
GO:0006690 icosanoid metabolic process | 5/43 (11.6%) | 139.4 (60.5–491.7) | 5/0

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology; NC = nonconvergent.

^a^ Active genes and GO biological process definitions are available in Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

Table 9 Top 10 Liver Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Genes with Changed Direction Up/Down
Rats
GO:0006805 xenobiotic metabolic process | 20/59 (33.9%) | 87.6 (59.6–136.7) | 18/2
GO:0001676 long-chain fatty acid metabolic process | 16/55 (29.1%) | 92.8 (52.7–142.7) | 15/1
GO:0006690 icosanoid metabolic process | 14/50 (28.0%) | 92.8 (52.7–142.7) | 13/1
GO:0033559 unsaturated fatty acid metabolic process | 16/54 (29.6%) | 92.8 (52.7–142.7) | 15/1
GO:0120254 olefinic compound metabolic process | 15/64 (23.4%) | 116.4 (63.4–152.0) | 13/2
GO:0006720 isoprenoid metabolic process | 17/41 (41.5%) | 143.6 (107.8–165.0) | 15/2
GO:0071384 cellular response to corticosteroid stimulus | 9/55 (16.4%) | 153.0 (59.6–271.9) | 6/3
GO:0071385 cellular response to glucocorticoid stimulus | 8/52 (15.4%) | 153.0 (59.6–271.9) | 5/3
GO:0098754 detoxification | 16/58 (27.6%) | 153.4 (98.2–219.2) | 16/0
GO:0071383 cellular response to steroid hormone stimulus | 10/62 (16.1%) | 158.6 (44.1–339.0) | 6/4
Mice
GO:0051983 regulation of chromosome segregation | 22/45 (48.9%) | 6.3 (0.9–28.2) | 19/3
GO:1901989 positive regulation of cell cycle phase transition | 19/53 (35.9%) | 6.3 (0.9–28.2) | 15/4
GO:1901992 positive regulation of mitotic cell cycle phase transition | 17/43 (39.5%) | 6.3 (0.9–28.2) | 13/4
GO:0007051 spindle organization | 15/40 (37.5%) | 6.9 (1.1–32.3) | 15/0
GO:0045931 positive regulation of mitotic cell cycle | 19/60 (31.7%) | 6.9 (1.1–32.3) | 13/6
GO:0007088 regulation of mitotic nuclear division | 18/47 (38.3%) | 7.7 (1.1–39.5) | 15/3
GO:0033044 regulation of chromosome organization | 27/69 (39.1%) | 7.7 (1.1–39.5) | 20/7
GO:0044770 cell cycle phase transition | 28/63 (44.4%) | 7.7 (1.1–39.5) | 21/7
GO:0044772 mitotic cell cycle phase transition | 22/55 (40.0%) | 7.7 (1.1–39.5) | 17/5
GO:0051783 regulation of nuclear division | 19/52 (36.5%) | 7.7 (1.1–39.5) | 16/3

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology.

^a^ Active genes and GO biological process definitions are available in Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

Table 10 Top 10 Lung Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Genes with Changed Direction Up/Down
Rats
GO:0007059 chromosome segregation | 9/41 (22.0%) | 208.6 (55.4–1,082.9) | 0/9
GO:0140694 nonmembrane-bounded organelle assembly | 6/59 (10.2%) | 236.8 (65.6–NC) | 0/6
GO:0007049 cell cycle | 6/45 (13.3%) | 247.7 (69.6–NC) | 0/6
GO:0048568 embryonic organ development | 5/47 (10.6%) | 264.4 (73.4–2,060.4) | 3/2
GO:0045931 positive regulation of mitotic cell cycle | 3/51 (5.9%) | 288.7 (135.6–NC) | 0/3
GO:1901989 positive regulation of cell cycle phase transition | 3/43 (7.0%) | 288.7 (135.6–NC) | 0/3
GO:1901990 regulation of mitotic cell cycle phase transition | 7/94 (7.5%) | 288.7 (135.6–NC) | 1/6
GO:0051301 cell division | 8/84 (9.5%) | 289.6 (102.8–NC) | 0/8
GO:1901987 regulation of cell cycle phase transition | 11/116 (9.5%) | 293.1 (122.5–NC) | 1/10
GO:0050728 negative regulation of inflammatory response | 5/51 (9.8%) | 293.3 (143.2–448.6) | 2/3
Mice
GO:0006260 DNA replication | 3/43 (7.0%) | 1.4 (0.5–1,130.8) | 3/0
GO:0006805 xenobiotic metabolic process | 5/56 (8.9%) | 2.9 (0.4–54.2) | 4/1
GO:0000209 protein polyubiquitination | 3/42 (7.1%) | 3.8 (0.8–14.9) | 3/0
GO:0016567 protein ubiquitination | 4/68 (5.9%) | 3.8 (0.8–14.9) | 4/0
GO:0032446 protein modification by small protein conjugation | 4/79 (5.1%) | 3.8 (0.8–14.9) | 4/0
GO:0006575 cellular modified amino acid metabolic process | 5/59 (8.5%) | 14.1 (2.1–56.6) | 5/0
GO:0048545 response to steroid hormone | 3/52 (5.8%) | 68.8 (9.1–117.4) | 2/1
GO:0008203 cholesterol metabolic process | 3/48 (6.3%) | 75.4 (33.3–148.1) | 2/1
GO:0016125 sterol metabolic process | 3/49 (6.1%) | 75.4 (33.3–148.1) | 2/1
GO:1902652 secondary alcohol metabolic process | 3/53 (5.7%) | 75.4 (33.3–148.1) | 2/1

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology; NC = nonconvergent.

^a^ Active genes and GO biological process definitions are available in Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

Table 11 Top 10 Ovary Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats Exposed to 1,4-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Genes with Changed Direction Up/Down
GO:0001667 ameboidal-type cell migration | 5/55 (9.1%) | 223.1 (90.9–432.8) | 4/1
GO:2001235 positive regulation of apoptotic signaling pathway | 6/58 (10.3%) | 282.7 (140.2–432.6) | 3/3
GO:0061041 regulation of wound healing | 5/59 (8.5%) | 309.9 (178.5–463.5) | 3/2
GO:0048639 positive regulation of developmental growth | 5/50 (10.0%) | 332.8 (176.6–485.1) | 3/2
GO:0030307 positive regulation of cell growth | 3/47 (6.4%) | 335.6 (203.0–460.4) | 2/1
GO:0015850 organic hydroxy compound transport | 5/60 (8.3%) | 347.9 (198.4–485.0) | 0/5
GO:0002526 acute inflammatory response | 3/43 (7.0%) | 354.0 (206.0–481.4) | 3/0
GO:2001242 regulation of intrinsic apoptotic signaling pathway | 6/75 (8.0%) | 366.2 (144.6–NC) | 4/2
GO:0051385 response to mineralocorticoid | 3/45 (6.7%) | 382.1 (233.3–525.2) | 1/2
GO:1903034 regulation of response to wounding | 5/69 (7.3%) | 383.0 (243.8–527.7) | 3/2

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology; NC = nonconvergent.

^a^ Active genes and GO biological process definitions are available in Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

Table 12 Most Potent Gene Ontology Biological Process Gene Set per Tissue, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Tissue | Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Genes with Changed Direction Up/Down
Rats
Liver | GO:0006805 xenobiotic metabolic process | 20/59 (33.9%) | 87.6^c^ (59.6−136.7) | 18/2
Kidney | GO:0044770 cell cycle phase transition | 4/58 (6.9%) | 121.0 (42.2−652.8) | 1/3
Heart | GO:0044770 cell cycle phase transition | 5/58 (8.6%) | 141.4 (55.9−292.9) | 0/5
Lung | GO:0007059 chromosome segregation | 9/41 (22.0%) | 208.6 (55.4−1,082.9) | 0/9
Ovary | GO:0001667 ameboidal-type cell migration | 5/55 (9.1%) | 223.1 (90.9−432.8) | 4/1
Mice
Lung | GO:0006260 DNA replication | 3/43 (7.0%) | 1.4^c^ (0.5−1,130.8) | 3/0
Liver | GO:0051983 regulation of chromosome segregation | 22/45 (48.9%) | 6.3 (0.9−28.2) | 19/3
Kidney | GO:0007623 circadian rhythm | 5/49 (10.2%) | 16.9 (2.0−793.4) | 3/2
Heart | GO:1901617 organic hydroxy compound biosynthetic process | 3/52 (5.8%) | 91.0 (25.1−495.5) | 3/0

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology.

^a^ Active genes and GO biological process definitions are available in Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

^c^ Transcriptional point of departure determined based on the lowest Gene Ontology biological process BMD_rd25_ 5th percentile value.

### Heart

#### Rats

The most sensitive GO biological processes for which a BMD value could be reliably calculated were cell cycle phase transition (GO:0044770) and mitotic cell cycle phase transition (GO:0044772), both with a 5th percentile BMD (BMD_L_) of 141.4 (55.9) ppm (Table 7).

#### Mice

The most sensitive GO biological processes for which a BMD value could be reliably calculated were organic hydroxy compound biosynthetic process (GO:1901617) and circadian rhythm (GO:0007623) with 5th percentile BMDs (BMD_L_s) of 91.0 (25.1) and 139.5 (37.4) ppm, respectively (Table 7). The full list of affected gene sets in the heart of female rats and mice can be found in Appendix G.

### Kidney

#### Rats

The most sensitive GO biological processes for which a BMD value could be reliably calculated were cell cycle phase transition (GO:0044770) and mitotic cell cycle phase transition (GO:0044772), both with a 5th percentile BMD (BMD_L_) of 121.0 (42.2) ppm (Table 8).

#### Mice

The most sensitive GO biological processes for which a BMD value could be reliably calculated were circadian rhythm (GO:0007623) and organic hydroxy compound transport (GO:0015850) with 5th percentile BMDs (BMD_L_s) of 16.9 (2.0) and 17.6 (3.9) ppm, respectively (Table 8). The full list of affected gene sets in the kidney of female rats and mice can be found in Appendix G.

### Liver

#### Rats

The most sensitive GO biological processes for which a BMD value could be reliably calculated were xenobiotic metabolic process (GO:0006805), long-chain fatty acid metabolic process (GO:0001676), icosanoid metabolic process (GO:0006690), and unsaturated fatty acid metabolic process (GO:0033559) with 5th percentile BMDs (BMD_L_s) of 87.6 (59.6), 92.8 (52.7), 92.8 (52.7), and 92.8 (52.7) ppm, respectively (Table 9).

#### Mice

The most sensitive GO biological processes for which a BMD value could be reliably calculated were regulation of chromosome segregation (GO:0051983), positive regulation of cell cycle phase transition (GO:1901989), and positive regulation of mitotic cell cycle phase transition (GO:1901992), all three with a 5th percentile BMD (BMD_L_) of 6.3 (0.9) ppm (Table 9). The full list of affected gene sets in the liver of female rats and mice can be found in Appendix G.

### Lung

#### Rats

The most sensitive GO biological processes for which a BMD value could be reliably calculated were chromosome segregation (GO:0007059) and nonmembrane-bounded organelle assembly (GO:0140694) with 5th percentile BMDs (BMD_L_s) of 208.6 (55.4) and 236.8 (65.6) ppm, respectively (Table 10).

#### Mice

The most sensitive GO biological processes for which a BMD value could be reliably calculated were DNA replication (GO:0006260) and xenobiotic metabolic process (GO:0006805) with 5th percentile BMDs (BMD_L_s) of 1.4 (0.5) and 2.9 (0.4) ppm, respectively (Table 10). The full list of affected gene sets in the lung of female rats and mice can be found in Appendix G.

### Ovary

#### Rats

The most sensitive GO biological processes for which a BMD value could be reliably calculated were ameboidal-type cell migration (GO:0001667) and positive regulation of apoptotic signaling pathway (GO:2001235) with 5th percentile BMDs (BMD_L_s) of 223.1 (90.9) and 282.7 (140.2) ppm, respectively (Table 11). The full list of affected gene sets in the ovary of female rats can be found in ‎Appendix G.

#### Mice

In mice exposed to 1,4-DCB, there were no active GO terms (i.e., no gene expression response at the gene set level).

### Gene Set Benchmark Dose Summary

A summary of the most potent gene set per tissue is provided in Table 12. In rats exposed to 1,4-DCB, the liver had the gene set with the lowest BMD 5th percentile value, corresponding to xenobiotic metabolic process (GO:0006805) with a BMD (BMD_L_) of 87.6 (59.6) ppm. In mice, the lung had the gene set with the lowest BMD 5th percentile value, corresponding to DNA replication (GO:0006260) with a BMD (BMD_L_) of 1.4 (0.5) ppm.

## Gene Benchmark Dose Analysis

The top 10 genes ranked by BMD potency are shown in the heart (Table 13), kidney (Table 14), liver (Table 15), lung (Table 16), and ovary (Table 17). No genes had estimated median BMD values <0.333 ppm with the exception of one lung gene in mice. As with the GO analysis, the biological or toxicological significance of the changes in gene expression shown in Table 13 to Table 17 should be interpreted with caution. The data primarily should be considered as a metric of potency for chemical-induced transcriptional changes that could serve as a conservative surrogate of estimated biological potency, and by extension toxicological potency, when more definitive toxicological data are unavailable.

Table 13 Top 10 Heart Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Gene Symbol^a^ | BMD_rd25_ (BMD_Lrd25_–BMD_Urd25_) in ppm | Maximum Fold Change | Direction of Expression Change
Rats
Lck | 31.7 (6.0–NC) | 1.4 | DOWN
Spp1 | 108.2 (30.6–345.5) | 1.7 | UP
Ccnb2 | 124.3 (51.4–277.6) | 2.1 | DOWN
Ccnb2-ps2 | 124.3 (51.4–277.6) | 2.1 | DOWN
Ccna2 | 158.4 (60.3–308.2) | 2.1 | DOWN
Kif18b | 165.4 (51.1–324.1) | 2.3 | DOWN
Prc1 | 173.4 (45.9–395.4) | 2.0 | DOWN
Mki67 | 176.8 (47.7–372.0) | 1.9 | DOWN
Rt1-da | 187.5 (72.3–411.3) | 1.6 | DOWN
Dbp | 189.0 (183.6–228.8) | 6.9 | UP
Mice
Krt18 | 0.6 (0.1–128.8) | 2.7 | UP
S100a4 | 1.3 (0.1–150.1) | 2.0 | UP
Star | 3.4 (0.5–66.1) | 1.8 | UP
Lcn2 | 4.5 (0.6–33.0) | 1.7 | DOWN
Ddit4 | 21.8 (4.0–82.2) | 2.3 | DOWN
Ephx1 | 52.9 (13.9–109.4) | 1.9 | UP
Dbp | 60.3 (18.1–122.4) | 4.7 | UP
Abcg1 | 91.1 (34.2–176.0) | 2.0 | UP
Bhlhe40 | 93.4 (38.8–174.3) | 1.8 | UP
Ifi44 | 95.0 (21.3–431.5) | 1.6 | DOWN

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; NC = nonconvergent.

^a^ Gene definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table 14 Top 10 Kidney Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Gene Symbol^a^ | BMD_rd25_ (BMD_Lrd25_–BMD_Urd25_) in ppm | Maximum Fold Change | Direction of Expression Change
Rats
Srebf1 | 31.8 (7.8–123.9) | 1.6 | UP
Ccnb2 | 77.8 (29.5–183.5) | 1.8 | DOWN
Ccnb2-ps2 | 77.8 (29.5–183.5) | 1.8 | DOWN
Cyp4a2 | 125.1 (49.5–193.2) | 3.1 | UP
Cyp4a3 | 137.6 (56.5–190.5) | 2.9 | UP
Kif22 | 139.6 (48.2–291.1) | 1.8 | DOWN
Mki67 | 150.4 (59.2–331.7) | 1.7 | DOWN
Cks2 | 164.3 (55.0–1,122.1) | 1.6 | DOWN
Dhcr7 | 190.4 (20.9–NC) | 1.5 | DOWN
Mfap4 | 210.5 (55.7–447.5) | 1.9 | DOWN
Mice
Chn1 | 5.4 (0.9–213.8) | 1.5 | DOWN
Ces1g | 7.6 (2.2–19.4) | 1.7 | UP
Acaa1b | 15.3 (3.2–268.4) | 1.5 | UP
Nfil3 | 15.4 (3.2–75.5) | 2.1 | DOWN
Dbp | 16.6 (1.9–100.5) | 4.1 | UP
Ces1d | 17.1 (2.1–1,486.2) | 1.5 | UP
Abcc3 | 18.0 (5.6–70.0) | 1.6 | DOWN
Rnf125 | 20.5 (3.2–175.4) | 1.6 | DOWN
Hlf | 21.7 (5.7–79.0) | 1.7 | UP
Slc51a | 26.9 (5.6–98.2) | 1.7 | UP

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; NC = nonconvergent.

^a^ Gene definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table 15 Top 10 Liver Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Gene Symbol^a^ | BMD_rd25_ (BMD_Lrd25_–BMD_Urd25_) in ppm | Maximum Fold Change | Direction of Expression Change
Rats
Cyp2b2 | 48.4 (25.0–78.3) | 87.1 | UP
Cyp2b1 | 69.9 (43.9–101.5) | 195.0 | UP
Abcc3 | 103.8 (60.2–157.7) | 4.8 | UP
Ugt2b1 | 105.4 (75.3–172.0) | 5.5 | UP
Ephx1 | 115.8 (61.5–183.9) | 5.6 | UP
Cyp2c6 | 117.1 (65.4–120.1) | 3.7 | UP
Loc100911718 | 117.1 (65.4–120.1) | 3.7 | UP
Car3/Ca3 | 117.8 (41.2–266.8) | 2.3 | DOWN
Egr1 | 127.0 (30.5–318.2) | 2.5 | DOWN
Aldh1a1 | 127.6 (110.1–130.6) | 8.0 | UP
Mice
Cdc20 | 5.6 (0.7–28.7) | 7.8 | UP
Cdk1 | 5.6 (0.8–24.0) | 5.3 | UP
Mest | 5.9 (1.4–49.6) | 1.5 | UP
Gstp2 | 6.6 (4.2–17.5) | 3.6 | UP
Ccnb1 | 6.9 (1.1–32.3) | 4.4 | UP
Cyp2a5 | 8.3 (6.0–29.6) | 11.6 | UP
Cyp2c29 | 8.4 (5.2–8.7) | 6.2 | UP
Ube2c | 8.5 (1.1–46.7) | 2.3 | UP
Cpsf4l | 8.9 (1.9–26.0) | 2.2 | DOWN
Gsta13 | 9.2 (4.0–16.5) | 209.7 | UP

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response.

^a^ Gene definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table 16 Top 10 Lung Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Gene Symbol^a^ | BMD_rd25_ (BMD_Lrd25_–BMD_Urd25_) in ppm | Maximum Fold Change | Direction of Expression Change
Rats
Ddit4 | 92.8 (13.6–256.6) | 2.2 | DOWN
Junb | 121.9 (39.9–278.5) | 1.8 | UP
Cebpd | 132.6 (41.7–216.4) | 2.0 | DOWN
Slc6a8 | 141.9 (48.1–1,438.7) | 1.5 | DOWN
Meg3 | 146.1 (40.1–395.1) | 1.9 | UP
Cenpf | 169.3 (51.1–1,294.8) | 1.6 | DOWN
Cenpw | 177.3 (58.2–542.9) | 1.7 | DOWN
Ier3 | 182.4 (51.2–426.7) | 1.6 | UP
Papss2 | 198.6 (83.7–NC) | 1.4 | DOWN
Ccl12 | 217.6 (62.0–475.4) | 1.9 | UP
Mice
Ces1g | <0.333^b^ (NR) | 3.5 | UP
Dtl | 0.6 (0.2–2.0) | 2.1 | UP
Ccna1 | 0.6 (0.3–1.7) | 2.4 | UP
Atp2b2 | 0.8 (0.3–3.7) | 1.6 | UP
Ugt1a6a | 1.0 (0.3–9.4) | 1.6 | UP
Gins2 | 1.3 (0.5–37.8) | 1.6 | UP
Pole | 1.5 (0.5–2,223.9) | 1.5 | UP
Ugt1a6b | 1.6 (0.5–11.1) | 1.6 | UP
Uhrf1 | 1.9 (0.6–1,766.4) | 1.5 | UP
Ube2t | 2.8 (0.8–11.3) | 1.6 | UP

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; NC = nonconvergent; NR = the BMD_Lrd25_–BMD_Urd25_ range is not reportable because the BMD_rd25_ median is below the lower limit of extrapolation (<1/3 of the lowest nonzero exposure concentration tested).

^a^ Gene definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ <0.333 = a best-fit model was identified and a BMD_rd25_ was estimated that was <1/3 of the lowest nonzero exposure concentration tested.

Table 17 Top 10 Ovary Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Gene Symbol^a,b^ | BMD_rd25_ (BMD_Lrd25_–BMD_Urd25_) in ppm | Maximum Fold Change | Direction of Expression Change
Rats
Fosl1 | 127.2 (22.7–291.4) | 11.4 | DOWN
Apoa1 | 187.9 (47.2–378.4) | 3.2 | DOWN
S100a9 | 199.6 (78.7–432.2) | 1.8 | UP
Acss1 | 213.3 (63.5–449.8) | 1.8 | UP
Cxcl12 | 246.7 (103.1–433.5) | 1.7 | UP
Tnfrsf12a | 255.3 (113.7–412.3) | 3.9 | DOWN
Slc26a2 | 258.7 (84.0–430.3) | 1.7 | UP
Aen | 291.1 (93.4–2,345.0) | 1.5 | DOWN
Vnn1 | 310.0 (166.8–452.8) | 6.9 | UP
Slc51a | 314.8 (131.0–483.1) | 3.1 | DOWN
Mice
Cyp2a4 | 48.8 (14.5–123.1) | 2.2 | UP
Gdf7 | 82.1 (23.7–170.5) | 5.4 | UP
Dbp | 83.6 (25.6–102.8) | 2.3 | UP
Hoxa10 | 103.4 (21.3–212.0) | 2.8 | UP
H2-q6 | 172.4 (73.4–1,326.3) | 1.5 | DOWN
Tuba4a | 230.8 (112.7–529.2) | 1.5 | UP
Hmgcs2 | 266.2 (197.3–401.9) | 1.4 | DOWN
Clu | 384.1 (260.5–737.6) | 1.3 | DOWN

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response.

^a^ Gene definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ Only eight ovary genes met the criteria in mice.

### Heart

#### Rats

The most sensitive upregulated genes with a calculated BMD were Spp1 (secreted phosphoprotein 1) and Dbp (D-box binding PAR bZIP transcription factor) with BMDs (BMD_L_s) of 108.2 (30.6) and 189.0 (183.6) ppm, respectively. The most sensitive genes exhibiting a decrease in expression were Lck (LCK proto-oncogene, Src family tyrosine kinase), Ccnb2 (cyclin B2), Ccnb2-ps2 (cyclin B2, pseudogene 2), Ccna2 (cyclin A2), Kif18b (kinesin family member 18B), Prc1 (protein regulator of cytokinesis 1), Mki67 (marker of proliferation Ki-67), and Rt1-da (RT1 class II, locus Da) with BMDs (BMD_L_s) of 31.7 (6.0), 124.3 (51.4), 124.3 (51.4), 158.4 (60.3), 165.4 (51.1), 173.4 (45.9), 176.8 (47.7), and 187.5 (72.3) ppm, respectively.

#### Mice

The most sensitive upregulated genes with a calculated BMD were Krt18 (keratin 18), S100a4 (S100 calcium-binding protein A4), Star (steroidogenic acute regulatory protein), Ephx1 (epoxide hydrolase 1, microsomal), Dbp (D site albumin promoter binding protein), Abcg1 (ATP-binding cassette subfamily G member 1), and Bhlhe40 (basic helix-loop-helix family, member e40) with BMDs (BMD_L_s) of 0.6 (0.1), 1.3 (0.1), 3.4 (0.5), 52.9 (13.9), 60.3 (18.1), 91.1 (34.2), and 93.4 (38.8) ppm, respectively. The most sensitive genes exhibiting a decrease in expression were Lcn2 (lipocalin 2), Ddit4 (DNA-damage-inducible transcript 4), and Ifi44 (interferon-induced protein 44) with BMDs (BMD_L_s) of 4.5 (0.6), 21.8 (4.0), and 95.0 (21.3) ppm, respectively.

### Kidney

#### Rats

The most sensitive genes exhibiting an increase in expression were Srebf1 (sterol regulatory element binding transcription factor 1), Cyp4a2 (cytochrome P450, family 4, subfamily a, polypeptide 2), and Cyp4a3 (cytochrome P450, family 4, subfamily a, polypeptide 3) with calculated BMD (BMD_L_s) of 31.8 (7.8), 125.1 (49.5), and 137.6 (56.5) ppm, respectively. The most sensitive downregulated genes with a calculated BMD were Ccnb2 (cyclin B2), Ccnb2-ps2 (cyclin B2, pseudogene 2), Kif22 (kinesin family member 22), Mki67 (marker of proliferation Ki-67), Cks2 (CDC28 protein kinase regulatory subunit 2), Dhcr7 (7-dehydrocholesterol reductase), and Mfap4 (microfibril associated protein 4) with BMDs (BMD_L_s) of 77.8 (29.5), 77.8 (29.5), 139.6 (48.2), 150.4 (59.2), 164.3 (55.0), 190.4 (20.9), and 210.5 (55.7) ppm, respectively.

#### Mice

The most sensitive genes exhibiting an increase in expression were Ces1g (carboxylesterase 1G), Acaa1b (acetyl-Coenzyme A acyltransferase 1B), Dbp (D site albumin promoter binding protein), Ces1d (carboxylesterase 1D), Hlf (hepatic leukemia factor), and Slc51a (solute carrier family 51, alpha subunit) with calculated BMDs (BMD_L_s) of 7.6 (2.2), 15.3 (3.2), 16.6 (1.9), 17.1 (2.1), 21.7 (5.7), and 26.9 (5.6) ppm, respectively. The most sensitive genes exhibiting a decrease in expression were Chn1 (chimerin 1), Nfil3 (nuclear factor, interleukin 3, regulated), Abcc3 (ATP-binding cassette, sub-family C member 3), and Rnf125 (ring finger protein 125) with calculated BMDs (BMD_L_s) of 5.4 (0.9), 15.4 (3.2), 18.0 (5.6), and 20.5 (3.2) ppm, respectively.

### Liver

#### Rats

The most sensitive genes exhibiting an increase in expression were Cyp2b2 (cytochrome P450, family 2, subfamily b, polypeptide 2), Cyp2b1 (cytochrome P450, family 2, subfamily b, polypeptide 1), Abcc3 (ATP-binding cassette subfamily C member 3), Ugt2b1 (UDP glucuronosyltransferase 2 family, polypeptide B1), Ephx1 (epoxide hydrolase 1), Cyp2c6 (cytochrome P450, family 2, subfamily C, polypeptide 6), Loc100911718 (cytochrome P450 2C6-like), and Aldh1a1 (aldehyde dehydrogenase 1 family, member A1) with calculated BMD (BMD_L_s) of 48.4 (25.0), 69.9 (43.9), 103.8 (60.2), 105.4 (75.3), 115.8 (61.5), 117.1 (65.4), 117.1 (65.4), and 127.6 (110.1) ppm, respectively. The most sensitive downregulated genes with a calculated BMD were Car3/Ca3 (carbonic anhydrase 3) and Egr1 (early growth response 1) with BMDs (BMD_L_s) of 117.8 (41.2) and 127.0 (30.5) ppm, respectively.

#### Mice

The most sensitive upregulated genes with a calculated BMD were Cdc20 (cell division cycle 20), Cdk1 (cyclin dependent kinase 1), Mest (mesoderm specific transcript), Gstp2 (glutathione S-transferase, pi 2), Ccnb1 (cyclin B1), Cyp2a5 (cytochrome P450, family 2, subfamily a, polypeptide 5), Cyp2c29 (cytochrome P450, family 2, subfamily c, polypeptide 29), Ube2c (ubiquitin-conjugating enzyme E2C), and Gsta13 (glutathione S-transferase alpha 13) with BMDs (BMD_L_s) of 5.6 (0.7), 5.6 (0.8), 5.9 (1.4), 6.6 (4.2), 6.9 (1.1), 8.3 (6.0), 8.4 (5.2), 8.5 (1.1), and 9.2 (4.0) ppm, respectively. One gene, Cpsf4l (cleavage and polyadenylation specific factor 4-like), was downregulated with a BMD (BMD_L_) of 8.9 (1.9) ppm.

### Lung

#### Rats

The most sensitive genes exhibiting an increase in expression were Junb (JunB proto-oncogene, AP-1 transcription factor subunit), Meg3 (maternally expressed 3), Ier3 (immediate early response 3), and Ccl12 (C-C motif chemokine ligand 12) with calculated BMD (BMD_L_s) of 121.9 (39.9), 146.1 (40.1), 182.4 (51.2), and 217.6 (62.0) ppm, respectively. The most sensitive downregulated genes with a calculated BMD were Ddit4 (DNA-damage-inducible transcript 4), Cebpd (CCAAT/enhancer binding protein delta), Slc6a8 (solute carrier family 6 member 8), Cenpf (centromere protein F), Cenpw (centromere protein W), and Papss2 (3'-phosphoadenosine 5'-phosphosulfate synthase 2) with BMDs (BMD_L_s) of 92.8 (13.6), 132.6 (41.7), 141.9 (48.1), 169.3 (51.1), 177.3 (58.2), and 198.6 (83.7) ppm, respectively.

#### Mice

The most sensitive lung gene in mice, exhibiting an increase in expression, was Ces1g (carboxylesterase 1G) with an estimated median BMD <0.333 ppm. The most sensitive upregulated genes with a calculated BMD were Dtl (denticleless E3 ubiquitin protein ligase), Ccna1 (cyclin A1), Atp2b2 (ATPase, Ca++ transporting, plasma membrane 2), Ugt1a6a (UDP glucuronosyltransferase 1 family, polypeptide A6A), Gins2 (GINS complex subunit 2), Pole (polymerase (DNA directed), epsilon), Ugt1a6b (UDP glucuronosyltransferase 1 family, polypeptide A6B), Uhrf1 (ubiquitin-like, containing PHD and RING finger domains, 1), and Ube2t (ubiquitin-conjugating enzyme E2T) with BMDs (BMD_L_s) of 0.6 (0.2), 0.6 (0.3), 0.8 (0.3), 1.0 (0.3), 1.3 (0.5), 1.5 (0.5), 1.6 (0.5), 1.9 (0.6), and 2.8 (0.8) ppm, respectively.

### Ovary

#### Rats

The most sensitive genes exhibiting an increase in expression were S100a9 (S100 calcium-binding protein A9), Acss1 (acyl-CoA synthetase short-chain family member 1), Cxcl12 (C-X-C motif chemokine ligand 12), Slc26a2 (solute carrier family 26 member 2), and Vnn1 (vanin 1) with calculated BMD (BMD_L_s) of 199.6 (78.7), 213.3 (63.5), 246.7 (103.1), 258.7 (84.0), and 310.0 (166.8) ppm, respectively. The most sensitive downregulated genes with a calculated BMD were Fosl1 (FOS like 1, AP-1 transcription factor subunit), Apoa1 (apolipoprotein A1), Tnfrsf12a (TNF receptor superfamily member 12A), Aen (apoptosis enhancing nuclease), and Slc51a (solute carrier family 51 member A) with BMDs (BMD_L_s) of 127.2 (22.7), 187.9 (47.2), 255.3 (113.7), 291.1 (93.4), and 314.8 (131.0) ppm, respectively.

#### Mice

Only eight genes met the criteria. Of these eight genes, the most sensitive upregulated genes with a calculated BMD were Cyp2a4 (cytochrome P450, family 2, subfamily a, polypeptide 4), Gdf7 (growth differentiation factor 7), Dbp (D site albumin promoter binding protein), Hoxa10 (homeobox A10), and Tuba4a (tubulin, alpha 4A) with BMDs (BMD_L_s) of 48.8 (14.5), 82.1 (23.7), 83.6 (25.6), 103.4 (21.3), and 230.8 (112.7) ppm, respectively. The most sensitive genes exhibiting a decrease in expression were H2-q6 (histocompatibility 2, Q region locus 6), Hmgcs2 (3-hydroxy-3-methylglutaryl-Coenzyme A synthase 2), and Clu (clusterin) with BMDs (BMD_L_s) of 172.4 (73.4), 266.2 (197.3), and 384.1 (260.5) ppm, respectively.

## Theoretical Inhaled Dose

To provide information relevant for route-to-route extrapolation, to allow for comparison between two dichlorobenzene isomers, and to normalize data for comparison of internal dose between species, a theoretical inhaled mg/kg/day dose was calculated for each species and exposure group. Information relevant to the calculations is provided below, with the calculated theoretical inhaled doses shown in Table 18.

- Estimates of minute volume (Mv) were based on EPA’s Methods for Derivation of Inhalation Reference Concentrations and Application of Inhalation Dosimetry^29^ as well as Recommendations for and Documentation of Biological Values for Use in Risk Assessment.^30^
- Study day 0 body weights (BW) were used in the calculations due to the short duration of the study and minimal effects on body weight.
- Target exposure concentrations, rather than actual exposure concentrations, were used for the calculations due to the high degree of congruency.

The inhaled dose over a 6-hour exposure period was calculated as:

- Dose (mg/kg/day) = C [(mg/m^3^)/1,000)] × Mv (L/min) × 360 min/day exposure ÷ BW (kg)

where

- C (mg/m^3^) = 0.0409 × C (ppm) × molecular weight of test article
- Mv (L/min) is estimated as LnMv = b0 + b1 × Ln(BW) where b0 and b1 are −0.578 and 0.821 for rats and 0.326 and 1.050 for mice, respectively.^29,30^

Table 18 Theoretical Inhaled Daily Dose (mg/kg/day) of 1,4-Dichlorobenzene Following Six-hour Whole-Body Inhalation Exposure

| 0 ppm | 1 ppm | 10 ppm | 50 ppm | 150 ppm | 400 ppm | 800 ppm
Rat | 0 | 1.64 | 16.36 | 81.58 | 245.18 | 653.76 | 1,305.97
Mouse | 0 | 2.46 | 24.58 | 122.86 | 368.16 | 982.02 | NA

Within each exposure group and species, calculations were performed for the core and internal concentration assessment animals separately, using group mean body weight data. The data presented here and used for internal dose assessment normalization (mg/kg/day) are a mean of the values calculated by the core and internal concentration assessment animals.

NA = not applicable.

## Internal Concentration Assessment

1,4-DCB concentrations were quantified in blood, lung, and liver on study day 4 (following the last exposure) and study day 5 (approximately 18 hours following the last exposure) using a validated analytical method (Appendix B). Data are reported before and after normalizing to the exposure concentration (ppm) and the estimated theoretical inhaled dose (mg/kg/day).

### Rats

On study day 4, blood 1,4-DCB concentration increased with increasing exposure concentration (Table 19). The increase was proportional to the exposure concentration up to 150 ppm as evidenced by the dose-normalized values (72.1–99.8 [ng/mL]/[mg/kg/day]). At 400 and 800 ppm, blood concentrations increased more than proportionally to the exposure concentration with normalized values of 152 and 136 (ng/mL)/(mg/kg/day), respectively, demonstrating saturation of metabolism and/or clearance processes.

Table 19 Summary of Blood, Lung, and Liver Concentration Data for Female Rats Exposed to 1,4-Dichlorobenzene for Five Days

Endpoint^a,b^ | 0 ppm | 1 ppm | 10 ppm | 50 ppm | 150 ppm | 400 ppm | 800 ppm
Study Day 4
n | 3 | 3 | 3 | 3 | 3 | 3 | 2
Blood
Blood concentration (ng/mL)^c^ | 0.398 ± 0.0127** | 152 ± 11.0* | 1,400 ± 70.2** | 8,140 ± 690** | 17,700 ± 2,370** | 99,100 ± 5,000** | 178,000 ± 52,500**
Normalized blood concentration [(ng/mL)/(mg/kg/day)]^d,e^ | −^f^ | 92.8 ± 6.70 | 85.6 ± 4.29 | 99.8 ± 8.45 | 72.1 ± 9.66 | 152 ± 7.65 | 136 ± 40.2
Normalized blood concentration [(ng/mL)/ppm]^e^ | − | 152 ± 11.0 | 140 ± 7.02 | 163 ± 13.8 | 118 ± 15.8 | 248 ± 12.5 | 222 ± 65.6
Liver
Liver concentration (ng/g) | 0.873 ± 0.0422** | 208 ± 11.1* | 1,680 ± 185** | 8,270 ± 771** | 37,900 ± 5,060** | 151,000 ± 12,700** | 207,000 ± 89,000**
Normalized liver concentration [(ng/g)/(mg/kg/day)]^d,e^ | − | 127 ± 6.80 | 103 ± 11.3 | 101 ± 9.45 | 155 ± 20.7 | 231 ± 19.5 | 159 ± 68.1
Normalized liver concentration [(ng/g)/ppm]^e^ | − | 208 ± 11.1 | 168 ± 18.5 | 165 ± 15.4 | 253 ± 33.8 | 378 ± 31.9 | 259 ± 111
Lung
Lung concentration (ng/g) | 0.408 ± 0.0132** | 120 ± 36.5* | 595 ± 158** | 3,830 ± 1,390** | 7,410 ± 305** | 37,800 ± 2,580** | 242,000 ± 134,000**
Normalized lung concentration [(ng/g)/(mg/kg/day)]^d,e^ | − | 73.4 ± 22.3 | 36.4 ± 9.65 | 47.0 ± 17.1 | 30.2 ± 1.24 | 57.8 ± 3.95 | 185 ± 103
Normalized lung concentration [(ng/g)/ppm]^e^ | − | 120 ± 36.5 | 59.5 ± 15.8 | 76.7 ± 27.9 | 49.4 ± 2.03 | 94.4 ± 6.46 | 303 ± 168
Study Day 5
n | 3 | 3 | 3 | 3 | 3 | 3 | 3
Blood
Blood concentration (ng/mL) | 0.477 ± 0.0264** | 4.69 ± 0.736* | 36.3 ± 4.94** | 250 ± 27.6** | 1,180 ± 165** | 2,610 ± 636** | 4,430 ± 537**
Normalized blood concentration [(ng/mL)/(mg/kg/day)] | − | 2.87 ± 0.450 | 2.22 ± 0.302 | 3.07 ± 0.338 | 4.82 ± 0.673 | 4.00 ± 0.973 | 3.39 ± 0.411
Normalized blood concentration [(ng/mL)/ppm] | − | 4.69 ± 0.736 | 3.63 ± 0.494 | 5.01 ± 0.551 | 7.88 ± 1.10 | 6.53 ± 1.59 | 5.54 ± 0.671
Liver
Liver concentration (ng/g) | 0.760 ± 0.0563** | 7.13 ± 1.29* | 69.2 ± 24.2** | 158 ± 13.5** | 1,300 ± 225** | 2,480 ± 413** | 3,810 ± 665**
Normalized liver concentration [(ng/g)/(mg/kg/day)] | − | 4.35 ± 0.787 | 4.23 ± 1.48 | 1.94 ± 0.166 | 5.31 ± 0.919 | 3.80 ± 0.632 | 2.92 ± 0.509
Normalized liver concentration [(ng/g)/ppm] | − | 7.13 ± 1.29 | 6.92 ± 2.42 | 3.17 ± 0.271 | 8.68 ± 1.50 | 6.21 ± 1.03 | 4.77 ± 0.831
Lung
Lung concentration (ng/g) | 0.482 ± 0.0559** | 4.31 ± 1.03* | 22.3 ± 3.66** | 352 ± 51.9** | 446 ± 42.1** | 1,660 ± 810** | 1,970 ± 381**
Normalized lung concentration [(ng/g)/(mg/kg/day)] | − | 2.63 ± 0.631 | 1.37 ± 0.224 | 4.32 ± 0.636 | 1.82 ± 0.172 | 2.53 ± 1.24 | 1.51 ± 0.292
Normalized lung concentration [(ng/g)/ppm] | − | 4.31 ± 1.03 | 2.23 ± 0.366 | 7.05 ± 1.04 | 2.97 ± 0.281 | 4.14 ± 2.03 | 2.46 ± 0.477

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm group. Statistical significance for the 0 ppm group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ If over 20% of the animals in a group were above the limit of detection (LOD), one-half of the LOD was substituted for values below the LOD. LOD for blood = 0.0960 ng/mL; LOD for liver = 0.288 ng/g; LOD for lung = 0.288 ng/g.

^c^ Statistical analysis performed by the Jonckheere (trend) and the Shirley or Dunn (pairwise) tests.

^d^ Theoretical inhaled doses estimated for the 1, 10, 50, 150, 400 and 800 ppm groups are 1.64, 16.36, 81.58, 245.18, 653.76 and 1,305.97 mg/kg/day, respectively.

^e^ Normalized concentrations were calculated by dividing the measured concentration in either ng/mL for blood or ng/g for tissues by either the theoretical inhaled dose (mg/kg/day) or nominal exposure concentration (ppm). No statistical analysis was performed on normalized endpoints.

^f^ Not applicable.

On study day 4, 1,4-DCB liver concentrations, in general, were similar to blood although lung concentrations were lower than those for blood (except the 800 ppm group), suggesting low tissue distribution and/or retention. As evidenced by the normalized values, liver concentration increased proportionally to the exposure concertation up to 50 ppm (101–127 [ng/g]/[mg/kg/day]) but increased more than proportionally to the exposure concentration ≥150 ppm with normalized values ranging from 155 to 231 (ng/g)/(mg/kg/day). In general, lung concentrations increased proportionally to the exposure concentration with normalized values ranging from 30.2 to 73.4 (ng/g)/(mg/kg/day), except at the highest exposure concentration at which the increase was more than proportional to the exposure concentration with a normalized value of 185 (ng/g)/(mg/kg/day).

On study day 5, blood, liver, and lung concentrations were much lower than on study day 4, demonstrating rapid elimination of 1,4-DCB. As observed for study day 4, concentrations in general were similar between blood and liver but lower in lung.

### Mice

On study day 4, blood 1,4-DCB concentration increased with increasing exposure concentration (Table 20). The increase was proportional to the exposure concentration up to 10 ppm as evidenced by the dose-normalized values (6.89–10.7 [ng/mL]/[mg/kg/day]). At concentrations ≥50 ppm, blood concentration increased more than proportionally to exposure concentration with normalized values ranging from 32 to 95.6 (ng/mL)/(mg/kg/day).

Table 20 Summary of Blood, Lung, and Liver Concentration Data for Female Mice Exposed to 1,4-Dichlorobenzene for Five Days

Endpoint^a,b^ | 0 ppm | 1 ppm | 10 ppm | 50 ppm | 150 ppm | 400 ppm
Study Day 4
n | 3 | 3 | 3^c^ | 2 | 3 | 3
Blood
Blood concentration (ng/mL) | BD^d^ | 16.9 ± 2.75 | 263 ± 28.7 | 4,940 ± 260 | 11,800 ± 1,380 | 93,900 ± 12,700
Normalized blood concentration [(ng/mL)/(mg/kg/day)]^e,f^ | −^g^ | 6.89 ± 1.12 | 10.7 ± 1.17 | 40.2 ± 2.12 | 32.0 ± 3.74 | 95.6 ± 12.9
Normalized blood concentration [(ng/mL)/ppm]^f^ | − | 16.9 ± 2.75 | 26.3 ± 2.87 | 98.8 ± 5.20 | 78.4 ± 9.18 | 235 ± 31.7
Liver
Liver concentration (ng/g) | BD | 9.43 ± 0.558 | 248 ± 19.5 | 5,910 ± 335 | 18,900 ± 1,940 | 141,000 ± 23,100
Normalized liver concentration [(ng/g)/(mg/kg/day)]^e,f^ | − | 3.84 ± 0.227 | 10.1 ± 0.792 | 48.1 ± 2.73 | 51.3 ± 5.28 | 143 ± 23.6
Normalized liver concentration [(ng/g)/ppm]^f^ | − | 9.43 ± 0.558 | 24.8 ± 1.95 | 118 ± 6.70 | 126 ± 13.0 | 352 ± 57.8
Lung
Lung concentration (ng/g) | BD | 10.7 ± 1.85 | 58.1 ± 3.30 | 14,600 ± 5,200 | 14,100 ± 4,000 | 205,000 ± 72,700
Normalized lung concentration [(ng/g)/(mg/kg/day)]^e,f^ | − | 4.37 ± 0.755 | 2.36 ± 0.134 | 119 ± 42.3 | 38.3 ± 10.9 | 209 ± 74.1
Normalized lung concentration [(ng/g)/ppm]^f^ | − | 10.7 ± 1.85 | 5.81 ± 0.330 | 292 ± 104 | 94.0 ± 26.7 | 513 ± 182
Study Day 5
n | 3^h^ | 3 | 3 | 3 | 3 | 3
Blood
Blood concentration (ng/mL) | BD | 0.0983 ± 0.0252 | 0.492 ± 0.264 | 2.24 ± 1.02 | 20.1 ± 8.44 | 23.8 ± 17.3
Normalized blood concentration [(ng/mL)/(mg/kg/day)] | − | 0.0400 ± 0.0102 | 0.0200 ± 0.0107 | 0.0182 ± 0.00826 | 0.0545 ± 0.0229 | 0.0242 ± 0.0176
Normalized blood concentration [(ng/mL)/ppm] | − | 0.0983 ± 0.0252 | 0.0492 ± 0.0264 | 0.0447 ± 0.0203 | 0.134 ± 0.0563 | 0.0595 ± 0.0433
Liver
Liver concentration (ng/g) | BD | BD | 0.656 ± 0.193 | 3.97 ± 0.833 | 27.3 ± 9.22 | 25.8 ± 12.1
Normalized liver concentration [(ng/g)/(mg/kg/day)] | − | BD | 0.0267 ± 0.00786 | 0.0323 ± 0.00678 | 0.0742 ± 0.0250 | 0.0263 ± 0.0123
Normalized liver concentration [(ng/g)/ppm] | − | BD | 0.0656 ± 0.0193 | 0.0793 ± 0.0167 | 0.182 ± 0.0614 | 0.0646 ± 0.0303
Lung
Lung concentration (ng/g) | BD | BD | 0.713 ± 0.414 | 1.27 ± 0.330 | 15.6 ± 3.46 | 27.0 ± 22.6
Normalized lung concentration [(ng/g)/(mg/kg/day)] | − | BD | 0.0290 ± 0.0168 | 0.0103 ± 0.00269 | 0.0423 ± 0.00941 | 0.0275 ± 0.0230
Normalized lung concentration [(ng/g)/ppm] | − | BD | 0.0713 ± 0.0414 | 0.0254 ± 0.00661 | 0.104 ± 0.0231 | 0.0676 ± 0.0565

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Data are presented as mean ± standard error.

^b^ If over 20% of the animals in a group were above the LOD, one-half of the LOD was substituted for values below the LOD. LOD for blood = 0.0960 ng/mL; LOD for liver = 0.288 ng/g; LOD for lung = 0.288 ng/g.

^c^ n = 2 for lung. One animal was identified as an outlier and thus excluded from analysis.

^d^ When the 0 ppm group did not have over 20% of its values above the LOD, no mean or standard error was calculated, and no statistical analysis was performed.

^e^ Theoretical inhaled doses estimated for the 1, 10, 50, 150, and 400 ppm groups are 2.46, 24.58, 122.86, 368.16, and 982.02 mg/kg/day, respectively.

^f^ Normalized concentrations were calculated by dividing the measured concentration in either ng/mL for blood or ng/g for tissues by either the theoretical inhaled dose (mg/kg/day) or nominal exposure concentration (ppm). No statistical analysis was performed on normalized endpoints.

^g^ Not applicable.

^h^ n = 2 for blood and lung. One animal for blood and one animal for lung were identified as outliers and thus excluded from analysis.

On study day 4, 1,4-DCB liver and lung concentrations, in general, were similar to blood (with the exception of lung concentrations in the 50 and 400 ppm groups) suggesting low tissue distribution and/or retention. As evidenced by the dose-normalized values, liver (3.84–10.1 [ng/g]/[mg/kg/day]) and lung (2.36–4.37 [ng/g]/[mg/kg/day]) concentrations increased proportionally to the exposure concentration up to 10 ppm, but the increase was more than proportional at concentrations ≥50 ppm (liver, 48.1–143 [ng/g]/[mg/kg/day]; lung, 38.3–209 [ng/g]/[mg/kg/day]).

On study day 5, blood, liver, and lung concentrations were much lower than on study day 4 with values falling below the limit of detection at 1 ppm for the tissues, demonstrating rapid elimination of 1,4-DCB. As observed for study day 4, concentrations in general were similar among blood, liver, and lung.

In general, when normalized to the theoretical inhaled dose, rats had higher blood and tissue concentrations of 1,4-DCB than mice at the lower exposure concentrations, although the difference was smaller at 400 ppm.