# Background

1,4-Dichlorobenzene (1,4-DCB) (CASRN: 106-46-7, U.S. Environmental Protection Agency [U.S. EPA] Chemical Dashboard: DTXSID1020431, PubChem CID: 4685, European Committee Number: 203-400-5), also known as para-DCB, is an organochlorine compound classified under chlorinated aromatic hydrocarbons.^2^ 1,4-DCB is frequently used in various industrial and household applications.^2^ Industrially, it is used in the synthesis of resins.^2,3^ With its distinctive, penetrating, and mothball-like odor, it is widely used as a fumigant for moth control and as a deodorizer in urinal cakes; it is has also been used an air freshener in domestic and public settings.^2^ Additionally, 1,4-DCB is registered as a pesticide by the U.S. EPA.^4^

The Occupational Safety and Health Administration has set a maximum workplace air concentration of 75 ppm of 1,4-DCB for an 8-hour workday,^5^ whereas the American Conference of Governmental Industrial Hygienists advises that the average airborne exposure should not exceed 10 ppm for an 8-hour work shift.^6^ Under the Safe Drinking Water Act, both the federal maximum contaminant level goal and the maximum contaminant level for 1,4-DCB are set to 75 μg/L.^7^ California’s Office of Environmental Health Hazard Assessment has developed acute, chronic, and 8-hour reference exposure levels of 1,500, 0.8, and 1.7 ppb, respectively.^8^ The U.S. Department of Health and Human Services has concluded that 1,4-DCB is reasonably anticipated to be a human carcinogen,^9^ and the International Agency for Research on Cancer (IARC) has classified it as possibly carcinogenic to humans (Group 2B).^10^ This conclusion is based on evidence from animal studies.^9,10^ Owing to its carcinogenic properties, the use of 1,4-DCB has been prohibited in the European Union for air fresheners since 2014 and in mothballs since 2007.^11^

Exposure to 1,4-DCB can occur through various routes, including inhalation, ingestion, and dermal contact.^2^ Inhalation exposure is particularly significant because of the volatility of 1,4-DCB, making occupational exposure a concern in industrial settings.^2^ Inhalation exposure is also of concern in environments where it is used as a deodorizer or fumigant.^2^ Data from animal experiments suggest that 1,4-DCB is rapidly and extensively absorbed through inhalation and oral routes, whereas no data on dermal absorption are available.^2^ Data from both humans and experimental animals suggest that the compound widely distributes throughout the body, particularly in lipid-rich tissues, because of its lipophilicity.^2^ 1,4-DCB is primarily metabolized in the liver by cytochrome P450 enzymes, mainly CYP2E1, resulting in an epoxide that is subsequently hydrolyzed to more water-soluble metabolites such as 2,5-dichlorophenol.^2,12^ These metabolites are then conjugated and primarily excreted through urine, with minor excretion via feces and exhaled air as demonstrated in animal studies.^2^

Short-term exposure to high concentrations of 1,4-DCB in humans can lead to acute central nervous system effects such as dizziness, headache, and nausea, as well as skin and eye irritation upon direct contact.^2^ Subacute or subchronic exposure to 1,4-DCB in animal models has also been linked to liver and kidney damage; hepatotoxicity is indicated by elevated liver enzymes and histopathological changes such as liver cell hypertrophy and necrosis, and nephrotoxicity manifests as proximal tubular damage and altered renal function markers.^2^ Chronic exposure has been associated with liver and kidney cancer, and there is sufficient evidence of carcinogenicity in animal studies,^2,10^ leading to the classification of 1,4-DCB as a possible human carcinogen by IARC.^10^

The primary mechanism of 1,4-DCB toxicity involves its bioactivation to reactive intermediates, such as epoxides, which are conjugated to glutathione during hepatic metabolism.^2,12^ These intermediates can induce oxidative stress and covalently bind to cellular macromolecules, leading to lipid peroxidation, protein damage, and DNA adduct formation.^2^ This oxidative damage is a significant factor contributing to the hepatotoxicity and nephrotoxicity observed in various studies.^2^

The primary purpose of these short-term toxicity studies is to characterize the biological potency of 1,4-DCB via inhalation exposure. The data from these studies are intended to support risk assessment and establishment of acceptable exposure levels of 1,4-DCB in environmental and occupational settings.