# Acknowledgments

This work was supported by the Intramural Research Program (ES103374 and ES103380) at the National Institute of Environmental Health Sciences (NIEHS), National Institutes of Health and performed for NIEHS under contracts 75N94025C00006, 75N96025C00003, 75N96024C00005, 75N96024C00002, GS-00F-173CA/75N96022F00055, 75N96023A00001, 75N96023D00001, GS00Q14OADU417 (Order No. HHSN273201600015U), HHSN273201500006C, HHSN273201400015C, and HHSN273201400027C.