# Appendix E Gene Set and Gene Definitions

Table E-1 Active Genes and Definitions within Top 10 Heart Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Category Name^a,b^ | Input Genes/Platform Genes in Gene Set (% Coverage) | Active Genes | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^c^ | Definition
Rats
GO:0044770 cell cycle phase transition | 5/58 (8.6%) | Usp22; Cks2; Ccnb2; Ccnb2-ps2; Ccna2 | 141.4 (55.9–292.9) | The cell cycle process by which a cell commits to entering the next cell cycle phase.
GO:0044772 mitotic cell cycle phase transition | 5/52 (9.6%) | Usp22; Cks2; Ccnb2; Ccnb2-ps2; Ccna2 | 141.4 (55.9–292.9) | The cell cycle process by which a cell commits to entering the next mitotic cell cycle phase.
GO:0051301 cell division | 6/84 (7.1%) | Nuf2; Cdca5; Kif18b; Ccnb2; Ccnb2-ps2; Ccna2 | 181.5 (65.8–517.4) | The process resulting in division and partitioning of components of a cell to form more cells; may or may not be accompanied by the physical separation of a cell into distinct, individually membrane-bounded daughter cells.
GO:0007049 cell cycle | 4/45 (8.9%) | Mki67; Cdca5; Kif18b; Cenpf | 192.5 (68.7–382.0) | The progression of biochemical and morphological phases and events that occur in a cell during successive cell replication or nuclear replication events. Canonically, the cell cycle comprises the replication and segregation of genetic material followed by the division of the cell, but in endocycles or syncytial cells nuclear replication or nuclear division may not be followed by cell division.
GO:0000226 microtubule cytoskeleton organization | 4/80 (5.0%) | Prc1; Nuf2; Kif18b; Ccnb2 | 197.5 (80.5–710.7) | A process that is carried out at the cellular level, which results in the assembly, arrangement of constituent parts, or disassembly of cytoskeletal structures comprising microtubules and their associated proteins.
GO:0007059 chromosome segregation | 4/41 (9.8%) | Smc2; Nuf2; Kif18b; Cenpf | 202.9 (85.1–551.4) | The process in which genetic material, in the form of chromosomes, is organized into specific structures and then physically separated and apportioned to two or more sets. In eukaryotes, chromosome segregation begins with the condensation of chromosomes, includes chromosome separation, and ends when chromosomes have completed movement to the spindle poles.
GO:1903047 mitotic cell cycle process | 11/149 (7.4%) | Usp22; Smc2; Prc1; Nuf2; Cdca5; Kif18b; Cks2; Ckap2; Ccnb2; Ccnb2-ps2; Ccna2 | 242.4 (96.3–435.9) | A process that is part of the mitotic cell cycle.
GO:0022402 cell cycle process | 12/194 (6.2%) | Usp22; Smc2; Prc1; Nuf2; Cdca5; Kif18b; Cks2; Ckap2; Cenpf; Ccnb2; Ccnb2-ps2; Ccna2 | 282.0 (108.6–1,328.0) | The cellular process that ensures successive accurate and complete genome replication and chromosome segregation.
GO:0019730 antimicrobial humoral response | 5/43 (11.6%) | Loc102549061; Hist1h2bq; H2bc8; Ccl7; Ccl2 | 333.8 (156.8–476.7) | An immune response against microbes mediated through a body fluid. Examples of this process are seen in the antimicrobial humoral response of Drosophila melanogaster and Mus musculus.
GO:0006959 humoral immune response | 5/80 (6.3%) | Loc102549061; Hist1h2bq; H2bc8; Ccl7; Ccl2 | 347.4 (174.4–695.6) | An immune response mediated through a body fluid.
Mice
GO:1901617 organic hydroxy compound biosynthetic process | 3/52 (5.8%) | Star; Hmgcs2; Ephx1 | 91.0 (25.1–495.5) | The chemical reactions and pathways resulting in the formation of organic hydroxy compound.
GO:0007623 circadian rhythm | 3/49 (6.1%) | Bhlhe40; Dbp; Nfil3 | 139.5 (37.4–273.5) | Any biological process in an organism that recurs with a regularity of approximately 24 hours.
GO:0030595 leukocyte chemotaxis | 3/49 (6.1%) | Ccl2; Ccl7; Cxcl1 | 178.4 (91.9–411.5) | The movement of a leukocyte in response to an external stimulus.
GO:0097529 myeloid leukocyte migration | 3/51 (5.9%) | Ccl2; Ccl7; Cxcl1 | 178.4 (91.9–411.5) | The movement of a myeloid leukocyte within or between different tissues and organs of the body.

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^33^ Official gene symbols from the Rat Genome Database^34^ are shown in the “Active Genes” column.

^b^ Only four heart GO biological process gene sets were active in mice.

^c^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

GO process descriptions and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-2 Active Genes and Definitions within Top 10 Kidney Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | Active Genes | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Definition
Rats
GO:0044770 cell cycle phase transition | 4/58 (6.9%) | Hspa8; Cks2; Ccnb2; Ccnb2-ps2 | 121.0 (42.2–652.8) | The cell cycle process by which a cell commits to entering the next cell cycle phase.
GO:0044772 mitotic cell cycle phase transition | 4/52 (7.7%) | Hspa8; Cks2; Ccnb2; Ccnb2-ps2 | 121.0 (42.2–652.8) | The cell cycle process by which a cell commits to entering the next mitotic cell cycle phase.
GO:0001822 kidney development | 6/57 (10.5%) | Thra; Hspa8; Hmgcs2; Cyp4a3; Cyp4a2; Agtr1a | 197.7 (91.7–305.6) | The process whose specific outcome is the progression of the kidney over time, from its formation to the mature structure. The kidney is an organ that filters the blood and/or excretes the end products of body metabolism in the form of urine.
GO:0019218 regulation of steroid metabolic process | 5/49 (10.2%) | Srebf1; Por; Nr1d1; Insig1; Dhcr7 | 224.1 (73.8–NC) | Any process that modulates the frequency, rate or extent of the chemical reactions and pathways involving steroids.
GO:0030324 lung development | 4/45 (8.9%) | Srebf1; Thra; Hmgcs2; Dhcr7 | 224.1 (73.8–NC) | The process whose specific outcome is the progression of the lung over time, from its formation to the mature structure. In all air-breathing vertebrates the lungs are developed from the ventral wall of the oesophagus as a pouch which divides into two sacs. In amphibians and many reptiles the lungs retain very nearly this primitive sac-like character, but in the higher forms the connection with the esophagus becomes elongated into the windpipe and the inner walls of the sacs become more and more divided, until, in the mammals, the air spaces become minutely divided into tubes ending in small air cells, in the walls of which the blood circulates in a fine network of capillaries. In mammals the lungs are more or less divided into lobes, and each lung occupies a separate cavity in the thorax.
GO:0006694 steroid biosynthetic process | 6/54 (11.1%) | Srebf1; Insig1; Hsd17b10; Hmgcs2; Dhcr7; Cyp1a1 | 225.9 (89.2–NC) | The chemical reactions and pathways resulting in the formation of steroids, compounds with a 1,2,cyclopentanoperhydrophenanthrene nucleus; includes de novo formation and steroid interconversion by modification.
GO:0008203 cholesterol metabolic process | 5/54 (9.3%) | Tsku; Srebf1; Insig1; Hmgcs2; Dhcr7 | 225.9 (89.2–NC) | The chemical reactions and pathways involving cholesterol, cholest-5-en-3 beta-ol, the principal sterol of vertebrates and the precursor of many steroids, including bile acids and steroid hormones. It is a component of the plasma membrane lipid bilayer and of plasma lipoproteins and can be found in all animal tissues.
GO:0016125 sterol metabolic process | 5/56 (8.9%) | Tsku; Srebf1; Insig1; Hmgcs2; Dhcr7 | 225.9 (89.2–NC) | The chemical reactions and pathways involving sterols, steroids with one or more hydroxyl groups and a hydrocarbon side-chain in the molecule.
GO:0046165 alcohol biosynthetic process | 6/42 (14.3%) | Srebf1; Pck1; Insig1; Hmgcs2; Ephx1; Dhcr7 | 225.9 (89.2–NC) | The chemical reactions and pathways resulting in the formation of alcohols, any of a class of compounds containing one or more hydroxyl groups attached to a saturated carbon atom.
GO:0001676 long-chain fatty acid metabolic process | 5/55 (9.1%) | Fads1; Ephx1; Cyp4a3; Cyp4a2; Cyp1a1 | 226.7 (96.8–365.3) | The chemical reactions and pathways involving long-chain fatty acids, A long-chain fatty acid is a fatty acid with a chain length between C13 and C22.
Mice
GO:0007623 circadian rhythm | 5/49 (10.2%) | Bhlhe40; Dbp; Nfil3; Ces1d; Bdnf | 16.9 (2.0–793.4) | Any biological process in an organism that recurs with a regularity of approximately 24 hours.
GO:0015850 organic hydroxy compound transport | 4/58 (6.9%) | Ces1d; Ces1g; Abcc3; Slc51a | 17.6 (3.9–778.1) | The directed movement of an organic hydroxy compound (organic alcohol) into, out of or within a cell, or between cells, by means of some agent such as a transporter or pore. An organic hydroxy compound is an organic compound having at least one hydroxy group attached to a carbon atom.
GO:0006869 lipid transport | 5/77 (6.5%) | Ces1d; Ces1g; Abcc3; Fabp1; Slc51a | 22.5 (5.6–84.1) | The directed movement of lipids into, out of or within a cell, or between cells, by means of some agent such as a transporter or pore. Lipids are compounds soluble in an organic solvent but not, or sparingly, in an aqueous solvent.
GO:0010565 regulation of cellular ketone metabolic process | 3/56 (5.4%) | Ces1d; Ces1g; Fabp1 | 107.2 (74.6–880.6) | Any process that modulates the chemical reactions and pathways involving any of a class of organic compounds that contain the carbonyl group, CO, and in which the carbonyl group is bonded only to carbon atoms. The general formula for a ketone is RCOR, where R and R are alkyl or aryl groups.
GO:0006805 xenobiotic metabolic process | 6/56 (10.7%) | Cyp2a5; Ugt2b5; Gsta2; Gsta1; Acaa1b; Cyp2e1 | 108.3 (48.2–389.5) | The chemical reactions and pathways involving a xenobiotic compound, a compound foreign to living organisms. Used of chemical compounds, e.g., a xenobiotic chemical, such as a pesticide.
GO:0015718 monocarboxylic acid transport | 3/52 (5.8%) | Abcc3; Fabp1; Slc51a | 112.1 (76.4–186.6) | The directed movement of monocarboxylic acids into, out of or within a cell, or between cells, by means of some agent such as a transporter or pore.
GO:0048511 rhythmic process | 6/89 (6.7%) | Bhlhe40; Dbp; Nfil3; Ces1d; Hlf; Bdnf | 129.9 (83.8–241.2) | Any process pertinent to the generation and maintenance of rhythms in the physiology of an organism.
GO:0033559 unsaturated fatty acid metabolic process | 5/40 (12.5%) | Cyp2a5; Cyp4a10; Ces2e; Cyp4a14; Cyp2e1 | 136.9 (55.1–282.5) | The chemical reactions and pathways involving an unsaturated fatty acid, any fatty acid containing one or more double bonds between carbon atoms.
GO:0006631 fatty acid metabolic process | 8/117 (6.8%) | Cyp2a5; Cyp4a10; Ces1d; Ces2e; Ces1g; Acaa1b; Cyp4a14; Cyp2e1 | 139.4 (60.5–491.7) | The chemical reactions and pathways involving fatty acids, aliphatic monocarboxylic acids liberated from naturally occurring fats and oils by hydrolysis.
GO:0006690 icosanoid metabolic process | 5/43 (11.6%) | Cyp2a5; Cyp4a10; Ces2e; Cyp4a14; Cyp2e1 | 139.4 (60.5–491.7) | The chemical reactions and pathways involving icosanoids, any of a group of C20 polyunsaturated fatty acids.

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology; NC = nonconvergent.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^33^ Official gene symbols from the Rat Genome Database^34^ are shown in the “Active Genes” column.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

GO process descriptions and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-3 Active Genes and Definitions within Top 10 Liver Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | Active Genes | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Definition
Rats
GO:0006805 xenobiotic metabolic process | 20/59 (33.9%) | Ugt2b1; Gstp1; Gstm2; Gsta4; Gsta1; Gsta3; Gsta2; Gsta5; Fmo1; Cyp3a2; Cyp3a23-3a1; Cyp2j4; Cyp2e1; Cyp2c6; Cyp2c11; Cyp2b2; Cyp2b1; Cbr1; Acaa1b; Acaa1a | 87.6 (59.6–136.7) | The chemical reactions and pathways involving a xenobiotic compound, a compound foreign to living organisms. Used of chemical compounds, e.g., a xenobiotic chemical, such as a pesticide.
GO:0001676 long-chain fatty acid metabolic process | 16/55 (29.1%) | Mgll; Gstp1; Gstm2; Gsta1; Fads1; Ephx1; Elovl6; Cyp2j4; Cyp2e1; Cyp2c6; Cyp2c11; Cyp2b2; Cyp2b1; Cpt2; Acot4; Acadl | 92.8 (52.7–142.7) | The chemical reactions and pathways involving long-chain fatty acids, A long-chain fatty acid is a fatty acid with a chain length between C13 and C22.
GO:0006690 icosanoid metabolic process | 14/50 (28.0%) | Mif; Mgll; Gstp1; Gsta1; Gsta2; Fads1; Ephx1; Cyp2j4; Cyp2e1; Cyp2c6; Cyp2c11; Cyp2b2; Cyp2b1; Comt | 92.8 (52.7–142.7) | The chemical reactions and pathways involving icosanoids, any of a group of C20 polyunsaturated fatty acids.
GO:0033559 unsaturated fatty acid metabolic process | 16/54 (29.6%) | Mif; Mgll; Gstp1; Gstm2; Gsta1; Gsta2; Fads1; Ephx1; Elovl6; Cyp2j4; Cyp2e1; Cyp2c6; Cyp2c11; Cyp2b2; Cyp2b1; Comt | 92.8 (52.7–142.7) | The chemical reactions and pathways involving an unsaturated fatty acid, any fatty acid containing one or more double bonds between carbon atoms.
GO:0120254 olefinic compound metabolic process | 15/64 (23.4%) | Srd5a1; Mgll; Gstp1; Gstm2; Gsta1; Fads1; Ephx1; Cyp3a2; Cyp2j4; Cyp2e1; Cyp2c6; Cyp2c11; Cyp2b2; Cyp2b1; Aldh1a1 | 116.4 (63.4–152.0) | The chemical reactions and pathways involving an olefinic compound, any compound which contains a carbon-carbon double bond (aka C=C).
GO:0006720 isoprenoid metabolic process | 17/41 (41.5%) | Srd5a1; Pecr; Mvd; Lss; Idi1; Hmgcs1; Hmgcr; Fdps; Fdft1; Dhdds; Cyp3a2; Cyp2j4; Cyp2e1; Cyp2c6; Cyp2c11; Aldh1a1; Acat2 | 143.6 (107.8–165.0) | The chemical reactions and pathways involving isoprenoid compounds, isoprene (2-methylbuta-1,3-diene) or compounds containing or derived from linked isoprene (3-methyl-2-butenylene) residues.
GO:0071384 cellular response to corticosteroid stimulus | 9/55 (16.4%) | Ugt2b1; Srd5a1; Ran; Pck1; Orm1; Gstp1; Ephx1; Eif4ebp1; Agtr1a | 153.0 (59.6–271.9) | Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a corticosteroid hormone stimulus. A corticosteroid is a steroid hormone that is produced in the adrenal cortex. Corticosteroids are involved in a wide range of physiologic systems such as stress response, immune response and regulation of inflammation, carbohydrate metabolism, protein catabolism, blood electrolyte levels, and behavior. They include glucocorticoids and mineralocorticoids.
GO:0071385 cellular response to glucocorticoid stimulus | 8/52 (15.4%) | Ugt2b1; Srd5a1; Pck1; Orm1; Gstp1; Ephx1; Eif4ebp1; Agtr1a | 153.0 (59.6–271.9) | Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a glucocorticoid stimulus. Glucocorticoids are hormonal C21 corticosteroids synthesized from cholesterol with the ability to bind with the cortisol receptor and trigger similar effects. Glucocorticoids act primarily on carbohydrate and protein metabolism and have anti- inflammatory effects.
GO:0098754 detoxification | 16/58 (27.6%) | Txnrd2; Txnrd1; Srxn1; Sod2; Slc22a1; Prdx3; Prdx2; Prdx1; Nqo1; Gstp1; Gstm2; Gsta3; Gsta2; Gsr; Aldh1a1; Akr7a3 | 153.4 (98.2–219.2) | Any process that reduces or removes the toxicity of a toxic substance. These may include transport of the toxic substance away from sensitive areas and to compartments or complexes whose purpose is sequestration of the toxic substance.
GO:0071383 cellular response to steroid hormone stimulus | 10/62 (16.1%) | Ugt2b1; Srd5a1; Ran; Pck1; Orm1; Gstp1; Ephx1; Eif4ebp1; Egr1; Agtr1a | 158.6 (44.1–339.0) | Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a steroid hormone stimulus.
Mice
GO:0051983 regulation of chromosome segregation | 22/45 (48.9%) | Nuf2; Ube2c; Aurkb; Smarcd2; Ccnb1; Cdk1; Cdc23; Spc24; Zwilch; Smc4; Cdc20; Knl1; Becn1; Tacc3; Cdca2; Ncapg2; Bub1; Hnrnpu; Birc5; Fbxo5; Ndc80; Chtf18 | 6.3 (0.9–28.2) | Any process that modulates the frequency, rate or extent of chromosome segregation, the process in which genetic material, in the form of chromosomes, is organized and then physically separated and apportioned to two or more sets.
GO:1901989 positive regulation of cell cycle phase transition | 19/53 (35.9%) | Ezh2; Ube2c; Ccnb1; Ccnd1; Cdk1; Cdc23; Rrm1; Cdc20; Ccnd2; Lmnb1; Aurka; Egfr; App; Birc5; Rrm2; Rad51c; Fbxo5; Ccne2; Dtl | 6.3 (0.9–28.2) | Any process that activates or increases the frequency, rate or extent of cell cycle phase transition.
GO:1901992 positive regulation of mitotic cell cycle phase transition | 17/43 (39.5%) | Ube2c; Ccnb1; Ccnd1; Cdk1; Cdc23; Rrm1; Cdc20; Ccnd2; Lmnb1; Egfr; App; Birc5; Rrm2; Rad51c; Fbxo5; Ccne2; Dtl | 6.3 (0.9–28.2) | Any process that activates or increases the frequency, rate, or extent of mitotic cell cycle phase transition.
GO:0007051 spindle organization | 15/40 (37.5%) | Nuf2; Aurkb; Aspm; Ccnb1; Cdc20; Uhrf1; Tacc3; Aurka; Haus3; Birc5; Ccnb2; Fbxo5; Ndc80; Stmn1; Kif11 | 6.9 (1.1–32.3) | A process that is carried out at the cellular level which results in the assembly, arrangement of constituent parts, or disassembly of the spindle, the array of microtubules and associated molecules that forms between opposite poles of a eukaryotic cell during DNA segregation and serves to move the duplicated chromosomes apart.
GO:0045931 positive regulation of mitotic cell cycle | 19/60 (31.7%) | Ube2c; Meis2; Ccnb1; Ccnd1; Cdk1; Cdc23; Rrm1; Cdc20; Stat5b; Ccnd2; Lmnb1; Egfr; App; Birc5; Rrm2; Rad51c; Fbxo5; Ccne2; Dtl | 6.9 (1.1–32.3) | Any process that activates or increases the rate or extent of progression through the mitotic cell cycle.
GO:0007088 regulation of mitotic nuclear division | 18/47 (38.3%) | Nuf2; Ube2c; Aurkb; Chek1; Ccnb1; Cdc23; Spc24; Igf1; Zwilch; Cdc20; Il1b; Knl1; Cdca2; Bub1; Birc5; Fgfr2; Fbxo5; Ndc80 | 7.7 (1.1–39.5) | Any process that modulates the frequency, rate or extent of mitosis.
GO:0033044 regulation of chromosome organization | 27/69 (39.1%) | Nuf2; Ube2c; Aurkb; Smarcd2; Ccnb1; Trp53; Cdk1; Dkc1; Cdc23; Spc24; Zwilch; Smc4; Cdc20; Top2a; Knl1; Becn1; Tacc3; Bub1; Hnrnpu; Birc5; Fen1; Pnkp; Fbxo5; Wdhd1; Mcm2; Ndc80; Senp6 | 7.7 (1.1–39.5) | Any process that modulates the frequency, rate or extent of a process involved in the formation, arrangement of constituent parts, or disassembly of a chromosome.
GO:0044770 cell cycle phase transition | 28/63 (44.4%) | Ezh2; Ptprc; Ube2c; Akap8l; Aurkb; Chek1; Ccnb1; Ccnd1; Cdk1; Timeless; Id4; Cdc20; Ccng1; Ccnd2; Nfib; Tacc3; Pole; Ccna2; Cks1b; App; Birc5; Tcf19; Ccnb2; Abcb1a; Ccne2; Arpp19; Ndc80; Skp2 | 7.7 (1.1–39.5) | The cell cycle process by which a cell commits to entering the next cell cycle phase.
GO:0044772 mitotic cell cycle phase transition | 22/55 (40.0%) | Ezh2; Ube2c; Chek1; Ccnb1; Ccnd1; Cdk1; Id4; Ccng1; Ccnd2; Nfib; Tacc3; Pole; Ccna2; Cks1b; App; Birc5; Tcf19; Ccnb2; Abcb1a; Ccne2; Arpp19; Skp2 | 7.7 (1.1–39.5) | The cell cycle process by which a cell commits to entering the next mitotic cell cycle phase.
GO:0051783 regulation of nuclear division | 19/52 (36.5%) | Nuf2; Ube2c; Aurkb; Chek1; Ccnb1; Cdc23; Spc24; Igf1; Zwilch; Cdc20; Il1b; Knl1; Cdca2; Bub1; Birc5; Rad51ap1; Fgfr2; Fbxo5; Ndc80 | 7.7 (1.1–39.5) | Any process that modulates the frequency, rate or extent of nuclear division, the partitioning of the nucleus and its genetic information.

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^33^ Official gene symbols from the Rat Genome Database^34^ are shown in the “Active Genes” column.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

GO process descriptions and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-4 Active Genes and Definitions within Top 10 Lung Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,4-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | Active Genes | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Definition
Rats
GO:0007059 chromosome segregation | 9/41 (22.0%) | Ttk; Smc2; Nuf2; Mad2l1; Kif18b; Dlgap5; Ctcf; Cenpw; Cenpf | 208.6 (55.4–1,082.9) | The process in which genetic material, in the form of chromosomes, is organized into specific structures and then physically separated and apportioned to two or more sets. In eukaryotes, chromosome segregation begins with the condensation of chromosomes, includes chromosome separation, and ends when chromosomes have completed movement to the spindle poles.
GO:0140694 nonmembrane-bounded organelle assembly | 6/59 (10.2%) | Plk4; Dlgap5; Cirbp; Cenpw; Cdc20; Ccnb2 | 236.8 (65.6–NC) | This biological process involves the aggregation, arrangement, and bonding together of a set of components to form a non-membrane-bounded organelle. Unlike traditional organelles enclosed by lipid membranes (e.g., nucleus, mitochondria), membraneless organelles are dynamic structures formed through processes like liquid-liquid phase separation. Examples include the nucleolus, stress granules, and P bodies. These organelles play crucial roles in various cellular functions, such as RNA processing, signal transduction, and stress responses. Their assembly is essential for maintaining cellular organization and function.
GO:0007049 cell cycle | 6/45 (13.3%) | Mybl1; Mki67; Cdca5; Kif18b; Cenpw; Cenpf | 247.7 (69.6–NC) | The progression of biochemical and morphological phases and events that occur in a cell during successive cell replication or nuclear replication events. Canonically, the cell cycle comprises the replication and segregation of genetic material followed by the division of the cell, but in endocycles or syncytial cells nuclear replication or nuclear division may not be followed by cell division.
GO:0048568 embryonic organ development | 5/47 (10.6%) | Slc6a8; Junb; Hsd17b7; Gdnf; Cebpb | 264.4 (73.4–2,060.4) | Development, taking place during the embryonic phase, of a tissue or tissues that work together to perform a specific function or functions. Development pertains to the process whose specific outcome is the progression of a structure over time, from its formation to the mature structure. Organs are commonly observed as visibly distinct structures but may also exist as loosely associated clusters of cells that work together to perform a specific function or functions.
GO:0045931 positive regulation of mitotic cell cycle | 3/51 (5.9%) | Cdca5; Crebbp; Cdc20 | 288.7 (135.6–NC) | Any process that activates or increases the rate or extent of progression through the mitotic cell cycle.
GO:1901989 positive regulation of cell cycle phase transition | 3/43 (7.0%) | Cdca5; Crebbp; Cdc20 | 288.7 (135.6–NC) | Any process that activates or increases the frequency, rate or extent of cell cycle phase transition.
GO:1901990 regulation of mitotic cell cycle phase transition | 7/94 (7.5%) | Ttk; Mad2l1; Cdca5; Ier3; Crebbp; Cenpf; Cdc20 | 288.7 (135.6–NC) | Any process that modulates the frequency, rate or extent of mitotic cell cycle phase transition.
GO:0051301 cell division | 8/84 (9.5%) | Nuf2; Cdca5; Kif18b; Cenpw; Cdc20; Ccnb2; Ccnb2-ps2; Ccna2 | 289.6 (102.8–NC) | The process resulting in division and partitioning of components of a cell to form more cells; may or may not be accompanied by the physical separation of a cell into distinct, individually membrane-bounded daughter cells.
GO:1901987 regulation of cell cycle phase transition | 11/116 (9.5%) | Ttk; Mapk14; Mad2l1; Cdca5; Ier3; Cry1; Crebbp; Cirbp; Cenpf; Cdc20; Apbb2 | 293.1 (122.5–NC) | Any process that modulates the frequency, rate or extent of cell cycle phase transition.
GO:0050728 negative regulation of inflammatory response | 5/51 (9.8%) | Nr1d2; Ier3; Hgf; Enpp3; Ahr | 293.3 (143.2–448.6) | Any process that stops, prevents, or reduces the frequency, rate or extent of the inflammatory response.
Mice
GO:0006260 DNA replication | 3/43 (7.0%) | Pole; Dtl; Gins2 | 1.4 (0.5–1,130.8) | The cellular metabolic process in which a cell duplicates one or more molecules of DNA. DNA replication begins when specific sequences, known as origins of replication, are recognized and bound by initiation proteins, and ends when the original DNA molecule has been completely duplicated and the copies topologically separated. The unit of replication usually corresponds to the genome of the cell, an organelle, or a virus. The template for replication can either be an existing DNA molecule or RNA.
GO:0006805 xenobiotic metabolic process | 5/56 (8.9%) | Gsta2; Gsta1; Cyp1a1; Ugt1a6a; Ugt1a6b | 2.9 (0.4–54.2) | The chemical reactions and pathways involving a xenobiotic compound, a compound foreign to living organisms. Used of chemical compounds, e.g., a xenobiotic chemical, such as a pesticide.
GO:0000209 protein polyubiquitination | 3/42 (7.1%) | Ube2t; Nqo1; Dtl | 3.8 (0.8–14.9) | Addition of multiple ubiquitin groups to a protein, forming a ubiquitin chain.
GO:0016567 protein ubiquitination | 4/68 (5.9%) | Uhrf1; Ube2t; Nqo1; Dtl | 3.8 (0.8–14.9) | The process in which one or more ubiquitin groups are added to a protein.
GO:0032446 protein modification by small protein conjugation | 4/79 (5.1%) | Uhrf1; Ube2t; Nqo1; Dtl | 3.8 (0.8–14.9) | A protein modification process in which one or more groups of a small protein, such as ubiquitin or a ubiquitin-like protein, are covalently attached to a target protein.
GO:0006575 cellular modified amino acid metabolic process | 5/59 (8.5%) | Gsta2; Mthfd1l; Gclc; Slc7a11; Gsta1 | 14.1 (2.1–56.6) | The chemical reactions and pathways involving compounds derived from amino acids, organic acids containing one or more amino substituents.
GO:0048545 response to steroid hormone | 3/52 (5.8%) | Lox; Ugt1a6a; Ugt1a6b | 68.8 (9.1–117.4) | Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a steroid hormone stimulus.
GO:0008203 cholesterol metabolic process | 3/48 (6.3%) | Ces1g; Hmgcs2; Tsku | 75.4 (33.3–148.1) | The chemical reactions and pathways involving cholesterol, cholest-5-en-3 beta-ol, the principal sterol of vertebrates and the precursor of many steroids, including bile acids and steroid hormones. It is a component of the plasma membrane lipid bilayer and of plasma lipoproteins and can be found in all animal tissues.
GO:0016125 sterol metabolic process | 3/49 (6.1%) | Ces1g; Hmgcs2; Tsku | 75.4 (33.3–148.1) | The chemical reactions and pathways involving sterols, steroids with one or more hydroxyl groups and a hydrocarbon side-chain in the molecule.
GO:1902652 secondary alcohol metabolic process | 3/53 (5.7%) | Ces1g; Hmgcs2; Tsku | 75.4 (33.3–148.1) | The chemical reactions and pathways involving secondary alcohol.

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology; NC = nonconvergent.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^33^ Official gene symbols from the Rat Genome Database^34^ are shown in the “Active Genes” column.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

GO process descriptions and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-5 Active Genes and Definitions within Top 10 Ovary Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats Exposed to 1,4-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | Active Genes | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Definition
GO:0001667 ameboidal-type cell migration | 5/55 (9.1%) | S100a9; Nrp1; Kdr; Cxcl12; Apoa1 | 223.1 (90.9–432.8) | Cell migration that is accomplished by extension and retraction of a pseudopodium.
GO:2001235 positive regulation of apoptotic signaling pathway | 6/58 (10.3%) | Vnn1; Tnfrsf12a; S100a9; Myc; Jak2; Ei24 | 282.7 (140.2–432.6) | Any process that activates or increases the frequency, rate or extent of apoptotic signaling pathway.
GO:0061041 regulation of wound healing | 5/59 (8.5%) | Tnfrsf12a; S100a9; Plg; F2r; Anxa5 | 309.9 (178.5–463.5) | Any process that modulates the rate, frequency, or extent of the series of events that restore integrity to a damaged tissue, following an injury.
GO:0048639 positive regulation of developmental growth | 5/50 (10.0%) | Tnfrsf12a; Nrp1; Mapk14; Cxcl12; Adrb2 | 332.8 (176.6–485.1) | Any process that activates, maintains or increases the rate of developmental growth.
GO:0030307 positive regulation of cell growth | 3/47 (6.4%) | Tnfrsf12a; Nrp1; Cxcl12 | 335.6 (203.0–460.4) | Any process that activates or increases the frequency, rate, extent or direction of cell growth.
GO:0015850 organic hydroxy compound transport | 5/60 (8.3%) | Slc51a; Slc10a2; Myc; Apoa1; Abcc4 | 347.9 (198.4–485.0) | The directed movement of an organic hydroxy compound (organic alcohol) into, out of or within a cell, or between cells, by means of some agent such as a transporter or pore. An organic hydroxy compound is an organic compound having at least one hydroxy group attached to a carbon atom.
GO:0002526 acute inflammatory response | 3/43 (7.0%) | Vnn1; Hp; A2m | 354.0 (206.0–481.4) | Inflammation which comprises a rapid, short-lived, relatively uniform response to acute injury or antigenic challenge and is characterized by accumulations of fluid, plasma proteins, and granulocytic leukocytes. An acute inflammatory response occurs within a matter of minutes or hours, and either resolves within a few days or becomes a chronic inflammatory response.
GO:2001242 regulation of intrinsic apoptotic signaling pathway | 6/75 (8.0%) | Vnn1; S100a9; Myc; Herpud1; Ei24; Cxcl12 | 366.2 (144.6–NC) | Any process that modulates the frequency, rate or extent of intrinsic apoptotic signaling pathway.
GO:0051385 response to mineralocorticoid | 3/45 (6.7%) | Maob; Grin2b; Fosl1 | 382.1 (233.3–525.2) | Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a mineralocorticoid stimulus. Mineralocorticoids are hormonal C21 corticosteroids synthesized from cholesterol and characterized by their similarity to aldosterone. Mineralocorticoids act primarily on water and electrolyte balance.
GO:1903034 regulation of response to wounding | 5/69 (7.3%) | Tnfrsf12a; S100a9; Plg; F2r; Anxa5 | 383.0 (243.8–527.7) | Any process that modulates the frequency, rate or extent of response to wounding.

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology; NC = nonconvergent.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^33^ Official gene symbols from the Rat Genome Database^34^ are shown in the “Active Genes” column.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

GO process descriptions and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-6 Gene Identifiers and Definitions for Female Rats Exposed to 1,4-Dichlorobenzene for Five Days^a^

Gene Symbol | Entrez Gene IDs | Probe IDs^b^ | Definition
Abcc3 | 140668 | ABCC3_7941 | Human Uniprot function (Human ABCC3): May act as an inducible transporter in the biliary and intestinal excretion of organic anions. Acts as an alternative route for the export of bile acids and glucuronides from cholestatic hepatocytes (By similarity). \{ECO:0000250\}.
Acss1 | 296259 | ACSS1_32386 | Human Uniprot function (Human ACSS1): Catalyzes the synthesis of acetyl-CoA from short-chain fatty acids (PubMed:16788062). Acetate is the preferred substrate (PubMed:16788062). Can also utilize propionate with a much lower affinity (By similarity). Provides acetyl-CoA that is utilized mainly for oxidation under ketogenic conditions (By similarity). Involved in thermogenesis under ketogenic conditions, using acetate as a vital fuel when carbohydrate availability is insufficient (By similarity). \{ECO:0000250\|UniProtKB:Q99NB1, ECO:0000269\|PubMed:16788062\}.
Aen | 361594 | AEN_7998 | Human Uniprot function (Human AEN): Exonuclease with activity against single- and double-stranded DNA and RNA. Mediates p53-induced apoptosis. When induced by p53 following DNA damage, digests double- stranded DNA to form single-stranded DNA and amplifies DNA damage signals, leading to enhancement of apoptosis. \{ECO:0000269\|PubMed:16171785, ECO:0000269\|PubMed:18264133\}.
Aldh1a1 | 24188 | ALDH1A1_8022 | Human Uniprot function (Human ALDH1A1): Can convert/oxidize retinaldehyde to retinoic acid. Binds free retinal and cellular retinol-binding protein-bound retinal (By similarity). May have a broader specificity and oxidize other aldehydes in vivo (PubMed:19296407, PubMed:26373694, PubMed:25450233). \{ECO:0000250\|UniProtKB:P51647, ECO:0000269\|PubMed:19296407, ECO:0000269\|PubMed:25450233, ECO:0000269\|PubMed:26373694\}.
Apoa1 | 25081 | APOA1_33150 | Human Uniprot function (Human APOA1): Participates in the reverse transport of cholesterol from tissues to the liver for excretion by promoting cholesterol efflux from tissues and by acting as a cofactor for the lecithin cholesterol acyltransferase (LCAT). As part of the SPAP complex, activates spermatozoa motility. \{ECO:0000269\|PubMed:1909888\}.
Car3/Ca3 | 54232 | CAR3_8196 | Rat Uniprot function (Rat Car3): Reversible hydration of carbon dioxide.
Ccl12 | 287562 | CCL12_8217 | Human Uniprot function (Human CCL13): Chemotactic factor that attracts monocytes, lymphocytes, basophils and eosinophils, but not neutrophils. Signals through CCR2B and CCR3 receptors. Plays a role in the accumulation of leukocytes at both sides of allergic and non-allergic inflammation. May be involved in the recruitment of monocytes into the arterial wall during the disease process of atherosclerosis. May play a role in the monocyte attraction in tissues chronically exposed to exogenous pathogens.
Ccna2 | 114494 | CCNA2_8221 | Human Uniprot function (Human CCNA2): Cyclin which controls both the G1/S and the G2/M transition phases of the cell cycle. Functions through the formation of specific serine/threonine protein kinase holoenzyme complexes with the cyclin-dependent protein kinases CDK1 or CDK2. The cyclin subunit confers the substrate specificity of these complexes and differentially interacts with and activates CDK1 and CDK2 throughout the cell cycle. \{ECO:0000269\|PubMed:1312467\}.
Ccnb2 | 363088 | CCNB2_8223 | Human Uniprot function (Human CCNB2): Essential for the control of the cell cycle at the G2/M (mitosis) transition.
Ccnb2-ps2 | 100364016 | CCNB2_8223 | No description available.
Cebpd | 25695 | CEBPD_8283 | Human Uniprot function (Human CEBPD): Transcription activator that recognizes two different DNA motifs: the CCAAT homology common to many promoters and the enhanced core homology common to many enhancers (PubMed:16397300). Important transcription factor regulating the expression of genes involved in immune and inflammatory responses (PubMed:16397300, PubMed:1741402). Transcriptional activator that enhances IL6 transcription alone and as heterodimer with CEBPB (PubMed:1741402). \{ECO:0000269\|PubMed:1741402\}.
Cenpf | 257649 | CENPF_8287 | Human Uniprot function (Human CENPF): Required for kinetochore function and chromosome segregation in mitosis. Required for kinetochore localization of dynein, LIS1, NDE1, and NDEL1. Regulates recycling of the plasma membrane by acting as a link between recycling vesicles and the microtubule network though its association with STX4 and SNAP25. Acts as a potential inhibitor of pocket protein-mediated cellular processes during development by regulating the activity of RB proteins during cell division and proliferation. May play a regulatory or permissive role in the normal embryonic cardiomyocyte cell cycle and in promoting continued mitosis in transformed, abnormally dividing neonatal cardiomyocytes. Interaction with RB directs embryonic stem cells toward a cardiac lineage. Involved in the regulation of DNA synthesis and hence cell cycle progression, via its C-terminus. Has a potential role regulating skeletal myogenesis and in cell differentiation in embryogenesis. Involved in dendritic cell regulation of T-cell immunity against chlamydia. \{ECO:0000269\|PubMed:12974617, ECO:0000269\|PubMed:17600710, ECO:0000269\|PubMed:7542657, ECO:0000269\|PubMed:7651420\}.
Cenpw | 689399 | CENPW_32846 | Human Uniprot function (Human CENPW): Component of the CENPA-NAC (nucleosome-associated) complex, a complex that plays a central role in assembly of kinetochore proteins, mitotic progression and chromosome segregation (By similarity). The CENPA-NAC complex recruits the CENPA-CAD (nucleosome distal) complex and may be involved in incorporation of newly synthesized CENPA into centromeres (By similarity). Part of a nucleosome-associated complex that binds specifically to histone H3-containing nucleosomes at the centromere, as opposed to nucleosomes containing CENPA. Component of the heterotetrameric CENP-T-W-S-X complex that binds and supercoils DNA, and plays an important role in kinetochore assembly. CENPW has a fundamental role in kinetochore assembly and function. It is one of the inner kinetochore proteins, with most further proteins binding downstream. Required for normal chromosome organization and normal progress through mitosis. \{ECO:0000250, ECO:0000269\| PubMed:19070575, ECO:0000269\|PubMed:19533040, ECO:0000269\|PubMed:21695110, ECO:0000269\|PubMed:22002061,ECO:0000269\|PubMed:22304917\}.
Cks2 | 498709 | CKS2_8325 | Human Uniprot function (Human CKS2): Binds to the catalytic subunit of the cyclin dependent kinases and is essential for their biological function.
Cxcl12 | 24772 | CXCL12_8410, CXCL12_32815 | Human Uniprot function (Human CXCL12): Chemoattractant active on T-lymphocytes and monocytes but not neutrophils. Activates the C-X-C chemokine receptor CXCR4 to induce a rapid and transient rise in the level of intracellular calcium ions and chemotaxis. SDF-1-beta(3-72) and SDF-1-alpha(3-67) show a reduced chemotactic activity. Binding to cell surface proteoglycans seems to inhibit formation of SDF-1- alpha(3-67) and thus to preserve activity on local sites. Also binds to atypical chemokine receptor ACKR3, which activates the beta-arrestin pathway and acts as a scavenger receptor for SDF-1. Binds to the allosteric site (site 2) of integrins and activates integrins ITGAV:ITGB3, ITGA4:ITGB1 and ITGA5:ITGB1 in a CXCR4-independent manner (PubMed:29301984). Acts as a positive regulator of monocyte migration and a negative regulator of monocyte adhesion via the LYN kinase. Stimulates migration of monocytes and T-lymphocytes through its receptors, CXCR4 and ACKR3, and decreases monocyte adherence to surfaces coated with ICAM-1, a ligand for beta-2 integrins. SDF1A/CXCR4 signaling axis inhibits beta-2 integrin LFA-1 mediated adhesion of monocytes to ICAM-1 through LYN kinase. Inhibits CXCR4-mediated infection by T-cell line-adapted HIV-1. Plays a protective role after myocardial infarction. Induces down-regulation and internalization of ACKR3 expressed in various cells. Has several critical functions during embryonic development; required for B-cell lymphopoiesis, myelopoiesis in bone marrow and heart ventricular septum formation. Stimulates the proliferation of bone marrow-derived B-cell progenitors in the presence of IL7 as well as growth of stromal cell-dependent pre-B-cells (By similarity). \{ECO:0000250\|UniProtKB:P40224, ECO:0000269\|PubMed:11069075, ECO:0000269\|PubMed:11859124, ECO:0000269\|PubMed:16107333, ECO:0000269\|PubMed:18802065, ECO:0000269\|PubMed:19255243, ECO:0000269\|PubMed:29301984, ECO:0000269\|PubMed:8752281\}.
Cyp2b1 | 24300 | CYP2B1_32451, CYP2B2_32473 | Human Uniprot function (Human CYP2B6): A cytochrome P450 monooxygenase involved in the metabolism of endocannabinoids and steroids (PubMed:21289075, PubMed:12865317). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (NADPH–hemoprotein reductase). Catalyzes the epoxidation of double bonds of arachidonoylethanolamide (anandamide) to 8,9-, 11,12-, and 14,15-epoxyeicosatrienoic acid ethanolamides (EpETrE-EAs), potentially modulating endocannabinoid system signaling (PubMed:21289075). Hydroxylates steroid hormones, including testosterone at C-16 and estrogens at C-2 (PubMed:12865317, PubMed:21289075). Plays a role in the oxidative metabolism of xenobiotics, including plant lipids and drugs (PubMed:11695850, PubMed:22909231). Acts as a 1,4-cineole 2-exo-monooxygenase (PubMed:11695850). \{ECO:0000269\|PubMed:11695850, ECO:0000269\|PubMed:12865317, ECO:0000269\|PubMed:21289075, ECO:0000269\|PubMed:22909231\}.; FUNCTION: Allele 2B6*9: Has low affinity for anandamide and can only produce 11,12 EpETrE-EAs. \{ECO:0000269\|PubMed:21289075\}.
Cyp2b2 | 361523 | CYP2B2_32473 | Human Uniprot function (Human CYP2B6): A cytochrome P450 monooxygenase involved in the metabolism of endocannabinoids and steroids (PubMed:21289075, PubMed:12865317). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (NADPH–hemoprotein reductase). Catalyzes the epoxidation of double bonds of arachidonoylethanolamide (anandamide) to 8,9-, 11,12-, and 14,15-epoxyeicosatrienoic acid ethanolamides (EpETrE-EAs), potentially modulating endocannabinoid system signaling (PubMed:21289075). Hydroxylates steroid hormones, including testosterone at C-16 and estrogens at C-2 (PubMed:21289075, PubMed:12865317). Plays a role in the oxidative metabolism of xenobiotics, including plant lipids and drugs (PubMed:11695850, PubMed:22909231). Acts as a 1,4-cineole 2-exo-monooxygenase (PubMed:11695850). \{ECO:0000269\|PubMed:11695850, ECO:0000269\|PubMed:12865317, ECO:0000269\|PubMed:21289075, ECO:0000269\|PubMed:22909231\}.; FUNCTION: Allele 2B6*9: Has low affinity for anandamide and can only produce 11,12 EpETrE-EAs. \{ECO:0000269\|PubMed:21289075\}.
Cyp2c6 | 293989 | CYP2C6V1_33169 | Rat Uniprot function (Rat Cyp2c6): Cytochromes P450 are a group of heme-thiolate monooxygenases. In liver microsomes, this enzyme is involved in an NADPH-dependent electron transport pathway. It oxidizes a variety of structurally unrelated compounds, including steroids, fatty acids, and xenobiotics.
Cyp4a2 | 24306 | CYP4A2_32530,CYP4A2_8426,CYP4A2_8425 | Human Uniprot function (Human CYP4A22): Catalyzes the omega- and (omega-1)-hydroxylation of various fatty acids such as laurate and palmitate. Shows no activity toward arachidonic acid and prostaglandin A1. Lacks functional activity in the kidney and does not contribute to renal 20-hydroxyeicosatetraenoic acid (20-HETE) biosynthesis. \{ECO:0000269\|PubMed:10860550, ECO:0000269\|PubMed:15611369\}.
Cyp4a3 | 298423 | CYP4A2_32530,CYP4A2_8426 | Human Uniprot function (Human CYP4Z1): A cytochrome P450 monooxygenase that catalyzes omega and omega-1 hydroxylation of saturated fatty acids. Exhibits preferential omega versus omega-1 regioselectivity and (R) versus (S) stereoselectivity for hydroxylation of dodecanoic (lauric) acid. Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (CPR; NADPH-ferrihemoprotein reductase). \{ECO:0000269\|PubMed:10869363\}.
Dbp | 24309 | DBP_8439 | Human Uniprot function (Human DBP): This transcriptional activator recognizes and binds to the sequence 5’-RTTAYGTAAY-3’ found in the promoter of genes such as albumin, CYP2A4 and CYP2A5. It is not essential for circadian rhythm generation, but modulates important clock output genes. May be a direct target for regulation by the circadian pacemaker component clock. May affect circadian period and sleep regulation.
Ddit4 | 140942 | DDIT4_8450 | Human Uniprot function (Human DDIT4): Regulates cell growth, proliferation and survival via inhibition of the activity of the mammalian target of rapamycin complex 1 (mTORC1). Inhibition of mTORC1 is mediated by a pathway that involves DDIT4/REDD1, AKT1, the TSC1-TSC2 complex and the GTPase RHEB. Plays an important role in responses to cellular energy levels and cellular stress, including responses to hypoxia and DNA damage. Regulates p53/TP53-mediated apoptosis in response to DNA damage via its effect on mTORC1 activity. Its role in the response to hypoxia depends on the cell type; it mediates mTORC1 inhibition in fibroblasts and thymocytes, but not in hepatocytes (By similarity). Required for mTORC1-mediated defense against viral protein synthesis and virus replication (By similarity). Inhibits neuronal differentiation and neurite outgrowth mediated by NGF via its effect on mTORC1 activity. Required for normal neuron migration during embryonic brain development. Plays a role in neuronal cell death. \{ECO:0000250, ECO:0000269\|PubMed:15545625, ECO:0000269\|PubMed:15632201, ECO:0000269\|PubMed:15988001, ECO:0000269\|PubMed:17005863, ECO:0000269\|PubMed:17379067, ECO:0000269\|PubMed:19557001, ECO:0000269\|PubMed:20166753, ECO:0000269\|PubMed:21460850\}.
Dhcr7 | 64191 | DHCR7_8466 | Human Uniprot function (Human DHCR7): 7-dehydrocholesterol reductase of the cholesterol biosynthetic pathway reducing the C7-C8 double bond of cholesta-5,7-dien-3beta-ol (7-dehydrocholesterol/7-DHC) and cholesta-5,7,24- trien-3beta-ol, two intermediates in that pathway. {ECO:0000269\|PubMed:25637936, ECO:0000269\|PubMed:9465114, ECO:0000269\|PubMed:9634533}.
Egr1 | 24330 | EGR1_8533 | Human Uniprot function (Human EGR1): Transcriptional regulator (PubMed:20121949). Recognizes and binds to the DNA sequence 5’-GCG(T/G)GGGCG-3’(EGR-site) in the promoter region of target genes (By similarity). Binds double-stranded target DNA, irrespective of the cytosine methylation status (PubMed:25258363, PubMed:25999311). Regulates the transcription of numerous target genes, and thereby plays an important role in regulating the response to growth factors, DNA damage, and ischemia. Plays a role in the regulation of cell survival, proliferation and cell death. Activates expression of p53/TP53 and TGFB1, and thereby helps prevent tumor formation. Required for normal progress through mitosis and normal proliferation of hepatocytes after partial hepatectomy. Mediates responses to ischemia and hypoxia; regulates the expression of proteins such as IL1B and CXCL2 that are involved in inflammatory processes and development of tissue damage after ischemia. Regulates biosynthesis of luteinizing hormone (LHB) in the pituitary (By similarity). Regulates the amplitude of the expression rhythms of clock genes: ARNTL/BMAL1, PER2 and NR1D1 in the liver via the activation of PER1 (clock repressor) transcription. Regulates the rhythmic expression of core-clock gene ARNTL/BMAL1 in the suprachiasmatic nucleus (SCN) (By similarity). \{ECO:0000250\|UniProtKB:P08046, ECO:0000269\|PubMed:20121949, ECO:0000269\|PubMed:25258363, ECO:0000269\|PubMed:25999311\}.
Ephx1 | 25315 | EPHX1_8567 | Human Uniprot function (Human EPHX1): Biotransformation enzyme that catalyzes the hydrolysis of arene and aliphatic epoxides to less reactive and more water soluble dihydrodiols by the trans addition of water (By similarity). Plays a role in the metabolism of endogenous lipids such as epoxide-containing fatty acids (PubMed:22798687). Metabolizes the abundant endocannabinoid 2-arachidonoylglycerol (2-AG) to free arachidonic acid (AA) and glycerol (PubMed:24958911). \{ECO:0000250\|UniProtKB:P07687, ECO:0000269\|PubMed:22798687, ECO:0000269\|PubMed:24958911\}.
Fosl1 | 25445 | FOSL1_8659 | Human Entrez Gene Summary (Human FOSL1): The Fos gene family consists of 4 members: FOS, FOSB, FOSL1, and FOSL2. These genes encode leucine zipper proteins that can dimerize with proteins of the JUN family, thereby forming the transcription factor complex AP-1. As such, the FOS proteins have been implicated as regulators of cell proliferation, differentiation, and transformation. Several transcript variants encoding different isoforms have been found for this gene. [provided by RefSeq, Jul 2014]
Ier3 | 294235 | IER3_8864 | Human Uniprot function (Human IER3): May play a role in the ERK signaling pathway by inhibiting the dephosphorylation of ERK by phosphatase PP2A-PPP2R5C holoenzyme. Acts also as an ERK downstream effector mediating survival. As a member of the NUPR1/RELB/IER3 survival pathway, may provide pancreatic ductal adenocarcinoma with remarkable resistance to cell stress, such as starvation or gemcitabine treatment. \{ECO:0000269\|PubMed:12356731, ECO:0000269\|PubMed:16456541, ECO:0000269\|PubMed:22565310\}.
Junb | 24517 | JUNB_8939 | Human Uniprot function (Human JUNB): Transcription factor involved in regulating gene activity following the primary growth factor response. Binds to the DNA sequence 5’-TGA[CG]TCA-3’.
Kif18b | 303575 | KIF18B_32882 | Human Uniprot function (Human KIF18B): In complex with KIF2C, constitutes the major microtubule plus-end depolymerizing activity in mitotic cells. Its major role may be to transport KIF2C and/or MAPRE1 along microtubules. \{ECO:0000269\|PubMed:20600703, ECO:0000269\|PubMed:21820309\}.
Kif22 | 293502 | KIF22_8963 | Human Uniprot function (Human KIF22): Kinesin family member that is involved in spindle formation and the movements of chromosomes during mitosis and meiosis. Binds to microtubules and to DNA (By similarity). Plays a role in congression of laterally attached chromosomes in NDC80-depleted cells (PubMed:25743205). \{ECO:0000250\|UniProtKB:Q9I869, ECO:0000269\|PubMed:25743205\}.
Lck | 313050 | LCK_32705 | Human Uniprot function (Human Lck): Non-receptor tyrosine-protein kinase that plays an essential role in the selection and maturation of developing T-cells in the thymus and in the function of mature T-cells. Plays a key role in T-cell antigen receptor (TCR)-linked signal transduction pathways. Constitutively associated with the cytoplasmic portions of the CD4 and CD8 surface receptors. Association of the TCR with a peptide antigen-bound MHC complex facilitates the interaction of CD4 and CD8 with MHC class II and class I molecules, respectively, thereby recruiting the associated LCK protein to the vicinity of the TCR/CD3 complex. LCK then phosphorylates tyrosine residues within the immunoreceptor tyrosine-based activation motifs (ITAM) of the cytoplasmic tails of the TCR-gamma chains and CD3 subunits, initiating the TCR/CD3 signaling pathway. Once stimulated, the TCR recruits the tyrosine kinase ZAP70, that becomes phosphorylated and activated by LCK. Following this, a large number of signaling molecules are recruited, ultimately leading to lymphokine production. LCK also contributes to signaling by other receptor molecules. Associates directly with the cytoplasmic tail of CD2, which leads to hyperphosphorylation and activation of LCK. Also plays a role in the IL2 receptor-linked signaling pathway that controls the T-cell proliferative response. Binding of IL2 to its receptor results in increased activity of LCK. Is expressed at all stages of thymocyte development and is required for the regulation of maturation events that are governed by both pre-TCR and mature alpha beta TCR. Phosphorylates other substrates, including RUNX3, PTK2B/PYK2, the microtubule-associated protein MAPT, RHOH or TYROBP. Interacts with FYB2 (PubMed:27335501). {ECO:0000269\| PubMed:16339550, ECO:0000269\|PubMed:16709819, ECO:0000269\|PubMed:20028775, ECO:0000269\|PubMed:20100835, ECO:0000269\|PubMed:20851766, ECO:0000269\|PubMed:21269457, ECO:0000269\|PubMed:22080863, ECO:0000269\|PubMed:27335501}.
Loc100911718 | 100911718 | CYP2C6V1_33169 | No description available.
Meg3 | 500717 | RGD1566401_32721 | No description available.
Mfap4 | 287382 | MFAP4_32762 | Human Uniprot function (Human MFAP4): Could be involved in calcium-dependent cell adhesion or intercellular interactions. May contribute to the elastic fiber assembly and/or maintenance(PubMed:26601954). \{ECO:0000269\|PubMed:26601954\}.
Mki67 | 291234 | MKI67_9232 | Human Uniprot function (Human MKI67): Required to maintain individual mitotic chromosomes dispersed in the cytoplasm following nuclear envelope disassembly (PubMed:27362226). Associates with the surface of the mitotic chromosome, the perichromosomal layer, and covers a substantial fraction of the chromosome surface (PubMed:27362226). Prevents chromosomes from collapsing into a single chromatin mass by forming a steric and electrostatic charge barrier: the protein has a high net electrical charge and acts as a surfactant, dispersing chromosomes and enabling independent chromosome motility (PubMed:27362226). Binds DNA, with a preference for supercoiled DNA and AT-rich DNA (PubMed:10878551). Does not contribute to the internal structure of mitotic chromosomes (By similarity). May play a role in chromatin organization (PubMed:24867636). It is however unclear whether it plays a direct role in chromatin organization or whether it is an indirect consequence of its function in maintaining mitotic chromosomes dispersed (Probable). \{ECO:0000250\|UniProtKB:E9PVX6, ECO:0000269\|PubMed:10878551, ECO:0000269\|PubMed:24867636, ECO:0000269\|PubMed:27362226\}.
Papss2 | 294103 | PAPSS2_33237 | Human Uniprot function (Human PAPSS2): Bifunctional enzyme with both ATP sulfurylase and APS kinase activity, which mediates two steps in the sulfate activation pathway. The first step is the transfer of a sulfate group to ATP to yield adenosine 5'-phosphosulfate (APS), and the second step is the transfer of a phosphate group from ATP to APS yielding 3'-phosphoadenylylsulfate (PAPS: activated sulfate donor used by sulfotransferase). In mammals, PAPS is the sole source of sulfate; APS appears to be only an intermediate in the sulfate-activation pathway. May have an important role in skeletogenesis during postnatal growth (By similarity). {ECO:0000250}.
Prc1 | 308761 | PRC1_9556 | Human Uniprot function (Human PRC1): Key regulator of cytokinesis that cross-links antiparallel microtubules at an average distance of 35 nM. Essential for controlling the spatiotemporal formation of the midzone and successful cytokinesis. Required for KIF14 localization to the central spindle and midbody. Required to recruit PLK1 to the spindle. Stimulates PLK1 phosphorylation of RACGAP1 to allow recruitment of ECT2 to the central spindle. Acts as an oncogene for promoting bladder cancer cells proliferation, apoptosis inhibition and carcinogenic progression (PubMed:17409436). \{ECO:0000269\|PubMed:12082078, ECO:0000269\|PubMed:15297875, ECO:0000269\|PubMed:15625105, ECO:0000269\|PubMed:16431929, ECO:0000269\|PubMed:17409436, ECO:0000269\|PubMed:19468300, ECO:0000269\|PubMed:20691902, ECO:0000269\|PubMed:9885575\}.
Rt1-da | 294269 | RT1-DA_9760 | No description available.
S100a9 | 94195 | S100A9_9775 | Human Uniprot function (Human S100A9): S100A9 is a calcium- and zinc-binding protein which plays a prominent role in the regulation of inflammatory processes and immune response. It can induce neutrophil chemotaxis, adhesion, can increase the bactericidal activity of neutrophils by promoting phagocytosis via activation of SYK, PI3K/AKT, and ERK1/2 and can induce degranulation of neutrophils by a MAPK-dependent mechanism. Predominantly found as calprotectin (S100A8/A9) which has a wide plethora of intra and extracellular functions. The intracellular functions include: facilitating leukocyte arachidonic acid trafficking and metabolism, modulation of the tubulin-dependent cytoskeleton during migration of phagocytes and activation of the neutrophilic NADPH-oxidase. Activates NADPH-oxidase by facilitating the enzyme complex assembly at the cell membrane, transferring arachidonic acid, an essential cofactor, to the enzyme complex and S100A8 contributes to the enzyme assembly by directly binding to NCF2/ P67PHOX. The extracellular functions involve proinflammatory, antimicrobial, oxidant-scavenging and apoptosis-inducing activities. Its proinflammatory activity includes recruitment of leukocytes, promotion of cytokine and chemokine production, and regulation of leukocyte adhesion and migration. Acts as an alarmin or a danger associated molecular pattern (DAMP) molecule and stimulates innate immune cells via binding to pattern recognition receptors such as Toll-like receptor 4 (TLR4) and receptor for advanced glycation endproducts (AGER). Binding to TLR4 and AGER activates the MAP-kinase and NF-kappa-B signaling pathways resulting in the amplification of the proinflammatory cascade. Has antimicrobial activity toward bacteria and fungi and exerts its antimicrobial activity probably via chelation of Zn(^2+^) which is essential for microbial growth. Can induce cell death via autophagy and apoptosis and this occurs through the cross-talk of mitochondria and lysosomes via reactive oxygen species (ROS) and the process involves BNIP3. Can regulate neutrophil number and apoptosis by an anti-apoptotic effect; regulates cell survival via ITGAM/ITGB and TLR4 and a signaling mechanism involving MEK-ERK. Its role as an oxidant scavenger has a protective role in preventing exaggerated tissue damage by scavenging oxidants. Can act as a potent amplifier of inflammation in autoimmunity as well as in cancer development and tumor spread. Has transnitrosylase activity; in oxidatively-modified low-density lipoprotein (LDL(ox))-induced S-nitrosylation of GAPDH on ’Cys-247’ proposed to transfer the NO moiety from NOS2/iNOS to GAPDH via its own S-nitrosylated Cys-3. The iNOS-S100A8/A9 transnitrosylase complex is proposed to also direct selective inflammatory stimulus-dependent S-nitrosylation of multiple targets such as ANXA5, EZR, MSN and VIM by recognizing a [IL]-x-C-x-x-[DE] motif. \{ECO:0000269\|PubMed:12626582, ECO:0000269\|PubMed:15331440, ECO:0000269\|PubMed:15598812, ECO:0000269\|PubMed:15642721, ECO:0000269\|PubMed:16258195, ECO:0000269\|PubMed:19087201, ECO:0000269\|PubMed:19122197, ECO:0000269\|PubMed:19402754, ECO:0000269\|PubMed:19534726, ECO:0000269\|PubMed:19935772, ECO:0000269\|PubMed:20103766, ECO:0000269\|PubMed:21325622, ECO:0000269\|PubMed:21487906, ECO:0000269\|PubMed:22363402, ECO:0000269\|PubMed:22804476, ECO:0000269\|PubMed:22808130, ECO:0000269\|PubMed:25417112, ECO:0000269\|PubMed:8423249\}.
Slc26a2 | 117267 | SLC26A2_33072 | Human Uniprot function (Human SLC26A2): Sulfate transporter. May play a role in endochondral bone formation. \{ECO:0000269\|PubMed:7923357\}.
Slc51a | 303879 | SLC51A_33157 | Human Uniprot function (Human SLC51A): Essential component of the Ost-alpha/Ost-beta complex, a heterodimer that acts as the intestinal basolateral transporter responsible for bile acid export from enterocytes into portal blood. Efficiently transports the major species of bile acids. \{ECO:0000269\|PubMed:16317684\}.
Slc6a8 | 50690 | SLC6A8_32561 | Human Uniprot function (Human SLC6A8): Required for the uptake of creatine in muscles and brain.
Spp1 | 25353 | SPP1_9929 | Human Uniprot function (Human SPP1): Binds tightly to hydroxyapatite. Appears to form an integral part of the mineralized matrix. Probably important to cell-matrix interaction.; FUNCTION: Acts as a cytokine involved in enhancing production of interferon-gamma and interleukin-12 and reducing production of interleukin-10 and is essential in the pathway that leads to type I immunity. \{ECO:0000250\}.
Srebf1 | 78968 | SREBF1_32750 | Human Uniprot function(Human SREBF1): [Sterol regulatory element-binding protein 1]: Precursor of the transcription factor form (Processed sterol regulatory element-binding protein 1), which is embedded in the endoplasmic reticulum membrane (PubMed:32322062). Low sterol concentrations promote processing of this form, releasing the transcription factor form that translocates into the nucleus and activates transcription of genes involved in cholesterol biosynthesis and lipid homeostasis (By similarity). \{ECO:0000250\|UniProtKB:Q9WTN3, ECO:0000269\|PubMed:32322062\}.; FUNCTION: [Processed sterol regulatory element-binding protein 1]: Key transcription factor that regulates expression of genes involved in cholesterol biosynthesis and lipid homeostasis (PubMed:8402897, PubMed:12177166, PubMed:32322062). Binds to the sterol regulatory element 1 (SRE-1) (5’-ATCACCCCAC-3’). Has dual sequence specificity binding to both an E-box motif (5’-ATCACGTGA-3’) and to SRE-1 (5’-ATCACCCCAC-3’) (PubMed:8402897, PubMed:12177166). Regulates the promoters of genes involved in cholesterol biosynthesis and the LDL receptor (LDLR) pathway of sterol regulation(PubMed:8402897, PubMed:12177166, PubMed:32322062). \{ECO:0000269\|PubMed:12177166, ECO:0000269\|PubMed:32322062, ECO:0000269\|PubMed:8402897\}.; FUNCTION: [Isoform SREBP-1A]: Isoform expressed only in select tissues, which has higher transcriptional activity compared to SREBP-1C (By similarity). Able to stimulate both lipogenic and cholesterogenic gene expression(PubMed:12177166). Has a role in the nutritional regulation of fatty acids and triglycerides in lipogenic organs such as the liver (By similarity). Required for innate immune response in macrophages by regulating lipid metabolism (By similarity). \{ECO:0000250\|UniProtKB:Q9WTN3, ECO:0000269\|PubMed:12177166\}.; FUNCTION: [Isoform SREBP-1C]: Predominant isoform expressed in most tissues, which has weaker transcriptional activity compared to isoform SREBP-1A (By similarity). Primarily controls expression of lipogenic gene (PubMed:12177166). Strongly activates global lipid synthesis in rapidly growing cells (By similarity). \{ECO:0000250\|UniProtKB:Q9WTN3, ECO:0000269\|PubMed:12177166\}.; FUNCTION: [Isoform SREBP-1aDelta]: The absence of Golgi proteolytic processing requirement makes this isoform constitutively active in transactivation of lipogenic gene promoters. \{ECO:0000305\|PubMed:7759101\}.; FUNCTION: [Isoform SREBP-1cDelta]: The absence of Golgi proteolytic processing requirement makes this isoform constitutively active in transactivation of lipogenic gene promoters. \{ECO:0000305\|PubMed:7759101\}.
Tnfrsf12a | 302965 | TNFRSF12A_10049 | Human Uniprot function (Human TNFRSF12A): Receptor for TNFSF12/TWEAK. Weak inducer of apoptosis in some cell types. Promotes angiogenesis and the proliferation of endothelial cells. May modulate cellular adhesion to matrix proteins. \{ECO:0000269\|PubMed:11728344\}.
Ugt2b1 | 286954 | UGT2B10_33303, UGT2B1_33224 | Human Uniprot function (Human UGT2B17): UDP-glucuronosyltransferase (UGT) that catalyzes phase II biotransformation reactions in which lipophilic substrates are conjugated with glucuronic acid to increase the metabolite’s water solubility, thereby facilitating excretion into either the urine or bile (PubMed:8798464, PubMed:16595710, PubMed:18719240, PubMed:19022937, PubMed:23288867). Catalyzes the glucuronidation of endogenous steroid hormones such as androgens (epitestosterone, androsterone) and estrogens (estradiol, epiestradiol) (PubMed:8798464, PubMed:16595710, PubMed:18719240, PubMed:19022937, PubMed:23288867). \{ECO:0000269\|PubMed:16595710, ECO:0000269\|PubMed:18719240, ECO:0000269\|PubMed:19022937, ECO:0000269\|PubMed:23288867, ECO:0000269\|PubMed:8798464\}.
Vnn1 | 29142 | VNN1_10157 | Human Uniprot function (Human VNN1): Amidohydrolase that hydrolyzes specifically one of the carboamide linkages in D-pantetheine thus recycling pantothenic acid (vitamin B5) and releasing cysteamine. \{ECO:0000269\|PubMed:10567687, ECO:0000269\|PubMed:11491533, ECO:0000269\|PubMed:25478849\}

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^35^ and Entrez Gene.^36^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Rat UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Rat Entrez Gene was used as the fourth resource.

^b^ In some cases, a probe may map to more than one gene, resulting in duplicate reporting of that probe mapped to different genes.

Gene definition version and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-7 Gene Identifiers and Definitions for Female Mice Exposed to 1,4-Dichlorobenzene for Five Days^a^

Gene Symbol | Entrez Gene IDs | Probe IDs^b^ | Definition
Abcc3 | 76408 | Abcc3_30114 | Human Uniprot function (Human ABCC3): May act as an inducible transporter in the biliary and intestinal excretion of organic anions. Acts as an alternative route for the export of bile acids and glucuronides from cholestatic hepatocytes (By similarity). \{ECO:0000250\}.
Abcg1 | 11307 | Abcg1_29054 | Human Uniprot function (Human ABCG1): Catalyzes the efflux of phospholipids such as sphingomyelin, cholesterol and its oxygenated derivatives like 7beta-hydroxycholesterol and this transport is coupled to hydrolysis of ATP (PubMed:17408620, PubMed:24576892). The lipid efflux is ALB-dependent (PubMed:16702602). Is an active component of the macrophage lipid export complex. Could also be involved in intracellular lipid transport processes. The role in cellular lipid homeostasis may not be limited to macrophages. Prevents cell death by transporting cytotoxic 7beta-hydroxycholesterol (PubMed:17408620). \{ECO:0000269\|PubMed:16702602, ECO:0000269\|PubMed:17408620, ECO:0000269\|PubMed:24576892\}.
Acaa1b | 235674 | Acaa1b_29729 | Human Entrez Gene Summary (Human ACAA1):This gene encodes an enzyme operative in the beta-oxidation system of the peroxisomes. Deficiency of this enzyme leads to pseudo-Zellweger syndrome. Alternative splicing results in multiple transcript variants. [provided by RefSeq, Jul 2008]
Atp2b2 | 11941 | Atp2b2_32103 | Human Uniprot function (Human ATP2B2): This magnesium-dependent enzyme catalyzes the hydrolysis of ATP coupled with the transport of calcium out of the cell.
Bhlhe40 | 20893 | Bhlhe40_32105,Bhlhe40_31406 | Human Uniprot function (Human BHLHE40): Transcriptional repressor involved in the regulation of the circadian rhythm by negatively regulating the activity of the clock genes and clock-controlled genes (PubMed:12397359, PubMed:18411297). Acts as the negative limb of a novel autoregulatory feedback loop (DEC loop) which differs from the one formed by the PER and CRY transcriptional repressors (PER/CRY loop) (PubMed:14672706). Both these loops are interlocked as it represses the expression of PER1/2 and in turn is repressed by PER1/2 and CRY1/2 (PubMed:15193144). Represses the activity of the circadian transcriptional activator: CLOCK-ARNTL/BMAL1\|ARNTL2/BMAL2 heterodimer by competing for the binding to E-box elements (5’-CACGTG-3’) found within the promoters of its target genes (PubMed:15560782). Negatively regulates its own expression and the expression of DBP and BHLHE41/DEC2 (PubMed:14672706). Acts as a corepressor of RXR and the RXR-LXR heterodimers and represses the ligand-induced RXRA and NR1H3/LXRA transactivation activity (PubMed:19786558). May be involved in the regulation of chondrocyte differentiation via the cAMP pathway (PubMed:19786558). Represses the transcription of NR0B2 and attenuates the transactivation of NR0B2 by the CLOCK-ARNTL/BMAL1 complex (PubMed:28797635). Drives the circadian rhythm of blood pressure through transcriptional repression of ATP1B1 in the cardiovascular system (PubMed:30012868). \{ECO:0000269\|PubMed:12397359, ECO:0000269\|PubMed:14672706, ECO:0000269\|PubMed:15193144, ECO:0000269\|PubMed:15560782, ECO:0000269\|PubMed:18411297, ECO:0000269\|PubMed:19786558, ECO:0000269\|PubMed:28797635, ECO:0000269\|PubMed:30012868\}.
Ccna1 | 12427 | Ccna1_31057 | Human Uniprot function (Human CCNA1): May be involved in the control of the cell cycle at the G1/S (start) and G2/M (mitosis) transitions. May primarily function in the control of the germline meiotic cell cycle and additionally in the control of mitotic cell cycle in some somatic cells. \{ECO:0000269\|PubMed:10022926\}.
Ccnb1 | 268697 | Ccnb1_31979 | Human Uniprot function (Human CCNB1): Essential for the control of the cell cycle at the G2/M (mitosis) transition. \{ECO:0000269\|PubMed:17495531,ECO:0000269\|PubMed:17495533\}.
Cdc20 | 107995 | Cdc20_30847 | Human Uniprot function (Human CDC20): Required for full ubiquitin ligase activity of the anaphase promoting complex/cyclosome (APC/C) and may confer substrate specificity upon the complex. Is regulated by the MAD2L1: in metaphase the MAD2L1-CDC20-APC/C ternary complex is inactive and in anaphase the CDC20-APC/C binary complex is active in degrading substrates. The CDC20-APC/C complex positively regulates formation of synaptic vesicle clustering at active zone to the presynaptic membrane in postmitotic neurons. CDC20-APC/C-induced degradation of NEUROD2 induces presynaptic differentiation. \{ECO:0000269\|PubMed:9637688, ECO:0000269\|PubMed:9734353, ECO:0000269\|PubMed:9811605\}.
Cdk1 | 12534 | Cdk1_31242 | Human Uniprot function (Human CDK1): Plays a key role in the control of the eukaryotic cell cycle by modulating the centrosome cycle as well as mitotic onset; promotes G2-M transition, and regulates G1 progress and G1-S transition via association with multiple interphase cyclins. Required in higher cells for entry into S-phase and mitosis. Phosphorylates PARVA/actopaxin, APC, AMPH, APC, BARD1, Bcl-xL/ BCL2L1, BRCA2, CALD1, CASP8, CDC7, CDC20, CDC25A, CDC25C, CC2D1A, CENPA, CSNK2 proteins/CKII, FZR1/CDH1, CDK7, CEBPB, CHAMP1, DMD/dystrophin, EEF1 proteins/EF-1, EZH2, KIF11/ EG5, EGFR, FANCG, FOS, GFAP, GOLGA2/GM130, GRASP1, UBE2A/hHR6A, HIST1H1 proteins/histone H1, HMGA1, HIVEP3/KRC, LMNA, LMNB, LMNC, LBR, LATS1, MAP1B, MAP4, MARCKS, MCM2, MCM4, MKLP1, MYB, NEFH, NFIC, NPC/nuclear pore complex, PITPNM1/NIR2, NPM1, NCL, NUCKS1, NPM1/numatrin, ORC1, PRKAR2A, EEF1E1/p18, EIF3F/p47, p53/TP53, NONO/p54NRB, PAPOLA, PLEC/plectin, RB1, TPPP, UL40/R2, RAB4A, RAP1GAP, RCC1, RPS6KB1/S6K1, KHDRBS1/SAM68, ESPL1, SKI, BIRC5/survivin, STIP1, TEX14, beta-tubulins, MAPT/TAU, NEDD1, VIM/vimentin, TK1, FOXO1, RUNX1/AML1, SAMHD1, SIRT2 and RUNX2. CDK1/CDC2-cyclin-B controls pronuclear union in interphase fertilized eggs. Essential for early stages of embryonic development. During G2 and early mitosis, CDC25A/B/C-mediated dephosphorylation activates CDK1/cyclin complexes which phosphorylate several substrates that trigger at least centrosome separation, Golgi dynamics, nuclear envelope breakdown and chromosome condensation. Once chromosomes are condensed and aligned at the metaphase plate, CDK1 activity is switched off by WEE1- and PKMYT1-mediated phosphorylation to allow sister chromatid separation, chromosome decondensation, reformation of the nuclear envelope and cytokinesis. Inactivated by PKR/EIF2AK2- and WEE1-mediated phosphorylation upon DNA damage to stop cell cycle and genome replication at the G2 checkpoint thus facilitating DNA repair. Reactivated after successful DNA repair through WIP1-dependent signaling leading to CDC25A/B/C-mediated dephosphorylation and restoring cell cycle progression. In proliferating cells, CDK1-mediated FOXO1 phosphorylation at the G2-M phase represses FOXO1 interaction with 14-3-3 proteins and thereby promotes FOXO1 nuclear accumulation and transcription factor activity, leading to cell death of postmitotic neurons. The phosphorylation of beta-tubulins regulates microtubule dynamics during mitosis. NEDD1 phosphorylation promotes PLK1-mediated NEDD1 phosphorylation and subsequent targeting of the gamma-tubulin ring complex (gTuRC) to the centrosome, an important step for spindle formation. In addition, CC2D1A phosphorylation regulates CC2D1A spindle pole localization and association with SCC1/RAD21 and centriole cohesion during mitosis. The phosphorylation of Bcl-xL/BCL2L1 after prolongated G2 arrest upon DNA damage triggers apoptosis. In contrast, CASP8 phosphorylation during mitosis prevents its activation by proteolysis and subsequent apoptosis. This phosphorylation occurs in cancer cell lines, as well as in primary breast tissues and lymphocytes. EZH2 phosphorylation promotes H3K27me3 maintenance and epigenetic gene silencing. CALD1 phosphorylation promotes Schwann cell migration during peripheral nerve regeneration. CDK1-cyclin-B complex phosphorylates NCKAP5L and mediates its dissociation from centrosomes during mitosis (PubMed:26549230). Regulates the amplitude of the cyclic expression of the core clock gene ARNTL/BMAL1 by phosphorylating its transcriptional repressor NR1D1, and this phosphorylation is necessary for SCF(FBXW7)-mediated ubiquitination and proteasomal degradation of NR1D1 (PubMed:27238018). \{ECO:0000269\|PubMed:16371510, ECO:0000269\|PubMed:16407259, ECO:0000269\|PubMed:16933150, ECO:0000269\|PubMed:17459720, ECO:0000269\|PubMed:18356527, ECO:0000269\|PubMed:18480403, ECO:0000269\|PubMed:19509060, ECO:0000269\|PubMed:19917720, ECO:0000269\|PubMed:20171170, ECO:0000269\|PubMed:20360007, ECO:0000269\|PubMed:20395957, ECO:0000269\|PubMed:20935635, ECO:0000269\|PubMed:20937773, ECO:0000269\|PubMed:21063390, ECO:0000269\|PubMed:23355470, ECO:0000269\|PubMed:23601106, ECO:0000269\|PubMed:23602554, ECO:0000269\|PubMed:25556658, ECO:0000269\|PubMed:26549230, ECO:0000269\|PubMed:27238018\}.; FUNCTION: (Microbial infection) Acts as a receptor for hepatitis C virus (HCV) in hepatocytes and facilitates its cell entry. {ECO:0000269\|PubMed:21516087\}.
Ces1d | 104158 | Ces1d_31073 | Human Uniprot function (Human CES1): Involved in the detoxification of xenobiotics and in the activation of ester and amide prodrugs (PubMed:7980644, PubMed:9169443, PubMed:9490062, PubMed:18762277). Hydrolyzes aromatic and aliphatic esters, but has no catalytic activity toward amides or a fatty acyl-CoA ester (PubMed:7980644, PubMed:9169443, PubMed:9490062, PubMed:18762277). Hydrolyzes the methyl ester group of cocaine to form benzoylecgonine (PubMed:7980644). Catalyzes the transesterification of cocaine to form cocaethylene (PubMed:7980644). Displays fatty acid ethyl ester synthase activity, catalyzing the ethyl esterification of oleic acid to ethyloleate (PubMed:7980644). Converts monoacylglycerides to free fatty acids and glycerol. Hydrolyzes of 2-arachidonoylglycerol and prostaglandins (PubMed:21049984). Hydrolyzes cellular cholesteryl esters to free cholesterols and promotes reverse cholesterol transport (RCT) by facilitating both the initial and final steps in the process (PubMed:18762277, PubMed:16024911, PubMed:11015575, PubMed:16971496). First of all, allows free cholesterol efflux from macrophages to extracellular cholesterol acceptors and secondly, releases free cholesterol from lipoprotein-delivered cholesteryl esters in the liver for bile acid synthesis or direct secretion into the bile (PubMed:18762277, PubMed:18599737, PubMed:16971496). \{ECO:0000269\|PubMed:11015575, ECO:0000269\|PubMed:16024911, ECO:0000269\|PubMed:16971496, ECO:0000269\|PubMed:18599737, ECO:0000269\|PubMed:18762277, ECO:0000269\|PubMed:21049984, ECO:0000269\|PubMed:7980644, ECO:0000269\|PubMed:9169443, ECO:0000269\|PubMed:9490062\}.
Ces1g | 12623 | Ces1g_30475 | No description available.
Chn1 | 108699 | Chn1_30496 | Human Uniprot function (Human CHN1): GTPase-activating protein for p21-rac and a phorbol ester receptor. Involved in the assembly of neuronal locomotor circuits as a direct effector of EPHA4 in axon guidance.
Clu | 12759 | Clu_30840 | Human Uniprot function (Human CLU): [Isoform 1]: Functions as extracellular chaperone that prevents aggregation of non-native proteins (PubMed:11123922, PubMed:19535339). Prevents stress-induced aggregation of blood plasma proteins (PubMed:11123922, PubMed:12176985, PubMed:17260971, PubMed:19996109). Inhibits formation of amyloid fibrils by APP, APOC2, B2M, CALCA, CSN3, SNCA and aggregation-prone LYZ variants (in vitro) (PubMed:12047389, PubMed:17412999, PubMed:17407782). Does not require ATP (PubMed:11123922). Maintains partially unfolded proteins in a state appropriate for subsequent refolding by other chaperones, such as HSPA8/HSC70 (PubMed:11123922). Does not refold proteins by itself (PubMed:11123922). Binding to cell surface receptors triggers internalization of the chaperone-client complex and subsequent lysosomal or proteasomal degradation (PubMed:21505792). Protects cells against apoptosis and against cytolysis by complement(PubMed:2780565). Intracellular forms interact with ubiquitin and SCF (SKP1-CUL1-F-box protein) E3 ubiquitin-protein ligase complexes and promote the ubiquitination and subsequent proteasomal degradation of target proteins (PubMed:20068069). Promotes proteasomal degradation of COMMD1 and IKBKB (PubMed:20068069). Modulates NF-kappa-B transcriptional activity (PubMed:12882985). A mitochondrial form suppresses BAX-dependent release of cytochrome c into the cytoplasm and inhibit apoptosis (PubMed:16113678, PubMed:17689225). Plays a role in the regulation of cell proliferation (PubMed:19137541). An intracellular form suppresses stress-induced apoptosis by stabilizing mitochondrial membrane integrity through interaction with HSPA5 (PubMed:22689054). Secreted form does not affect caspase or BAX-mediated intrinsic apoptosis and TNF-induced NF-kappa-B-activity (PubMed:24073260). Secreted form act as an important modulator during neuronal differentiation through interaction with STMN3 (By similarity). Plays a role in the clearance of immune complexes that arise during cell injury (By similarity). \{ECO:0000250\|UniProtKB:P05371, ECO:0000250\|UniProtKB:Q06890, ECO:0000269\|PubMed:11123922, ECO:0000269\|PubMed:12047389, ECO:0000269\|PubMed:12176985, ECO:0000269\|PubMed:12882985,ECO:0000269\|PubMed:16113678, ECO:0000269\|PubMed:17260971, ECO:0000269\|PubMed:17407782, ECO:0000269\|PubMed:17412999, ECO:0000269\|PubMed:17689225, ECO:0000269\|PubMed:19137541, ECO:0000269\|PubMed:19535339, ECO:0000269\|PubMed:19996109, ECO:0000269\|PubMed:20068069, ECO:0000269\|PubMed:21505792, ECO:0000269\|PubMed:22689054, ECO:0000269\|PubMed:24073260, ECO:0000269\|PubMed:2780565\}.; FUNCTION: [Isoform 6]: Does not affect caspase or BAX-mediated intrinsic apoptosis and TNF-induced NF-kappa-B-activity. \{ECO:0000269\|PubMed:24073260\}.; FUNCTION: [Isoform 4]: Does not affect caspase or BAX-mediated intrinsic apoptosis and TNF-induced NF-kappa-B-activity (PubMed:24073260). Promotes cell death through interaction with BCL2L1 that releases and activates BAX (PubMed:21567405). \{ECO:0000269\|PubMed:21567405, ECO:0000269\|PubMed:24073260\}.
Cpsf4l | 52670 | Cpsf4l_31365 | No description available.
Cyp2a4 | 13086 | Cyp2a4_30021 | Mouse Uniprot function (Mouse Cyp2a4): Highly active in the 15-alpha-hydroxylation of testosterone. Also active in the 15-alpha-hydroxylation of progesterone and androstenedione. Little or no activity on corticosterone, pregnenolone, dehydroepiandrosterone, estradiol or estriol.
Cyp2a5 | 13087 | Cyp2a5_31713 | Mouse Uniprot function (Mouse Cyp2a5): Exhibits a high coumarin 7-hydroxylase activity.
Cyp2c29 | 13095 | Cyp2c29_31205 | Mouse Uniprot function (Mouse Cyp2c29): A cytochrome P450 monooxygenase that selectively catalyzes the epoxidation of 14,15 double bond of (5Z,8Z,11Z,14Z)-eicosatetraenoic acid (arachidonate) forming 14,15-epoxyeicosatrienoic acid (14,15-EET) regioisomer. Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (CPR; NADPH--hemoprotein reductase).
Dbp | 13170 | Dbp_31391 | Human Uniprot function (Human DBP): This transcriptional activator recognizes and binds to the sequence 5’-RTTAYGTAAY-3’ found in the promoter of genes such as albumin, CYP2A4 and CYP2A5. It is not essential for circadian rhythm generation, but modulates important clock output genes. May be a direct target for regulation by the circadian pacemaker component clock. May affect circadian period and sleep regulation.
Ddit4 | 74747 | Ddit4_29434 | Human Uniprot function (Human DDIT4): Regulates cell growth, proliferation and survival via inhibition of the activity of the mammalian target of rapamycin complex 1 (mTORC1). Inhibition of mTORC1 is mediated by a pathway that involves DDIT4/REDD1, AKT1, the TSC1-TSC2 complex and the GTPase RHEB. Plays an important role in responses to cellular energy levels and cellular stress, including responses to hypoxia and DNA damage. Regulates p53/TP53-mediated apoptosis in response to DNA damage via its effect on mTORC1 activity. Its role in the response to hypoxia depends on the cell type; it mediates mTORC1 inhibition in fibroblasts and thymocytes, but not in hepatocytes (By similarity). Required for mTORC1-mediated defense against viral protein synthesis and virus replication (By similarity). Inhibits neuronal differentiation and neurite outgrowth mediated by NGF via its effect on mTORC1 activity. Required for normal neuron migration during embryonic brain development. Plays a role in neuronal cell death. \{ECO:0000250, ECO:0000269\|PubMed:15545625, ECO:0000269\|PubMed:15632201, ECO:0000269\|PubMed:15988001, ECO:0000269\|PubMed:17005863, ECO:0000269\|PubMed:17379067, ECO:0000269\|PubMed:19557001, ECO:0000269\|PubMed:20166753, ECO:0000269\|PubMed:21460850\}.
Dtl | 76843 | Dtl_29371 | Human Uniprot function (Human DTL): Substrate-specific adapter of a DCX (DDB1-CUL4-X-box) E3 ubiquitin-protein ligase complex required for cell cycle control, DNA damage response and translesion DNA synthesis. The DCX(DTL) complex, also named CRL4(CDT2) complex, mediates the polyubiquitination and subsequent degradation of CDT1, CDKN1A/p21(CIP1), FBH1, KMT5A and (PubMed:16861906, PubMed:16949367, PubMed:16964240, PubMed:17085480, PubMed:18703516, PubMed:18794347, PubMed:18794348, PubMed:19332548, PubMed:20129063, PubMed:23478441 PubMed:23478445, PubMed:23677613, PubMed:27906959). CDT1 degradation in response to DNA damage is necessary to ensure proper cell cycle regulation of DNA replication (PubMed:16861906 PubMed:16949367, PubMed:17085480). CDKN1A/p21(CIP1) degradation during S phase or following UV irradiation is essential to control replication licensing (PubMed:18794348, PubMed:19332548). KMT5A degradation is also important for a proper regulation of mechanisms such as TGF-beta signaling, cell cycle progression, DNA repair and cell migration (PubMed:23478445). Most substrates require their interaction with PCNA for their polyubiquitination: substrates interact with PCNA via their PIP-box, and those containing the “K+4’ motif in the PIP box, recruit the DCX(DTL) complex, leading to their degradation. In undamaged proliferating cells, the DCX(DTL) complex also promotes the “Lys-164’ monoubiquitination of PCNA, thereby being involved in PCNA-dependent translesion DNA (PubMed:20129063, PubMed:23478441, PubMed:23478445, PubMed:23677613). The DDB1-CUL4A-DTL E3 ligase complex regulates the circadian clock function by mediating the ubiquitination and degradation of CRY1 (PubMed:26431207). \{ECO:0000269\|PubMed:16861906, ECO:0000269\|PubMed:16949367, ECO:0000269\|PubMed:16964240 ECO:0000269\|PubMed:17085480, ECO:0000269\|PubMed:18703516, ECO:0000269\|PubMed:18794347, ECO:0000269\|PubMed:18794348 ECO:0000269\|PubMed:19332548, ECO:0000269\|PubMed:20129063, ECO:0000269\|PubMed:23478441, ECO:0000269\|PubMed:23478445 ECO:0000269\|PubMed:23677613, ECO:0000269\|PubMed:26431207, ECO:0000269\|PubMed:27906959\}.
Ephx1 | 13849 | Ephx1_29453 | Human Uniprot function (Human EPHX1): Biotransformation enzyme that catalyzes the hydrolysis of arene and aliphatic epoxides to less reactive and more water soluble dihydrodiols by the trans addition of water (By similarity). Plays a role in the metabolism of endogenous lipids such as epoxide-containing fatty acids (PubMed:22798687). Metabolizes the abundant endocannabinoid 2-arachidonoylglycerol (2-AG) to free arachidonic acid (AA) and glycerol (PubMed:24958911). \{ECO:0000250\|UniProtKB:P07687, ECO:0000269\|PubMed:22798687, ECO:0000269\|PubMed:24958911\}.
Gdf7 | 238057 | Gdf7_29562 | Human Uniprot function (Human GDF7): May play an active role in the motor area of the primate neocortex. \{ECO:0000250\}.
Gins2 | 272551 | Gins2_84152 | Human Uniprot function (Human GINS2): The GINS complex plays an essential role in the initiation of DNA replication, and progression of DNA replication forks. GINS complex seems to bind preferentially to single- stranded DNA. \{ECO:0000269\|PubMed:17417653\}.
Gsta13 | 100042295 | Gsta1_31374 | No description available.
Gstp2 | 14869 | Gstp1_30795 | Mouse Uniprot function (Mouse Gstp2): Conjugation of reduced glutathione to a wide number of exogenous and endogenous hydrophobic electrophiles. Cannot metabolize 1-chloro-2,4-dinitrobenzene.
H2-q6 | 110557 | H2-q6_31131 | No description available.
Hlf | 217082 | Hlf_30768 | Human Entrez Gene Summary (Human HLF): This gene encodes a member of the proline and acidic-rich (PAR) protein family, a subset of the bZIP transcription factors. The encoded protein forms homodimers or heterodimers with other PAR family members and binds sequence-specific promoter elements to activate transcription. Chromosomal translocations fusing portions of this gene with the E2A gene cause a subset of childhood B-lineage acute lymphoid leukemias. Alternatively spliced transcript variants have been described, but their biological validity has not been determined. [provided by RefSeq, Jul 2008]
Hmgcs2 | 15360 | Hmgcs2_29615 | Human Uniprot function (Human HMGCS2): Catalyzes the first irreversible step in ketogenesis, condensing acetyl-CoA to acetoacetyl-CoA to form HMG-CoA, which is converted by HMG-CoA reductase (HMGCR) into mevalonate. \{ECO:0000269\|PubMed:11228257, ECO:0000269\|PubMed:23751782, ECO:0000269\|PubMed:29597274\}.
Hoxa10 | 15395 | Hoxa10_31922 | Human Uniprot function (Human HOXA10): Sequence-specific transcription factor which is part of a developmental regulatory system that provides cells with specific positional identities on the anterior-posterior axis. Binds to the DNA sequence 5’-AA[AT]TTTTATTAC-3’.
Ifi44 | 99899 | Ifi44_29813 | Human Uniprot function (Human IFI44): This protein aggregates to form microtubular structures. \{ECO:0000250\}.
Krt18 | 16668 | Krt18_29525 | Human Uniprot function (Human KRT18): Involved in the uptake of thrombin-antithrombin complexes by hepatic cells (By similarity). When phosphorylated, plays a role in filament reorganization. Involved in the delivery of mutated CFTR to the plasma membrane. Together with KRT8, is involved in interleukin-6 (IL-6)-mediated barrier protection. \{ECO:0000250, ECO:0000269\|PubMed:15529338, ECO:0000269\|PubMed:16424149, ECO:0000269\|PubMed:17213200, ECO:0000269\|PubMed:7523419, ECO:0000269\|PubMed:8522591, ECO:0000269\|PubMed:9298992, ECO:0000269\|PubMed:9524113\}.
Lcn2 | 16819 | Lcn2_30771 | Human Uniprot function (Human LCN2): Iron-trafficking protein involved in multiple processes such as apoptosis, innate immunity and renal development (PubMed:12453413, PubMed:27780864, PubMed:20581821). Binds iron through association with 2,5-dihydroxybenzoic acid (2,5-DHBA), a siderophore that shares structural similarities with bacterial enterobactin, and delivers or removes iron from the cell, depending on the context. Iron-bound form (holo-24p3) is internalized following binding to the SLC22A17 (24p3R) receptor, leading to release of iron and subsequent increase of intracellular iron concentration. In contrast, association of the iron-free form (apo-24p3) with the SLC22A17 (24p3R) receptor is followed by association with an intracellular siderophore, iron chelation and iron transfer to the extracellular medium, thereby reducing intracellular iron concentration. Involved in apoptosis due to interleukin-3 (IL3) deprivation: iron-loaded form increases intracellular iron concentration without promoting apoptosis, while iron-free form decreases intracellular iron levels, inducing expression of the proapoptotic protein BCL2L11/BIM, resulting in apoptosis (By similarity). Involved in innate immunity; limits bacterial proliferation by sequestering iron bound to microbial siderophores, such as enterobactin (PubMed:27780864). Can also bind siderophores from M.tuberculosis (PubMed:15642259, PubMed:21978368). \{ECO:0000250\|UniProtKB:P11672, ECO:0000269\|PubMed:12453413, ECO:0000269\|PubMed:15642259, ECO:0000269\|PubMed:20581821, ECO:0000269\|PubMed:21978368, ECO:0000269\|PubMed:27780864\}.
Mest | 17294 | Mest_29181 | Human Entrez Gene Summary (Human MEST): This gene encodes a member of the alpha/beta hydrolase superfamily. It is imprinted, exhibiting preferential expression from the paternal allele in fetal tissues, and isoform-specific imprinting in lymphocytes. The loss of imprinting of this gene has been linked to certain types of cancer and may be due to promotor switching. The encoded protein may play a role in development. Alternatively spliced transcript variants encoding multiple isoforms have been identified for this gene. Pseudogenes of this gene are located on the short arm of chromosomes 3 and 4, and the long arm of chromosomes 6 and 15. [provided by RefSeq, Dec 2011]
Nfil3 | 18030 | Nfil3_31222 | Human Uniprot function (Human NFIL3): Acts as a transcriptional regulator that recognizes and binds to the sequence 5’-[GA]TTA[CT]GTAA[CT]-3’, a sequence present in many cellular and viral promoters. Represses transcription from promoters with activating transcription factor (ATF) sites. Represses promoter activity in osteoblasts (By similarity). Represses transcriptional activity of PER1 (By similarity). Represses transcriptional activity of PER2 via the B-site on the promoter (By similarity). Activates transcription from the interleukin-3 promoter in T-cells. Competes for the same consensus-binding site with PAR DNA-binding factors (DBP, HLF and TEF) (By similarity). Component of the circadian clock that acts as a negative regulator for the circadian expression of PER2 oscillation in the cell-autonomous core clock (By similarity). Protects pro-B cells from programmed cell death (By similarity). Represses the transcription of CYP2A5 (By similarity). Positively regulates the expression and activity of CES2 by antagonizing the repressive action of NR1D1 on CES2 (By similarity). \{ECO:0000250\|UniProtKB:O08750, ECO:0000269\|PubMed:1620116, ECO:0000269\|PubMed:7565758, ECO:0000269\|PubMed:8836190\}.
Pole | 18973 | Pole_31952 | Human Uniprot function (Human POLE): Catalytic component of the DNA polymerase epsilon complex (PubMed:10801849). Participates in chromosomal DNA replication (By similarity). Required during synthesis of the leading DNA strands at the replication fork, binds at/or near replication origins and moves along DNA with the replication fork (By similarity). Has 3’-5’ proofreading exonuclease activity that corrects errors arising during DNA replication (By similarity). Involved in DNA synthesis during DNA repair (PubMed:20227374, PubMed:27573199). Along with DNA polymerase POLD1 and DNA polymerase POLK, has a role in excision repair (NER) synthesis following UV irradiation (PubMed:20227374). \{ECO:0000250\|UniProtKB:P21951, ECO:0000269\|PubMed:10801849, ECO:0000269\|PubMed:20227374, ECO:0000269\|PubMed:27573199\}.
Rnf125 | 67664 | Rnf125_32252, C730049O14RIK_31254 | Human Uniprot function (Human RNF125): E3 ubiquitin-protein ligase that mediates ubiquitination and subsequent proteasomal degradation of target proteins, such as DDX58/RIG-I, MAVS/IPS1, IFIH1/MDA5, JAK1 and p53/TP53 (PubMed:15843525, PubMed:17460044, PubMed:17643463, PubMed:26027934, PubMed:26471729, PubMed:25591766, PubMed:27411375). Acts as a negative regulator of type I interferon production by mediating ubiquitination of DDX58/RIG-I at ’Lys-181’, leading to DDX58/RIG-I degradation (PubMed:17460044, PubMed:26471729). Mediates ubiquitination and subsequent degradation of p53/TP53 (PubMed:25591766). Mediates ubiquitination and subsequent degradation of JAK1 (PubMed:26027934). Acts as a positive regulator of T-cell activation (PubMed:15843525). \{ECO:0000269\|PubMed:15843525, ECO:0000269\|PubMed:17460044, ECO:0000269\|PubMed:17643463, ECO:0000269\|PubMed:25591766, ECO:0000269\|PubMed:26027934, ECO:0000269\|PubMed:26471729, ECO:0000269\|PubMed:27411375\}.
S100a4 | 20198 | S100a4_30373 | Human Entrez Gene Summary (Human S100A4): The protein encoded by this gene is a member of the S100 family of proteins containing 2 EF-hand calcium-binding motifs. S100 proteins are localized in the cytoplasm and/ or nucleus of a wide range of cells, and involved in the regulation of a number of cellular processes such as cell cycle progression and differentiation. S100 genes include at least 13 members which are located as a cluster on chromosome 1q21. This protein may function in motility, invasion, and tubulin polymerization. Chromosomal rearrangements and altered expression of this gene have been implicated in tumor metastasis. Multiple alternatively spliced variants, encoding the same protein, have been identified. [provided by RefSeq, Jul 2008]
Slc51a | 106407 | Slc51a_29138 | Human Uniprot function (Human SLC51A): Essential component of the Ost-alpha/Ost-beta complex, a heterodimer that acts as the intestinal basolateral transporter responsible for bile acid export from enterocytes into portal blood. Efficiently transports the major species of bile acids. \{ECO:0000269\|PubMed:16317684\}.
Star | 20845 | Star_29723 | Human Uniprot function (Human STAR): Plays a key role in steroid hormone synthesis by enhancing the metabolism of cholesterol into pregnenolone. Mediates the transfer of cholesterol from the outer mitochondrial membrane to the inner mitochondrial membrane where it is cleaved to pregnenolone. \{ECO:0000269\|PubMed:7761400, ECO:0000269\|PubMed:7892608, ECO:0000269\|PubMed:8948562\}.
Tuba4a | 22145 | Tuba4a_29527 | Human Uniprot function (Human TUBA4A): Tubulin is the major constituent of microtubules. It binds two moles of GTP, one at an exchangeable site on the beta chain and one at a non-exchangeable site on the alpha chain.
Ube2c | 68612 | Ube2c_31522 | Human Uniprot function (Human UBE2C): Accepts ubiquitin from the E1 complex and catalyzes its covalent attachment to other proteins. In vitro catalyzes ‘Lys-11’- and ‘Lys-48’-linked polyubiquitination. Acts as an essential factor of the anaphase promoting complex/cyclosome (APC/C), a cell cycle-regulated ubiquitin ligase that controls progression through mitosis. Acts by initiating ‘Lys-11’-linked polyubiquitin chains on APC/C substrates, leading to the degradation of APC/C substrates by the proteasome and promoting mitotic exit. \{ECO:0000269\|PubMed:15558010, ECO:0000269\|PubMed:18485873, ECO:0000269\|PubMed:19820702, ECO:0000269\|PubMed:19822757, ECO:0000269\|PubMed:20061386, ECO:0000269\|PubMed:27259151\}.
Ube2t | 67196 | Ube2t_30503 | Human Uniprot function (Human UBE2T): Accepts ubiquitin from the E1 complex and catalyzes its covalent attachment to other proteins. Catalyzes monoubiquitination. Involved in mitomycin-C (MMC)-induced DNA repair. Acts as a specific E2 ubiquitin-conjugating enzyme for the Fanconi anemia complex by associating with E3 ubiquitin-protein ligase FANCL and catalyzing monoubiquitination of FANCD2, a key step in the DNA damage pathway (PubMed:16916645, PubMed:17938197, PubMed:19111657, PubMed:19589784, PubMed:28437106). Also mediates monoubiquitination of FANCL and FANCI (PubMed:16916645, PubMed:17938197, PubMed:19111657, PubMed:19589784). May contribute to ubiquitination and degradation of BRCA1 (PubMed:19887602). In vitro able to promote polyubiquitination using all 7 ubiquitin Lys residues, but may prefer ‘Lys-11’-, ‘Lys-27’-, ‘Lys-48’- and ‘Lys-63’-linked polyubiquitination (PubMed:20061386). \{ECO:0000269\|PubMed:16916645, ECO:0000269\|PubMed:17938197, ECO:0000269\|PubMed:19111657, ECO:0000269\|PubMed:19589784, ECO:0000269\|PubMed:19887602, ECO:0000269\|PubMed:20061386, ECO:0000269\|PubMed:28437106\}.
Ugt1a6a | 94284 | Ugt1a7c_29171 | No description available.
Ugt1a6b | 394435 | Ugt1a6a_29170 | No description available.
Uhrf1 | 18140 | Uhrf1_30587 | Human Uniprot function (Human UHRF1): Multidomain protein that acts as a key epigenetic regulator by bridging DNA methylation and chromatin modification. Specifically recognizes and binds hemimethylated DNA at replication forks via its YDG domain and recruits DNMT1 methyltransferase to ensure faithful propagation of the DNA methylation patterns through DNA replication. In addition to its role in maintenance of DNA methylation, also plays a key role in chromatin modification: through its tudor-like regions and PHD-type zinc fingers, specifically recognizes and binds histone H3 trimethylated at ‘Lys-9’ (H3K9me3) and unmethylated at ‘Arg-2’ (H3R2me0), respectively, and recruits chromatin proteins. Enriched in pericentric heterochromatin where it recruits different chromatin modifiers required for this chromatin replication. Also localizes to euchromatic regions where it negatively regulates transcription possibly by impacting DNA methylation and histone modifications. Has E3 ubiquitin-protein ligase activity by mediating the ubiquitination of target proteins such as histone H3 and PML. It is still unclear how E3 ubiquitin-protein ligase activity is related to its role in chromatin in vivo. May be involved in DNA repair. \{ECO:0000269\|PubMed:10646863, ECO:0000269\|PubMed:15009091, ECO:0000269\|PubMed:15361834, ECO:0000269\|PubMed:17673620, ECO:0000269\|PubMed:17967883, ECO:0000269\|PubMed:19056828, ECO:0000269\|PubMed:21745816, ECO:0000269\|PubMed:21777816, ECO:0000269\|PubMed:22945642\}.

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^35^ and Entrez Gene.^36^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Mouse UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Mouse Entrez Gene was used as the fourth resource.

^b^ In some cases, a probe may map to more than one gene, resulting in duplicate reporting of that probe mapped to different genes.

Gene definition version and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.