# Appendix C Animal Identifiers

Table C-1 Animal Numbers and FASTQ Data File Names for Female Rats Exposed to 1,4-Dichlorobenzene for Five Days

Animal Number | Selection | Group | Exposure Concentration (ppm) | Survived to Study Termination | Tissue | FASTQ File ID
1 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DR1F1HE_S118_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DR1F1KI_S117_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DR1F1LI_S127_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DR1F1LU_S127_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DR1F1OV_S53_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DR1F2HE_S149_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DR1F2KI_S148_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DR1F2LI_S118_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DR1F2LU_S118_R1_001.fastq.gz^a^
2 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DR1F2OV_S44_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DR1F3HE_S131_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DR1F3KI_S130_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DR1F3LI_S140_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DR1F3LU_S140_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DR1F3OV_S66_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DR1F4HE_S128_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DR1F4KI_S127_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DR1F4LI_S137_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DR1F4LU_S137_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DR1F4OV_S63_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DR1F5HE_S138_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DR1F5KI_S137_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DR1F5LI_S147_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DR1F5LU_S147_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DR1F5OV_S73_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DR1F6HE_S139_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DR1F6KI_S138_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DR1F6LI_S148_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DR1F6LU_S148_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DR1F6OV_S74_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DR1F7HE_S126_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DR1F7KI_S125_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DR1F7LI_S135_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DR1F7LU_S135_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DR1F7OV_S61_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DR1F8HE_S150_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DR1F8KI_S149_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DR1F8LI_S119_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DR1F8LU_S119_R1_001.fastq.gz^a^
8 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DR1F8OV_S45_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DR1F9HE_S133_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DR1F9KI_S132_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DR1F9LI_S142_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DR1F9LU_S142_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DR1F9OV_S68_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DR1F10HE_S132_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DR1F10KI_S131_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DR1F10LI_S141_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DR1F10LU_S141_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DR1F10OV_S67_R1_001.fastq.gz
11 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
12 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
13 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
101 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Heart | 4DR2F101HE_S140_R1_001.fastq.gz
101 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Kidney | 4DR2F101KI_S139_R1_001.fastq.gz
101 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Liver | 4DR2F101LI_S149_R1_001.fastq.gz
101 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Lung | 4DR2F101LU_S149_R1_001.fastq.gz
101 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Ovary | 4DR2F101OV_S75_R1_001.fastq.gz
102 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Heart | 4DR2F102HE_S152_R1_001.fastq.gz
102 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Kidney | 4DR2F102KI_S151_R1_001.fastq.gz
102 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Liver | 4DR2F102LI_S121_R1_001.fastq.gz
102 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Lung | 4DR2F102LU_S121_R1_001.fastq.gz^a^
102 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Ovary | 4DR2F102OV_S47_R1_001.fastq.gz
103 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Heart | 4DR2F103HE_S144_R1_001.fastq.gz
103 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Kidney | 4DR2F103KI_S143_R1_001.fastq.gz
103 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Liver | 4DR2F103LI_S153_R1_001.fastq.gz
103 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Lung | 4DR2F103LU_S153_R1_001.fastq.gz
103 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Ovary | 4DR2F103OV_S79_R1_001.fastq.gz
104 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Heart | 4DR2F104HE_S119_R1_001.fastq.gz
104 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Kidney | 4DR2F104KI_S118_R1_001.fastq.gz
104 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Liver | 4DR2F104LI_S128_R1_001.fastq.gz
104 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Lung | 4DR2F104LU_S128_R1_001.fastq.gz
104 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Ovary | 4DR2F104OV_S54_R1_001.fastq.gz
105 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Heart | 4DR2F105HE_S113_R1_001.fastq.gz
105 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Kidney | NA
105 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Liver | 4DR2F105LI_S122_R1_001.fastq.gz
105 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Lung | 4DR2F105LU_S122_R1_001.fastq.gz
105 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Ovary | 4DR2F105OV_S48_R1_001.fastq.gz
106 | ICA Animals | 1,4-Dichlorobenzene | 1 | Yes | None | NA
107 | ICA Animals | 1,4-Dichlorobenzene | 1 | Yes | None | NA
108 | ICA Animals | 1,4-Dichlorobenzene | 1 | Yes | None | NA
201 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Heart | 4DR3F201HE_S129_R1_001.fastq.gz
201 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Kidney | 4DR3F201KI_S128_R1_001.fastq.gz
201 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Liver | 4DR3F201LI_S138_R1_001.fastq.gz
201 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Lung | 4DR3F201LU_S138_R1_001.fastq.gz
201 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Ovary | 4DR3F201OV_S64_R1_001.fastq.gz
202 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Heart | 4DR3F202HE_S123_R1_001.fastq.gz
202 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Kidney | 4DR3F202KI_S122_R1_001.fastq.gz
202 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Liver | 4DR3F202LI_S132_R1_001.fastq.gz
202 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Lung | 4DR3F202LU_S132_R1_001.fastq.gz
202 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Ovary | 4DR3F202OV_S58_R1_001.fastq.gz
203 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Heart | 4DR3F203HE_S134_R1_001.fastq.gz
203 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Kidney | 4DR3F203KI_S133_R1_001.fastq.gz
203 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Liver | 4DR3F203LI_S143_R1_001.fastq.gz
203 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Lung | 4DR3F203LU_S143_R1_001.fastq.gz
203 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Ovary | 4DR3F203OV_S69_R1_001.fastq.gz
204 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Heart | 4DR3F204HE_S151_R1_001.fastq.gz
204 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Kidney | 4DR3F204KI_S150_R1_001.fastq.gz
204 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Liver | 4DR3F204LI_S120_R1_001.fastq.gz
204 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Lung | 4DR3F204LU_S120_R1_001.fastq.gz^a^
204 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Ovary | 4DR3F204OV_S46_R1_001.fastq.gz
205 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Heart | 4DR3F205HE_S130_R1_001.fastq.gz
205 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Kidney | 4DR3F205KI_S129_R1_001.fastq.gz
205 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Liver | 4DR3F205LI_S139_R1_001.fastq.gz
205 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Lung | 4DR3F205LU_S139_R1_001.fastq.gz
205 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Ovary | 4DR3F205OV_S65_R1_001.fastq.gz
206 | ICA Animals | 1,4-Dichlorobenzene | 10 | Yes | None | NA
207 | ICA Animals | 1,4-Dichlorobenzene | 10 | Yes | None | NA
208 | ICA Animals | 1,4-Dichlorobenzene | 10 | Yes | None | NA
301 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Heart | 4DR4F301HE_S135_R1_001.fastq.gz
301 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Kidney | 4DR4F301KI_S134_R1_001.fastq.gz
301 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Liver | 4DR4F301LI_S144_R1_001.fastq.gz
301 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Lung | 4DR4F301LU_S144_R1_001.fastq.gz
301 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Ovary | 4DR4F301OV_S70_R1_001.fastq.gz
302 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Heart | 4DR4F302HE_S114_R1_001.fastq.gz
302 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Kidney | 4DR4F302KI_S113_R1_001.fastq.gz
302 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Liver | 4DR4F302LI_S123_R1_001.fastq.gz
302 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Lung | 4DR4F302LU_S123_R1_001.fastq.gz
302 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Ovary | 4DR4F302OV_S49_R1_001.fastq.gz
303 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Heart | 4DR4F303HE_S143_R1_001.fastq.gz
303 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Kidney | 4DR4F303KI_S142_R1_001.fastq.gz
303 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Liver | 4DR4F303LI_S152_R1_001.fastq.gz
303 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Lung | 4DR4F303LU_S152_R1_001.fastq.gz
303 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Ovary | 4DR4F303OV_S78_R1_001.fastq.gz
304 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Heart | 4DR4F304HE_S116_R1_001.fastq.gz
304 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Kidney | 4DR4F304KI_S115_R1_001.fastq.gz
304 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Liver | 4DR4F304LI_S125_R1_001.fastq.gz
304 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Lung | 4DR4F304LU_S125_R1_001.fastq.gz
304 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Ovary | 4DR4F304OV_S51_R1_001.fastq.gz
305 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Heart | 4DR4F305HE_S121_R1_001.fastq.gz
305 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Kidney | 4DR4F305KI_S120_R1_001.fastq.gz
305 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Liver | 4DR4F305LI_S130_R1_001.fastq.gz
305 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Lung | 4DR4F305LU_S130_R1_001.fastq.gz
305 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Ovary | 4DR4F305OV_S56_R1_001.fastq.gz
306 | ICA Animals | 1,4-Dichlorobenzene | 50 | Yes | None | NA
307 | ICA Animals | 1,4-Dichlorobenzene | 50 | Yes | None | NA
308 | ICA Animals | 1,4-Dichlorobenzene | 50 | Yes | None | NA
401 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Heart | 4DR5F401HE_S146_R1_001.fastq.gz
401 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Kidney | 4DR5F401KI_S145_R1_001.fastq.gz
401 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Liver | 4DR5F401LI_S155_R1_001.fastq.gz
401 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Lung | 4DR5F401LU_S155_R1_001.fastq.gz
401 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Ovary | 4DR5F401OV_S81_R1_001.fastq.gz
402 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Heart | 4DR5F402HE_S148_R1_001.fastq.gz
402 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Kidney | 4DR5F402KI_S147_R1_001.fastq.gz
402 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Liver | 4DR5F402LI_S117_R1_001.fastq.gz
402 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Lung | 4DR5F402LU_S117_R1_001.fastq.gz^a^
402 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Ovary | 4DR5F402OV_S43_R1_001.fastq.gz
403 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Heart | 4DR5F403HE_S137_R1_001.fastq.gz
403 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Kidney | 4DR5F403KI_S136_R1_001.fastq.gz
403 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Liver | 4DR5F403LI_S146_R1_001.fastq.gz
403 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Lung | 4DR5F403LU_S146_R1_001.fastq.gz
403 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Ovary | 4DR5F403OV_S72_R1_001.fastq.gz
404 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Heart | 4DR5F404HE_S117_R1_001.fastq.gz
404 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Kidney | 4DR5F404KI_S116_R1_001.fastq.gz
404 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Liver | 4DR5F404LI_S126_R1_001.fastq.gz
404 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Lung | 4DR5F404LU_S126_R1_001.fastq.gz
404 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Ovary | 4DR5F404OV_S52_R1_001.fastq.gz
405 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Heart | 4DR5F405HE_S127_R1_001.fastq.gz
405 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Kidney | 4DR5F405KI_S126_R1_001.fastq.gz
405 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Liver | 4DR5F405LI_S136_R1_001.fastq.gz
405 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Lung | 4DR5F405LU_S136_R1_001.fastq.gz
405 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Ovary | 4DR5F405OV_S62_R1_001.fastq.gz
406 | ICA Animals | 1,4-Dichlorobenzene | 150 | Yes | None | NA
407 | ICA Animals | 1,4-Dichlorobenzene | 150 | Yes | None | NA
408 | ICA Animals | 1,4-Dichlorobenzene | 150 | Yes | None | NA
501 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Heart | 4DR6F501HE_S145_R1_001.fastq.gz
501 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Kidney | 4DR6F501KI_S144_R1_001.fastq.gz
501 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Liver | 4DR6F501LI_S154_R1_001.fastq.gz
501 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Lung | 4DR6F501LU_S154_R1_001.fastq.gz
501 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Ovary | 4DR6F501OV_S80_R1_001.fastq.gz
502 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Heart | 4DR6F502HE_S147_R1_001.fastq.gz
502 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Kidney | 4DR6F502KI_S146_R1_001.fastq.gz
502 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Liver | 4DR6F502LI_S156_R1_001.fastq.gz
502 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Lung | 4DR6F502LU_S156_R1_001.fastq.gz^b^
502 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Ovary | 4DR6F502OV_S82_R1_001.fastq.gz
503 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Heart | 4DR6F503HE_S115_R1_001.fastq.gz
503 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Kidney | 4DR6F503KI_S114_R1_001.fastq.gz
503 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Liver | 4DR6F503LI_S124_R1_001.fastq.gz
503 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Lung | 4DR6F503LU_S124_R1_001.fastq.gz
503 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Ovary | 4DR6F503OV_S50_R1_001.fastq.gz
504 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Heart | 4DR6F504HE_S141_R1_001.fastq.gz
504 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Kidney | 4DR6F504KI_S140_R1_001.fastq.gz
504 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Liver | 4DR6F504LI_S150_R1_001.fastq.gz
504 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Lung | 4DR6F504LU_S150_R1_001.fastq.gz^b^
504 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Ovary | 4DR6F504OV_S76_R1_001.fastq.gz
505 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Heart | 4DR6F505HE_S136_R1_001.fastq.gz
505 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Kidney | 4DR6F505KI_S135_R1_001.fastq.gz
505 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Liver | 4DR6F505LI_S145_R1_001.fastq.gz
505 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Lung | 4DR6F505LU_S145_R1_001.fastq.gz
505 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Ovary | 4DR6F505OV_S71_R1_001.fastq.gz
506 | ICA Animals | 1,4-Dichlorobenzene | 400 | Yes | None | NA
507 | ICA Animals | 1,4-Dichlorobenzene | 400 | Yes | None | NA
508 | ICA Animals | 1,4-Dichlorobenzene | 400 | Yes | None | NA
601 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Heart | 4DR7F601HE_S124_R1_001.fastq.gz
601 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Kidney | 4DR7F601KI_S123_R1_001.fastq.gz
601 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Liver | 4DR7F601LI_S133_R1_001.fastq.gz
601 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Lung | 4DR7F601LU_S133_R1_001.fastq.gz
601 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Ovary | 4DR7F601OV_S59_R1_001.fastq.gz
602 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Heart | 4DR7F602HE_S120_R1_001.fastq.gz
602 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Kidney | 4DR7F602KI_S119_R1_001.fastq.gz
602 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Liver | 4DR7F602LI_S129_R1_001.fastq.gz
602 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Lung | 4DR7F602LU_S129_R1_001.fastq.gz
602 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Ovary | 4DR7F602OV_S55_R1_001.fastq.gz
603 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Heart | 4DR7F603HE_S122_R1_001.fastq.gz
603 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Kidney | 4DR7F603KI_S121_R1_001.fastq.gz
603 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Liver | 4DR7F603LI_S131_R1_001.fastq.gz
603 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Lung | 4DR7F603LU_S131_R1_001.fastq.gz
603 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Ovary | 4DR7F603OV_S57_R1_001.fastq.gz
604 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Heart | 4DR7F604HE_S142_R1_001.fastq.gz
604 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Kidney | 4DR7F604KI_S141_R1_001.fastq.gz
604 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Liver | 4DR7F604LI_S151_R1_001.fastq.gz
604 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Lung | 4DR7F604LU_S151_R1_001.fastq.gz
604 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Ovary | 4DR7F604OV_S77_R1_001.fastq.gz
605 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Heart | 4DR7F605HE_S125_R1_001.fastq.gz
605 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Kidney | 4DR7F605KI_S124_R1_001.fastq.gz
605 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Liver | 4DR7F605LI_S134_R1_001.fastq.gz
605 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Lung | 4DR7F605LU_S134_R1_001.fastq.gz
605 | Core Animals | 1,4-Dichlorobenzene | 800 | Yes | Ovary | 4DR7F605OV_S60_R1_001.fastq.gz
606 | ICA Animals | 1,4-Dichlorobenzene | 800 | Yes | None | NA
607 | ICA Animals | 1,4-Dichlorobenzene | 800 | Yes | None | NA
608 | ICA Animals | 1,4-Dichlorobenzene | 800 | No | None | NA

ICA = internal concentration assessment; NA = no transcriptomics data collected for selected animal.

^a^ Removed due to quality control fail.

^b^ Removed due to principal component analysis/inter-replicate correlation analysis outlier.

Table C-2 Animal Numbers and FASTQ Data File Names for Female Mice Exposed to 1,4-Dichlorobenzene for Five Days

Animal Number | Selection | Group | Exposure Concentration (ppm) | Survived to Study Termination | Tissue | FASTQ File ID
1 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DM1F1HE_S43_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DM1F1KI_S43_R1_001.fastq.gz^a^
1 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DM1F1LI_S49_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DM1F1LU_S49_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DM1F1OV_S131_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DM1F2HE_S66_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DM1F2KI_S66_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DM1F2LI_S72_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DM1F2LU_S72_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DM1F2OV_S154_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DM1F3HE_S41_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DM1F3KI_S41_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DM1F3LI_S47_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DM1F3LU_S47_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DM1F3OV_S129_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DM1F4HE_S53_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DM1F4KI_S53_R1_001.fastq.gz^a^
4 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DM1F4LI_S59_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DM1F4LU_S59_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DM1F4OV_S141_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DM1F5HE_S61_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DM1F5KI_S61_R1_001.fastq.gz^a^
5 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DM1F5LI_S67_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DM1F5LU_S67_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DM1F5OV_S149_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DM1F6HE_S58_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DM1F6KI_S58_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DM1F6LI_S64_R1_001.fastq.gz^b^
6 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DM1F6LU_S64_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DM1F6OV_S146_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DM1F7HE_S71_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DM1F7KI_S71_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DM1F7LI_S42_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DM1F7LU_S42_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DM1F7OV_S124_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DM1F8HE_S59_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DM1F8KI_S59_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DM1F8LI_S65_R1_001.fastq.gz^b^
8 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DM1F8LU_S65_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DM1F8OV_S147_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DM1F9HE_S57_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DM1F9KI_S57_R1_001.fastq.gz^b^
9 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DM1F9LI_S63_R1_001.fastq.gz^b^
9 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DM1F9LU_S63_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DM1F9OV_S145_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Heart | 4DM1F10HE_S72_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 4DM1F10KI_S72_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Liver | 4DM1F10LI_S43_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Lung | 4DM1F10LU_S43_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 4DM1F10OV_S125_R1_001.fastq.gz
11 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
12 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
13 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
101 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Heart | 4DM2F101HE_S50_R1_001.fastq.gz
101 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Kidney | 4DM2F101KI_S50_R1_001.fastq.gz
101 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Liver | 4DM2F101LI_S56_R1_001.fastq.gz
101 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Lung | 4DM2F101LU_S56_R1_001.fastq.gz
101 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Ovary | 4DM2F101OV_S138_R1_001.fastq.gz
102 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Heart | 4DM2F102HE_S52_R1_001.fastq.gz
102 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Kidney | 4DM2F102KI_S52_R1_001.fastq.gz
102 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Liver | 4DM2F102LI_S58_R1_001.fastq.gz
102 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Lung | 4DM2F102LU_S58_R1_001.fastq.gz
102 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Ovary | 4DM2F102OV_S140_R1_001.fastq.gz
103 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Heart | 4DM2F103HE_S62_R1_001.fastq.gz
103 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Kidney | 4DM2F103KI_S62_R1_001.fastq.gz
103 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Liver | 4DM2F103LI_S68_R1_001.fastq.gz
103 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Lung | 4DM2F103LU_S68_R1_001.fastq.gz
103 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Ovary | 4DM2F103OV_S150_R1_001.fastq.gz
104 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Heart | 4DM2F104HE_S44_R1_001.fastq.gz
104 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Kidney | 4DM2F104KI_S44_R1_001.fastq.gz
104 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Liver | 4DM2F104LI_S50_R1_001.fastq.gz
104 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Lung | 4DM2F104LU_S50_R1_001.fastq.gz
104 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Ovary | 4DM2F104OV_S132_R1_001.fastq.gz
105 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Heart | 4DM2F105HE_S38_R1_001.fastq.gz
105 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Kidney | 4DM2F105KI_S38_R1_001.fastq.gz^a^
105 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Liver | 4DM2F105LI_S44_R1_001.fastq.gz
105 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Lung | 4DM2F105LU_S44_R1_001.fastq.gz
105 | Core Animals | 1,4-Dichlorobenzene | 1 | Yes | Ovary | 4DM2F105OV_S126_R1_001.fastq.gz
106 | ICA Animals | 1,4-Dichlorobenzene | 1 | Yes | None | NA
107 | ICA Animals | 1,4-Dichlorobenzene | 1 | Yes | None | NA
108 | ICA Animals | 1,4-Dichlorobenzene | 1 | Yes | None | NA
201 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Heart | 4DM3F201HE_S49_R1_001.fastq.gz
201 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Kidney | 4DM3F201KI_S49_R1_001.fastq.gz
201 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Liver | 4DM3F201LI_S55_R1_001.fastq.gz
201 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Lung | 4DM3F201LU_S55_R1_001.fastq.gz
201 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Ovary | 4DM3F201OV_S137_R1_001.fastq.gz
202 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Heart | 4DM3F202HE_S48_R1_001.fastq.gz
202 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Kidney | 4DM3F202KI_S48_R1_001.fastq.gz^a^
202 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Liver | 4DM3F202LI_S54_R1_001.fastq.gz
202 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Lung | 4DM3F202LU_S54_R1_001.fastq.gz
202 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Ovary | 4DM3F202OV_S136_R1_001.fastq.gz
203 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Heart | 4DM3F203HE_S54_R1_001.fastq.gz
203 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Kidney | 4DM3F203KI_S54_R1_001.fastq.gz
203 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Liver | 4DM3F203LI_S60_R1_001.fastq.gz
203 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Lung | 4DM3F203LU_S60_R1_001.fastq.gz
203 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Ovary | 4DM3F203OV_S142_R1_001.fastq.gz
204 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Heart | 4DM3F204HE_S60_R1_001.fastq.gz
204 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Kidney | 4DM3F204KI_S60_R1_001.fastq.gz
204 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Liver | 4DM3F204LI_S66_R1_001.fastq.gz^b^
204 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Lung | 4DM3F204LU_S66_R1_001.fastq.gz
204 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Ovary | 4DM3F204OV_S148_R1_001.fastq.gz
205 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Heart | 4DM3F205HE_S40_R1_001.fastq.gz
205 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Kidney | 4DM3F205KI_S40_R1_001.fastq.gz
205 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Liver | 4DM3F205LI_S46_R1_001.fastq.gz
205 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Lung | 4DM3F205LU_S46_R1_001.fastq.gz
205 | Core Animals | 1,4-Dichlorobenzene | 10 | Yes | Ovary | 4DM3F205OV_S128_R1_001.fastq.gz
206 | ICA Animals | 1,4-Dichlorobenzene | 10 | Yes | None | NA
207 | ICA Animals | 1,4-Dichlorobenzene | 10 | Yes | None | NA
208 | ICA Animals | 1,4-Dichlorobenzene | 10 | Yes | None | NA
301 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Heart | 4DM4F301HE_S45_R1_001.fastq.gz
301 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Kidney | 4DM4F301KI_S45_R1_001.fastq.gz
301 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Liver | 4DM4F301LI_S51_R1_001.fastq.gz
301 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Lung | 4DM4F301LU_S51_R1_001.fastq.gz
301 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Ovary | 4DM4F301OV_S133_R1_001.fastq.gz
302 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Heart | 4DM4F302HE_S39_R1_001.fastq.gz
302 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Kidney | 4DM4F302KI_S39_R1_001.fastq.gz
302 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Liver | 4DM4F302LI_S45_R1_001.fastq.gz
302 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Lung | 4DM4F302LU_S45_R1_001.fastq.gz
302 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Ovary | 4DM4F302OV_S127_R1_001.fastq.gz
303 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Heart | 4DM4F303HE_S65_R1_001.fastq.gz
303 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Kidney | 4DM4F303KI_S65_R1_001.fastq.gz^a^
303 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Liver | 4DM4F303LI_S71_R1_001.fastq.gz
303 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Lung | 4DM4F303LU_S71_R1_001.fastq.gz
303 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Ovary | 4DM4F303OV_S153_R1_001.fastq.gz
304 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Heart | 4DM4F304HE_S63_R1_001.fastq.gz
304 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Kidney | 4DM4F304KI_S63_R1_001.fastq.gz
304 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Liver | 4DM4F304LI_S69_R1_001.fastq.gz
304 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Lung | 4DM4F304LU_S69_R1_001.fastq.gz
304 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Ovary | 4DM4F304OV_S151_R1_001.fastq.gz
305 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Heart | 4DM4F305HE_S67_R1_001.fastq.gz
305 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Kidney | 4DM4F305KI_S67_R1_001.fastq.gz
305 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Liver | 4DM4F305LI_S73_R1_001.fastq.gz
305 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Lung | 4DM4F305LU_S73_R1_001.fastq.gz
305 | Core Animals | 1,4-Dichlorobenzene | 50 | Yes | Ovary | 4DM4F305OV_S155_R1_001.fastq.gz
306 | ICA Animals | 1,4-Dichlorobenzene | 50 | Yes | None | NA
307 | ICA Animals | 1,4-Dichlorobenzene | 50 | No | None | NA
308 | ICA Animals | 1,4-Dichlorobenzene | 50 | Yes | None | NA
401 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Heart | 4DM5F401HE_S56_R1_001.fastq.gz
401 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Kidney | 4DM5F401KI_S56_R1_001.fastq.gz
401 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Liver | 4DM5F401LI_S62_R1_001.fastq.gz
401 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Lung | 4DM5F401LU_S62_R1_001.fastq.gz
401 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Ovary | 4DM5F401OV_S144_R1_001.fastq.gz
402 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Heart | 4DM5F402HE_S69_R1_001.fastq.gz
402 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Kidney | 4DM5F402KI_S69_R1_001.fastq.gz^a^
402 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Liver | 4DM5F402LI_S40_R1_001.fastq.gz
402 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Lung | 4DM5F402LU_S40_R1_001.fastq.gz
402 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Ovary | 4DM5F402OV_S122_R1_001.fastq.gz
403 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Heart | 4DM5F403HE_S42_R1_001.fastq.gz
403 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Kidney | 4DM5F403KI_S42_R1_001.fastq.gz
403 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Liver | 4DM5F403LI_S48_R1_001.fastq.gz^c^
403 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Lung | 4DM5F403LU_S48_R1_001.fastq.gz
403 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Ovary | 4DM5F403OV_S130_R1_001.fastq.gz
404 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Heart | 4DM5F404HE_S64_R1_001.fastq.gz
404 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Kidney | 4DM5F404KI_S64_R1_001.fastq.gz
404 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Liver | 4DM5F404LI_S70_R1_001.fastq.gz
404 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Lung | 4DM5F404LU_S70_R1_001.fastq.gz
404 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Ovary | 4DM5F404OV_S152_R1_001.fastq.gz
405 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Heart | 4DM5F405HE_S68_R1_001.fastq.gz
405 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Kidney | 4DM5F405KI_S68_R1_001.fastq.gz
405 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Liver | 4DM5F405LI_S74_R1_001.fastq.gz
405 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Lung | 4DM5F405LU_S74_R1_001.fastq.gz
405 | Core Animals | 1,4-Dichlorobenzene | 150 | Yes | Ovary | 4DM5F405OV_S156_R1_001.fastq.gz
406 | ICA Animals | 1,4-Dichlorobenzene | 150 | Yes | None | NA
407 | ICA Animals | 1,4-Dichlorobenzene | 150 | Yes | None | NA
408 | ICA Animals | 1,4-Dichlorobenzene | 150 | Yes | None | NA
501 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Heart | 4DM6F501HE_S55_R1_001.fastq.gz
501 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Kidney | 4DM6F501KI_S55_R1_001.fastq.gz
501 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Liver | 4DM6F501LI_S61_R1_001.fastq.gz
501 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Lung | 4DM6F501LU_S61_R1_001.fastq.gz
501 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Ovary | 4DM6F501OV_S143_R1_001.fastq.gz
502 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Heart | 4DM6F502HE_S47_R1_001.fastq.gz
502 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Kidney | 4DM6F502KI_S47_R1_001.fastq.gz
502 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Liver | 4DM6F502LI_S53_R1_001.fastq.gz
502 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Lung | 4DM6F502LU_S53_R1_001.fastq.gz
502 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Ovary | 4DM6F502OV_S135_R1_001.fastq.gz
503 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Heart | 4DM6F503HE_S70_R1_001.fastq.gz
503 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Kidney | 4DM6F503KI_S70_R1_001.fastq.gz
503 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Liver | 4DM6F503LI_S41_R1_001.fastq.gz
503 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Lung | 4DM6F503LU_S41_R1_001.fastq.gz
503 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Ovary | 4DM6F503OV_S123_R1_001.fastq.gz
504 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Heart | 4DM6F504HE_S51_R1_001.fastq.gz
504 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Kidney | 4DM6F504KI_S51_R1_001.fastq.gz
504 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Liver | 4DM6F504LI_S57_R1_001.fastq.gz
504 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Lung | 4DM6F504LU_S57_R1_001.fastq.gz
504 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Ovary | 4DM6F504OV_S139_R1_001.fastq.gz
505 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Heart | 4DM6F505HE_S46_R1_001.fastq.gz
505 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Kidney | 4DM6F505KI_S46_R1_001.fastq.gz
505 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Liver | 4DM6F505LI_S52_R1_001.fastq.gz
505 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Lung | 4DM6F505LU_S52_R1_001.fastq.gz
505 | Core Animals | 1,4-Dichlorobenzene | 400 | Yes | Ovary | 4DM6F505OV_S134_R1_001.fastq.gz
506 | ICA Animals | 1,4-Dichlorobenzene | 400 | Yes | None | NA
507 | ICA Animals | 1,4-Dichlorobenzene | 400 | Yes | None | NA
508 | ICA Animals | 1,4-Dichlorobenzene | 400 | Yes | None | NA

ICA = internal concentration assessment; NA = no transcriptomics data collected for selected animal.

^a^ Removed due to potential tissue contamination.

^b^ Removed due to quality control fail.

^c^ Removed due to principal component analysis/inter-replicate correlation analysis outlier.