# Appendix A Chemical Characterization and Generation of Chamber Concentrations

## A.1 Procurement and Characterization of 1,4-Dichlorobenzene

1,4-Dichlorobenzene (1,4-DCB) was obtained from Finetech Industry Limited (Wuhan, China) in a single lot (20240416001). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of the 1,4-DCB studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

The identity and purity of lot 20240416001, a white crystal at room temperature, was evaluated using gas chromatography (GC) with mass spectrometry (MS) detection (Table A-1, System A). The MS spectrum (Figure A-1) was consistent with the National Institute of Standards and Technology library spectrum for 1,4-DCB (Figure A-2) and a certified reference material of 1,4-DCB (lot LRAD1967, Sigma Aldrich). There were no impurity peaks present at ≥0.1%. The overall purity of the test article was estimated at approximately 100%.

Bulk 1,4-DCB was stored in the original shipping container at room temperature. Reanalysis of the bulk chemical was performed by the analytical chemistry laboratory within 30 days of study termination and no degradation was detected (Table A-1, System B).

## A.2 Vapor Concentration Monitoring

Exposure chamber and room concentrations of 1,4-DCB were monitored using an online GC equipped with a flame ionization detector (FID) (Table A-1, System C). All chambers were sampled at approximately twice per hour during exposure through Teflon tubing connected to each exposure chamber’s relative-humidity sampling lines at a location close to the GC/FID. The samples flowed into a 16-port Hastelloy^®^-C stream-select valve that directed a continuous stream of sampled atmosphere to a 6-port Hastelloy-C gas-sampling valve with a 1 mL sample loop. Valves were mounted in a dedicated valve oven located on top of the GC oven. The valve oven temperature was maintained at approximately 175°C. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and GC allowed for digital measurement of sample flow (approximately 1 L/min).

The online GCs were checked for suitability before the start of each exposure day and after every ninth sample throughout the exposure period using a standard 1,4-DCB vapor supplied by a standard generator (KIN-TEK Analytical, Inc., La Marque, TX). The online GC/FID at the testing facility was calibrated by quantitative determination of 1,4-DCB in exposure chamber samples on sorbent tubes (ORBO-101 and ORBO-100; graphitized carbon black; Supelco; Bellefonte, PA) and analyzed using an offline GC/FID at the analytical chemistry laboratory (Table A-1, System D). Prior to the study, stability of 1,4-DCB on sorbent tubes was confirmed for up to 7 days when stored at ambient (extracted) or refrigerated (either extracted or unextracted) temperatures. Known volumes of atmosphere from each inhalation exposure chamber were collected using a calibrated critical-orifice controlled sampler at a constant flow rate. The sorbent samples were extracted with acetone containing propylbenzene internal standard (IS) and transferred to autosampler vials for analysis on the offline GC/FID. Online GC/FID calibration was established by correlating the chamber concentrations determined from analysis of the sorbent gas-sampling tubes against the online monitor peak area determined at the time of sampling.

Summaries of the chamber vapor concentrations are given in Table A-2. The mean concentrations were all within the acceptance criteria of 10% for all exposure groups. Concentration relative standard deviation (RSD) was within acceptance criteria of 10% except for the 1 ppm chamber (rat and mouse). For the 1 ppm chamber, mainly because of the sensitivity of and fluctuation in the siphon/dilution system, the concentration RSD was 18% in the rat study and 22% in the mouse study. The high RSD of the 1 ppm chamber was considered to have no effect on the study results. The number of acceptable samples was ≥94% for all exposure groups of every study except for the 1 ppm rat and mouse chambers, which were 65% and 74%, respectively. The individual concentration data collected from the exposure room frequently exceeded the limit of detection (LOD; 0.02 ppm) with concentrations ≤0.053 ppm during the rat study and ≤0.034 ppm during the mouse study. The control chambers remained below the LOD for the entirety of both studies. These deviations were considered to have no effect on the study results, given that the mean concentrations were 100% of targets for both 1 ppm and 10 ppm chambers.

## A.3 Vapor Generation and Exposure System

A diagram of the generation and distribution system is shown in Figure A-3. Solid 1,4-DCB was melted in a heated reservoir (target >150°F) and pumped through heated lines (approximately 140°F) by a fluid metering pump into a heated (approximately 280°F) glass vaporizer column containing 6 mm glass beads and wrapped around the full length by heat tape. A waste collection flask was connected to the bottom of the column for collection of residual 1,4-DCB not completely vaporized within the vaporizer column.

Preheated (approximately 260°F) nitrogen entered the column from below, vaporized 1,4-DCB, and carried the vapor from the generator cabinet located in the control room to the distribution manifold located in the exposure room through a heated (approximately 300°F) Teflon^®^ transport line. The mixture of nitrogen and 1,4-DCB was diluted with heated (approximately 160°F) air before it entered the distribution manifold. The pressure in the distribution manifold was kept fixed, which ensured constant flow through the manifold and into all chambers as the flow of vapor to each chamber was adjusted. Concentration in the manifold was determined by the chemical pump rate, dilution air flow rate, nitrogen flow rate, and special modifications to the distribution manifold. Specifically, to achieve the 1 ppm exposure concentration, siphon/heated dilution lines were used to reduce the main manifold concentration approximately 30-fold before delivering the vapor to the 1 ppm chamber. Additionally, to ensure appropriate build up and decay times, heated entrainment air was added to the 10, 50, and 150 ppm delivery lines. Heated dilution air was also added to the 1 ppm siphon exhaust line to prevent potential blockage caused by solidified 1,4-DCB, which was at high concentration in the line.

Individual heated (approximately 200°F) Teflon delivery lines carried the vapor from the exposure valves in the distribution cabinet to the chamber inlets. The exposure valves diverted vapor delivery to the manifold exhaust until the generation system was stable, and exposures were ready to proceed. 1,4-DCB vapor delivery rates to each chamber were controlled by precision metering valves at the manifold. When the exposure started, the exposure valves actuated and directed the vapor into the chamber inlet where it was diluted with conditioned air to achieve the desired exposure concentration.

Conditioned air was defined as the mix of air derived from each exposure chamber’s wet and dry air duct supplies. The temperature of the resultant mixture of air was adjusted by passage over a temperature-controlled radiator after sequential treatment with Purafil^®^, charcoal, and high-efficiency particulate air (HEPA) filters. Air for the ducts was either passed over desiccant lowering the dew point (dry duct) or injected with clean steam raising the dew point (wet duct). Approximately 10% excess capacity of vapor was available for adjustments to chamber concentrations, as necessary. The excess capacity was emptied into the exhaust line from the manifold through a manually controlled adjustable flowmeter valve set to maintain constant pressure within the manifold. An alarm system automatically alerted the operator when any temperature controller detected a temperature outside of operating range. In addition, a variable power transformer limited power to each heater, thereby guarding against a temperature controller failure that could lead to excessive heating.

The exposure system consisted of seven exposure chambers with target test article concentrations of 0 (control group), 1, 10, 50, 150, 400, and 800 ppm. The inhalation exposure chamber (Lab Products, Inc., Seaford, DE) was designed so that uniform vapor concentrations could be maintained throughout the chamber with catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A small particle detector (Model 3022A; TSI, Inc., Shoreview, MN) was used in the exposure chambers, both with and without animals, to ensure vapor (not aerosol) was produced. Particle counts of fewer than 200 particles/cm^3^ are typical of an exposure atmosphere when no generation is occurring. Particle counts above this level, especially if the counts increase with exposure concentration and are above the level during the off-exposure period, suggest a contribution to the aerosol concentration from the generation system. No particle counts above the minimum resolvable level were detected.

## A.4 Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined prior to (without animals) and during (with animals) the studies. The time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) were estimated from the concentration versus time curves.

The theoretical prediction of T_90_ as suggested by a 1.7 m^3^ chamber mixing volume and a 15 ft^3^/min flow rate was approximately 9.2 minutes. Estimated T_90_ ranged from 8 to 13 minutes for all chambers without animals except the 1 ppm chamber, which had a T_90_ of 19 minutes. Estimated T_10_ ranged from 9 to 13 minutes without animals. Buildup and decay of vapor concentrations were measured for the lowest (1 ppm) and highest (800 ppm for rat; 400 ppm for mouse) exposure concentration chambers during the studies. For the rat study, T_90_ ranged from 9 to 10 minutes and T_10_ ranged from 10 to 12 minutes. For the mouse study, T_90_ ranged from 11 to 13 minutes and T_10_ ranged from 10 to 11 minutes for both chambers. A T_90_ value of 12 minutes was used for the studies.

Prior to the studies, the persistence of 1,4-DCB was monitored in the 400 and 800 ppm chambers after exposure without animals present. The concentration of 1,4-DCB reached 1% of starting concentration (T_1_) in ≤37 minutes. During the studies and with animals present, T_1_ was ≤75 minutes. The reason for the prolonged T_1_ values is unknown, but the prolonged T_1_ values were considered to have no effect on study findings given the low levels compared to the target chamber concentrations.

Concentration uniformity was evaluated in all exposure chambers without animals present. Vapor was sampled from 12 chamber positions, one in the front and one in the back, for each of the six possible animal cage positions per chamber and measured using the online monitor (Table A-1, System C). Uniformity measurements were all within the acceptable criterion of <5% of the RSD. Uniformity measurements were made during the studies from the lowest (1 ppm) and highest (800 ppm for rat; 400 ppm for mouse) exposure concentration chambers. All measurements met acceptable criteria and were comparable to the results prior to study start.

To measure stability and purity of 1,4-DCB in the generation and delivery system, samples of the test atmosphere were collected from the distribution line, generator reservoir, and the highest, lowest, and control exposure concentration chambers for both studies at the beginning and end of the exposure day and extracted with methanol. In addition, analysis was performed on a second set of samples collected from the same locations and exposure times and extracted in a second solvent (acetone) to demonstrate that any impurities in 1,4-DCB (if present) were not obscured by the primary solvent (methanol). Exposure atmosphere samples were collected on ORBO 101 (800 and 400 ppm for rats and mice, respectively) and ORBO 100 (1 ppm and control) CarboTrap B sorbent tubes. All sample collections included an SKC, Inc. (Eighty Four, PA) silica gel sorbent tube arranged in series with the ORBO primary tube. Samples were shipped on ice to the analytical chemistry laboratory for analysis (Table A-1, System D). No impurity peaks were present in any samples. Peaks were not observed in the silica gel samples, demonstrating 100% capture of the inhalation exposure atmosphere onto the ORBO 101 and ORBO 100 sorbent media. Stability and purity of 1,4-DCB was maintained throughout the exposure system.

To demonstrate acceptable stability and composition of the test article in the inhalation exposure system while animals were present in the exposure chambers, samples for stability analysis were collected by the testing facility from the distribution line, the two highest and the lowest exposure concentration chambers, and the vapor generator reservoir during the rat study. Additionally, the exposure system reservoir was sampled during the mouse study. The purity of 1,4-DCB in the exposure system with animals present in the exposure chambers was approximately 100%. Impurities with peak areas >0.1% of the total peak area were not present.

Table A-1 Gas Chromatography Systems Used in the Five-day Inhalation Studies of 1,4-Dichlorobenzene

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Mass spectrometry with electron impact ionization | Restek Rtx-1 (30 m × 0.25 mm ID, 1.0 µm film thickness) | Helium at 1 mL/min | 80°C for 2 minutes, then 5°C/min to 250°C, held for 5 minutes
System B
Mass spectrometry with electron impact ionization | Restek Rtx-1 (30 m × 0.25 mm ID, 1.0 µm film thickness) | Helium at 1 mL/min | 80°C for 2 minutes, then 10°C/min to 250°C, held for 5 minutes
System C
Flame ionization (250°C) | Restek Rtx-5 (15 m × 0.53 mm ID, 1.5 µm film thickness) | Nitrogen at 7.9 psi | Isothermal at 110°C
System D
Flame ionization (250°C) | Agilent DB-5a (30 m × 0.32 mm ID, 1.5 μm film thickness) | Helium at 1 mL/min | 80°C for 2 minutes, then 5°C/min to 150°C, then 20°C/min to 250°C, held for 4 minutes

ID = internal diameter.

Table A-2 Summary of Chamber Concentrations in the Five-day Inhalation Study of 1,4-Dichlorobenzene

Exposure Date | Target Concentration (ppm) | Total Number of Readings | Determined Concentration (ppm)^a^ | Percent of Target ± RSD | Acceptable Samples (%)^b^
Rat Chambers
January 23–27, 2025 | 0 (Room) | 84 | ND^c^ | NA | 35
January 23–27, 2025 | 0 | 80 | ND^c^ | NA | 96
| 1 | 130 | 1.00 ± 0.18 | 100 ± 18 | 65
| 10 | 80 | 10.0 ± 0.4 | 100 ± 4 | 99
| 50 | 80 | 49.8 ± 0.5 | 100 ± 1 | 100
| 150 | 80 | 152 ± 2 | 102 ± 2 | 100
| 400 | 80 | 403 ± 9 | 101 ± 2 | 100
| 800 | 111 | 795 ± 11 | 99 ± 1 | 100
Mouse Chambers
February 13–17, 2025 | 0 (Room) | 83 | ND^c^ | NA | 54
| 0 | 83 | ND | NA | 100
| 1 | 114 | 0.974 ± 0.215 | 97 ± 22 | 74
| 10 | 80 | 9.99 ± 0.39 | 100 ± 4 | 94
| 50 | 82 | 49.8 ± 0.5 | 100 ± 1 | 100
| 150 | 82 | 150 ± 2 | 100 ± 1 | 100
| 400 | 120 | 396 ± 9 | 99 ± 2 | 98

RSD = relative standard deviation; ND = not detectable; NA = not applicable.

^a^ Data shown as mean of readings ± standard deviation.

^b^ Acceptable range: Target concentration ± 10%; except for room and 0 ppm chamber: <limit of detection (LOD; 0.02 ppm).

^c^ Daily mean concentrations were below the LOD; however, some individual readings were above the LOD with maximum readings of 0.053 and 0.034 ppm in the rat and mouse exposure rooms, respectively.

Figure A-1

Mass Spectrum of 1,4-Dichlorobenzene

Figure A-2

Library Reference Spectrum of 1,4-Dichlorobenzene

Figure A-3

Schematic of the Vapor Generation and Delivery System in the Inhalation Studies of 1,4-Dichlorobenzene