# References

1 National Information Standards Organization (NISO). CRediT (Contributor Roles Taxonomy). Baltimore, MD: National Information Standards Organization; 2024. [Accessed: July 26, 2024]. https://credit.niso.org/
2 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for dichlorobenzenes. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service, Agency for Toxic Substances and Disease Registry; 2006. [Accessed: April 22, 2025]. https://www.atsdr.cdc.gov/ToxProfiles/tp10.pdf
3 Organisation for Economic Co-operation and Development (OECD). SIDS initial assessment report for SIAM 13: 1,2-Dichlorobenzene. Paris, France: Organisation for Economic Co-operation and Development; 2001. [Accessed: April 22, 2025]. https://hpvchemicals.oecd.org/ui/handler.axd?id=40127CF8-F9A5-4437-BC08-0E1199DF65C7
4 U.S. Environmental Protection Agency (USEPA). Technical factsheet on: o-Dichlorobenzene. Washington, DC: U.S. Environmental Protection Agency; 2014. [Accessed: February 10, 2026]. https://nepis.epa.gov/Exe/ZyPURL.cgi?Dockey=P1010FFG.txt
5 New Jersey Department of Health and Senior Services (NJDHSS). Hazardous substance fact sheet: 1,2-Dichlorobenzene. Trenton, NJ: New Jersey Department of Health and Senior Services; 2005. [Accessed: April 22, 2025]. https://nj.gov/health/eoh/rtkweb/documents/fs/0642.pdf
6 Occupational Safety and Health Administration (OSHA). 29 CFR § 1910.1000: Table Z-1 limits for air contaminants. Washington, DC: U.S. Department of Labor, Occupational Safety and Health Administration; 2025. [Accessed: April 29, 2025]. https://www.osha.gov/laws-regs/regulations/standardnumber/1910/1910.1000TABLEZ1
7 American Conference of Governmental Industrial Hygienists (ACGIH). ACGIH Data Hub: o-Dichlorobenzene. Cincinnati, OH: American Conference of Governmental Industrial Hygienists; 2025. [Accessed: April 22, 2025]. https://www.acgih.org/o-dichlorobenzene/
8 New York State Department of Health. New York State human health fact sheet: Ambient water quality value for protection of sources of potable water. Washington, DC: U.S. Environmental Protection Agency; 1998. [Accessed: August 28, 2025]. https://19january2021snapshot.epa.gov/sites/static/files/2015-06/ny_hh_46_w_03121998.pdf
9 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of 1,2-dichlorobenzene (o-dichlorobenzene) (CAS No. 95-50-1) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, National Toxicology Program; 1985. NTP Technical Report No. 255. NIH Publication No. 86-2511. [Accessed: October 15, 2025]. https://ntp.niehs.nih.gov/go/tr255abs
10 U.S. Environmental Protection Agency (USEPA). Integrated Risk Information System (IRIS) chemical assessment summary: 1,2-Dichlorobenzene; CASRN 95-50-1. Washington, DC: U.S. Environmental Protection Agency, National Center for Environmental Assessment; 1990. [Accessed: April 22, 2025]. https://iris.epa.gov/ChemicalLanding/&substance_nmbr=408
11 International Agency for Research on Cancer (IARC). Some chemicals that cause tumours of the kidney or urinary bladder in rodents and some other substances. (IARC monographs on the evaluation of carcinogenic risks to humans; vol. 73). Lyon, France: International Agency for Research on Cancer; 1999. [Accessed: April 29, 2025]. https://publications.iarc.who.int/91
12 Hoglen NC, Younis HS, Hartley DP, Gunawardhana L, Lantz RC, Sipes IG. 1,2-Dichlorobenzene-induced lipid peroxidation in male Fischer 344 rats is Kupffer cell dependent. Toxicol Sci. 1998; 46(2):376–385. 10.1006/toxs.1998.2523 10048141
13 Younis HS, Parrish AR, Sipes IG. The role of hepatocellular oxidative stress in Kupffer cell activation during 1,2-dichlorobenzene-induced hepatotoxicity. Toxicol Sci. 2003; 76(1):201–211. 10.1093/toxsci/kfg207 12915711
14 Hissink E, van Ommen B, Bogaards JJ, van Bladeren PJ. Hepatic epoxide concentrations during biotransformation of 1,2- and 1,4-dichlorobenzene: The use of in vitro and in vivo metabolism, kinetics and PB-PK modeling. In: Snyder R, Kocsis JJ, Sipes IG, Kalf GF, Jollow DJ, Greim H, Monks TJ, Witmer CM, editors. Biological Reactive Intermediates V: Basic Mechanistic Research in Toxicology and Human Risk Assessment. New York, NY: Springer; 1996. p. 129-133. 10.1007/978-1-4757-9480-9_18
15 Aiso S, Takeuchi T, Arito H, Nagano K, Yamamoto S, Matsushima T. Carcinogenicity and chronic toxicity in mice and rats exposed by inhalation to para-dichlorobenzene for two years. J Vet Med Sci. 2005; 67(10):1019–1029. 10.1292/jvms.67.1019 16276058
16 BioSpyder. TempO-Seq® assay user guide. Carlsbad, CA: BioSpyder Technologies, Inc.; 2022. Document 100802 rev C. [Accessed: August 25, 2025]. https://www.biospyder.com/s/100802-TempO-Seq-User-Guide-rev-C-r8r7.pdf
17 Langmead B, Trapnell C, Pop M, Salzberg SL. Ultrafast and memory-efficient alignment of short DNA sequences to the human genome. Genome Biol. 2009; 10(3):R25. 10.1186/gb-2009-10-3-r25 19261174
18 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
19 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
20 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
21 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
22 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
23 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
24 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill; 1957.
25 National Toxicology Program (NTP). NTP research report on National Toxicology Program approach to genomic dose-response modeling. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2018. NTP Research Report No. 5. 10.22427/NTP-RR-5
26 Yang L, Allen BC, Thomas RS. BMDExpress: A software tool for the benchmark dose analyses of genomic data. BMC Genomics. 2007;8:387. 10.1186/1471-2164-8-387 17961223
27 Gwinn WM, Auerbach SS, Parham F, Stout MD, Waidyanatha S, Mutlu E, Collins B, Paules RS, Merrick BA, Ferguson S, et al. Evaluation of 5-day in vivo rat liver and kidney with high-throughput transcriptomics for estimating benchmark doses of apical outcomes. Toxicol Sci. 2020; 176(2):343–354. 10.1093/toxsci/kfaa081 32492150
28 Brennan A, Chang D, Cowden J, Davidson-Fritz S, Dean J, Devito M, Ford J, Everett L, Harrill A, Hester S, et al. Standard methods for development of EPA Transcriptomic Assessment Products (ETAPs). Research Triangle Park, NC: U.S. Environmental Protection Agency, Office of Research and Development, Center for Public Health and Environmental Assessment, Center for Computational Toxicology and Exposure; 2024. EPA Report No. EPA/600/X-23/083. [Accessed: February 10, 2026]. 10.23645/epacomptox.25365496
29 Auerbach SS, Ballin JD, Blake JC, Browning DB, Collins BJ, Cora MC, Fernando RA, Fostel JM, Liu YF, Luh J, et al. NIEHS report on the in vivo repeat dose biological potency study of perfluorohexanesulfonamide (CASRN 41997-13-1) in Sprague Dawley (Hsd:Sprague Dawley® SD®) rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institute of Environmental Health Sciences; 2023. NIEHS Report 10. 10.22427/niehs-10
30 National Toxicology Program (NTP). NIEHS 12: Chemical Effects in Biological Systems (CEBS) data repository. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2025. 10.22427/NIEHS-DATA-NIEHS-12
31 U.S. Environmental Protection Agency (USEPA). Methods for derivation of inhalation reference concentrations and application of inhalation dosimetry. Research Triangle Park, NC: U.S. Environmental Protection Agency, Office of Research and Development, Office of Health and Environmental Assessment, Environmental Criteria and Assessment Office; 1994. EPA Report No. EPA/600/8-90/066F. [Accessed: October 21, 2025]. https://www.epa.gov/risk/methods-derivation-inhalation-reference-concentrations-and-application-inhalation-dosimetry
32 U.S. Environmental Protection Agency (USEPA). Recommendations for and documentation of biological values for use in risk assessment. Cincinnati, OH: U.S. Environmental Protection Agency, Office of Research and Development, Office of Health and Environmental Assessment, Environmental Criteria and Assessment Office; 1988. EPA Report No. EPA/600/6-87/008. [Accessed: October 6, 2025]. https://assessments.epa.gov/risk/document/&deid%3D34855
33 Liu J, Hara K, Kashimura S, Hamanaka T, Tomojiri S, Tanaka K. Gas chromatographic-mass spectrometric analysis of dichlorobenzene isomers in human blood with headspace solid-phase microextraction. J Chromatogr B Biomed Sci Appl. 1999; 731(2):217–221. 10.1016/S0378-4347(99)00226-1 10510774
34 Watanabe K, Hasegawa K, Yamagishi I, Nozawa H, Takaba M, Suzuki O. Simple isotope dilution headspace-GC-MS analysis of naphthalene and p-dichlorobenzene in whole blood and urine. Anal Sci. 2009; 25(11):1301–1305. 10.2116/analsci.25.1301 19907086
35 Gene Ontology Consortium (GOC). Geneontology: The gene ontology resource. 2025. [Accessed: October 17, 2025]. https://geneontology.org/
36 Medical College of Wisconsin. Rat Genome Database. Milwaukee, WI: Medical College of Wisconsin; 2025. [Accessed: October 17, 2025]. https://rgd.mcw.edu/
37 UniProt Consortium. UniProtKB. 2025. [Accessed: October 17, 2025]. https://www.uniprot.org/uniprotkb/
38 National Center for Biotechnology Information (NCBI). Entrez Gene. Bethesda, MD: U.S. Department of Health and Human Services, National Institutes of Health, National Library of Medicine, National Center for Biotechnology Information; 2025. [Accessed: October 17, 2025]. https://www.ncbi.nlm.nih.gov/gene/