# Summary

1,2-Dichlorobenzene (1,2-DCB) is a chlorinated aromatic hydrocarbon that is widely used in industrial applications, including as a solvent for waxes, resins, and paints, and it serves as an ingredient in the production of disinfectants and deodorants. These studies used a transcriptomic approach and standard toxicological endpoints to estimate the in vivo biological potency of 1,2-DCB. The data from these studies are intended to support risk assessment and establishment of acceptable exposure levels of 1,2-DCB in environmental and occupational settings.

In rats exposed to 1,2-DCB, the most sensitive apical endpoint was an increase in relative liver weight with a calculated benchmark dose (benchmark dose lower confidence limit)—BMD (BMD_L_)—of 57.9 (29.9) ppm. Increases in relative right and left kidney weights were the next most sensitive apical endpoint changes observed with BMDs (BMD_L_s) of 93.1 (43.2) and 101.4 (40.9) ppm, respectively. In mice exposed to 1,2-DCB, the most sensitive apical endpoint was a decrease in alkaline phosphatase activity with a BMD (BMD_L_) of 33.4 (10.9) ppm. The next most sensitive apical endpoints observed were increases in absolute and relative liver weights with BMDs (BMD_L_s) of 57.4 (36.4) and 60.5 (37.7) ppm, respectively.

In the heart, transcriptional changes at the gene set level were calculated to occur at a BMD (BMD_L_) as low as 148.7 (58.2) ppm in rats, corresponding to cellular response to hydrogen peroxide (GO:0070301), and as low as 4.4 (1.7) ppm in mice, corresponding to cellular modified amino acid metabolic process (GO:0006575). The most sensitive heart genes for which a reliable BMD could be determined were Prc1, with a BMD (BMD_L_) of 3.0 (0.7) ppm, in rats and Rsad2, with a BMD (BMD_L_) of 1.3 (0.5) ppm, in mice.

In the kidney, transcriptional changes at the gene set level were calculated to occur at a BMD (BMD_L_) as low as 114.0 (73.9) ppm in rats, corresponding to embryonic organ development (GO:0048568), and as low as 2.3 (0.6) ppm in mice, corresponding to organic hydroxy compound transport (GO:0015850). The most sensitive kidney gene in rats for which a reliable BMD could be determined was Slc51a with a BMD (BMD_L_) of 36.3 (8.9) ppm. The most sensitive kidney gene in mice for which a reliable BMD could be determined was Cdk2 with a BMD (BMD_L_) of 0.9 (0.2) ppm.

In the liver, transcriptional changes at the gene set level were calculated to occur at a BMD (BMD_L_) as low as 29.8 (25.3) ppm in rats, corresponding to xenobiotic metabolic process (GO:0006805), and as low as 1.5 (0.5) ppm in mice, corresponding to positive regulation of lipid biosynthetic process (GO:0046889). The most sensitive liver genes for which a reliable BMD could be determined were Sult1c3 in rats and Dbp in mice with BMDs (BMD_L_s) of 16.4 (3.3) and 0.7 (0.2) ppm, respectively.

In the lung, transcriptional changes at the gene set level were calculated to occur at a BMD (BMD_L_) as low as 175.9 (109.3) ppm in rats, corresponding to detoxification (GO:0098754), cellular oxidant detoxification (GO:0098869), and cellular detoxification (GO:1990748), and as low as 2.1 (0.7) ppm in mice, corresponding to unsaturated fatty acid metabolic process (GO:0033559). One lung gene in mice had a BMD estimate below the lower limit of extrapolation (<0.333 ppm). The most sensitive lung genes for which a reliable BMD could be determined were Akr1b8/Akr1b15, with a BMD (BMD_L_) of 118.9 (36.3) ppm, in rats and Il4 and Ces1g in mice, both with a BMD (BMD_L_) of 0.6 (0.2) ppm.

In the ovary, transcriptional changes at the gene set level were calculated to occur at a BMD (BMD_L_) as low as 156.7 (50.8) ppm in rats, corresponding to kidney development (GO:0001822), gonad development (GO:0008406), and male gonad development (GO:0008584), and as low as 108.0 (35.9) ppm in mice, corresponding to hemopoiesis (GO:0030097). The most sensitive ovary genes for which a reliable BMD could be determined were Ddit4 in rats and Syn1 in mice with BMDs (BMD_L_s) of 102.9 (27.9) and 0.6 (0.2) ppm, respectively.

Under the conditions of this short-term transcriptomic study in female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6D2F1/Crl mice, the most sensitive point of departure with a reliable estimate in rats was a transcriptional change in a heart gene, Prc1, with a BMD (BMD_L_) of 3.0 (0.7) ppm. Transcriptional changes at the gene set level provided potency estimates slightly higher than Prc1 and apical endpoints provided potency estimates higher than Prc1. In mice, the most sensitive point of departure with a reliable estimate was a transcriptional change in two lung genes, Il4 and Ces1g, and an ovary gene, Syn1, all three with a BMD (BMD_L_) of 0.6 (0.2) ppm. Transcriptional changes at the gene set level provided potency estimates slightly higher than Il4, Ces1g, and Syn1 and apical endpoints provided potency estimates higher than Il4, Ces1g, and Syn1.