# Results

## Apical Endpoint Analysis

### Animal Condition, Body Weights, and Organ Weights

#### Rats

All internal concentration assessment and core rats exposed to 1,2-dichlorobenzene (1,2-DCB) survived to the end of the study. In the 500 ppm group, all core animals began exhibiting a ruffled coat on study day 1, with one rat also noted with mild ataxia on study days 0 and 2 and being lethargic on study day 1 (‎Appendix G). There was a negative trend and significant decrease in terminal body weight in the 500 ppm group compared to the 0 ppm group (Table 2). The benchmark dose (benchmark dose lower confidence limit)—BMD (BMD_L_)—for decreased terminal body weight was 227.1 (116.4) ppm (Table 3). The BMDs for body weights were reviewed by a subject matter expert for anomalous modeling results (i.e., when the traditional statistics are notably different from the calculated BMD values).

Table 2 Summary of Body Weights and Body Weight Gain of Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Endpoint^a,b^ | 0 ppm | 1 ppm | 10 ppm | 30 ppm | 100 ppm | 250 ppm | 500 ppm | BMD_1Std_ (ppm) | BMD_L1Std_ (ppm)
Rats
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Body Weight
Study Day
0 | 200.1 ± 3.6 | 203.2 ± 3.2 | 211.4 ± 2.9 | 206.5 ± 4.2 | 196.2 ± 2.2 | 198.9 ± 4.2 | 207.9 ± 4.7 | ND | ND
4 | 205.4 ± 3.7* | 204.6 ± 4.3 | 207.6 ± 3.1 | 207.8 ± 4.8 | 197.9 ± 2.1 | 199.7 ± 4.9 | 187.0 ± 6.0* | 298.0 | 137.9
5 | 204.2 ± 3.3** | 206.9 ± 4.0 | 207.5 ± 3.3 | 207.8 ± 4.8 | 196.6 ± 3.4 | 200.2 ± 4.5 | 179.9 ± 3.6** | 227.1 | 116.5
Body Weight Gain
Study Day Interval
0–5 | 4.1 ± 0.9** | 3.7 ± 0.9 | −3.9 ± 2.3 | 1.3 ± 2.0 | 0.4 ± 2.7 | 1.3 ± 1.1 | −28.0 ± 1.7** | 273.4 | 215.6
Mice
n | 10 | 5 | 5 | 5 | 5 | 8 | NA | NA | NA
Body Weight
Study Day
0 | 21.1 ± 0.3 | 21.4 ± 0.4 | 22.2 ± 0.3 | 21.6 ± 0.2 | 21.0 ± 0.6 | 21.2 ± 0.4 | NA | ND | ND
2 | 20.4 ± 0.3** | 21.4 ± 0.5 | 21.7 ± 0.4 | 20.7 ± 0.3 | 20.0 ± 0.8 | 17.6 ± 0.4** | NA | 107.8 | 62.4
3 | 20.4 ± 0.3** | 21.4 ± 0.6 | 21.7 ± 0.5 | 20.5 ± 0.4 | 20.4 ± 0.7 | 17.6 ± 0.4** | NA | 118.5 | 69.5
4 | 20.5 ± 0.4** | 21.0 ± 0.6 | 21.4 ± 0.5 | 20.5 ± 0.4 | 20.8 ± 0.7 | 17.5 ± 0.5** | NA | 133.3 | 82.8
5 | 20.3 ± 0.4 | 20.8 ± 0.5 | 21.3 ± 0.7 | 20.5 ± 0.5 | 21.0 ± 0.7 | 18.5 ± 0.4*^c^ | NA | ND | ND
Body Weight Gain
Study Day Interval
0–5 | −0.8 ± 0.2* | −0.7 ± 0.3 | −0.9 ± 0.5 | −1.1 ± 0.5 | 0.0 ± 0.2 | −2.9 ± 0.3**^c^ | NA | 159.8 | 115.4

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm group. Statistical significance for the 0 ppm group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to 1 standard deviation from the mean; NA = not applicable; ND = not determined.

^a^ Data are displayed as mean ± standard error of the mean; body weight data are presented in grams.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ n = 7. One animal was euthanized moribund on study day 4.

Table 3 Summary of Select Organ Weights of Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Endpoint^a,b,c^ | 0 ppm | 1 ppm | 10 ppm | 30 ppm | 100 ppm | 250 ppm | 500 ppm | BMD_1Std_ (ppm) | BMD_L1Std_ (ppm)
Rats
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Terminal Body Wt. (g) | ^204.2 ±^ 3.3** | 206.9 ± 4.0 | 207.5 ± 3.3 | 207.8 ± 4.8 | 196.6 ± 3.4 | 200.2 ± 4.5 | 179.9 ± 3.6** | 227.1 | 116.4
Left Kidney
Relative (mg/g)^d^ | 3.12 ± 0.03** | 3.25 ± 0.07 | 3.23 ± 0.13 | 3.15 ± 0.04 | 3.39 ± 0.09* | 3.45 ± 0.05** | 3.69 ± 0.11** | 101.4 | 40.9
Right Kidney
Relative (mg/g) | 3.20 ± 0.05** | 3.24 ± 0.06 | 3.32 ± 0.08 | 3.15 ± 0.10 | 3.49 ± 0.11** | 3.56 ± 0.06** | 3.84 ± 0.11** | 93.1 | 43.2
Liver
Absolute (g) | 7.37 ± 0.18** | 7.67 ± 0.23 | 7.81 ± 0.18 | 7.93 ± 0.31 | 7.93 ± 0.25 | 9.08 ± 0.43** | 9.68 ± 0.47** | 114.0 | 41.8
Relative (mg/g) | 36.08 ± 0.46** | 37.06 ± 0.61 | 37.65 ± 0.72 | 38.12 ± 0.94 | 40.29 ± 0.77** | 45.29 ± 1.22** | 53.80 ± 2.04** | 57.9 | 29.9
Mice
n | 10 | 5 | 5 | 5 | 5 | 7 | NA | NA | NA
Terminal Body Wt. (g) | 20.3 ± 0.4 | 20.8 ± 0.5 | 21.3 ± 0.7 | 20.5 ± 0.5 | 21.0 ± 0.7 | 18.5 ± 0.4* | NA | ND | ND
Right Kidney
Relative (mg/g) | 6.49 ± 0.13*^e^ | 6.36 ± 0.13 | 6.21 ± 0.25 | 6.62 ± 0.20 | 6.38 ± 0.09 | 7.17 ± 0.17* | NA | 161.5 | 82.3
Liver
Absolute (g) | 0.94 ± 0.05** | 0.96 ± 0.03 | 0.90 ± 0.03 | 0.92 ± 0.04 | 1.16 ± 0.05** | 1.41 ± 0.04** | NA | 57.4 | 36.4
Relative (mg/g) | 46.05 ± 1.74** | 46.51 ± 1.52 | 42.45 ± 1.25 | 44.73 ± 0.75 | 55.36 ± 1.40** | 76.01 ± 2.05** | NA | 60.5 | 37.7

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm group. Statistical significance for the 0 ppm group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to 1 standard deviation from the mean; NA = not applicable; ND = not determined.

^a^ Descriptions of organ weight endpoints and changes are provided in ‎Appendix F.

^b^ Data are displayed as mean ± standard error of the mean.

^c^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^Relative organ weights (organ weight-to-body weight ratios) are given as mg organ weight/g body weight.

^e^n = 9. One value was excluded as an outlier.

At study termination, relative left and right kidney weights showed significant pairwise increases at ≥100 ppm with positive trends; the BMDs (BMD_L_s) for increased relative left and right kidney weights were 101.4 (40.9) and 93.1 (43.2) ppm, respectively (Table 3). A significant increase in absolute and relative liver weights occurred in the ≥250 and ≥100 ppm groups, respectively; both endpoints had positive trends. The BMDs (BMD_L_s) for increased absolute and relative liver weights were 114.0 (41.8) and 57.9 (29.9) ppm, respectively. The BMDs for all organ weights were reviewed by a subject matter expert for anomalous modeling results (i.e., when the traditional statistics are notably different from the calculated BMD values). Significant trend and pairwise comparisons were not observed in absolute left or right kidney weights or absolute or relative heart or lung weights (‎Appendix G).

#### Mice

In the internal concentration assessment mice, there was one accidental death in the 1 ppm group on study day 1 and two mice in the 250 ppm group were found dead, one each on study days 3 and 4. All core mice exposed to 1,2-DCB survived to the end of the study with the exception of one mouse in the 250 ppm group that presented as lethargic, had shallow breathing, and was euthanized moribund on study day 4 (‎Appendix G). There was a significant decrease in terminal body weight, although a significant trend was not found (Table 2).

At study termination, relative right kidney weight exhibited a positive trend and was significantly increased in the 250 ppm group with a BMD (BMD_L_) of 161.5 (82.3) ppm (Table 3). There was also a significant increase in absolute and relative liver weights in the ≥100 ppm groups with positive trends. The BMDs (BMD_L_s) for increased absolute and relative liver weights were 57.4 (36.4) and 60.5 (37.7) ppm, respectively. Significant trend and pairwise comparisons were not observed in absolute right kidney weight or absolute or relative left kidney, heart, or lung weights (‎Appendix G).

### Clinical Pathology

#### Rats

At study termination, there were no hematology parameters that exhibited significant trend and pairwise comparisons (‎Appendix G).

The albumin/globulin (A/G) ratio had a positive trend with a significant increase in the 500 ppm group (Table 4); the increase in the ratio was mainly driven by a mild (nonsignificant) decrease in globulin concentrations (‎Appendix G). The BMD (BMD_L_) for increased A/G ratio was 182.3 (99.4) ppm. There was a positive trend in cholesterol concentration and a significant increase in the 500 ppm group; the BMD (BMD_L_) was 238.4 (147.3) ppm. Glucose concentration had a negative trend with a significant decrease in the 500 ppm group; the BMD (BMD_L_) was 360.3 (183.9) ppm. Bile salt/acid concentration had a positive trend and significant increases in the 250 and 500 ppm groups; the BMD (BMD_L_) was 143.8 (45.9) ppm.

Table 4 Summary of Select Clinical Chemistry Data for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Endpoint^a,b,c^ | 0 ppm | 1 ppm | 10 ppm | 30 ppm | 100 ppm | 250 ppm | 500 ppm | BMD_1Std_ (ppm) | BMD_L1Std_ (ppm)
Rats
A/G Ratio | 3.02 ± 0.11** (10) | 3.12 ± 0.07 (5) | 2.96 ± 0.14 (5) | 2.78 ± 0.19 (5) | 3.06 ± 0.12 (5) | 3.39 ± 0.11 (5) | 3.69 ± 0.11** (5) | 182.3 | 99.4
Cholesterol (mg/dL) | 87.7 ± 2.8** (10) | 89.0 ± 2.8 (5) | 82.6 ± 0.7 (5) | 93.8 ± 7.5 (5) | 97.0 ± 3.2 (5) | 94.8 ± 5.4 (5) | 134.8 ± 8.1** (5) | 238.4 | 147.3
Glucose (mg/dL) | 135.0 ± 6.7** (10) | 144.6 ± 6.1 (5) | 129.8 ± 1.8 (5) | 135.0 ± 6.4 (5) | 127.8 ± 2.5 (5) | 130.2 ± 15.6 (5) | 104.8 ± 2.4** (5) | 360.3 | 183.9
Bile Salts/Acids (µmol/L) | 6.0 ± 1.3** (10) | 4.6 ± 0.8 (5) | 9.3 ± 3.0 (4) | 13.6 ± 3.8 (5) | 15.2 ± 5.5 (5) | 23.0 ± 5.6** (5) | 42.4 ± 12.6** (5) | 143.8 | 45.9
Mice
Cholesterol (mg/dL) | 115.8 ± 4.9** (5) | 126.5 ± 15.5 (2) | 129.0 ± 13.0 (2) | 133.0 (1) | 141.0 (1) | 194.3 ± 10.3** (4) | NA | NVM | NVM
Alanine Aminotransferase (IU/L) | 58.9 ± 11.8** (8) | 102.8 ± 45.6 (4) | 40.0 ± 2.0 (2) | 78.3 ± 12.2 (3) | 84.2 ± 17.3 (5) | 248.6 ± 34.2** (7) | NA | 157.8 | 108.9
Alkaline Phosphatase (IU/L) | 191.5 ± 8.1** (8) | 234.8 ± 9.7 (4) | 159.5 ± 26.5 (2) | 175.7 ± 11.9 (3) | 129.2 ± 5.3** (5) | 109.4 ± 3.1** (7) | NA | 33.4 | 10.9
Sorbitol Dehydrogenase (IU/L) | 25.6 ± 1.1** (7) | 28.0 ± 0.1 (2) | 28.9 ± 4.4 (2) | 22.0 ± 5.5 (3) | 40.9 ± 6.7** (4) | 108.6 ± 7.0** (7) | NA | 93.0 | 56.8

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm group. Statistical significance for the 0 ppm group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to 1 standard deviation from the mean; NA = not applicable; A/G ratio = albumin/globulin ratio; NVM = nonviable model.

^a^ Data are displayed as mean ± standard error of the mean (number of animals).

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests. Data with sample size of one were included in the trend test but excluded from the pairwise test.

^c^ Clinical chemistry data not reported were removed as outliers or were due to preanalytical or analytical conditions or errors, including but not limited to below linearity, short sample, quantity not sufficient, or extreme hemolysis.

When measured on clinical chemistry analyzers using standard reagents, normal rat baseline total and direct bilirubin blood concentrations are usually below the lower limit of quantification (LOQ); the LOQ for total bilirubin and direct bilirubin were 0.15 and 0.08 mg/dL, respectively. In this study, all the total and direct bilirubin values for the 0–250 ppm groups were below LOQ (‎Appendix G) and therefore no statistical analysis was performed on these parameters. However, in the 500 ppm group, almost all the total and direct bilirubin individual animal values were above the LOQ, ranging between 0.16–0.23 mg/dL (n = 3) and 0.11–0.19 mg/dL, (n = 5), respectively.

#### Mice

Because of serum volume limitations (i.e., quantity not sufficient), some pairwise statistical comparisons across different exposed groups and involving different parameters (‎Appendix G) were underpowered and may not accurately reflect the existence of “no effect.”

Cholesterol concentration and alanine aminotransferase (ALT) activity had positive trends with significant increases in the 250 ppm group; the BMD (BMD_L_) for ALT was 157.8 (108.9) ppm (Table 4). A BMD (BMD_L_) for increased cholesterol was not determined because no viable model was available. Alkaline phosphatase activity had a negative trend with significant decreases in the 100 and 250 ppm groups with a BMD (BMD_L_) of 33.4 (10.9) ppm. Sorbitol dehydrogenase activity had a positive trend, with significant increases in the 100 and 250 ppm groups with a BMD (BMD_L_) of 93.0 (56.8) ppm.

Similar to rats, normal mouse baseline total and direct bilirubin blood concentrations are usually below the LOQ; the LOQ for total bilirubin and direct bilirubin were 0.15 and 0.08 mg/dL, respectively. In this study, all the total and direct bilirubin values for the 0–100 ppm groups were below LOQ (‎Appendix G) and therefore no statistical analysis was performed on these parameters. However, in the 250 ppm group, some of the total and direct bilirubin individual animal values were above the LOQ, with one total bilirubin value of 0.18 mg/dL and direct bilirubin values ranging between 0.09 and 0.1 mg/dL (n = 4).

### Apical Endpoint Benchmark Dose Summary

A summary of the calculated BMDs for each toxicological endpoint, by species, is provided in Table 5. The endpoint-specific lowest-observed-effect level (LOEL) and no-observed-effect level (NOEL) are included and could be informative for endpoints that lack a calculated BMD either because no viable model was available or because the estimated BMD was below the lower limit of extrapolation (<0.333 ppm).

Table 5 BMD, BMD_L_, LOEL, and NOEL Summary for Apical Endpoints, Sorted by BMD or LOEL from Low to High, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Endpoint | BMD_1Std_ (ppm) | BMD_L1Std_ (ppm) | LOEL (ppm)^a^ | NOEL (ppm) | Direction of Change
Rats
Relative Liver Weight | 57.9 | 29.9 | 100 | 30 | UP
Relative Right Kidney Weight | 93.1 | 43.2 | 100 | 30 | UP
Relative Left Kidney Weight | 101.4 | 40.9 | 100 | 30 | UP
Absolute Liver Weight | 114.0 | 41.8 | 250 | 100 | UP
Bile Salts/Acids | 143.8 | 45.9 | 250 | 100 | UP
A/G Ratio | 182.3 | 99.4 | 500 | 250 | UP
Terminal Body Weight | 227.1 | 116.4 | 500 | 250 | DOWN
Cholesterol | 238.4 | 147.3 | 500 | 250 | UP
Body Weight Gain | 273.4 | 215.6 | 500 | 250 | DOWN
Body Weight on Study Day 4 | 298.0 | 137.9 | 500 | 250 | DOWN
Glucose | 360.3 | 183.9 | 500 | 250 | DOWN
Mice
Alkaline Phosphatase | 33.4 | 10.9 | 100 | 30 | DOWN
Absolute Liver Weight | 57.4 | 36.4 | 100 | 30 | UP
Relative Liver Weight | 60.5 | 37.7 | 100 | 30 | UP
Sorbitol Dehydrogenase | 93.0 | 56.8 | 100 | 30 | UP
Body Weight on Study Day 2 | 107.8 | 62.4 | 250 | 100 | DOWN
Body Weight on Study Day 3 | 118.5 | 69.5 | 250 | 100 | DOWN
Body Weight on Study Day 4 | 133.3 | 82.8 | 250 | 100 | DOWN
Alanine Aminotransferase | 157.8 | 108.9 | 250 | 100 | UP
Body Weight Gain | 159.8 | 115.4 | 250 | 100 | DOWN
Relative Right Kidney Weight | 161.5 | 82.3 | 250 | 100 | UP
Cholesterol | NVM | NVM | 250 | 100 | UP

BMD = benchmark dose; BMD_L_ = benchmark dose lower confidence limit; LOEL = lowest-observed-effect level; NOEL = no-observed-effect level; BMD_1Std_ = benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to 1 standard deviation from the mean; A/G ratio = albumin/globulin ratio; NVM = no viable model.

^a^ Values in bold text indicate the LOEL of endpoints for which a BMD could not be calculated.

## Gene Set Benchmark Dose Analysis

Chemical-induced alterations in heart, kidney, liver, lung, and ovary gene transcript expression were examined to determine those gene sets most sensitive to 1,2-DCB exposure. To that end, BMD analysis of transcripts and gene sets (Gene Ontology [GO] biological process) was conducted to determine the potency of the chemical to elicit gene expression changes in the heart, kidney, liver, lung, and ovary. This analysis used transcript-level BMD data to assess an aggregate score of gene set potency (5th percentile of transcript BMDs) and enrichment.

The “active” gene sets with the lowest 5th percentile BMD values are shown for the heart (Table 6), kidney (Table 7), liver (Table 8), lung (Table 9), and ovary (Table 10), with a summary of the top gene set per tissue based on lowest BMD 5th percentile provided in Table 11. No gene sets had estimated 5th percentile BMD values <0.333 ppm. The gene sets shown in Table 6 to Table 10 should be interpreted with caution from the standpoint of the underlying biological mechanism and any relationship to toxicity or toxic agents referenced in the GO term definitions. The data primarily should be considered as a metric of potency for chemical-induced transcriptional changes (i.e., a concerted biological change) that could serve as a surrogate of estimated biological potency and, by extension, toxicological potency when more definitive toxicological data are unavailable.

Table 6 Top 10 Heart Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Genes with Changed Direction Up/Down
Rats
GO:0070301 cellular response to hydrogen peroxide | 5/57 (8.8%) | 148.7 (58.2–382.1) | 4/1
GO:0044770 cell cycle phase transition | 3/58 (5.2%) | 161.5 (81.6–247.4) | 0/3
GO:0044772 mitotic cell cycle phase transition | 3/52 (5.8%) | 161.5 (81.6–247.4) | 0/3
GO:0048872 homeostasis of number of cells | 5/58 (8.6%) | 171.1 (90.5–395.6) | 3/2
GO:0001568: blood vessel development | 5/45 (11.1%) | 174.1 (96.0–271.1) | 1/4
GO:0001936 regulation of endothelial cell proliferation | 6/48 (12.5%) | 176.6 (107.9–257.6) | 3/3
GO:0010594 regulation of endothelial cell migration | 6/58 (10.3%) | 176.6 (107.9–257.6) | 4/2
GO:0010634 positive regulation of epithelial cell migration | 4/51 (7.8%) | 176.6 (107.9–257.6) | 2/2
GO:0071229 cellular response to acid chemical | 5/54 (9.3%) | 179.7 (66.7–285.1) | 1/4
GO:0071230 cellular response to amino acid stimulus | 5/50 (10.0%) | 179.7 (66.7–285.1) | 1/4
Mice
GO:0006575 cellular modified amino acid metabolic process | 3/59 (5.1%) | 4.4 (1.7–16.7) | 3/0
GO:0030097 hemopoiesis | 5/56 (8.9%) | 58.8 (17.9–116.1) | 2/3
GO:0002687 positive regulation of leukocyte migration | 4/50 (8.0%) | 69.1 (38.2–113.2) | 4/0
GO:0030595 leukocyte chemotaxis | 3/49 (6.1%) | 69.1 (38.2–113.2) | 3/0
GO:0043087 regulation of GTPase activity | 3/59 (5.1%) | 69.1 (38.2–113.2) | 3/0
GO:0043547 positive regulation of GTPase activity | 3/42 (7.1%) | 69.1 (38.2–113.2) | 3/0
GO:0097529 myeloid leukocyte migration | 3/51 (5.9%) | 69.1 (38.2–113.2) | 3/0
GO:0007178 transmembrane receptor protein serine/threonine kinase signaling pathway | 4/52 (7.7%) | 87.5 (41.0–425.7) | 3/1
GO:0009617 response to bacterium | 6/114 (5.3%) | 101.1 (52.8–140.7) | 3/3
GO:0002685 regulation of leukocyte migration | 5/69 (7.3%) | 101.1 (54.7–142.2) | 5/0

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology.

^a^ Active genes and GO biological process definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

Table 7 Top 10 Kidney Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Genes with Changed Direction Up/Down
Rats
GO:0048568 embryonic organ development | 3/47 (6.4%) | 114.0 (73.9–NC) | 0/3
GO:0072330 monocarboxylic acid biosynthetic process | 6/56 (10.7%) | 151.9 (109.0–183.8) | 3/3
GO:0120161 regulation of cold-induced thermogenesis | 9/55 (16.4%) | 151.9 (109.0–183.8) | 3/6
GO:0098754 detoxification | 12/58 (20.7%) | 163.7 (105.1–421.6) | 9/3
GO:1990748 cellular detoxification | 10/51 (19.6%) | 163.7 (105.1–421.6) | 7/3
GO:0015718 monocarboxylic acid transport | 8/64 (12.5%) | 165.8 (52.8–289.8) | 3/5
GO:0006805 xenobiotic metabolic process | 11/59 (18.6%) | 169.1 (112.1–177.2) | 10/1
GO:0009062 fatty acid catabolic process | 14/41 (34.2%) | 169.1 (112.1–177.2) | 12/2
GO:0072329 monocarboxylic acid catabolic process | 15/49 (30.6%) | 169.1 (112.1–177.2) | 13/2
GO:0098869 cellular oxidant detoxification | 8/43 (18.6%) | 171.4 (84.7–903.1) | 6/2
Mice
GO:0015850 organic hydroxy compound transport | 6/58 (10.3%) | 2.3 (0.6–219.7) | 4/2
GO:0033559 unsaturated fatty acid metabolic process | 7/40 (17.5%) | 2.6 (1.2–54.7) | 5/2
GO:0055088 lipid homeostasis | 5/52 (9.6%) | 2.7 (0.8–13.0) | 4/1
GO:0006869 lipid transport | 11/77 (14.3%) | 3.0 (0.8–9.9) | 5/6
GO:0044242 cellular lipid catabolic process | 7/44 (15.9%) | 3.0 (0.8–401.3) | 3/4
GO:1905952 regulation of lipid localization | 4/52 (7.7%) | 3.0 (0.8–401.3) | 1/3
GO:0015718 monocarboxylic acid transport | 8/52 (15.4%) | 3.0 (0.9–401.3) | 2/6
GO:0031589 cell-substrate adhesion | 3/40 (7.5%) | 3.1 (0.9–792.8) | 0/3
GO:0031669 cellular response to nutrient levels | 5/62 (8.1%) | 3.3 (1.0–408.4) | 1/4
GO:0090277 positive regulation of peptide hormone secretion | 3/40 (7.5%) | 3.5 (1.2–24.1) | 1/2

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology; NC = nonconvergent.

^a^ Active genes and GO biological process definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

Table 8 Top 10 Liver Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Genes with Changed Direction Up/Down
Rats
GO:0006805 xenobiotic metabolic process | 31/59 (52.5%) | 29.8 (25.3–89.7) | 22/9
GO:0098754 detoxification | 30/58 (51.7%) | 33.8 (18.2–99.6) | 21/9
GO:1990748 cellular detoxification | 23/51 (45.1%) | 33.8 (18.2–99.6) | 14/9
GO:0048872 homeostasis of number of cells | 20/58 (34.5%) | 34.9 (10.5–93.0) | 20/0
GO:0006690 icosanoid metabolic process | 20/50 (40.0%) | 35.9 (19.9–101.2) | 12/8
GO:0033559 unsaturated fatty acid metabolic process | 24/54 (44.4%) | 35.9 (19.9–101.2) | 13/11
GO:1901136 carbohydrate derivative catabolic process | 16/49 (32.7%) | 36.3 (9.5–438.0) | 14/2
GO:0120254 olefinic compound metabolic process | 28/64 (43.8%) | 37.4 (9.5–455.2) | 15/13
GO:0044770 cell cycle phase transition | 26/58 (44.8%) | 38.7 (14.3–79.1) | 26/0
GO:0098869 cellular oxidant detoxification | 22/43 (51.2%) | 40.1 (11.7–95.6) | 13/9
Mice
GO:0046889 positive regulation of lipid biosynthetic process | 15/45 (33.3%) | 1.5 (0.5–5.5) | 6/9
GO:0045834 positive regulation of lipid metabolic process | 21/61 (34.4%) | 2.1 (0.7–5.0) | 9/12
GO:0002708 positive regulation of lymphocyte mediated immunity | 6/40 (15.0%) | 2.2 (0.6–6.3) | 1/5
GO:0006805 xenobiotic metabolic process | 25/56 (44.6%) | 2.2 (0.3–88.7) | 17/8
GO:0048511 rhythmic process | 25/89 (28.1%) | 2.9 (0.9–13.7) | 17/8
GO:0097191 extrinsic apoptotic signaling pathway | 15/56 (26.8%) | 2.9 (0.9–13.7) | 12/3
GO:0019218 regulation of steroid metabolic process | 17/46 (37.0%) | 3.5 (0.9–4,078.8) | 10/7
GO:0002705 positive regulation of leukocyte mediated immunity | 7/47 (14.9%) | 3.7 (0.9–4,079.6) | 2/5
GO:0002706 regulation of lymphocyte mediated immunity | 8/59 (13.6%) | 3.7 (0.9–4,079.6) | 3/5
GO:0120254 olefinic compound metabolic process | 26/51 (51%) | 3.7 (0.8–4,080.3) | 14/12

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology.

^a^ Active genes and GO biological process definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

Table 9 Top 10 Lung Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Genes with Changed Direction Up/Down
Rats
GO:0098754 detoxification | 11/58 (19.0%) | 175.9 (109.3–224.0) | 7/4
GO:0098869 cellular oxidant detoxification | 10/43 (23.3%) | 175.9 (109.3–224.0) | 6/4
GO:1990748 cellular detoxification | 10/51 (19.6%) | 175.9 (109.3–224.0) | 6/4
GO:0019362 pyridine nucleotide metabolic process | 5/40 (12.5%) | 181.2 (46.6–348.4) | 5/0
GO:0046496 nicotinamide nucleotide metabolic process | 5/40 (12.5%) | 181.2 (46.6–348.4) | 5/0
GO:0072524 pyridine-containing compound metabolic process | 5/41 (12.2%) | 181.2 (37.4–352.1) | 5/0
GO:0001676 long-chain fatty acid metabolic process | 5/55 (9.1%) | 193.6 (60.7–298.8) | 5/0
GO:0006690 icosanoid metabolic process | 5/50 (10.0%) | 193.6 (60.7–298.8) | 5/0
GO:0006805 xenobiotic metabolic process | 6/59 (10.2%) | 193.6 (60.7–298.8) | 5/1
GO:0033559 unsaturated fatty acid metabolic process | 5/54 (9.3%) | 193.6 (60.7–298.8) | 5/0
Mice
GO:0033559 unsaturated fatty acid metabolic process | 8/40 (20.0%) | 2.1 (0.7–4.8) | 8/0
GO:0008203 cholesterol metabolic process | 8/48 (16.7%) | 2.4 (0.7–5.8) | 8/0
GO:0016125 sterol metabolic process | 8/49 (16.3%) | 2.4 (0.7–5.8) | 8/0
GO:1902652 secondary alcohol metabolic process | 10/53 (18.9%) | 2.4 (0.7–5.8) | 10/0
GO:0002708 positive regulation of lymphocyte mediated immunity | 4/40 (10.0%) | 2.8 (0.9–843.5) | 3/1
GO:0120254 olefinic compound metabolic process | 11/51 (21.6%) | 3.5 (0.7–53.9) | 11/0
GO:0006690 icosanoid metabolic process | 8/43 (18.6%) | 3.7 (0.9–11.6) | 8/0
GO:0006805 xenobiotic metabolic process | 14/56 (25.0%) | 3.8 (1.0–10.4) | 13/1
GO:0006066 alcohol metabolic process | 22/90 (24.4%) | 5.0 (0.9–60.7) | 22/0
GO:0015850 organic hydroxy compound transport | 7/58 (12.1%) | 5.1 (1.3–26.0) | 7/0

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology.

^a^ Active genes and GO biological process definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

Table 10 Top 10 Ovary Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Genes with Changed Direction Up/Down
Rats
GO:0001822 kidney development | 4/57 (7.0%) | 156.7 (50.8–280.4) | 4/0
GO:0008406 gonad development | 3/51 (5.9%) | 156.7 (50.8–280.4) | 2/1
GO:0008584 male gonad development | 3/46 (6.5%) | 156.7 (50.8–280.4) | 2/1
GO:0045582 positive regulation of T cell differentiation | 3/40 (7.5%) | 160.7 (51.6–289.6) | 3/0
GO:0016055 Wnt signaling pathway | 4/41 (9.8%) | 162.6 (54.1–417.6) | 4/0
GO:0030217 T cell differentiation | 3/48 (6.3%) | 162.6 (54.1–417.6) | 3/0
GO:0030856 regulation of epithelial cell differentiation | 3/53 (5.7%) | 163.7 (49.2–293.8) | 3/0
GO:0006694 steroid biosynthetic process | 3/54 (5.6%) | 175.7 (70.6–293.3) | 1/2
GO:0008203 cholesterol metabolic process | 3/54 (5.6%) | 175.7 (70.6–293.3) | 1/2
GO:0016125 sterol metabolic process | 3/56 (5.4%) | 175.7 (70.6–293.3) | 1/2
Mice
GO:0030097 hemopoiesis | 3/56 (5.4%) | 108.0 (35.9–NC) | 2/1
GO:0072594 establishment of protein localization to organelle | 5/77 (6.5%) | 110.3 (57.1–152.8) | 3/2
GO:0048167 regulation of synaptic plasticity | 4/75 (5.3%) | 119.5 (80.8–248.7) | 1/3
GO:0050777 negative regulation of immune response | 3/53 (5.7%) | 125.7 (60.1–425.4) | 3/0
GO:0006898 receptor-mediated endocytosis | 3/48 (6.3%) | 136.8 (83.0–271.7) | 3/0
GO:0043409 negative regulation of MAPK cascade | 3/47 (6.4%) | 136.8 (83.0–271.7) | 3/0
GO:0045580 regulation of T cell differentiation | 3/60 (5.0%) | 149.2 (81.9–684.2) | 2/1
GO:0002761 regulation of myeloid leukocyte differentiation | 3/50 (6.0%) | 153.6 (37.5–NC) | 2/1
GO:0016050 vesicle organization | 3/54 (5.6%) | 155.0 (87.7–288.7) | 1/2
GO:0051235 maintenance of location | 3/46 (6.5%) | 155.5 (74.0–NC) | 2/1

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology; NC = nonconvergent.

^a^ Active genes and GO biological process definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

Table 11 Most Potent Gene Ontology Biological Process Gene Set per Tissue, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Tissue | Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Genes with Changed Direction Up/Down
Rats
Liver | GO:0006805 xenobiotic metabolic process | 31/59 (52.5%) | 29.8^c^ (25.3−89.7) | 22/9
Kidney | GO:0048568 embryonic organ development | 3/47 (6.4%) | 114.0 (73.9−NC) | 0/3
Heart | GO:0070301 cellular response to hydrogen peroxide | 5/57 (8.8%) | 148.7 (58.2−382.1) | 4/1
Ovary | GO:0001822 kidney development | 4/57 (7.0%) | 156.7 (50.8−280.4) | 4/0
Lung | GO:0098754 detoxification | 11/58 (19.0%) | 175.9 (109.3−224.0) | 7/4
Mice
Liver | GO:0046889 positive regulation of lipid biosynthetic process | 15/45 (33.3%) | 1.5^c^ (0.5−5.5) | 6/9
Lung | GO:0033559 unsaturated fatty acid metabolic process | 8/40 (20.0%) | 2.1 (0.7−4.8) | 8/0
Kidney | GO:0015850 organic hydroxy compound transport | 6/58 (10.3%) | 2.3 (0.6−219.7) | 4/2
Heart | GO:0006575 cellular modified amino acid metabolic process | 3/59 (5.1%) | 4.4 (1.7−16.7) | 3/0
Ovary | GO:0030097 hemopoiesis | 3/56 (5.4%) | 108.0 (35.9−NC) | 2/1

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology; NC = nonconvergent.

^a^ Active genes and GO biological process definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

^c^ Transcriptional point of departure determined based on the lowest Gene Ontology biological process BMD_rd25_ 5th percentile value.

### Heart

#### Rats

The most sensitive GO biological processes for which a BMD value could be reliably calculated were cellular response to hydrogen peroxide (GO:0070301), cell cycle phase transition (GO:0044770), and mitotic cell cycle phase transition (GO:0044772) with 5th percentile BMDs (BMD_L_s) of 148.7 (58.2), 161.5 (81.6), and 161.5 (81.6) ppm, respectively (Table 6).

#### Mice

The most sensitive GO biological processes for which a BMD value could be reliably calculated were cellular modified amino acid metabolic process (GO:0006575) and hemopoiesis (GO:0030097) with 5th percentile BMDs (BMD_L_s) of 4.4 (1.7) and 58.8 (17.9) ppm, respectively (Table 6). The full list of affected gene sets in the heart of female rats and mice can be found in ‎Appendix G.

### Kidney

#### Rats

The most sensitive GO biological processes for which a BMD value could be reliably calculated were embryonic organ development (GO:0048568) and monocarboxylic acid biosynthetic process (GO:0072330), and regulation of cold-induced thermogenesis (GO:0120161) with 5th percentile BMDs (BMD_L_s) of 114.0 (73.9), 151.9 (109.0), and 151.9 (109.0) ppm, respectively (Table 7).

#### Mice

The most sensitive GO biological processes for which a BMD value could be reliably calculated were organic hydroxy compound transport (GO:0015850) and unsaturated fatty acid metabolic process (GO:0033559) with 5th percentile BMDs (BMD_L_s) of 2.3 (0.6) and 2.6 (1.2) ppm, respectively (Table 7). The full list of affected gene sets in the kidney of female rats and mice can be found in Appendix G.

### Liver

#### Rats

The most sensitive GO biological processes for which a BMD value could be reliably calculated were xenobiotic metabolic process (GO:0006805), detoxification (GO:0098754), and cellular detoxification (GO:1990748) with 5th percentile BMDs (BMD_L_s) of 29.8 (25.3), 33.8 (18.2), and 33.8 (18.2) ppm, respectively (Table 8).

#### Mice

The most sensitive GO biological processes for which a BMD value could be reliably calculated were positive regulation of lipid biosynthetic process (GO:0046889) and positive regulation of lipid metabolic process (GO:0045834) with 5th percentile BMDs (BMD_L_s) of 1.5 (0.5) and 2.1 (0.7) ppm, respectively (Table 8). The full list of affected gene sets in the liver of female rats and mice can be found in Appendix G.

### Lung

#### Rats

The most sensitive GO biological processes for which a BMD value could be reliably calculated were detoxification (GO:0098754), cellular oxidant detoxification (GO:0098869), and cellular detoxification (GO:1990748), all three with a 5th percentile BMD (BMD_L_) of 175.9 (109.3) ppm (Table 9).

#### Mice

The most sensitive GO biological processes for which a BMD value could be reliably calculated were unsaturated fatty acid metabolic process (GO:0033559), cholesterol metabolic process (GO:0008203), sterol metabolic process (GO:0016125), and secondary alcohol metabolic process (GO:1902652) with 5th percentile BMDs (BMD_L_s) of 2.1 (0.7), 2.4 (0.7), 2.4 (0.7), and 2.4 (0.7) ppm, respectively (Table 9). The full list of affected gene sets in the lung of female rats and mice can be found in ‎Appendix G.

### Ovary

#### Rats

The most sensitive GO biological processes for which a BMD value could be reliably calculated were kidney development (GO:0001822), gonad development (GO:0008406), and male gonad development (GO:0008584), all three with a 5th percentile BMD (BMD_L_) of 156.7 (50.8) ppm (Table 10).

#### Mice

The most sensitive GO biological processes for which a BMD value could be reliably calculated were hemopoiesis (GO:0030097) and establishment of protein localization to organelle (GO:0072594) with 5th percentile BMDs (BMD_L_s) of 108.0 (35.9) and 110.3 (57.1) ppm, respectively (Table 10). The full list of affected gene sets in the ovary of female rats and mice can be found in ‎Appendix G.

### Gene Set Benchmark Dose Summary

A summary of the most potent gene set per tissue is provided in Table 11. In both rats and mice exposed to 1,2-DCB, the liver had the gene set with the lowest BMD 5th percentile value, corresponding to xenobiotic metabolic process (GO:0006805) and positive regulation of lipid biosynthetic process (GO:0046889), respectively. The BMDs (BMD_L_s) were 29.8 (25.3) and 1.5 (0.5) ppm, respectively.

## Gene Benchmark Dose Analysis

The top 10 genes ranked by BMD potency are shown in the heart (Table 12), kidney (Table 13), liver (Table 14), lung (Table 15), and ovary (Table 16). No genes had estimated median BMD values <0.333 ppm with the exception of one lung gene in mice. As with the GO analysis, the biological or toxicological significance of the changes in gene expression shown in Table 12 to Table 16 should be interpreted with caution. The data primarily should be considered as a metric of potency for chemical-induced transcriptional changes that could serve as a conservative surrogate of estimated biological potency, and by extension toxicological potency, when more definitive toxicological data are unavailable.

Table 12 Top 10 Heart Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Gene Symbol^a^ | BMD_rd25_ (BMD_Lrd25_–BMD_Urd25_) in ppm | Maximum Fold Change | Direction of Expression Change
Rats
Prc1 | 3.0 (0.7–11.5) | 1.9 | DOWN
Lcn2 | 9.4 (2.0–68.3) | 1.5 | DOWN
Loc103689966 | 16.0 (4.8–46.6) | 1.8 | DOWN
Marcksl1 | 16.0 (4.8–46.6) | 1.8 | DOWN
Loc102549061/H2bc3 | 23.0 (3.2–134.3) | 1.8 | DOWN
Plk4 | 93.9 (16.1–257.2) | 1.7 | DOWN
Apln | 95.9 (12.4–646.3) | 1.5 | DOWN
Ccnb2 | 102.8 (40.3–179.2) | 2.3 | DOWN
Ccnb2-ps2 | 102.8 (40.3–179.2) | 2.3 | DOWN
Pcbd1 | 105.6 (32.0–234.3) | 1.5 | DOWN
Mice
Rsad2 | 1.3 (0.5–803.9) | 1.7 | DOWN
Prc1 | 1.8 (0.8–7.9) | 2.3 | DOWN
Hlf | 1.9 (0.9–4.4) | 1.9 | UP
Tcap | 2.5 (1.1–5.8) | 2.0 | UP
Nfil3 | 2.5 (1.2–5.2) | 1.8 | DOWN
Mthfd1l | 2.6 (1.1–5.8) | 2.2 | UP
Ifi44 | 3.1 (1.2–7.9) | 1.8 | DOWN
Bhlhe40 | 3.9 (1.6–7.7) | 2.0 | UP
Gnmt | 3.9 (1.8–9.4) | 1.5 | UP
Cldn5 | 4.4 (1.7–8.9) | 1.8 | DOWN

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response.

^a^ Gene definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table 13 Top 10 Kidney Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Gene Symbol^a^ | BMD_rd25_ (BMD_Lrd25_–BMD_Urd25_) in ppm | Maximum Fold Change | Direction of Expression Change
Rats
Slc51a | 36.3 (8.9–107.4) | 4.3 | UP
Acot12 | 50.5 (14.6–364.9) | 1.5 | UP
Ak2 | 55.5 (10.9–369.9) | 1.5 | DOWN
Slc6a8 | 64.0 (12.6–553.1) | 1.4 | DOWN
Atf4 | 83.3 (22.9–NC) | 1.3 | DOWN
Gstp1 | 109.9 (66.6–115.1) | 4.0 | UP
Ugt2b37 | 120.6 (29.3–243.9) | 2.1 | UP
Slc5a6 | 120.9 (20.6–266.0) | 2.0 | DOWN
Ipo13 | 140.9 (44.7–585.6) | 1.5 | DOWN
Fgf13 | 142.6 (57.8–251.8) | 2.2 | DOWN
Mice
Cdk2 | 0.9 (0.2–21.5) | 1.7 | DOWN
Dbp | 1.0 (0.3–3.1) | 5.9 | UP
Slc51a | 1.0 (0.2–4.6) | 2.6 | UP
Ndrg1 | 1.2 (0.8–4.6) | 2.2 | DOWN
Tsku | 1.6 (0.5–429.6) | 2.3 | UP
Cdkn1a | 1.7 (0.5–5.2) | 2.6 | DOWN
Slfn4 | 2.0 (0.5–9.3) | 1.7 | DOWN
Cyp2a5 | 2.2 (0.9–5.5) | 1.9 | UP
Hlf | 2.2 (1.2–4.0) | 2.0 | UP
Tk1 | 2.4 (0.7–3,488.7) | 1.7 | UP

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; NC = nonconvergent.

^a^ Gene definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table 14 Top 10 Liver Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Gene Symbol^a^ | BMD_rd25_ (BMD_Lrd25_–BMD_Urd25_) in ppm | Maximum Fold Change | Direction of Expression Change
Rats
Sult1c3 | 16.4 (3.3–58.9) | 3.1 | DOWN
Aldh1a1 | 16.7 (15.9–19.5) | 10.1 | UP
Unc93b1 | 16.9 (1.9–97.7) | 1.6 | UP
Ephx1 | 24.0 (9.9–93.0) | 11.4 | UP
Slc37a4 | 28.5 (9.6–67.2) | 1.5 | UP
Gsta2 | 29.8 (25.3–89.7) | 6.1 | UP
Gsta5 | 29.8 (25.3–89.7) | 6.1 | UP
Ccnb2 | 31.8 (9.7–76.6) | 2.2 | UP
Ccnb2-ps2 | 31.8 (9.7–76.6) | 2.2 | UP
Ces1f | 32.6 (4.7–797.6) | 1.4 | UP
Mice
Dbp | 0.7 (0.2–1.9) | 8.1 | UP
Il1b | 0.8 (0.1–8.6) | 2.1 | DOWN
Cyp2d9 | 1.0 (0.2–255.2) | 2.1 | UP
Cyp7a1 | 1.2 (0.3–6.3) | 3.6 | UP
Creld2 | 1.4 (0.4–4.6) | 2.3 | DOWN
Hlf | 1.4 (0.6–3.3) | 2.9 | UP
Chka | 1.4 (0.4–3.8) | 2.4 | DOWN
Nfil3 | 1.4 (0.6–4.0) | 2.1 | DOWN
Cyp3a44 | 1.7 (0.2–170.3) | 2.3 | DOWN
Por | 1.8 (0.7–4.6) | 1.8 | UP

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response.

^a^ Gene definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table 15 Top 10 Lung Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Gene Symbol^a^ | BMD_rd25_ (BMD_Lrd25_–BMD_Urd25_) in ppm | Maximum Fold Change | Direction of Expression Change
Rats
Akr1b8/Akr1b15 | 118.9 (36.3–218.3) | 2.8 | UP
Fetub | 130.0 (123.9–205.5) | 1.8 | UP
Nqo1 | 149.7 (60.4–240.0) | 2.9 | UP
Lpar2 | 167.5 (64.1–1,083.9) | 1.4 | UP
Gstp1 | 172.0 (99.1–204.4) | 2.7 | UP
Dbp | 174.8 (76.5–268.1) | 8.1 | UP
Srxn1 | 179.8 (119.4–243.7) | 3.8 | UP
Me1 | 181.2 (46.6–348.4) | 1.6 | UP
Aldoc | 181.2 (28.3–355.9) | 1.7 | UP
Jchain | 184.1 (49.3–866.9) | 2.1 | DOWN
Mice
Nqo1 | <0.333^b^ (NR) | 9.1 | UP
Il4 | 0.6 (0.2–345.6) | 2.1 | UP
Ces1g | 0.6 (0.2–1.7) | 8.9 | UP
Dbp | 1.3 (0.7–2.2) | 7.5 | UP
Hlf | 1.5 (0.8–2.9) | 3.0 | UP
Ifit3 | 1.5 (0.6–5.5) | 1.6 | UP
Adm | 1.7 (0.5–5.1) | 2.2 | DOWN
Tspan4 | 1.7 (0.7–4.7) | 2.2 | UP
Chil3 | 1.7 (0.2–274.5) | 1.5 | UP
Cyp2a4 | 1.9 (0.6–4.2) | 5.4 | UP

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; NR = the BMD_Lrd25_–BMD_Urd25_ range is not reportable because the BMD_rd25_ median is below the lower limit of extrapolation (<1/3 of the lowest nonzero exposure concentration tested).

^a^ Gene definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

^b^ <0.333 = a best-fit model was identified and a BMD_rd25_ was estimated that was <1/3 of the lowest nonzero exposure concentration tested.

Table 16 Top 10 Ovary Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Gene Symbol^a^ | BMD_rd25_ (BMD_Lrd25_–BMD_Urd25_) in ppm | Maximum Fold Change | Direction of Expression Change
Rats
Ddit4 | 102.9 (27.9–243.8) | 2.0 | DOWN
Gria2 | 109.6 (25.0–243.9) | 2.2 | UP
Lef1 | 112.3 (21.0–NC) | 1.4 | UP
Dbp | 118.3 (23.1–172.4) | 2.6 | UP
Hmgcs1 | 122.8 (15.7–263.5) | 3.1 | DOWN
Svs5 | 123.9 (15.5–244.1) | 6.5 | DOWN
Elovl5 | 139.3 (22.0–469.0) | 1.6 | UP
Pxmp2 | 141.6 (35.9–260.6) | 1.8 | UP
Ace | 152.6 (50.1–271.2) | 1.7 | UP
Maob | 157.3 (28.0–280.7) | 2.0 | UP
Mice
Syn1 | 0.6 (0.2–3.3) | 2.6 | DOWN
Tmem182 | 0.9 (0.2–3.9) | 2.8 | UP
Pcolce | 1.9 (0.5–1,026.5) | 1.5 | DOWN
Hsd3b1 | 2.1 (0.6–10.4) | 1.6 | DOWN
Hlf | 2.2 (1.1–5.0) | 2.1 | UP
Dbp | 2.3 (1.0–5.4) | 2.2 | UP
Adh1 | 2.4 (1.0–5.5) | 3.0 | DOWN
Ecm1 | 2.5 (0.7–1,117.8) | 1.6 | DOWN
Rgs2 | 2.6 (0.6–519.9) | 1.5 | UP
Pecam1 | 3.5 (1.0–379.9) | 1.5 | DOWN

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; NC = nonconvergent.

^a^ Gene definitions are available in ‎Appendix E and in the Chemical Effects in Biological Systems (CEBS) data repository: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

### Heart

#### Rats

All 10 of the most sensitive heart genes were downregulated. These genes were Prc1 (protein regulator of cytokinesis 1), Lcn2 (lipocalin 2), Loc103689966 (MARCKS-related protein-like), Marcksl1 (MARCKS-like 1), Loc102549061/H2bc3 (H2B clustered histone 3), Plk4 (polo-like kinase 4), Apln (apelin), Ccnb2 (cyclin B2), Ccnb2-ps2 (cyclin B2, pseudogene 2), and Pcbd1 (pterin-4 alpha-carbinolamine dehydratase 1) with BMDs (BMD_L_s) of 3.0 (0.7), 9.4 (2.0), 16.0 (4.8), 16.0 (4.8), 23.0 (3.2), 93.9 (16.1), 95.9 (12.4), 102.8 (40.3), 102.8 (40.3), and 105.6 (32.0) ppm, respectively.

#### Mice

Half of the top 10 most sensitive heart genes were upregulated and the other half were downregulated. The upregulated genes with a calculated BMD were Hlf (hepatic leukemia factor), Tcap (titin-cap), Mthfd1l (methylenetetrahydrofolate dehydrogenase (NADP+ dependent) 1-like), Bhlhe40 (basic helix-loop-helix family, member e40), and Gnmt (glycine N-methyltransferase) with BMD (BMD_L_s) of 1.9 (0.9), 2.5 (1.1), 2.6 (1.1), 3.9 (1.6), and 3.9 (1.8) ppm, respectively. The downregulated genes with a calculated BMD were Rsad2 (radical S-adenosyl methionine domain containing 2), Prc1 (protein regulator of cytokinesis 1), Nfil3 (nuclear factor, interleukin 3, regulated), Ifi44 (interferon-induced protein 44), and Cldn5 (claudin 5) with BMDs (BMD_L_s) of 1.3 (0.5), 1.8 (0.8), 2.5 (1.2), 3.1 (1.2), and 4.4 (1.7) ppm, respectively.

### Kidney

#### Rats

The most sensitive upregulated genes with a calculated BMD were Slc51a (solute carrier family 51 member A), Acot12 (acyl-CoA thioesterase 12), Gstp1 (glutathione S-transferase pi 1), and Ugt2b37 (UDP-glucuronosyltransferase 2 family, member 37) with BMDs (BMD_L_s) of 36.3 (8.9), 50.5 (14.6), 109.9 (66.6), and 120.6 (29.3) ppm, respectively. The most sensitive genes exhibiting a decrease in expression were Ak2 (adenylate kinase 2), Slc6a8 (solute carrier family 6 member 8), Atf4 (activating transcription factor 4), Slc5a6 (solute carrier family 5 member 6), Ipo13 (importin 13), and Fgf13 (fibroblast growth factor 13) with BMDs (BMD_L_s) of 55.5 (10.9), 64.0 (12.6), 83.3 (22.9), 120.9 (20.6), 140.9 (44.7), and 142.6 (57.8) ppm, respectively.

#### Mice

The most sensitive upregulated genes with a calculated BMD were Dbp (D site albumin promoter binding protein), Slc51a (solute carrier family 51, alpha subunit), Tsku (tsukushi, small leucine rich proteoglycan), Cyp2a5 (cytochrome P450, family 2, subfamily a, polypeptide 5), Hlf (hepatic leukemia factor), and Tk1 (thymidine kinase 1) with BMDs (BMD_L_s) of 1.0 (0.3), 1.0 (0.2), 1.6 (0.5), 2.2 (0.9), 2.2 (1.2), and 2.4 (0.7) ppm, respectively. The most sensitive downregulated genes with a calculated BMD were Cdk2 (cyclin dependent kinase 2), Ndrg1 (N-myc downstream regulated gene 1), Cdkn1a (cyclin dependent kinase inhibitor 1A), and Slfn4 (schlafen 4) with BMDs (BMD_L_s) of 0.9 (0.2), 1.2 (0.8), 1.7 (0.5), and 2.0 (0.5) ppm, respectively.

### Liver

#### Rats

The most sensitive upregulated genes with a calculated BMD were Aldh1a1 (aldehyde dehydrogenase 1 family, member A1), Unc93b1 (unc-93 homolog B1, TLR signaling regulator), Ephx1 (epoxide hydrolase 1), Slc37a4 (solute carrier family 37 member 4), Gsta2 (glutathione S-transferase alpha 2), Gsta5 (glutathione S-transferase alpha 5), Ccnb2 (cyclin B2), Ccnb2-ps2 (cyclin B2, pseudogene 2), and Ces1f (carboxylesterase 1F) with BMD (BMD_L_s) of 16.7 (15.9), 16.9 (1.9), 24.0 (9.9), 28.5 (9.6), 29.8 (25.3), 29.8 (25.3), 31.8 (9.7), 31.8 (9.7), and 32.6 (4.7) ppm, respectively. One gene, Sult1c3 (sulfotransferase family 1C member 3), was downregulated with a BMD (BMD_L_) of 16.4 (3.3) ppm.

#### Mice

Half of the top 10 most sensitive liver genes were upregulated while the other half were downregulated. The upregulated genes with a calculated BMD were Dbp (D site albumin promoter binding protein), Cyp2d9 (cytochrome P450, family 2, subfamily d, polypeptide 9), Cyp7a1 (cytochrome P450, family 7, subfamily a, polypeptide 1), Hlf (hepatic leukemia factor), and Por (cytochrome p450 oxidoreductase) with BMD (BMD_L_s) of 0.7 (0.2), 1.0 (0.2), 1.2 (0.3), 1.4 (0.6), and 1.8 (0.7) ppm, respectively. The genes exhibiting a decrease in expression were Il1b (interleukin 1 beta), Creld2 (cysteine-rich with EGF-like domains 2), Chka (choline kinase alpha), Nfil3 (nuclear factor, interleukin 3, regulated), and Cyp3a44 (cytochrome P450, family 3, subfamily a, polypeptide 44) with BMDs (BMD_L_s) of 0.8 (0.1), 1.4 (0.4), 1.4 (0.4), 1.4 (0.6), and 1.7 (0.2) ppm, respectively.

### Lung

#### Rats

The most sensitive upregulated genes with a calculated BMD were Akr1b8/Akr1b15 (aldo-keto reductase family 1 member B15), Fetub (fetuin B), Nqo1 (NAD(P)H quinone dehydrogenase 1), Lpar2 (lysophosphatidic acid receptor 2), Gstp1 (glutathione S-transferase pi 1), Dbp (D-box binding PAR bZIP transcription factor), Srxn1 (sulfiredoxin 1), Me1 (malic enzyme 1), and Aldoc (aldolase, fructose-bisphosphate C) with BMD (BMD_L_s) of 118.9 (36.3), 130.0 (123.9), 149.7 (60.4), 167.5 (64.1), 172.0 (99.1), 174.8 (76.5), 179.8 (119.4), 181.2 (46.6), and 181.2 (28.3) ppm, respectively. One gene, Jchain (joining chain of multimeric IgA and IgM), was downregulated with a BMD (BMD_L_) of 184.1 (49.3) ppm.

#### Mice

The most sensitive lung gene in mice, exhibiting an increase in expression, was Nqo1 (NAD(P)H dehydrogenase, quinone 1) with an estimated median BMD <0.333 ppm. The most sensitive upregulated genes with a calculated BMD were Il4 (interleukin 4), Ces1g (carboxylesterase 1G), Dbp (D site albumin promoter binding protein), Hlf (hepatic leukemia factor), Ifit3 (interferon-induced protein with tetratricopeptide repeats 3), Tspan4 (tetraspanin 4), Chil3 (chitinase-like 3), and Cyp2a4 (cytochrome P450, family 2, subfamily a, polypeptide 4) with BMDs (BMD_L_s) of 0.6 (0.2), 0.6 (0.2), 1.3 (0.7), 1.5 (0.8), 1.5 (0.6), 1.7 (0.7), 1.7 (0.2), and 1.9 (0.6) ppm, respectively. One gene, Adm (adrenomedullin), was downregulated with a BMD (BMD_L_) of 1.7 (0.5) ppm.

### Ovary

#### Rats

The most sensitive upregulated genes with a calculated BMD were Gria2 (glutamate ionotropic receptor AMPA type subunit 2), Lef1 (lymphoid enhancer binding factor 1), Dbp (D-box binding PAR bZIP transcription factor), Elovl5 (ELOVL fatty acid elongase 5), Pxmp2 (peroxisomal membrane protein 2), Ace (angiotensin I converting enzyme), and Maob (monoamine oxidase B) with BMD (BMD_L_s) of 109.6 (25.0), 112.3 (21.0), 118.3 (23.1), 139.3 (22.0), 141.6 (35.9), 152.6 (50.1), and 157.3 (28.0) ppm, respectively. The most sensitive genes exhibiting a decrease in expression were Ddit4 (DNA-damage-inducible transcript 4), Hmgcs1 (3-hydroxy-3-methylglutaryl-CoA synthase 1), and Svs5 (seminal vesicle secretory protein 5) with BMD (BMD_L_s) of 102.9 (27.9), 122.8 (15.7), and 123.9 (15.5) ppm, respectively.

#### Mice

The most sensitive upregulated genes with a calculated BMD were Tmem182 (transmembrane protein 182), Hlf (hepatic leukemia factor), Dbp (D site albumin promoter binding protein), and Rgs2 (regulator of G-protein signaling 2) with BMDs (BMD_L_s) of 0.9 (0.2), 2.2 (1.1), 2.3 (1.0), and 2.6 (0.6) ppm, respectively. The most sensitive genes exhibiting a decrease in expression were Syn1 (synapsin I), Pcolce (procollagen C-endopeptidase enhancer protein), Hsd3b1 (hydroxy-delta-5-steroid dehydrogenase, 3 beta- and steroid delta-isomerase 1), Adh1 (alcohol dehydrogenase 1 (class I)), Ecm1 (extracellular matrix protein 1), and Pecam1 (platelet/endothelial cell adhesion molecule 1) with BMDs (BMD_L_s) of 0.6 (0.2), 1.9 (0.5), 2.1 (0.6), 2.4 (1.0), 2.5 (0.7), and 3.5 (1.0) ppm, respectively.

## Theoretical Inhaled Dose

To provide information relevant for route-to-route extrapolation, to allow for comparison between two dichlorobenzene isomers, and to normalize data for comparison of internal dose between species, a theoretical inhaled mg/kg/day dose was calculated for each species and exposure group. Information relevant to the calculations is provided below, with the calculated theoretical inhaled doses shown in Table 17.

- Estimates of minute volume (Mv) were based on EPA’s Methods for Derivation of Inhalation Reference Concentrations and Application of Inhalation Dosimetry^31^ as well as Recommendations for and Documentation of Biological Values for Use in Risk Assessment.^32^
- Study day 0 body weights (BW) were used in the calculations due to the short duration of the study and minimal effects on body weight.
- Target exposure concentrations, rather than actual exposure concentrations, were used for the calculations due to the high degree of congruency.

The inhaled dose over a 6-hour exposure period was calculated as:

Dose (mg/kg/day) = C [(mg/m^3^)/1,000)] × Mv (L/min) × 360 min/day exposure ÷ BW (kg)

where

C (mg/m^3^) = 0.0409 × C (ppm) × molecular weight of test article

Mv (L/min) is estimated as LnMv = b0 + b1 × Ln(BW) where b0 and b1 are −0.578 and 0.821 for rats and 0.326 and 1.050 for mice, respectively.^31,32^

Table 17 Theoretical Inhaled Daily Dose (mg/kg/day) of 1,2-Dichlorobenzene Following Six-hour Whole-Body Inhalation Exposure

| 0 ppm | 1 ppm | 10 ppm | 30 ppm | 100 ppm | 250 ppm | 500 ppm
Rat | 0 | 1.62 | 16.11 | 48.42 | 162.13 | 403.23 | 808.75
Mouse | 0 | 2.48 | 24.74 | 74.20 | 247.18 | 618.16 | NA

Within each exposure group and species, calculations were performed for the core and internal concentration assessment animals separately, using group mean body weight data. The data presented here and used for internal dose assessment normalization (mg/kg/day) are a mean of the values calculated by the core and internal concentration assessment animals.

NA = not applicable.

## Internal Concentration Assessment

1,2-DCB concentrations were quantified in blood, lung, and liver on study day 4 (following the last exposure) and study day 5 (approximately 18 hours following the last exposure) using a validated analytical method (‎Appendix B). Data are reported before and after normalizing to the exposure concentration (ppm) and to the estimated theoretical inhaled dose (mg/kg/day).

### Rats

On study day 4, blood 1,2-DCB concentration increased with increasing exposure concentration (Table 18). The increase was proportional to the exposure concentration up to 100 ppm as evidenced by the dose-normalized values (4.46–6.86 [ng/mL]/[mg/kg/day]). At 250 and 500 ppm, blood concentrations increased more than proportionally to the exposure concentration with normalized values of 48.4 and 122 (ng/mL)/(mg/kg/day), respectively, demonstrating saturation of metabolism and/or clearance processes.

Table 18 Summary of Blood, Lung, and Liver Concentration Data for Female Rats Exposed to 1,2-Dichlorobenzene for Five Days

Endpoint^a,b^ | 0 ppm | 1 ppm | 10 ppm | 30 ppm | 100 ppm | 250 ppm | 500 ppm
Study Day 4
n | 3 | 3 | 3 | 3 | 3 | 3 | 3
Blood
Blood concentration (ng/mL) | BD^c^ | 11.1 ± 0.742 | 80.6 ± 11.9 | 216 ± 9.07 | 816 ± 18.4 | 19,500 ± 700 | 98,300 ± 16,700
Normalized blood concentration [(ng/mL)/(mg/kg/day)]^d,e^ | −^f^ | 6.86 ± 0.458 | 5.01 ± 0.740 | 4.46 ± 0.187 | 5.03 ± 0.113 | 48.4 ± 1.74 | 122 ± 20.6
Normalized blood concentration [(ng/mL)/ppm]^e^ | − | 11.1 ± 0.742 | 8.06 ± 1.19 | 7.20 ± 0.302 | 8.16 ± 0.184 | 78.0 ± 2.80 | 197 ± 33.3
Liver
Liver concentration (ng/g) | BD | 15.4 ± 1.82 | 77.7 ± 18.3 | 237 ± 17.5 | 881 ± 57.0 | 36,000 ± 4,720 | 213,000 ± 45,200
Normalized liver concentration [(ng/g)/(mg/kg/day)]^d,e^ | − | 9.54 ± 1.12 | 4.82 ± 1.14 | 4.89 ± 0.361 | 5.43 ± 0.352 | 89.4 ± 11.7 | 264 ± 55.9
Normalized liver concentration [(ng/g)/ppm]^e^ | − | 15.4 ± 1.82 | 7.77 ± 1.83 | 7.90 ± 0.582 | 8.81 ± 0.570 | 144 ± 18.9 | 427 ± 90.5
Lung
Lung concentration (ng/g) | BD | 18.1 ± 4.45 | 63.0 ± 20.0 | 543 ± 187 | 1,120 ± 306 | 7,410 ± 1,770 | 95,400 ± 54,300
Normalized lung concentration [(ng/g)/(mg/kg/day)]^d,e^ | − | 11.2 ± 2.75 | 3.91 ± 1.24 | 11.2 ± 3.87 | 6.92 ± 1.89 | 18.4 ± 4.39 | 118 ± 67.1
Normalized lung concentration [(ng/g)/ppm]^e^ | − | 18.1 ± 4.45 | 6.30 ± 2.00 | 18.1 ± 6.24 | 11.2 ± 3.06 | 29.6 ± 7.08 | 191 ± 109
Study Day 5
n | 3 | 3 | 3 | 3 | 3 | 3 | 3
Blood
Blood concentration (ng/mL) | BD | BD | 0.491 ± 0.104 | 1.25 ± 0.379 | 6.80 ± 0.586 | 41.1 ± 4.05 | 434 ± 155
Normalized blood concentration [(ng/mL)/(mg/kg/day)] | − | BD | 0.0305 ± 0.00647 | 0.0258 ± 0.00782 | 0.0419 ± 0.00361 | 0.102 ± 0.0101 | 0.537 ± 0.192
Normalized blood concentration [(ng/mL)/ppm] | − | BD | 0.0491 ± 0.0104 | 0.0416 ± 0.0126 | 0.0680 ± 0.00586 | 0.164 ± 0.0162 | 0.868 ± 0.310
Liver
Liver concentration (ng/g) | BD | BD | 1.10 ± 0.519 | 1.65 ± 0.124 | 6.92 ± 0.698 | 24.3 ± 2.11 | 156 ± 65.8
Normalized liver concentration [(ng/g)/(mg/kg/day)] | − | BD | 0.0680 ± 0.0322 | 0.0340 ± 0.00257 | 0.0427 ± 0.00431 | 0.0603 ± 0.00523 | 0.193 ± 0.0813
Normalized liver concentration [(ng/g)/ppm] | − | BD | 0.110 ± 0.0519 | 0.0549 ± 0.00415 | 0.0692 ± 0.00698 | 0.0972 ± 0.00843 | 0.313 ± 0.132
Lung
Lung concentration (ng/g) | BD | BD | BD | 1.32 ± 0.692 | 6.57 ± 2.24 | 24.2 ± 7.02 | 231 ± 114
Normalized lung concentration [(ng/g)/(mg/kg/day)] | − | BD | BD | 0.0272 ± 0.0143 | 0.0405 ± 0.0138 | 0.0599 ± 0.0174 | 0.286 ± 0.141
Normalized lung concentration [(ng/g)/ppm] | − | BD | BD | 0.0439 ± 0.0231 | 0.0657 ± 0.0224 | 0.0967 ± 0.0281 | 0.462 ± 0.227

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Data are presented as mean ± standard error.

^b^ If over 20% of the animals in a group were above the LOD, one-half of the LOD was substituted for values below the LOD. LOD for blood = 0.157 ng/mL; LOD for liver = 0.471 ng/g; LOD for lung = 0.471 ng/g.

^c^ When the 0 ppm group did not have over 20% of its values above the LOD, no mean or standard error was calculated, and no statistical analysis was performed.

^d^ Theoretical inhaled doses estimated for the 1, 10, 30, 100, 250, and 500 ppm groups are 1.62, 16.11, 48.42, 162.13, 403.23, and 808.75 mg/kg/day, respectively.

^e^ Normalized concentrations were calculated by dividing the measured concentration in either ng/mL for blood or ng/g for tissues by either the theoretical inhaled dose (mg/kg/day) or nominal exposure concentration (ppm). No statistical analysis was performed on normalized endpoints.

^f^ Not applicable.

On study day 4, 1,2-DCB liver and lung concentrations, in general, were similar to blood (except for 250 ppm lung where concentration was lower than blood and 250 and 500 ppm liver where concentration was higher than blood), suggesting low tissue distribution and/or retention. As observed with blood, tissue concentrations, in general, increased proportionally to exposure concentration up to 100 ppm as evidenced by the normalized values (ng/g)/(mg/kg/day) (liver, 4.82–9.54; lung, 3.91–11.2). At 250 and 500 ppm, tissue concentrations increased more than proportionally to the exposure concentration with normalized values (ng/g)/(mg/kg/day), respectively, of 89.4 and 264 for the liver and 18.4 and 118 for the lung.

On study day 5, blood, liver, and lung concentrations were much lower than on study day 4 with concentrations falling below the limit of detection (LOD) at 1 ppm (all matrices) and 10 ppm (lung only) demonstrating rapid elimination of 1,2-DCB. As observed for study day 4, concentrations in general were similar between blood and tissues.

### Mice

On study day 4, blood 1,2-DCB concentration increased with increasing exposure concentration (Table 19). The increase was proportional to the exposure concentration up to 100 ppm as evidenced by the dose-normalized values (3.41–4.47 [ng/mL]/[mg/kg/day]). At 250 ppm, blood concentrations increased more than proportionally to the exposure concentration with a normalized value of 90.3 (ng/mL)/(mg/kg/day).

Table 19 Summary of Blood, Lung, and Liver Concentration Data for Female Mice Exposed to 1,2-Dichlorobenzene for Five Days

Endpoint^a,b^ | 0 ppm | 1 ppm | 10 ppm | 30 ppm | 100 ppm | 250 ppm
Study Day 4
n | 3 | 2 | 3 | 3 | 3 | 3
Blood
Blood concentration (ng/mL) | BD^c^ | 8.99 ± 1.62 | 111 ± 10.8 | 320 ± 44.2 | 842 ± 108 | 55,800 ± 20,700
Normalized blood concentration [(ng/mL)/(mg/kg/day)]^d,e^ | −^f^ | 3.63 ± 0.652 | 4.47 ± 0.436 | 4.31 ± 0.596 | 3.41 ± 0.438 | 90.3 ± 33.5
Normalized blood concentration [(ng/mL)/ppm]^e^ | − | 8.99 ± 1.62 | 11.1 ± 1.08 | 10.7 ± 1.47 | 8.42 ± 1.08 | 223 ± 82.7
Liver
Liver concentration (ng/g) | BD | 12.9 ± 0.80 | 89.8 ± 11.4 | 347 ± 78.0 | 1,220 ± 181 | 92,900 ± 13,600
Normalized liver concentration [(ng/g)/(mg/kg/day)]^d,e^ | − | 5.21 ± 0.323 | 3.63 ± 0.461 | 4.68 ± 1.05 | 4.93 ± 0.733 | 150 ± 21.9
Normalized liver concentration [(ng/g)/ppm]^e^ | − | 12.9 ± 0.80 | 8.98 ± 1.14 | 11.6 ± 2.60 | 12.2 ± 1.81 | 372 ± 54.2
Lung
Lung concentration (ng/g) | BD | 7.86 ± 0.12 | 129 ± 41.3 | 194 ± 70.3 | 388 ± 73.7 | 57,700 ± 9,400
Normalized lung concentration [(ng/g)/(mg/kg/day)]^d,e^ | − | 3.18 ± 0.0485 | 5.23 ± 1.67 | 2.62 ± 0.948 | 1.57 ± 0.298 | 93.3 ± 15.2
Normalized lung concentration [(ng/g)/ppm]^e^ | − | 7.86 ± 0.12 | 12.9 ± 4.13 | 6.48 ± 2.34 | 3.88 ± 0.737 | 231 ± 37.6
Study Day 5
n | 3 | 3 | 3 | 3^g^ | 3 | 3^h^
Blood
Blood concentration (ng/mL) | BD | BD | BD | 2.78 ± 2.71 | 1.00 ± 0.875 | 5.97 ± 2.12
Normalized blood concentration [(ng/mL)/(mg/kg/day)] | − | BD | BD | 0.0375 ± 0.0365 | 0.00405 ± 0.00354 | 0.00966 ± 0.00343
Normalized blood concentration [(ng/mL)/ppm] | − | BD | BD | 0.0928 ± 0.0902 | 0.0100 ± 0.00875 | 0.0239 ± 0.00848
Liver
Liver concentration (ng/g) | BD | BD | BD | 0.749 ± 0.351 | 1.99 ± 0.313 | 30.4 ± 8.45
Normalized liver concentration [(ng/g)/(mg/kg/day)] | − | BD | BD | 0.0101 ± 0.00473 | 0.00804 ± 0.00127 | 0.0491 ± 0.0137
Normalized liver concentration [(ng/g)/ppm] | − | BD | BD | 0.0250 ± 0.0117 | 0.0199 ± 0.00313 | 0.121 ± 0.0338
Lung
Lung concentration (ng/g) | BD | BD | BD | 0.497 ± 0.133 | 1.16 ± 0.326 | 7.50 ± 1.68
Normalized lung concentration [(ng/g)/(mg/kg/day)] | − | BD | BD | 0.00669 ± 0.00179 | 0.00471 ± 0.00132 | 0.0121 ± 0.00271
Normalized lung concentration [(ng/g)/ppm] | − | BD | BD | 0.0166 ± 0.00443 | 0.0116 ± 0.00326 | 0.0300 ± 0.0067

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Data are presented as mean ± standard error.

^b^ If over 20% of the animals in a group were above the LOD, one-half of the LOD was substituted for values below the LOD. LOD for blood = 0.157 ng/mL; LOD for liver = 0.471 ng/g; LOD for lung = 0.471 ng/g.

^c^ When the 0 ppm group did not have over 20% of its values above the LOD, no mean or standard error was calculated, and no statistical analysis was performed.

^d^ Theoretical inhaled doses estimated for the 1, 10, 30, 100, and 250 ppm groups are 2.48, 24.74, 74.20, 247.18, and 618.16 mg/kg/day, respectively.

^e^ Normalized concentrations were calculated by dividing the measured concentration in either ng/mL for blood or ng/g for tissues by either the theoretical inhaled dose (mg/kg/day) or nominal exposure concentration (ppm). No statistical analysis was performed on normalized endpoints.

^f^ Not applicable.

^g^ n = 2 for blood. No samples were received for one animal.

^h^ n = 2 for liver and lung. No samples were received for one animal.

On study day 4, 1,2-DCB liver and lung concentrations were similar to blood, suggesting low tissue distribution and/or retention. As observed with the blood, lung and liver concentrations, in general, increased proportionally to exposure concentration up to 100 ppm as evidenced by the normalized values (ng/g)/(mg/kg/day) (liver, 3.63–5.21; lung, 1.57–5.23). At 250 ppm, tissue concentrations increased more than proportionally to the exposure concentration, with dose-normalized values of 150 and 93.3 (ng/g)/(mg/kg/day) for liver and lung, respectively.

On study day 5, blood, liver, and lung concentrations were much lower than on study day 4 with concentrations falling below the LOD at 1 ppm and 10 ppm in all matrices demonstrating rapid elimination of 1,2-DCB. As observed for study day 4, concentrations in general were similar between blood and tissues.

In general, when normalized to the theoretical inhaled dose, there were no apparent species differences in blood and tissue concentrations of 1,2-DCB at study days 4 or 5.