# Background

1,2-Dichlorobenzene (1,2-DCB) (CASRN: 95-50-1, U.S. Environmental Protection Agency [U.S. EPA] Chemical Dashboard: DTXSID6020430, PubChem CID: 7239, European Committee Number: 202-425-9), also known as ortho-DCB, is an organochlorine compound classified under chlorinated aromatic hydrocarbons.^2^ 1,2-DCB is widely used in industrial applications, including as a solvent for waxes, resins, and paints, as well as a precursor in the manufacture of agrochemicals and dyestuffs.^3,4^ Additionally, it serves as an ingredient in the production of disinfectants and deodorants.^3,4^

Both the Occupational Safety and Health Administration and the National Institute for Occupational Safety and Health have determined that exposure to 1,2-DCB should not exceed a ceiling of 50 ppm for an 8-hour workday^5; 6^ whereas the American Conference of Governmental Industrial Hygienists advises that the average airborne exposure should not exceed 25 ppm for an 8-hour work shift.^7^ Under the Safe Drinking Water Act, both the federal maximum contaminant level goal and the maximum contaminant level for 1,2-DCB are set at 600 µg/L.^4; 8^ The chronic oral reference dose from the U.S. EPA’s Integrated Risk Information System is 0.09 mg/kg body weight/day (mg/kg/day) and is based on a no-observed-adverse-effect level (NOAEL) of 120 mg/kg/day (adjusted to 85.7 mg/kg/day based on 5 days/week gavage), the highest dose of the National Toxicology Program 2-year carcinogenicity studies of 1,2-DCB,^9^ and a 1,000-fold uncertainty factor.^10^ The International Agency for Research on Cancer concluded that 1,2-DCB is not classifiable as to its carcinogenicity to humans (Group 3).^11^

Exposure to 1,2-DCB can occur through various routes, including inhalation, ingestion, and dermal contact.^2,3,5^ Inhalation exposure is particularly significant because of the volatility of 1,2-DCB, making occupational exposure a concern in industrial settings.^2,3^ Upon exposure, 1,2-DCB is absorbed efficiently via the lungs and gastrointestinal tract.^2^ It is distributed widely in the body, with a preference for adipose tissues given its lipophilicity.^2^ The metabolism of 1,2-DCB involves hepatic cytochrome P450 enzymes, mainly CYP2E1, leading to the formation of potentially toxic metabolites, including chlorophenols, dichlorocatechols, quinones, and epoxides.^2,12,13^ These metabolites are subsequently conjugated to glutathione and excreted primarily via the urine.^2^

1,2-DCB has demonstrated several toxicological effects that vary depending on the duration of exposure. Acute exposure can result in central nervous system depression, with symptoms including dizziness, headaches, and in severe instances, unconsciousness; it also causes irritation to the eyes, skin, and respiratory tract.^3,5^ Subacute or subchronic exposure to 1,2-DCB in animal models has been linked to liver and kidney damage; hepatotoxicity is indicated by elevated liver enzymes and histopathological changes such as liver cell hypertrophy and necrosis, and nephrotoxicity manifests as proximal tubular damage and altered renal function markers.^2-4,10^ Chronic exposure studies in rats and mice concluded that there was no evidence of carcinogenicity; however, there were positive trends for alveolar/bronchiolar carcinoma in the lungs of male mice and malignant histiocytic lymphoma in male and female mice. Increases in the incidences of renal tubular regeneration in the kidney were also observed in male mice.^9^

The toxic effects of 1,2-DCB are primarily mediated through its metabolism to reactive intermediates such as epoxides that can induce oxidative stress and cellular damage.^2,12-14^ The metabolites formed during detoxification by the liver can covalently bind to cellular macromolecules, leading to lipid peroxidation, protein damage, and DNA adduct formation that can subsequently disrupt normal cellular functions and lead to organ toxicity.^2,12^ Additionally, the induction of inflammatory pathways by 1,2-DCB may contribute to the observed toxic effects, particularly in hepatic tissues.^12,13^

The primary purpose of these short-term toxicity studies is to characterize the biological potency of 1,2-DCB via inhalation exposure. The data from these studies are intended to support risk assessment and establishment of acceptable exposure levels of 1,2-DCB in environmental and occupational settings.