# Appendix G Supplemental Data

The following supplemental files are available at https://doi.org/10.22427/NIEHS-DATA-NIEHS-12.

## G.1 Materials and Methods

Materials and Methods

## G.2 Theoretical Inhaled Dose

Theoretical Inhaled Dose

## G.3 Rats

### G.3.1 Apical Benchmark Dose Analysis

BMD, NOEL and LOEL Summary for Apical Endpoints

BMDExpress Project File_Rat_Apical (bm2 format)

Clinical Chemistry Summary

Mean Body Weights Summary

Organ Weights Summary

### G.3.2 Genomic Benchmark Dose Analysis

GEO/SRA: https://www.ncbi.nlm.nih.gov/bioproject/1304578

All Organ Principal Components Analysis Files

Animal and Fastaq Metadata

Attenuation-adjusted Raw Read Counts Rat Study

Benchmark Dose Analysis Rat Heart

Benchmark Dose Analysis Rat Kidney

Benchmark Dose Analysis Rat Liver

Benchmark Dose Analysis Rat Lung

Benchmark Dose Analysis Rat Ovary

BMDExpress Expression Data Heart

BMDExpress Expression Data Kidney

BMDExpress Expression Data Liver

BMDExpress Expression Data Lung

BMDExpress Expression Data Ovary

BMDExpress GO Biological Process BMD Results Rat Heart

BMDExpress GO Biological Process BMD Results Rat Kidney

BMDExpress GO Biological Process BMD Results Rat Liver

BMDExpress GO Biological Process BMD Results Rat Lung

BMDExpress GO Biological Process BMD Results Rat Ovary

BMDExpress Individual Gene BMD Results Rat Heart

BMDExpress Individual Gene BMD Results Rat Kidney

BMDExpress Individual Gene BMD Results Rat Liver

BMDExpress Individual Gene BMD Results Rat Lung

BMDExpress Individual Gene BMD Results Rat Ovary

BMDExpress Project File Rat Genomic (bm2 format)

BMDExpress Project File Rat Genomic (JSON format)

Curve Fit Rat Heart

Curve Fit Rat Kidney

Curve Fit Rat Liver

Curve Fit Rat Lung

Curve Fit Rat Ovary

Most Potent GO Biological Process In Each Tissue

One-way ANOVA_Rat_Heart

One-way ANOVA_Rat_Kidney

One-way ANOVA_Rat_Liver

One-way ANOVA_Rat_Lung

One-way ANOVA_Rat_Ovary

Rat DCB eFDR Synthetic Null Analysis

TempO-Seq S1500v1.2 Full Manifest Rattus Norvegicus

Top 10 Genes Ranked by Potency of Perturbation Heart

Top 10 Genes Ranked by Potency of Perturbation Kidney

Top 10 Genes Ranked by Potency of Perturbation Liver

Top 10 Genes Ranked by Potency of Perturbation Lung

Top 10 Genes Ranked by Potency of Perturbation Ovary

Top 10 GO Biological Process Gene Sets Heart

Top 10 GO Biological Process Gene Sets Kidney

Top 10 GO Biological Process Gene Sets Liver

Top 10 GO Biological Process Gene Sets Lung

Top 10 GO Biological Process Gene Sets Ovary

Transcriptomics Data QC Report

### G.3.3 Study Tables

I01 - Animal Removal Summary

I02 - Animal Removals

I04 - Mean Body Weights and Survival

I04G - Mean Body Weight Gain

I05 - Clinical Observations Summary

PA06 - Organ Weights Summary

PA41 - Clinical Chemistry Summary

PA43 - Hematology Summary

PA48 - Blood and Tissue Concentration

### G.3.4 Individual Animal Data

Individual Animal Blood and Tissue Concentration Data

Individual Animal Body Weight Data

Individual Animal Clinical Chemistry Data

Individual Animal Clinical Observations Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

## G.4 Mice

### G.4.1 Apical Benchmark Dose Analysis

BMD, NOEL and LOEL Summary for Apical Endpoints

BMDExpress Project File Mouse Apical (bm2 format)

Clinical Chemistry Summary

Mean Body Weights Summary

Organ Weights Summary

### G.4.2 Genomic Benchmark Dose Analysis

GEO/SRA: https://www.ncbi.nlm.nih.gov/bioproject/1304935

All Organ Principal Components Analysis Files

Animal and Fastaq Metadata

Attenuation-adjusted Raw Read Counts Mouse Study

Benchmark Dose Analysis Mouse Heart

Benchmark Dose Analysis Mouse Kidney

Benchmark Dose Analysis Mouse Liver

Benchmark Dose Analysis Mouse Lung

Benchmark Dose Analysis Mouse Ovary

BMDExpress Expression Data Heart

BMDExpress Expression Data Kidney

BMDExpress Expression Data Liver

BMDExpress Expression Data Lung

BMDExpress Expression Data Ovary

BMDExpress GO Biological Process BMD Results Mouse Heart

BMDExpress GO Biological Process BMD Results Mouse Kidney

BMDExpress GO Biological Process BMD Results Mouse Liver

BMDExpress GO Biological Process BMD Results Mouse Lung

BMDExpress GO Biological Process BMD Results Mouse Ovary

BMDExpress Individual Gene BMD Results Mouse Heart

BMDExpress Individual Gene BMD Results Mouse Kidney

BMDExpress Individual Gene BMD Results Mouse Liver

BMDExpress Individual Gene BMD Results Mouse Lung

BMDExpress Individual Gene BMD Results Mouse Ovary

BMDExpress Project File Mouse Genomic (bm2 format)

BMDExpress Project File Mouse Genomic (JSON format)

Curve Fit Mouse Heart

Curve Fit Mouse Kidney

Curve Fit Mouse Liver

Curve Fit Mouse Lung

Curve Fit Mouse Ovary

Mouse DCB eFDR Synthetic Null Analysis

Most Potent GO Biological Process In Each Tissue

One-way ANOVA_Mouse_Heart

One-way ANOVA_Mouse_Kidney

One-way ANOVA_Mouse_Liver

One-way ANOVA_Mouse_Lung

One-way ANOVA_Mouse_Ovary

TempO-Seq S1500v1.2 Full Manifest Mus Musculus

Top 10 Genes Ranked by Potency of Perturbation Heart

Top 10 Genes Ranked by Potency of Perturbation Kidney

Top 10 Genes Ranked by Potency of Perturbation Liver

Top 10 Genes Ranked by Potency of Perturbation Lung

Top 10 Genes Ranked by Potency of Perturbation Ovary

Top 10 GO Biological Process Gene Sets Heart

Top 10 GO Biological Process Gene Sets Kidney

Top 10 GO Biological Process Gene Sets Liver

Top 10 GO Biological Process Gene Sets Lung

Top 10 GO Biological Process Gene Sets Ovary

Transcriptomics Data QC Report

### G.4.3 Study Tables

I01 - Animal Removal Summary

I02 - Animal Removals

I04 - Mean Body Weights and Survival

I04G - Mean Body Weight Gain

I05 - Clinical Observations Summary

PA06 - Organ Weights Summary

PA41 - Clinical Chemistry Summary

PA48 - Blood and Tissue Concentration

### G.4.4 Individual Animal Data

Individual Animal Blood and Tissue Concentration Data

Individual Animal Body Weight Data

Individual Animal Clinical Chemistry Data

Individual Animal Clinical Observations Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

## G.5 Software

### G.5.1 Analysis Pipeline Evaluation

Analysis Pipeline Evaluation

DTT tBMD Pipeline bm2

EPA tBMD Pipeline bm2

### G.5.2 BMDExpress Preview Software

BMDExpress Preview Software

https://github.com/auerbachs/BMDExpress-3/releases/download/3.20.141/BMDExpress3_windows-x64_3_20_0141.exe