# Appendix E Gene Set and Gene Definitions

Table E-1 Active Genes and Definitions within Top 10 Heart Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | Active Genes | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Definition
Rats
GO:0070301 cellular response to hydrogen peroxide | 5/57 (8.8%) | Tnfaip3; Nol3; Myh7; Lcn2; Bnip3 | 148.7 (58.2–382.1) | Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a hydrogen peroxide (H_2_O_2_) stimulus.
GO:0044770 cell cycle phase transition | 3/58 (5.2%) | Ccnb2; Ccnb2-ps2; Ccna2 | 161.5 (81.6–247.4) | The cell cycle process by which a cell commits to entering the next cell cycle phase.
GO:0044772 mitotic cell cycle phase transition | 3/52 (5.8%) | Ccnb2; Ccnb2-ps2; Ccna2 | 161.5 (81.6–247.4) | The cell cycle process by which a cell commits to entering the next mitotic cell cycle phase.
GO:0048872 homeostasis of number of cells | 5/58 (8.6%) | Tnfaip3; Mef2c; Hmox1; Col6a1; Ccnb2 | 171.1 (90.5–395.6) | Any biological process involved in the maintenance of the steady-state number of cells within a population of cells.
GO:0001568: blood vessel development | 5/45 (11.1%) | Mef2c; Loxl1; Col3a1; Col1a2; Apln | 174.1 (96.0–271.1) | The process whose specific outcome is the progression of a blood vessel over time, from its formation to the mature structure. The blood vessel is the vasculature carrying blood.
GO:0001936 regulation of endothelial cell proliferation | 6/48 (12.5%) | Xdh; Stat1; Sparc; Mef2c; Hmox1; Apln | 176.6 (107.9–257.6) | Any process that modulates the frequency, rate, or extent of endothelial cell proliferation.
GO:0010594 regulation of endothelial cell migration | 6/58 (10.3%) | Sparc; Mef2c; Lcn2; Hmox1; Glul; Fgf1 | 176.6 (107.9–257.6) | Any process that modulates the rate, frequency, or extent of the orderly movement of an endothelial cell into the extracellular matrix to form an endothelium.
GO:0010634 positive regulation of epithelial cell migration | 4/51 (7.8%) | Sparc; Lcn2; Hmox1; Fgf1 | 176.6 (107.9–257.6) | Any process that activates or increases the frequency, rate or extent of epithelial cell migration.
GO:0071229 cellular response to acid chemical | 5/54 (9.3%) | Myh7; Col6a1; Col4a1; Col3a1; Col1a2 | 179.7 (66.7–285.1) | Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a stimulus by the chemical structure of the anion portion of the dissociated acid (rather than the acid acting as a proton donor). The acid chemical may be in gaseous, liquid or solid form.
GO:0071230 cellular response to amino acid stimulus | 5/50 (10.0%) | Myh7; Col6a1; Col4a1; Col3a1; Col1a2 | 179.7 (66.7–285.1) | Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of an amino acid stimulus. An amino acid is a carboxylic acid containing one or more amino groups.
Mice
GO:0006575 cellular modified amino acid metabolic process | 3/59 (5.1%) | Gnmt; Mthfd1l; Gsta1 | 4.4 (1.7–16.7) | The chemical reactions and pathways involving compounds derived from amino acids, organic acids containing one or more amino substituents.
GO:0030097 hemopoiesis | 5/56 (8.9%) | Alas1; Alas2; Slc11a2; Hba-a1; Hba-a2 | 58.8 (17.9–116.1) | The process whose specific outcome is the progression of the myeloid and lymphoid derived organ/tissue systems of the blood and other parts of the body over time, from formation to the mature structure. The site of hemopoiesis is variable during development, but occurs primarily in bone marrow or kidney in many adult vertebrates.
GO:0002687 positive regulation of leukocyte migration | 4/50 (8.0%) | Serpine1; Ccl12; Ccl2; Ccl7 | 69.1 (38.2–113.2) | Any process that activates or increases the frequency, rate, or extent of leukocyte migration.
GO:0030595 leukocyte chemotaxis | 3/49 (6.1%) | Ccl12; Ccl2; Ccl7 | 69.1 (38.2–113.2) | The movement of a leukocyte in response to an external stimulus.
GO:0043087 regulation of GTPase activity | 3/59 (5.1%) | Ccl12; Ccl2; Ccl7 | 69.1 (38.2–113.2) | Any process that modulates the rate of GTP hydrolysis by a GTPase.
GO:0043547 positive regulation of GTPase activity | 3/42 (7.1%) | Ccl12; Ccl2; Ccl7 | 69.1 (38.2–113.2) | Any process that activates or increases the activity of a GTPase.
GO:0097529 myeloid leukocyte migration | 3/51 (5.9%) | Ccl12; Ccl2; Ccl7 | 69.1 (38.2–113.2) | The movement of a myeloid leukocyte within or between different tissues and organs of the body.
GO:0007178 transmembrane receptor protein serine/threonine kinase signaling pathway | 4/52 (7.7%) | Cldn5; Ccl2; Bambi; Stat3 | 87.5 (41.0–425.7) | A series of molecular signals initiated by the binding of an extracellular ligand to a receptor on the surface of the target cell where the receptor possesses serine/ threonine kinase activity, and ending with regulation of a downstream cellular process, e.g., transcription.
GO:0009617 response to bacterium | 6/114 (5.3%) | Serpine1; Ccl2; Ifi44; Gsta1; Hba-a1; Hba-a2 | 101.1 (52.8–140.7) | Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a stimulus from a bacterium.
GO:0002685 regulation of leukocyte migration | 5/69 (7.3%) | Mif; Serpine1; Ccl12; Ccl2; Ccl7 | 101.1 (54.7–142.2) | Any process that modulates the frequency, rate, or extent of leukocyte migration.

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^35^ Official gene symbols from the Rat Genome Database^36^ are shown in the “Active Genes” column.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

GO process descriptions and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-2 Active Genes and Definitions within Top 10 Kidney Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | Active Genes | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Definition
Rats
GO:0048568 embryonic organ development | 3/47 (6.4%) | Slc6a8; Gatm; Atf4 | 114.0 (73.9–NC) | Development, taking place during the embryonic phase, of a tissue or tissues that work together to perform a specific function or functions. Development pertains to the process whose specific outcome is the progression of a structure over time, from its formation to the mature structure. Organs are commonly observed as visibly distinct structures, but may also exist as loosely associated clusters of cells that work together to perform a specific function or functions.
GO:0072330 monocarboxylic acid biosynthetic process | 6/56 (10.7%) | Hsd17b10; Gstp1; Gstm2; Gatm; Cd74; Aldh1a1 | 151.9 (109.0–183.8) | The chemical reactions and pathways resulting in the formation of monocarboxylic acids, any organic acid containing one carboxyl (-COOH) group.
GO:0120161 regulation of cold-induced thermogenesis | 9/55 (16.4%) | Prlr; Mfap2; Gnas; Gatm; Decr1; Cpt2; Atf4; Bmal1; Aldh1a1 | 151.9 (109.0–183.8) | Any process that modulates the frequency, rate or extent of cold-induced thermogenesis.
GO:0098754 detoxification | 12/58 (20.7%) | Srxn1; Sod3; Slc22a2; Nqo1; Gstp1; Gstm2; Gsta3; Gsta2; Gpx3; Cat; Aldh1a1; Akr7a3 | 163.7 (105.1–421.6) | Any process that reduces or removes the toxicity of a toxic substance. These may include transport of the toxic substance away from sensitive areas and to compartments or complexes whose purpose is sequestration of the toxic substance.
GO:1990748 cellular detoxification | 10/51 (19.6%) | Srxn1; Sod3; Slc22a2; Nqo1; Gstp1; Gstm2; Gsta2; Gpx3; Cat; Aldh1a1 | 163.7 (105.1–421.6) | Any process carried out at the cellular level that reduces or removes the toxicity of a toxic substance. These may include transport of the toxic substance away from sensitive areas and to compartments or complexes whose purpose is sequestration of the toxic substance.
GO:0015718 monocarboxylic acid transport | 8/64 (12.5%) | Slc6a8; Slc5a6; Slc51a; Slc22a7; Slc22a2; Plin2; Cpt2; Abcc4 | 165.8 (52.8–289.8) | The directed movement of monocarboxylic acids into, out of or within a cell, or between cells, by means of some agent such as a transporter or pore.
GO:0006805 xenobiotic metabolic process | 11/59 (18.6%) | Gstp1; Gstm2; Gsta1; Gsta3; Gsta2; Gsta5; Fmo3; Cyp2f4; Cyp2e1; Acaa1b; Acaa1a | 169.1 (112.1–177.2) | The chemical reactions and pathways involving a xenobiotic compound, a compound foreign to living organisms. Used of chemical compounds, e.g., a xenobiotic chemical, such as a pesticide.
GO:0009062 fatty acid catabolic process | 14/41 (34.2%) | Pck1; Hsd17b10; Hao2; Gcdh; Ehhadh; Eci2; Eci1; Decr1; Cpt2; Acox1; Acadm; Acaa2; Acaa1b; Acaa1a | 169.1 (112.1–177.2) | The chemical reactions and pathways resulting in the breakdown of a fatty acid, any of the aliphatic monocarboxylic acids that can be liberated by hydrolysis from naturally occurring fats and oils. Fatty acids are predominantly straight-chain acids of 4 to 24 carbon atoms, which may be saturated or unsaturated; branched fatty acids and hydroxy fatty acids also occur, and very long chain acids of over 30 carbons are found in waxes.
GO:0072329 monocarboxylic acid catabolic process | 15/49 (30.6%) | Pck1; Hsd17b10; Hao2; Gcdh; Ehhadh; Eci2; Eci1; Decr1; Cryl1; Cpt2; Acox1; Acadm; Acaa2; Acaa1b; Acaa1a | 169.1 (112.1–177.2) | The chemical reactions and pathways resulting in the breakdown of monocarboxylic acids, any organic acid containing one carboxyl (-COOH) group.
GO:0098869 cellular oxidant detoxification | 8/43 (18.6%) | Srxn1; Sod3; Nqo1; Gstp1; Gstm2; Gsta2; Gpx3; Cat | 171.4 (84.7–903.1) | Any process carried out at the cellular level that reduces or removes the toxicity superoxide radicals or hydrogen peroxide.
Mice
GO:0015850 organic hydroxy compound transport | 6/58 (10.3%) | Apoc3; Ldlr; Ceacam2; Abcc3; Tsku; Slc51a | 2.3 (0.6–219.7) | The directed movement of an organic hydroxy compound (organic alcohol) into, out of or within a cell, or between cells, by means of some agent such as a transporter or pore. An organic hydroxy compound is an organic compound having at least one hydroxy group attached to a carbon atom.
GO:0033559 unsaturated fatty acid metabolic process | 7/40 (17.5%) | Cyp2a5; Cd74; Cyp4a10; Gstp2; Ces2e; Ces2b; Cyp4a14 | 2.6 (1.2–54.7) | The chemical reactions and pathways involving an unsaturated fatty acid, any fatty acid containing one or more double bonds between carbon atoms.
GO:0055088 lipid homeostasis | 5/52 (9.6%) | Lpl; Insig1; Apoc3; Ldlr; Tsku | 2.7 (0.8–13.0) | Any process involved in the maintenance of an internal steady state of lipid within an organism or cell.
GO:0006869 lipid transport | 11/77 (14.3%) | Ppard; Apoc3; Ldlr; Ceacam2; Abcc3; Ace; Fabp7; Tsku; Slc22a7; Fabp1; Slc51a | 3.0 (0.8–9.9) | The directed movement of lipids into, out of or within a cell, or between cells, by means of some agent such as a transporter or pore. Lipids are compounds soluble in an organic solvent but not, or sparingly, in an aqueous solvent.
GO:0044242 cellular lipid catabolic process | 7/44 (15.9%) | Lpl; Ppard; Acadm; Apoc3; Acat2; Eci1; Hao2 | 3.0 (0.8–401.3) | The chemical reactions and pathways resulting in the breakdown of lipids, as carried out by individual cells.
GO:1905952 regulation of lipid localization | 4/52 (7.7%) | Lpl; Ppard; Igfbp3; Apoc3 | 3.0 (0.8–401.3) | Any process that modulates the frequency, rate or extent of lipid localization.
GO:0015718 monocarboxylic acid transport | 8/52 (15.4%) | Ppard; Ceacam2; Abcc3; Ace; Fabp7; Slc22a7; Fabp1; Slc51a | 3.0 (0.9–401.3) | The directed movement of monocarboxylic acids into, out of or within a cell, or between cells, by means of some agent such as a transporter or pore.
GO:0031589 cell-substrate adhesion | 3/40 (7.5%) | Ppard; Lamb1; Itga6 | 3.1 (0.9–792.8) | The attachment of a cell to the underlying substrate via adhesion molecules.
GO:0031669 cellular response to nutrient levels | 5/62 (8.1%) | Lpl; Ppard; Cdkn1a; Bmf; Glul | 3.3 (1.0–408.4) | Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a stimulus reflecting the presence, absence, or concentration of nutrients.
GO:0090277 positive regulation of peptide hormone secretion | 3/40 (7.5%) | Apln; Ppard; Glul | 3.5 (1.2–24.1) | Any process that increases the rate, frequency, or extent of the regulated release of a peptide hormone from secretory granules.

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology; NC = nonconvergent.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^35^ Official gene symbols from the Rat Genome Database^36^ are shown in the “Active Genes” column.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

GO process descriptions and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-3 Active Genes and Definitions within Top 10 Liver Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | Active Genes | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Definition
Rats
GO:0006805 xenobiotic metabolic process | 31/59 (52.5%) | Ugt2b1; Ugt1a3; Ugt1a2; Ugt1a6; Ugt1a1; Ugt1a9; Sult1c3; Sult1b1; Gstp1; Gstm7; Gstm2; Gsta4; Gsta1; Gsta3; Gsta2; Gsta5; Fmo3; Cyp3a2; Cyp2j4; Cyp2e1; Cyp2d5; Cyp2d3; Cyp2d1; Cyp2b3; Cyp2b1; Cyp1a2; Cbr1; Acaa1b; Acaa1a; Abcc2; Abcb11 | 29.8 (25.3–89.7) | The chemical reactions and pathways involving a xenobiotic compound, a compound foreign to living organisms. Used of chemical compounds, e.g., a xenobiotic chemical, such as a pesticide.
GO:0098754 detoxification | 30/58 (51.7%) | Txnrd1; Srxn1; Sod3; Sod2; Ptgs1; Prdx3; Prdx2; Prdx1; Nqo1; Nfe2l2; Mt2a; Mt2-ps1; Mt1; Hp; Gstp1; Gstm7; Gstm2; Gsta3; Gsta2; Gsr; Gpx7; Gpx4; Gpx1; Fabp1; Cp; Apom; Ambp; Aldh1a1; Akr7a3; Abcc2 | 33.8 (18.2–99.6) | Any process that reduces or removes the toxicity of a toxic substance. These may include transport of the toxic substance away from sensitive areas and to compartments or complexes whose purpose is sequestration of the toxic substance.
GO:1990748 cellular detoxification | 23/51 (45.1%) | Txnrd1; Srxn1; Sod3; Sod2; Ptgs1; Prdx3; Prdx2; Prdx1; Nqo1; Hp; Gstp1; Gstm7; Gstm2; Gsta2; Gsr; Gpx7; Gpx4; Gpx1; Fabp1; Cp; Apom; Ambp; Aldh1a1 | 33.8 (18.2–99.6) | Any process carried out at the cellular level that reduces or removes the toxicity of a toxic substance. These may include transport of the toxic substance away from sensitive areas and to compartments or complexes whose purpose is sequestration of the toxic substance.
GO:0048872 homeostasis of number of cells | 20/58 (34.5%) | Tuba1a; Slc40a1; Slc37a4; Rpa1; Ripk3; Rac1; Prdx2; Prdx1; Ppp2r3c; Polb; Map7; Ppp2ca; Ikbkb; Hmox1; Hif1a; Ccnb2; Casp3; Bax; Bak1; Abl1 | 34.9 (10.5–93.0) | Any biological process involved in the maintenance of the steady-state number of cells within a population of cells.
GO:0006690 icosanoid metabolic process | 20/50 (40.0%) | Tnfrsf1a; Ptgs1; Mif; Mgll; Gstp1; Gsta1; Gsta2; Gpx4; Gpx1; Ephx1; Cyp4f4; Cyp2j4; Cyp2e1; Cyp2d5; Cyp2d3; Cyp2d1; Cyp2b3; Cyp2b1; Cyp1a2; Acox1 | 35.9 (19.9–101.2) | The chemical reactions and pathways involving icosanoids, any of a group of C20 polyunsaturated fatty acids.
GO:0033559 unsaturated fatty acid metabolic process | 24/54 (44.4%) | Tnfrsf1a; Scd; Ptgs1; Mif; Mgll; Gstp1; Gstm7; Gstm2; Gsta1; Gsta2; Gpx4; Gpx1; Ephx1; Elovl5; Cyp4f4; Cyp2j4; Cyp2e1; Cyp2d5; Cyp2d3; Cyp2d1; Cyp2b3; Cyp2b1; Cyp1a2; Acox1 | 35.9 (19.9–101.2) | The chemical reactions and pathways involving an unsaturated fatty acid, any fatty acid containing one or more double bonds between carbon atoms.
GO:1901136 carbohydrate derivative catabolic process | 16/49 (32.7%) | Vnn1; Pklr; Pgam1; Nudt9; Hprt1; Hmmr; Gapdh; Fuca1; Eno3; Dpys; Ces1f; Cd44; Amdhd2; Aldoa; Aldh1a1; Acot2 | 36.3 (9.5–438.0) | The chemical reactions and pathways resulting in the breakdown of carbohydrate derivative.
GO:0120254 olefinic compound metabolic process | 28/64 (43.8%) | Srd5a1; Rbp1; Ptgs1; Pnpla2; Mgll; Inhba; Gstp1; Gstm7; Gstm2; Gsta1; Gpx4; Gpx1; Ephx1; Dhrs7; Cyp4f4; Cyp3a2; Cyp2j4; Cyp2e1; Cyp2d5; Cyp2d3; Cyp2d1; Cyp2b3; Cyp2b1; Cyp1a2; Cyp17a1; Ces1f; Ces1d; Aldh1a1 | 37.4 (9.5–455.2) | The chemical reactions and pathways involving an olefinic compound, any compound which contains a carbon-carbon double bond (aka C=C).
GO:0044770 cell cycle phase transition | 26/58 (44.8%) | Usp22; Rps6; Rb1; Pole; Mnat1; Itgb1; Hspa8; Gadd45a; Eif4ebp1; Eif4e; E2f1; Cks2; Chek2; Cdk6; Cdk4; Cdc25a; Cdc20; Ccng1; Ccnf; Ccnd1; Ccnb2; Ccnb2-ps2; Ccna2; Birc5; App; Akap8 | 38.7 (14.3–79.1) | The cell cycle process by which a cell commits to entering the next cell cycle phase.
GO:0098869 cellular oxidant detoxification | 22/43 (51.2%) | Txnrd1; Srxn1; Sod3; Sod2; Ptgs1; Prdx3; Prdx2; Prdx1; Nqo1; Hp; Gstp1; Gstm7; Gstm2; Gsta2; Gsr; Gpx7; Gpx4; Gpx1; Fabp1; Cp; Apom; Ambp | 40.1 (11.7–95.6) | Any process carried out at the cellular level that reduces or removes the toxicity superoxide radicals or hydrogen peroxide.
Mice
GO:0046889 positive regulation of lipid biosynthetic process | 15/45 (33.3%) | Apoe; Fgf1; Cd74; Elovl5; Igf1; Cyp7a1; Mapk9; Ppara; Il1b; Lpgat1; Por; Scp2; Abcd1; Apoa5; Abcg1 | 1.5 (0.5–5.5) | Any process that activates or increases the frequency, rate or extent of the chemical reactions and pathways resulting in the formation of lipids.
GO:0045834 positive regulation of lipid metabolic process | 21/61 (34.4%) | Gdf15; Apoe; Fgf1; Cd74; Elovl5; Igf1; Cyp7a1; Mapk9; Ppara; Ces1g; Il1b; Lpgat1; Por; Scp2; Nucb2; Mup1; Abcd1; Fabp1; Apoa5; Fgf21; Abcg1 | 2.1 (0.7–5.0) | Any process that activates or increases the frequency, rate or extent of the chemical reactions and pathways involving lipids.
GO:0002708 positive regulation of lymphocyte mediated immunity | 6/40 (15.0%) | Rsad2; Stat5b; Il1b; C3; H2-t23; Lamp1 | 2.2 (0.6–6.3) | Any process that activates or increases the frequency, rate, or extent of lymphocyte mediated immunity.
GO:0006805 xenobiotic metabolic process | 25/56 (44.6%) | Cyp2c38; Cyp2c39; Fmo5; Gsta2; Cyp2j5; Cyp2c29; Cyp2d9; Cbr1; Cyp3a41b; Cyp2b10; Gstp2; Gsta3; Cyp3a41a; Cyp2a4; Cyp2c54; Gstm5; Gsta1; Abcc2; Cyp2c55; Cyp3a44; Cyp2e1; Cyp1a2; Ugt1a6a; Ugt1a6b; Gstm2 | 2.2 (0.3–88.7) | The chemical reactions and pathways involving a xenobiotic compound, a compound foreign to living organisms. Used of chemical compounds, e.g., a xenobiotic chemical, such as a pesticide.
GO:0048511 rhythmic process | 25/89 (28.1%) | Foxo3; Inhba; Ezh2; Afp; Src; Prkaa1; Dbp; Cdk1; Nfil3; Sgpl1; Igf1; Timeless; Gfpt1; Top2a; Suv39h1; Hlf; Mapk9; Ppara; Stat5b; Dnm1l; Mtnr1a; Egfr; Atf5; Mup1; Dtl | 2.9 (0.9–13.7) | Any process pertinent to the generation and maintenance of rhythms in the physiology of an organism.
GO:0097191 extrinsic apoptotic signaling pathway | 15/56 (26.8%) | Foxo3; Hmgb2; Inhba; Mcl1; Igf1; Cttn; Krt8; Bex3; Lcn2; Parp2; Il1b; Tlr3; Bax; Prdx2; Krt18 | 2.9 (0.9–13.7) | A series of molecular signals in which a signal is conveyed from the cell surface to trigger the apoptotic death of a cell. The pathway starts with either a ligand binding to a cell surface receptor, or a ligand being withdrawn from a cell surface receptor (e.g., in the case of signaling by dependence receptors), and ends when the execution phase of apoptosis is triggered.
GO:0019218 regulation of steroid metabolic process | 17/46 (37.0%) | Fmo5; Apoe; Fgf1; Insig1; Igf1; Pank2; Ephx2; Stub1; Dhcr7; Fgfr4; Cyp7a1; Stat5b; Ces1g; Por; Scp2; Asah1; Abcg1 | 3.5 (0.9–4,078.8) | Any process that modulates the frequency, rate or extent of the chemical reactions and pathways involving steroids.
GO:0002705 positive regulation of leukocyte mediated immunity | 7/47 (14.9%) | Rsad2; Tyrobp; Stat5b; Il1b; C3; H2-t23; Lamp1 | 3.7 (0.9–4,079.6) | Any process that activates or increases the frequency, rate, or extent of leukocyte mediated immunity.
GO:0002706 regulation of lymphocyte mediated immunity | 8/59 (13.6%) | Nckap1l; Rsad2; Stat5b; Il1b; C3; H2-t23; Ccr2; Lamp1 | 3.7 (0.9–4,079.6) | Any process that modulates the frequency, rate, or extent of lymphocyte mediated immunity.
GO:0120254 olefinic compound metabolic process | 26/51 (51%) | Cyp2c38; Cyp2c39; Inhba; Afp; Gpx4; Cyp2j5; Adh1; Cyp2c29; Cyp2d9; Rdh7; Ephx2; Cyp2b10; Gstp2; Stat5b; Cyp2a4; Cyp2c54; Aldh1a1; Cyp2c55; Scp2; Ephx1; Cyp4a31; Hsd17b6; Cyp2e1; Cyp1a2; Srd5a1; Lrat | 3.7 (0.8–4,080.3) | The chemical reactions and pathways involving an olefinic compound, any compound which contains a carbon-carbon double bond (aka C=C).

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^35^ Official gene symbols from the Rat Genome Database^36^ are shown in the “Active Genes” column.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

GO process descriptions and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-4 Active Genes and Definitions within Top 10 Lung Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | Active Genes | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Definition
Rats
GO:0098754 detoxification | 11/58 (19.0%) | Txnrd1; Srxn1; Selenow; Prdx1; Nqo1; Hbb-bs; Hbbl1; Hbb; Gstp1; Gsta3; Gpx4 | 175.9 (109.3–224.0) | Any process that reduces or removes the toxicity of a toxic substance. These may include transport of the toxic substance away from sensitive areas and to compartments or complexes whose purpose is sequestration of the toxic substance.
GO:0098869 cellular oxidant detoxification | 10/43 (23.3%) | Txnrd1; Srxn1; Selenow; Prdx1; Nqo1; Hbb-bs; Hbbl1; Hbb; Gstp1; Gpx4 | 175.9 (109.3–224.0) | Any process carried out at the cellular level that reduces or removes the toxicity superoxide radicals or hydrogen peroxide.
GO:1990748 cellular detoxification | 10/51 (19.6%) | Txnrd1; Srxn1; Selenow; Prdx1; Nqo1; Hbb-bs; Hbbl1; Hbb; Gstp1; Gpx4 | 175.9 (109.3–224.0) | Any process carried out at the cellular level that reduces or removes the toxicity of a toxic substance. These may include transport of the toxic substance away from sensitive areas and to compartments or complexes whose purpose is sequestration of the toxic substance.
GO:0019362 pyridine nucleotide metabolic process | 5/40 (12.5%) | Txnrd1; Nqo1; Me1; Aldoc; Aldoa | 181.2 (46.6–348.4) | The chemical reactions and pathways involving a pyridine nucleotide, a nucleotide characterized by a pyridine derivative as a nitrogen base.
GO:0046496 nicotinamide nucleotide metabolic process | 5/40 (12.5%) | Txnrd1; Nqo1; Me1; Aldoc; Aldoa | 181.2 (46.6–348.4) | The chemical reactions and pathways involving nicotinamide nucleotides, any nucleotide that contains combined nicotinamide.
GO:0072524 pyridine-containing compound metabolic process | 5/41 (12.2%) | Txnrd1; Nqo1; Me1; Aldoc; Aldoa | 181.2 (37.4–352.1) | The chemical reactions and pathways involving a pyridine-containing compound, i.e., any compound that contains pyridine or a formal derivative thereof.
GO:0001676 long-chain fatty acid metabolic process | 5/55 (9.1%) | Gstp1; Gsta1; Gpx4; Cyp2e1; Cd36 | 193.6 (60.7–298.8) | The chemical reactions and pathways involving long-chain fatty acids, A long-chain fatty acid is a fatty acid with a chain length between C13 and C22.
GO:0006690 icosanoid metabolic process | 5/50 (10.0%) | Mif; Gstp1; Gsta1; Gpx4; Cyp2e1 | 193.6 (60.7–298.8) | The chemical reactions and pathways involving icosanoids, any of a group of C20 polyunsaturated fatty acids.
GO:0006805 xenobiotic metabolic process | 6/59 (10.2%) | Gstp1; Gsta4; Gsta1; Gsta3; Cyp2e1; Cbr1 | 193.6 (60.7–298.8) | The chemical reactions and pathways involving a xenobiotic compound, a compound foreign to living organisms. Used of chemical compounds, e.g., a xenobiotic chemical, such as a pesticide.
GO:0033559 unsaturated fatty acid metabolic process | 5/54 (9.3%) | Mif; Gstp1; Gsta1; Gpx4; Cyp2e1 | 193.6 (60.7–298.8) | The chemical reactions and pathways involving an unsaturated fatty acid, any fatty acid containing one or more double bonds between carbon atoms.
Mice
GO:0033559 unsaturated fatty acid metabolic process | 8/40 (20.0%) | Cyp2a5; Gpx4; Mif; Gstp2; Acox1; Ptgs2; Cyp2a4; Ephx1 | 2.1 (0.7–4.8) | The chemical reactions and pathways involving an unsaturated fatty acid, any fatty acid containing one or more double bonds between carbon atoms.
GO:0008203 cholesterol metabolic process | 8/48 (16.7%) | Prkaa1; Sqle; G6pdx; Prkaa2; Ces1g; Il4; Tsku; Cat | 2.4 (0.7–5.8) | The chemical reactions and pathways involving cholesterol, cholest-5-en-3 beta-ol, the principal sterol of vertebrates and the precursor of many steroids, including bile acids and steroid hormones. It is a component of the plasma membrane lipid bilayer and of plasma lipoproteins and can be found in all animal tissues.
GO:0016125 sterol metabolic process | 8/49 (16.3%) | Prkaa1; Sqle; G6pdx; Prkaa2; Ces1g; Il4; Tsku; Cat | 2.4 (0.7–5.8) | The chemical reactions and pathways involving sterols, steroids with one or more hydroxyl groups and a hydrocarbon side-chain in the molecule.
GO:1902652 secondary alcohol metabolic process | 10/53 (18.9%) | Idh3g; Prkaa1; Sqle; G6pdx; Prkaa2; Ces1g; Il4; Idh3a; Tsku; Cat | 2.4 (0.7–5.8) | The chemical reactions and pathways involving secondary alcohol.
GO:0002708 positive regulation of lymphocyte mediated immunity | 4/40 (10.0%) | Rsad2; Pnp; Il4; Il6 | 2.8 (0.9–843.5) | Any process that activates or increases the frequency, rate, or extent of lymphocyte mediated immunity.
GO:0120254 olefinic compound metabolic process | 11/51 (21.6%) | Cyp2a5; Afp; Gpx4; Adh1; Gstp2; Ptgs2; Cyp2a4; Aldh1a1; Scp2; Ephx1; Lrat | 3.5 (0.7–53.9) | No description available.
GO:0006690 icosanoid metabolic process | 8/43 (18.6%) | Cyp2a5; Gpx4; Mif; Gstp2; Acox1; Ptgs2; Cyp2a4; Ephx1 | 3.7 (0.9–11.6) | The chemical reactions and pathways involving icosanoids, any of a group of C20 polyunsaturated fatty acids.
GO:0006805 xenobiotic metabolic process | 14/56 (25.0%) | Cyp2a5; Gsta2; Fmo3; Cbr1; Gstp2; Gsta3; Ugt1a1; Cyp2a4; Gsta1; Cryz; Acaa1a; Ugt1a6a; Ugt1a6b; Gstm2 | 3.8 (1.0–10.4) | The chemical reactions and pathways involving a xenobiotic compound, a compound foreign to living organisms. Used of chemical compounds, e.g., a xenobiotic chemical, such as a pesticide.
GO:0006066 alcohol metabolic process | 22/90 (24.4%) | Idh3g; Prkaa1; Adh1; Sqle; G6pdx; Prkaa2; Pck2; Tpi1; Abhd4; Pcbd1; Ces1g; Il4; Dpm2; Adh5; Aldh1a1; Idh3a; Aldh3a2; Scp2; Tsku; Ephx1; Cat; Lrat | 5.0 (0.9–60.7) | The chemical reactions and pathways involving alcohols, any of a class of compounds containing one or more hydroxyl groups attached to a saturated carbon atom.
GO:0015850 organic hydroxy compound transport | 7/58 (12.1%) | Slc16a3; Ces1g; Abcc4; Scp2; Tsku; Ceacam1; Slc16a7 | 5.1 (1.3–26.0) | The directed movement of an organic hydroxy compound (organic alcohol) into, out of or within a cell, or between cells, by means of some agent such as a transporter or pore. An organic hydroxy compound is an organic compound having at least one hydroxy group attached to a carbon atom.

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^35^ Official gene symbols from the Rat Genome Database^36^ are shown in the “Active Genes” column.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

GO process descriptions and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-5 Active Genes and Definitions within Top 10 Ovary Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by 5th Percentile Benchmark Dose, for Female Rats and Mice Exposed to 1,2-Dichlorobenzene for Five Days

Category Name^a^ | Input Genes/Platform Genes in Gene Set (% Coverage) | Active Genes | BMD_rd25_ 5th Percentile of Gene Set Transcripts (BMD_Lrd25_–BMD_Urd25_) (ppm)^b^ | Definition
Rats
GO:0001822 kidney development | 4/57 (7.0%) | Ace; Ret; Lef1; Gata3 | 156.7 (50.8–280.4) | The process whose specific outcome is the progression of the kidney over time, from its formation to the mature structure. The kidney is an organ that filters the blood and/or excretes the end products of body metabolism in the form of urine.
GO:0008406 gonad development | 3/51 (5.9%) | Ace; Hmgcs1; Gata3 | 156.7 (50.8–280.4) | The process whose specific outcome is the progression of the gonad over time, from its formation to the mature structure. The gonad is an animal organ that produces gametes; in some species it also produces hormones.
GO:0008584 male gonad development | 3/46 (6.5%) | Ace; Hmgcs1; Gata3 | 156.7 (50.8–280.4) | The process whose specific outcome is the progression of the male gonad over time, from its formation to the mature structure.
GO:0045582 positive regulation of T cell differentiation | 3/40 (7.5%) | Tgfbr2; Lef1; Gata3 | 160.7 (51.6–289.6) | Any process that activates or increases the frequency, rate or extent of T cell differentiation.
GO:0016055 Wnt signaling pathway | 4/41 (9.8%) | Prkaa2; Fzd7; Lef1; Gata3 | 162.6 (54.1–417.6) | The series of molecular signals initiated by binding of a Wnt protein to a frizzled family receptor on the surface of the target cell and ending with a change in cell state.
GO:0030217 T cell differentiation | 3/48 (6.3%) | Fzd7; Lef1; Gata3 | 162.6 (54.1–417.6) | The process in which a precursor cell type acquires characteristics of a more mature T-cell. A T cell is a type of lymphocyte whose defining characteristic is the expression of a T cell receptor complex.
GO:0030856 regulation of epithelial cell differentiation | 3/53 (5.7%) | Lef1; Gata3; Dmbt1 | 163.7 (49.2–293.8) | Any process that modulates the frequency, rate or extent of epithelial cell differentiation.
GO:0006694 steroid biosynthetic process | 3/54 (5.6%) | Prkaa2; Idi1; Hmgcs1 | 175.7 (70.6–293.3) | The chemical reactions and pathways resulting in the formation of steroids, compounds with a 1,2,cyclopentanoperhydrophenanthrene nucleus; includes de novo formation and steroid interconversion by modification.
GO:0008203 cholesterol metabolic process | 3/54 (5.6%) | Prkaa2; Idi1; Hmgcs1 | 175.7 (70.6–293.3) | The chemical reactions and pathways involving cholesterol, cholest-5-en-3 beta-ol, the principal sterol of vertebrates and the precursor of many steroids, including bile acids and steroid hormones. It is a component of the plasma membrane lipid bilayer and of plasma lipoproteins and can be found in all animal tissues.
GO:0016125 sterol metabolic process | 3/56 (5.4%) | Prkaa2; Idi1; Hmgcs1 | 175.7 (70.6–293.3) | The chemical reactions and pathways involving sterols, steroids with one or more hydroxyl groups and a hydrocarbon side-chain in the molecule.
Mice
GO:0030097 hemopoiesis | 3/56 (5.4%) | Tacc3; Hba-a2; Cdk6 | 108.0 (35.9–NC) | The process whose specific outcome is the progression of the myeloid and lymphoid derived organ/tissue systems of the blood and other parts of the body over time, from formation to the mature structure. The site of hemopoiesis is variable during development, but occurs primarily in bone marrow or kidney in many adult vertebrates.
GO:0072594 establishment of protein localization to organelle | 5/77 (6.5%) | Mmp12; Sqstm1; Dnajc15; Cd68; Timm9 | 110.3 (57.1–152.8) | The directed movement of a protein to a specific location on or in an organelle. Encompasses establishment of localization in the membrane or lumen of a membrane-bounded organelle.
GO:0048167 regulation of synaptic plasticity | 4/75 (5.3%) | Apoe; Grin2c; Sqstm1; Syn1 | 119.5 (80.8–248.7) | A process that modulates synaptic plasticity, the ability of synapses to change as circumstances require. They may alter function, such as increasing or decreasing their sensitivity, or they may increase or decrease in actual numbers.
GO:0050777 negative regulation of immune response | 3/53 (5.7%) | Nckap1l; Mmp12; Lilrb4b | 125.7 (60.1–425.4) | Any process that stops, prevents, or reduces the frequency, rate or extent of the immune response, the immunological reaction of an organism to an immunogenic stimulus.
GO:0006898 receptor-mediated endocytosis | 3/48 (6.3%) | Apoe; Hmmr; Lilrb4b | 136.8 (83.0–271.7) | An endocytosis process in which cell surface receptors ensure specificity of transport. A specific receptor on the cell surface binds tightly to the extracellular macromolecule (the ligand) that it recognizes; the plasma-membrane region containing the receptor-ligand complex then undergoes endocytosis, forming a transport vesicle containing the receptor-ligand complex and excluding most other plasma-membrane proteins. Receptor-mediated endocytosis generally occurs via clathrin-coated pits and vesicles.
GO:0043409 negative regulation of MAPK cascade | 3/47 (6.4%) | Apoe; Lilrb4b; Rgs2 | 136.8 (83.0–271.7) | Any process that stops, prevents, or reduces the frequency, rate or extent of signal transduction mediated by the MAPKKK cascade.
GO:0045580 regulation of T cell differentiation | 3/60 (5.0%) | Nckap1l; Ctla2a; Lilrb4b | 149.2 (81.9–684.2) | Any process that modulates the frequency, rate or extent of T cell differentiation.
GO:0002761 regulation of myeloid leukocyte differentiation | 3/50 (6.0%) | Fbn1; Lilrb4b; Cdk6 | 153.6 (37.5–NC) | Any process that modulates the frequency, rate, or extent of myeloid leukocyte differentiation.
GO:0016050 vesicle organization | 3/54 (5.6%) | Apoe; Sqstm1; Trappc6a | 155.0 (87.7–288.7) | A process that is carried out at the cellular level which results in the assembly, arrangement of constituent parts, or disassembly of a vesicle.
GO:0051235 maintenance of location | 3/46 (6.5%) | Apoe; Fbn1; Tacc3 | 155.5 (74.0–NC) | Any process in which a cell, substance or cellular entity, such as a protein complex or organelle, is maintained in a location and prevented from moving elsewhere.

BMD_rd25_ = benchmark dose corresponding to a benchmark response set to a 25% change in the median response; BMD_Lrd25_ = benchmark dose lower confidence limit corresponding to a benchmark response set to a 25% change in the median response; BMD_Urd25_ = benchmark dose upper confidence limit corresponding to a benchmark response set to a 25% change in the median response; GO = Gene Ontology; NC = nonconvergent.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^35^ Official gene symbols from the Rat Genome Database^36^ are shown in the “Active Genes” column.

^b^ 5th percentile = the value below which 5% of transcript benchmark dose values fall.

GO process descriptions and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-6 Gene Identifiers and Definitions for Female Rats Exposed to 1,2-Dichlorobenzene for Five Days^a^

Gene Symbol | Entrez Gene IDs | Probe IDs^b^ | Definition
Ace | 24310 | Ace_34123 | Human Uniprot function (Human ACE): Converts angiotensin I to angiotensin II by release of the terminal His-Leu, this results in an increase of the vasoconstrictor activity of angiotensin. Also able to inactivate bradykinin, a potent vasodilator. Has also a glycosidase activity which releases GPI-anchored proteins from the membrane by cleaving the mannose linkage in the GPI moiety.
Acot12 | 170570 | ACOT12_32718 | Human Uniprot function (Human ACOT12): Acyl-CoA thioesterases are a group of enzymes that catalyze the hydrolysis of acyl-CoAs to the free fatty acid and coenzyme A (CoASH), providing the potential to regulate intracellular levels of acyl-CoAs, free fatty acids and CoASH (PubMed:16951743). Acyl-coenzyme A thioesterase 12/ACOT12 preferentially hydrolyzes acetyl-CoA (PubMed:16951743).\{ECO:0000269\|PubMed:16951743, ECO:0000303\|PubMed:16951743\}.
Ak2 | 24184 | RGD1562178_32879 | Human Uniprot function (Human AK2): Catalyzes the reversible transfer of the terminal phosphate group between ATP and AMP. Plays an important role in cellular energy homeostasis and in adenine nucleotide metabolism. Adenylate kinase activity is critical for regulation of the phosphate utilization and the AMP de novo biosynthesis pathways. Plays a key role in hematopoiesis.\{ECO:0000255\|HAMAP-Rule:MF\_03168, ECO:0000269\|PubMed:19043416\}.
Akr1b8/Akr1b15 | 286921 | AKR1B8_8013 | Human Uniprot function (Human AKR1B10): Catalyzes the NADPH-dependent reduction of a wide variety of carbonyl-containing compounds to their corresponding alcohols (PubMed:9565553, PubMed:18087047, PubMed:12732097, PubMed:19013440, PubMed:19563777). Displays strong enzymatic activity toward all-trans-retinal, 9-cis-retinal, and 13-cis-retinal (PubMed:12732097, PubMed:18087047). Plays a critical role in detoxifying dietary and lipid-derived unsaturated carbonyls, such as crotonaldehyde, 4-hydroxynonenal, trans-2-hexenal, trans-2,4-hexadienal and their glutathione- conjugates carbonyls (GS-carbonyls) (PubMed:19013440, PubMed:19563777). Displays no reductase activity toward glucose (PubMed:12732097). \{ECO:0000269\|PubMed:12732097, ECO:0000269\|PubMed:18087047, ECO:0000269\|PubMed:19013440, ECO:0000269\|PubMed:19563777, ECO:0000269\|PubMed:9565553\}.
Aldh1a1 | 24188 | ALDH1A1_8022 | Human Uniprot function (Human ALDH1A1): Can convert/oxidize retinaldehyde to retinoic acid. Binds free retinal and cellular retinol-binding protein-bound retinal (By similarity). May have a broader specificity and oxidize other aldehydes in vivo (PubMed:19296407, PubMed:26373694, PubMed:25450233). \{ECO:0000250\|UniProtKB:P51647, ECO:0000269\|PubMed:19296407, ECO:0000269\|PubMed:25450233, ECO:0000269\|PubMed:26373694\}.
Aldoc | 24191 | ALDOC_8034 | Human Entrez Gene Summary (Human ALDOC): This gene encodes a member of the class I fructose-biphosphate aldolase gene family. Expressed specifically in the hippocampus and Purkinje cells of the brain, the encoded protein is a glycolytic enzyme that catalyzes the reversible aldol cleavage of fructose-1,6-biphosphate and fructose 1-phosphate to dihydroxyacetone phosphate and either glyceraldehyde-3-phosphate or glyceraldehyde, respectively. [provided by RefSeq, Jul 2008]
Apln | 58812 | APLN_33320 | Human Uniprot function (Human APLN): Endogenous ligand for the apelin receptor (APLNR) (PubMed:10525157). Drives internalization of the apelin receptor (By similarity). Apelin-36 dissociates more hardly than (pyroglu)apelin-13 from APLNR (By similarity). Hormone involved in the regulation of cardiac precursor cell movements during gastrulation and heart morphogenesis (By similarity). Has an inhibitory effect on cytokine production in response to T-cell receptor/CD3 cross-linking; the oral intake of apelin in the colostrum and the milk might therefore modulate immune responses in neonates (By similarity). Plays a role in early coronary blood vessels formation (By similarity). Mediates myocardial contractility in an ERK1/2-dependent manner (By similarity). May also have a role in the central control of body fluid homeostasis by influencing vasopressin release and drinking behavior (By similarity). \{ECO:0000250\|UniProtKB:Q4TTN8, ECO:0000250\|UniProtKB:Q9R0R3, ECO:0000250\|UniProtKB:Q9R0R4, ECO:0000269\|PubMed:10525157\}.; FUNCTION: (Microbial infection) Endogenous ligand for the apelin receptor (APLNR), an alternative coreceptor with CD4 for HIV-1 infection (PubMed:11090199). Inhibits HIV-1 entry in cells coexpressing CD4 and APLNR (PubMed:11090199). Apelin-36 has a greater inhibitory activity on HIV infection than other synthetic apelin derivatives (PubMed:11090199). \{ECO:0000269\|PubMed:11090199\}.
Atf4 | 79255 | ATF4_8096 | Human Uniprot function (Human ATF4): Transcription factor that binds the cAMP response element (CRE) (consensus: 5'-GTGACGT[AC][AG]-3') and acts both as a regulator of normal metabolic and redox processes, and as a master transcription factor during the integrated stress response (ISR) (PubMed:1847461, PubMed:16682973, PubMed:31444471, PubMed:32132707). Binds to asymmetric CRE's as a heterodimer and to palindromic CRE's as a homodimer (By similarity). Core effector of the ISR, which is required for adaptation to various stress, such as endoplasmic reticulum (ER) stress, amino acid starvation, mitochondrial stress or oxidative stress (PubMed:32132707). During the ISR, ATF4 protein is translated in response to eIF-2-alpha/EIF2S1 phosphorylation caused by stress, and acts as a master transcription factor of stress-responsive genes in order to promote cell recovery (PubMed:32132707). Protects cells against metabolic consequences of ER oxidation by promoting expression of genes linked to amino acid sufficiency and resistance to oxidative stress (By similarity). Regulates the induction of DDIT3/CHOP and asparagine synthetase (ASNS) in response to amino acid deprivation or endoplasmic reticulum (ER) stress (PubMed:11960987). Together with DDIT3/CHOP, mediates ER-mediated cell death by promoting expression of genes involved in cellular amino acid metabolic processes, mRNA translation and the unfolded protein response (UPR) in response to ER stress (By similarity). ATF4 and DDIT3/CHOP activate the transcription of TRIB3 and promote ER stress-induced neuronal cell-death by regulating the expression of BBC3/PUMA (PubMed:15775988, PubMed:18940792). During ER stress response, activates the transcription of NLRP1, possibly in concert with other factors (PubMed:26086088). Activates expression of genes required to promote cell recovery in response to mitochondrial stress (PubMed:32132706, PubMed:32132707). Independently of the ISR, also required for normal metabolic processes: plays a key role in embryonic lens formation, fetal liver hematopoiesis, bone development and synaptic plasticity (By similarity). Acts as a regulator of osteoblast differentiation in response to phosphorylation by RPS6KA3/RSK2: phosphorylation in osteoblasts enhances transactivation activity and promotes expression of osteoblast-specific genes and post-transcriptionally regulates the synthesis of Type I collagen, the main constituent of the bone matrix (PubMed:15109498). Cooperates with FOXO1 in osteoblasts to regulate glucose homeostasis through suppression of beta-cell production and decrease in insulin production (By
Atf4 | 79255 | ATF4_8096 | similarity). Activates transcription of SIRT4 (By similarity). Regulates the circadian expression of the core clock component PER2 and the serotonin transporter SLC6A4 (By similarity). Binds in a circadian time-dependent manner to the cAMP response elements (CRE) in the SLC6A4 and PER2 promoters and periodically activates the transcription of these genes (By similarity). Mainly acts as a transcriptional activator in cellular stress adaptation, but it can also act as a transcriptional repressor: acts as a regulator of synaptic plasticity by repressing transcription, thereby inhibiting induction and maintenance of long-term memory (By similarity). Regulates synaptic functions via interaction with DISC1 in neurons, which inhibits ATF4 transcription factor activity by disrupting ATF4 dimerization and DNA-binding (PubMed:31444471). {ECO:0000250\|UniProtKB:Q06507, ECO:0000269\|PubMed:11960987, ECO:0000269\|PubMed:15109498, ECO:0000269\|PubMed:15775988, ECO:0000269\|PubMed:16682973, ECO:0000269\|PubMed:1847461, ECO:0000269\|PubMed:18940792, ECO:0000269\|PubMed:26086088, ECO:0000269\|PubMed:31444471, ECO:0000269\|PubMed:32132706, ECO:0000269\|PubMed:32132707}.; FUNCTION: (Microbial infection) Binds to a Tax-responsive enhancer element in the long terminal repeat of HTLV-I. {ECO:0000269\|PubMed:1847461}.
Ccnb2 | 363088 | CCNB2_8223 | Human Uniprot function (Human CCNB2): Essential for the control of the cell cycle at the G2/M (mitosis) transition.
Ccnb2-ps2 | 100364016 | CCNB2_8223 | No description available.
Ces1f | 100125372 | CESL1_32986 | Human Uniprot function (Human CES1): Involved in the detoxification of xenobiotics and in the activation of ester and amide prodrugs (PubMed:7980644, PubMed:9169443, PubMed:9490062, PubMed:18762277). Hydrolyzes aromatic and aliphatic esters, but has no catalytic activity toward amides or a fatty acyl-CoA ester (PubMed:7980644, PubMed:9169443, PubMed:9490062, PubMed:18762277). Hydrolyzes the methyl ester group of cocaine to form benzoylecgonine (PubMed:7980644). Catalyzes the transesterification of cocaine to form cocaethylene (PubMed:7980644). Displays fatty acid ethyl ester synthase activity, catalyzing the ethyl esterification of oleic acid to ethyloleate (PubMed:7980644). Converts monoacylglycerides to free fatty acids and glycerol. Hydrolyzes of 2-arachidonoylglycerol and prostaglandins (PubMed:21049984). Hydrolyzes cellular cholesteryl esters to free cholesterols and promotes reverse cholesterol transport (RCT) by facilitating both the initial and final steps in the process (PubMed:18762277, PubMed:16024911, PubMed:11015575, PubMed:16971496). First of all, allows free cholesterol efflux from macrophages to extracellular cholesterol acceptors and secondly, releases free cholesterol from lipoprotein-delivered cholesteryl esters in the liver for bile acid synthesis or direct secretion into the bile (PubMed:18762277, PubMed:18599737, PubMed:16971496). \{ECO:0000269\|PubMed:11015575, ECO:0000269\|PubMed:16024911, ECO:0000269\|PubMed:16971496, ECO:0000269\|PubMed:18599737, ECO:0000269\|PubMed:18762277, ECO:0000269\|PubMed:21049984, ECO:0000269\|PubMed:7980644, ECO:0000269\|PubMed:9169443, ECO:0000269\|PubMed:9490062\}.
Dbp | 24309 | DBP_8439 | Human Uniprot function (Human DBP): This transcriptional activator recognizes and binds to the sequence 5’-RTTAYGTAAY-3’ found in the promoter of genes such as albumin, CYP2A4 and CYP2A5. It is not essential for circadian rhythm generation, but modulates important clock output genes. May be a direct target for regulation by the circadian pacemaker component clock. May affect circadian period and sleep regulation.
Ddit4 | 140942 | DDIT4_8450 | Human Uniprot function (Human DDIT4): Regulates cell growth, proliferation and survival via inhibition of the activity of the mammalian target of rapamycin complex 1 (mTORC1). Inhibition of mTORC1 is mediated by a pathway that involves DDIT4/REDD1, AKT1, the TSC1-TSC2 complex and the GTPase RHEB. Plays an important role in responses to cellular energy levels and cellular stress, including responses to hypoxia and DNA damage. Regulates p53/TP53-mediated apoptosis in response to DNA damage via its effect on mTORC1 activity. Its role in the response to hypoxia depends on the cell type; it mediates mTORC1 inhibition in fibroblasts and thymocytes, but not in hepatocytes (By similarity). Required for mTORC1-mediated defense against viral protein synthesis and virus replication (By similarity). Inhibits neuronal differentiation and neurite outgrowth mediated by NGF via its effect on mTORC1 activity. Required for normal neuron migration during embryonic brain development. Plays a role in neuronal cell death. \{ECO:0000250, ECO:0000269\|PubMed:15545625, ECO:0000269\|PubMed:15632201, ECO:0000269\|PubMed:15988001, ECO:0000269\|PubMed:17005863, ECO:0000269\|PubMed:17379067, ECO:0000269\|PubMed:19557001, ECO:0000269\|PubMed:20166753, ECO:0000269\|PubMed:21460850\}.
Elovl5 | 171400 | ELOVL5_8556 | Human Uniprot function (Human ELOVL5): Catalyzes the first and rate-limiting reaction of the four reactions that constitute the long-chain fatty acids elongation cycle. This endoplasmic reticulum-bound enzymatic process allows the addition of 2 carbons to the chain of long- and very long-chain fatty acids (VLCFAs) per cycle. Condensing enzyme that acts specifically toward polyunsaturated acyl-CoA with the higher activity toward C18:3(n-6) acyl-CoA. May participate in the production of monounsaturated and of polyunsaturated VLCFAs of different chain lengths that are involved in multiple biological processes as precursors of membrane lipids and lipid mediators (By similarity) (PubMed:10970790, PubMed:20937905). In conditions where the essential linoleic and alpha linoleic fatty acids are lacking it is also involved in the synthesis of Mead acid from oleic acid (By similarity). \{ECO:0000250\|UniProtKB:Q8BHI7, ECO:0000255\|HAMAP-Rule:MF\_03205, ECO:0000269\|PubMed:10970790, ECO:0000269\|PubMed:20937905\}.
Ephx1 | 25315 | EPHX1_8567 | Human Uniprot function (Human EPHX1): Biotransformation enzyme that catalyzes the hydrolysis of arene and aliphatic epoxides to less reactive and more water soluble dihydrodiols by the trans addition of water (By similarity). Plays a role in the metabolism of endogenous lipids such as epoxide-containing fatty acids (PubMed:22798687). Metabolizes the abundant endocannabinoid 2-arachidonoylglycerol (2-AG) to free arachidonic acid (AA) and glycerol (PubMed:24958911). \{ECO:0000250\|UniProtKB:P07687, ECO:0000269\|PubMed:22798687, ECO:0000269\|PubMed:24958911\}.
Fetub | 83928 | FETUB_33027 | Human Uniprot function (Human FETUB): Protease inhibitor required for egg fertilization. Required to prevent premature zona pellucida hardening before fertilization, probably by inhibiting the protease activity of ASTL, a protease that mediates the cleavage of ZP2 and triggers zona pellucida hardening (By similarity). \{ECO:0000250\}.
Fgf13 | 84488 | FGF13_32529 | Human Uniprot function (Human FGF13): Microtubule-binding protein which directly binds tubulin and is involved in both polymerization and stabilization of microtubules (By similarity). Through its action on microtubules, may participate in the refinement of axons by negatively regulating axonal and leading processes branching (By similarity). Plays a crucial role in neuron polarization and migration in the cerebral cortex and the hippocampus (By similarity). May regulate voltage-gated sodium channels transport and function (PubMed:15282281). May also play a role in MAPK signaling (By similarity). Required for the
Fgf13 | 84488 | FGF13_32529 | development of axonal initial segment-targeting inhibitory GABAergic synapses made by chandelier neurons (By similarity). \{ECO:0000250\|UniProtKB:P70377, ECO:0000269\|PubMed:15282281\}.
Gria2 | 29627 | GRIA2_33071 | Human Uniprot function (Human GRIA2): Receptor for glutamate that functions as ligand-gated ion channel in the central nervous system and plays an important role in excitatory synaptic transmission. L-glutamate acts as an excitatory neurotransmitter at many synapses in the central nervous system. Binding of the excitatory neurotransmitter L-glutamate induces a conformation change, leading to the opening of the cation channel, and thereby converts the chemical signal to an electrical impulse. The receptor then desensitizes rapidly and enters a transient inactive state, characterized by the presence of bound agonist. In the presence of CACNG4 or CACNG7 or CACNG8, shows resensitization which is characterized by a delayed accumulation of current flux upon continued application of glutamate. Through complex formation with NSG1, GRIP1 and STX12 controls the intracellular fate of AMPAR and the endosomal sorting of the GRIA2 subunit toward recycling and membrane targeting (By similarity). \{ECO:0000250\|UniProtKB:P19491, ECO:0000269\|PubMed:20614889\}.
Gsta2 | 24422 | GSTA2_8756 | Human Uniprot function (Human GSTA2): Conjugation of reduced glutathione to a wide number of exogenous and endogenous hydrophobic electrophiles.
Gsta5 | 494499 | GSTA2_8756 | Human Uniprot function (Human GSTA5): Conjugation of reduced glutathione to a wide number of exogenous and endogenous hydrophobic electrophiles.
Gstp1 | 24426 | GSTP1_8762 | Human Uniprot function (Human GSTP1): Conjugation of reduced glutathione to a wide number of exogenous and endogenous hydrophobic electrophiles. Involved in the formation of glutathione conjugates of both prostaglandin A2 (PGA2) and prostaglandin J2 (PGJ2) (PubMed:9084911). Participates in the formation of novel hepoxilin regioisomers (PubMed:21046276). Regulates negatively CDK5 activity via p25/ p35 translocation to prevent neurodegeneration. \{ECO:0000269\|PubMed:21046276, ECO:0000269\|PubMed:21668448, ECO:0000269\|PubMed:9084911\}.
Hmgcs1 | 29637 | HMGCS1_8811 | Human Uniprot function (Human HMGCS1): Catalyzes the condensation of acetyl-CoA with acetoacetyl-CoA to form HMG-CoA, which is converted by HMG-CoA reductase (HMGCR) into mevalonate, a precursor for cholesterol synthesis. \{ECO:0000269\|PubMed:7913309\}.
Ipo13 | 116458 | IPO13_8908 | Human Uniprot function (Human IPO13): Functions in nuclear protein import as nuclear transport receptor. Serves as receptor for nuclear localization signals (NLS) in cargo substrates. Is thought to mediate docking of the importin/substrate complex to the nuclear pore complex (NPC) through binding to nucleoporin and the complex is subsequently translocated through the pore by an energy requiring, Ran-dependent mechanism. At the nucleoplasmic side of the NPC, Ran binds to the importin, the importin/substrate complex dissociates and importin is re-exported from the nucleus to the cytoplasm where GTP hydrolysis releases Ran. The directionality of nuclear import is thought to be conferred by an asymmetric distribution of the GTP- and GDP-bound forms of Ran between the cytoplasm and nucleus (By similarity). Mediates the nuclear import of UBC9, the RBM8A/MAGOH complex, PAX6 and probably other members of the paired homeobox family. Also mediates nuclear export of eIF-1A, and the cytoplasmic release of eIF-1A is triggered by the loading of import substrates onto IPO13. \{ECO:0000250, ECO:0000269\|PubMed:11447110, ECO:0000269\|PubMed:15143176\}.
Jchain | 360922 | IGJ_32511 | Human Uniprot function (Human JCHAIN): Serves to link two monomer units of either IgM or IgA. In the case of IgM, the J chain-joined dimer is a nucleating unit for the IgM pentamer, and in the case of IgA it induces dimers and/or larger polymers. It also helps to bind these immunoglobulins to secretory component.
Lcn2 | 170496 | LCN2_32481 | Human Uniprot function (Human LCN2): Iron-trafficking protein involved in multiple processes such as apoptosis, innate immunity and renal development (PubMed:12453413, PubMed:27780864, PubMed:20581821). Binds iron through association with 2,5-dihydroxybenzoic acid (2,5-DHBA), a siderophore that shares structural similarities with bacterial enterobactin, and delivers or removes iron from the cell, depending on the context. Iron-bound form (holo-24p3) is internalized following binding to the SLC22A17 (24p3R) receptor, leading to release of iron and subsequent increase of intracellular iron concentration. In contrast, association of the iron-free form (apo-24p3) with the SLC22A17 (24p3R) receptor is followed by association with an intracellular siderophore, iron chelation and iron transfer to the extracellular medium, thereby reducing intracellular iron concentration. Involved in apoptosis due to interleukin-3 (IL3) deprivation: iron-loaded form increases intracellular iron concentration without promoting apoptosis, while iron-free form decreases intracellular iron levels, inducing expression of the proapoptotic protein BCL2L11/BIM, resulting in apoptosis (By similarity). Involved in innate immunity; limits bacterial proliferation by sequestering iron bound to microbial siderophores, such as enterobactin (PubMed:27780864). Can also bind siderophores from M. tuberculosis (PubMed:15642259, PubMed:21978368). \{ECO:0000250\|UniProtKB:P11672, ECO:0000269\|PubMed:12453413, ECO:0000269\|PubMed:15642259, ECO:0000269\|PubMed:20581821, ECO:0000269\|PubMed:21978368, ECO:0000269\|PubMed:27780864\}.
Lef1 | 161452 | LEF1_32825 | Human Uniprot function (Human LEF1): Transcription factor that binds DNA in a sequence-specific manner (PubMed:2010090). Participates in the Wnt signaling pathway (By similarity). Activates transcription of target genes in the presence of CTNNB1 and EP300 (By similarity). PIAG antagonizes both Wnt-dependent and Wnt-independent activation by LEF1 (By similarity). TLE1, TLE2, TLE3 and TLE4 repress transactivation mediated by LEF1 and CTNNB1 (PubMed:11266540). Regulates T-cell receptor alpha enhancer function (PubMed:19653274). Required for IL17A expressing gamma-delta T-cell maturation and development, via binding to regulator loci of BLK to modulate expression (By similarity). May play a role in hair cell differentiation and follicle morphogenesis (By similarity). {ECO:0000250\|UniProtKB:P27782, ECO:0000269\|PubMed:11266540, ECO:0000269\|PubMed:19653274, ECO:0000269\|PubMed:2010090}.; FUNCTION: [Isoform 1]: Transcriptionally activates MYC and CCND1 expression and enhances proliferation of pancreatic tumor cells. {ECO:0000269\|PubMed:19653274}.; FUNCTION: [Isoform 3]: Lacks the CTNNB1 interaction domain and may therefore be an antagonist for Wnt signaling. {ECO:0000269\| PubMed:11326276}.; FUNCTION: [Isoform 5]: Transcriptionally activates the fibronectin promoter, binds to and represses transcription from the E-cadherin promoter in a CTNNB1-independent manner, and is involved in reducing cellular aggregation and increasing cell migration of pancreatic cancer cells. {ECO:0000269\|PubMed:19653274}.
Loc102549061/H2bc3 | 102549061 | LOC102549061_32836 | No description available.
Loc103689966 | 103689966 | MARCKSL1_32320 | No description available.
Lpar2 | 498609 | LPAR2_9151 | Human Uniprot function (Human LPAR2): Receptor for lysophosphatidic acid (LPA), a mediator of diverse cellular activities. Seems to be coupled to the G(i)/G(o), G(12)/G(13), and G(q) families of heteromeric G proteins. Plays a key role in phospholipase C-beta (PLC-beta) signaling pathway. Stimulates phospholipase C (PLC) activity in a manner that is independent of RALA activation. \{ECO:0000269\|PubMed:15143197, ECO:0000269\|PubMed:19306925\}.
Maob | 25750 | MAOB_9179 | Human Uniprot function (Human MAOB): Catalyzes the oxidative deamination of biogenic and xenobiotic amines and has important functions in the metabolism of neuroactive and vasoactive amines in the central nervous system and peripheral tissues. MAOB preferentially degrades benzylamine and phenylethylamine.
Marcksl1 | 81520 | MARCKSL1_32320 | Human Uniprot function (Human MARCKSL1): Controls cell movement by regulating actin cytoskeleton homeostasis and filopodium and lamellipodium formation (PubMed:22751924). When unphosphorylated, induces cell migration (By similarity). When phosphorylated by MAPK8, induces actin bundles formation and stabilization, thereby reducing actin plasticity, hence restricting cell movement, including neuronal migration (By similarity). May be involved in coupling the protein kinase C and calmodulin signal transduction systems (By similarity). \{ECO:0000250\|UniProtKB:P28667, ECO:0000269\|PubMed:22751924\}.
Me1 | 24552 | ME1_9215 | Human Uniprot function (Human ME1): This gene encodes a cytosolic, NADP-dependent enzyme that generates NADPH for fatty acid biosynthesis. The activity of this enzyme, the reversible oxidative decarboxylation of malate, links the glycolytic and citric acid cycles. The regulation of expression for this gene is complex. Increased expression can result from elevated levels of thyroid hormones or by higher proportions of carbohydrates in the diet. [provided by RefSeq, Jul 2008]
Nqo1 | 24314 | NQO1_33055 | Human Uniprot function (Human NQO1): The enzyme apparently serves as a quinone reductase in connection with conjugation reactions of hydroquinones involved in detoxification pathways as well as in biosynthetic processes such as the vitamin K-dependent gamma-carboxylation of glutamate residues in prothrombin synthesis.
Pcbd1 | 29700 | PCBD1_9435 | Human Uniprot function (Human PCBD1): Involved in tetrahydrobiopterin biosynthesis. Seems to both prevent the formation of 7-pterins and accelerate the formation of quinonoid-BH2. Coactivator for HNF1A- dependent transcription. Regulates the dimerization of homeodomain protein HNF1A and enhances its transcriptional activity.
Plk4 | 310344 | PLK4_9505 | Human Uniprot function (Human PLK4): Serine/threonine-protein kinase that plays a central role in centriole duplication. Able to trigger procentriole formation on the surface of the parental centriole cylinder, leading to the recruitment of centriole biogenesis proteins such as SASS6, CENPJ/CPAP, CCP110, CEP135 and gamma-tubulin. When overexpressed, it is able to induce centrosome amplification through the simultaneous generation of multiple procentrioles adjoining each parental centriole during S phase. Phosphorylates 'Ser-151' of FBXW5 during the G1/S transition, leading to inhibit FBXW5 ability to ubiquitinate SASS6. Its central role in centriole replication suggests a possible role in tumorigenesis, centrosome aberrations being frequently observed in tumors. Also involved in deuterosome-mediated centriole amplification in multiciliated that can generate more than 100 centrioles. Also involved in trophoblast differentiation by phosphorylating HAND1, leading to disrupt the interaction between HAND1 and MDFIC and activate HAND1. Phosphorylates CDC25C and CHEK2. Required for the recruitment of STIL to the centriole and for
Plk4 | 310344 | PLK4_9505 | STIL-mediated centriole amplification (PubMed:22020124). \{ECO:0000269\|PubMed:16244668, ECO:0000269\|PubMed:16326102, ECO:0000269\|PubMed:17681131, ECO:0000269\|PubMed:18239451, ECO:0000269\|PubMed:19164942, ECO:0000269\|PubMed:21725316, ECO:0000269\|PubMed:22020124, ECO:0000269\|PubMed:27796307\}.
Prc1 | 308761 | PRC1_9556 | Human Uniprot function (Human PRC1): Key regulator of cytokinesis that cross-links antiparallel microtubules at an average distance of 35 nM. Essential for controlling the spatiotemporal formation of the midzone and successful cytokinesis. Required for KIF14 localization to the central spindle and midbody. Required to recruit PLK1 to the spindle. Stimulates PLK1 phosphorylation of RACGAP1 to allow recruitment of ECT2 to the central spindle. Acts as an oncogene for promoting bladder cancer cells proliferation, apoptosis inhibition and carcinogenic progression (PubMed:17409436). \{ECO:0000269\|PubMed:12082078, ECO:0000269\|PubMed:15297875, ECO:0000269\|PubMed:15625105, ECO:0000269\|PubMed:16431929, ECO:0000269\|PubMed:17409436, ECO:0000269\|PubMed:19468300, ECO:0000269\|PubMed:20691902, ECO:0000269\|PubMed:9885575\}.
Pxmp2 | 29533 | PXMP2_9629 | Human Uniprot function (Human PXMP2): Seems to be involved in pore-forming activity and may contribute to the unspecific permeability of the peroxisomal membrane.
Slc37a4 | 29573 | SLC37A4_9871 | Human Uniprot function (Human SLC37A4): Inorganic phosphate and glucose-6-phosphate antiporter of the endoplasmic reticulum. Transports cytoplasmic glucose-6-phosphate into the lumen of the endoplasmic reticulum and translocates inorganic phosphate into the opposite direction . Forms with glucose-6-phosphatase the complex responsible for glucose production through glycogenolysis and gluconeogenesis. Hence, it plays a central role in homeostatic regulation of blood glucose levels. \{ECO:0000269\|PubMed:10026167, ECO:0000269\|PubMed:21949678\}.
Slc51a | 303879 | SLC51A_33157 | Human Uniprot function (Human SLC51A): Essential component of the Ost-alpha/Ost-beta complex, a heterodimer that acts as the intestinal basolateral transporter responsible for bile acid export from enterocytes into portal blood. Efficiently transports the major species of bile acids. \{ECO:0000269\|PubMed:16317684\}.
Slc5a6 | 170551 | SLC5A6_9881 | Human Uniprot function (Human SLC5A6): Transports pantothenate, biotin and lipoate in the presence of sodium.
Slc6a8 | 50690 | SLC6A8_32561 | Human Uniprot function (Human SLC6A8): Required for the uptake of creatine in muscles and brain.
Srxn1 | 296271 | SRXN1_9943 | Human Uniprot function (Human SRXN1): Contributes to oxidative stress resistance by reducing cysteine-sulfinic acid formed under exposure to oxidants in the peroxiredoxins PRDX1, PRDX2, PRDX3 and PRDX4. Does not act on PRDX5 or PRDX6. May catalyze the reduction in a multi-step process by acting both as a specific phosphotransferase and a thioltransferase. \{ECO:0000269\|PubMed:15448164, ECO:0000269\|PubMed:15590625\}.
Sult1c3 | 65185 | SULT1C3_9971 | Human Uniprot function (Human SULT1C3): [Isoform 1]: Sulfotransferase that utilizes 3’-phospho-5’-adenylyl sulfate (PAPS) as sulfonate donor. Has sulfotransferase activity toward various substrates, such as bile acids, thyroid hormones and toward xenobiotic compounds such as chlorophenols and hydroxypyrenes. Lithocholic acid appears to be the best substrate among the endogenous compounds tested and 3,3’,5,5’-tetrachloro-4,4’-biphenyldiol shows the highest specific activity among the xenobiotic compounds. \{ECO:0000269\|PubMed:17425406, ECO:0000269\|PubMed:17936463, ECO:0000269\|PubMed:28992322\}.; FUNCTION: [Isoform 2]: Exhibits weak sulphating activity and only toward chlorophenols (pentachlorophenol and 3,3’,5,5’-tetrachloro-4,4’-biphenyldiol). \{ECO:0000269\|PubMed:28992322\}.
Svs5 | 171027 | SVS5_33083 | Rat Entrez Gene Summary (Rat Svs5): Androgen-regulated serine-rich structural protein [RGD, Feb 2006]
Ugt2b37 | 29623 | UGT2B15_33121 | Human Uniprot function (Human UGT2B28): [Isoform 1]: UDP-glucuronosyltransferase (UGT) that catalyzes phase II biotransformation reactions in which lipophilic substrates are conjugated with glucuronic acid to increase the metabolite’s water solubility, thereby facilitating excretion into either the urine or bile (PubMed:11300766). Essential for the elimination and detoxification of drugs, xenobiotics and endogenous compounds (PubMed:11300766). Catalyzes the glucuronidation of endogenous steroid hormones such as androgens (androsterone, 3alpha-androstanediol) and estrogens (estradiol, estrone) (PubMed:11300766). Catalyzes the glucuronidation of bile acid substrates, which are natural detergents for dietary lipids absorption (PubMed:11300766). Displays glucuronidation activity toward the phenolic compounds eugenol (PubMed:11300766). \{ECO:0000269\|PubMed:11300766\}.; FUNCTION: [Isoform 2]: Lack UDP-glucuronosyltransferase (UGT) activity. \{ECO:0000269\|PubMed:11300766\}.
Unc93b1 | 361689 | UNC93B1_10134 | Human Uniprot function (Human UNC93B1): Plays an important role in innate and adaptive immunity by regulating nucleotide-sensing Toll-like receptor (TLR) signaling. Required for the transport of a subset of TLRs (including TLR3, TLR7 and TLR9) from the endoplasmic reticulum to endolysosomes where they can engage pathogen nucleotides and activate signaling cascades. May play a role in autoreactive B-cells removal. \{ECO:0000269\|PubMed:19006693\}.

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^37^ and Entrez Gene.^38^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Rat UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Rat Entrez Gene was used as the fourth resource.

^b^ In some cases, a probe may map to more than one gene, resulting in duplicate reporting of that probe mapped to different genes.

Gene definition version and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Table E-7 Gene Identifiers and Definitions for Female Mice Exposed to 1,2-Dichlorobenzene for Five Days^a^

Gene Symbol | Entrez Gene IDs | Probe IDs^b^ | Definition
Adh1 | 11522 | Adh1_84160 | Human Entrez Gene Summary (Human ADH1C): This gene encodes class I alcohol dehydrogenase, gamma subunit, which is a member of the alcohol dehydrogenase family. Members of this enzyme family metabolize a wide variety of substrates, including ethanol, retinol, other aliphatic alcohols, hydroxysteroids, and lipid peroxidation products. Class I alcohol dehydrogenase, consisting of several homo- and heterodimers of alpha, beta, and gamma subunits, exhibits high activity for ethanol oxidation to acetaldehyde, thus playing a major role in ethanol catabolism. Three genes encoding alpha, beta and gamma subunits are tandemly organized in a genomic segment as a gene cluster. An association between ADH1C polymorphism and alcohol dependence has not been established. [provided by RefSeq, Sep 2019]
Adm | 11535 | Adm_30365 | Human Uniprot function (Human ADM): AM and PAMP are potent hypotensive and vasodilatator agents. Numerous actions have been reported most related to the physiologic control of fluid and electrolyte homeostasis. In the kidney, am is diuretic and natriuretic, and both am and pamp inhibit aldosterone secretion by direct adrenal actions. In pituitary gland, both peptides at physiologically relevant doses inhibit basal ACTH secretion. Both peptides appear to act in brain and pituitary gland to facilitate the loss of plasma volume, actions which complement their hypotensive effects in blood vessels.
Bhlhe40 | 20893 | Bhlhe40_32105 | Human Uniprot function (Human BHLHE40): Transcriptional repressor involved in the regulation of the circadian rhythm by negatively regulating the activity of the clock genes and clock-controlled genes (PubMed:12397359, PubMed:18411297). Acts as the negative limb of a novel autoregulatory feedback loop (DEC loop) which differs from the one formed by the PER and CRY transcriptional repressors (PER/CRY loop) (PubMed:14672706). Both these loops are interlocked as it represses the expression of PER1/2 and in turn is repressed by PER1/2 and CRY1/2 (PubMed:15193144). Represses the activity of the circadian transcriptional activator: CLOCK-ARNTL/BMAL1\|ARNTL2/BMAL2 heterodimer by competing for the binding to E-box elements (5’-CACGTG-3’) found within the promoters of its target genes (PubMed:15560782). Negatively regulates its own expression and the expression of DBP and BHLHE41/DEC2 (PubMed:14672706). Acts as a corepressor of RXR and the RXR-LXR heterodimers and represses the ligand-induced RXRA and NR1H3/LXRA transactivation activity (PubMed:19786558). May be involved in the regulation of chondrocyte differentiation via the cAMP pathway (PubMed:19786558). Represses the transcription of NR0B2 and attenuates the transactivation of NR0B2 by the CLOCK-ARNTL/BMAL1 complex (PubMed:28797635). Drives the circadian rhythm of blood pressure through transcriptional repression of ATP1B1 in the cardiovascular system (PubMed:30012868). \{ECO:0000269\|PubMed:12397359, ECO:0000269\|PubMed:14672706, ECO:0000269\|PubMed:15193144, ECO:0000269\|PubMed:15560782, ECO:0000269\|PubMed:18411297, ECO:0000269\|PubMed:19786558, ECO:0000269\|PubMed:28797635, ECO:0000269\|PubMed:30012868\}.
Cdk2 | 12566 | Cdk2_31446 | Human Uniprot function (Human CDK2): Serine/threonine-protein kinase involved in the control of the cell cycle; essential for meiosis, but dispensable for mitosis. Phosphorylates CTNNB1, USP37, p53/TP53, NPM1, CDK7, RB1, BRCA2, MYC, NPAT, EZH2. Triggers duplication of centrosomes and DNA. Acts at the G1-S transition to promote the E2F transcriptional program and the initiation of DNA synthesis, and modulates G2 progression; controls the timing of entry into mitosis/meiosis by controlling the subsequent activation of cyclin B/CDK1 by phosphorylation, and coordinates the activation of cyclin B/CDK1 at the centrosome and in the nucleus. Crucial role in orchestrating a fine balance between cellular proliferation, cell death, and DNA repair in human embryonic stem cells (hESCs). Activity of CDK2 is maximal during S phase and G2; activated by interaction with cyclin E during the early stages of DNA synthesis to permit G1-S transition, and subsequently activated by cyclin A2 (cyclin A1 in germ cells) during the late stages of DNA replication to drive the transition from S phase to mitosis, the G2 phase. EZH2 phosphorylation promotes H3K27me3 maintenance and epigenetic gene silencing. Phosphorylates CABLES1 (By similarity). Cyclin E/CDK2 prevents oxidative stress-mediated Ras-induced senescence by phosphorylating MYC. Involved in G1-S phase DNA damage checkpoint that prevents cells with damaged DNA from initiating mitosis; regulates homologous recombination-dependent repair by phosphorylating BRCA2, this phosphorylation is low in S phase when recombination is active, but increases as cells progress toward mitosis. In response to DNA damage, double-strand break repair by homologous recombination a reduction of CDK2-mediated BRCA2 phosphorylation. Phosphorylation of RB1 disturbs its interaction with E2F1. NPM1 phosphorylation by cyclin E/CDK2 promotes its dissociates from unduplicated centrosomes, thus initiating centrosome duplication. Cyclin E/CDK2-mediated phosphorylation of NPAT at G1-S transition and until prophase stimulates the NPAT-mediated activation of histone gene transcription during S phase. Required for vitamin D-mediated growth inhibition by being itself inactivated. Involved in the nitric oxide- (NO) mediated signaling in a nitrosylation/activation-dependent manner. USP37 is activated by phosphorylation and thus triggers G1-S transition. CTNNB1 phosphorylation regulates insulin internalization. Phosphorylates FOXP3 and negatively regulates its transcriptional activity and protein stability (By similarity). Phosphorylates CDK2AP2 (PubMed:12944431). Phosphorylates ERCC6 which is essential for its chromatin remodeling activity at DNA double-strand breaks (PubMed:29203878).\{ECO:0000250\|UniProtKB:P97377, ECO:0000269\|PubMed:10499802, ECO:0000269\|PubMed:10884347, ECO:0000269\|PubMed:10995386, ECO:0000269\|PubMed:10995387, ECO:0000269\|PubMed:11051553, ECO:0000269\|PubMed:11113184, ECO:0000269\|PubMed:12944431, ECO:0000269\|PubMed:15800615, ECO:0000269\|PubMed:17495531, ECO:0000269\|PubMed:18372919, ECO:0000269\|PubMed:19966300, ECO:0000269\|PubMed:20079829, ECO:0000269\|PubMed:20147522, ECO:0000269\|PubMed:20195506, ECO:0000269\|PubMed:20935635, ECO:0000269\| PubMed:21262353, ECO:0000269\|PubMed:21319273, ECO:0000269\|PubMed:21596315, ECO:0000269\|PubMed:28666995, ECO:0000269\|PubMed:29203878\}.
Cdkn1a | 12575 | Cdkn1a_30669 | Human Uniprot function (Human CDKN1A): May be involved in p53/TP53 mediated inhibition of cellular proliferation in response to DNA damage. Binds to and inhibits cyclin-dependent kinase activity, preventing phosphorylation of critical cyclin-dependent kinase substrates and blocking cell cycle progression. Functions in the nuclear localization and assembly of cyclin D-CDK4 complex and promotes its kinase activity toward RB1. At higher stoichiometric ratios, inhibits the kinase activity of the cyclin D-CDK4 complex. Inhibits DNA synthesis by DNA polymerase delta by competing with POLD3 for PCNA binding (PubMed:11595739). Plays an important role in controlling cell cycle progression and DNA damage-induced G2 arrest (PubMed:9106657). \{ECO:0000269\|PubMed:11595739, ECO:0000269\|PubMed:8242751, ECO:0000269\|PubMed:9106657\}.
Ces1g | 12623 | Ces1g_30475 | No description available.
Chil3 | 12655 | Chil3_30648 | Mouse Uniprot function (Mouse Chil3): Lectin that binds saccharides with a free amino group, such as glucosamine or galactosamine. Binding to oligomeric saccharides is much stronger than binding to mono- or disaccharides. Also binds chitin and heparin. Has weak hexosaminidase activity but no chitinase activity. Has chemotactic activity for T-lymphocytes, bone marrow cells and eosinophils. May play a role in inflammation and allergy.
Chka | 12660 | Chka_29307 | Human Uniprot function (Human CHKA): Has a key role in phospholipid biosynthesis and may contribute to tumor cell growth. Catalyzes the first step in phosphatidylcholine biosynthesis. Contributes to phosphatidylethanolamine biosynthesis. Phosphorylates choline and ethanolamine. Has higher activity with choline. \{ECO:0000269\|PubMed:19915674\}.
Cldn5 | 12741 | Cldn5_31612 | Human Uniprot function (Human CLDN5): Plays a major role in tight junction-specific obliteration of the intercellular space. \{ECO:0000250\}.
Creld2 | 76737 | Creld2_31000 | Human Uniprot function (Human CRELD2): Protein disulfide isomerase (By similarity). Might play a role in the unfolded protein response (By similarity). May regulate transport of alpha4-beta2 neuronal acetylcholine receptor (PubMed:16238698). \{ECO:0000250\|UniProtKB:Q9CYA0, ECO:0000269\|PubMed:16238698\}.
Cyp2a4 | 13086 | Cyp2a4_30021 | Mouse Uniprot function (Mouse Cyp2a4): Highly active in the 15-alpha-hydroxylation of testosterone. Also active in the 15-alpha-hydroxylation of progesterone and androstenedione. Little or no activity on corticosterone, pregnenolone, dehydroepiandrosterone, estradiol or estriol.
Cyp2a5 | 13087 | Cyp2a5_31713 | Mouse Uniprot function (Mouse Cyp2a5): Exhibits a high coumarin 7-hydroxylase activity.
Cyp2d9 | 13105 | Cyp2d9_31050 | Mouse Uniprot function (Mouse Cyp2d9): Cytochromes P450 are a group of heme-thiolate monooxygenases. In liver microsomes, this enzyme is involved in an NADPH dependent electron transport pathway. It oxidizes a variety of structurally unrelated compounds, including steroids, fatty acids, and xenobiotics.
Cyp3a44 | 337924 | Cyp3a44_29466 | Mouse Uniprot function (Mouse Cyp3a44): Cytochromes P450 are a group of heme-thiolate monooxygenases. In liver microsomes, this enzyme is involved in an NADPH-dependent electron transport pathway. It oxidizes a variety of structurally unrelated compounds, including steroids, fatty acids, and xenobiotics.
Cyp7a1 | 13122 | Cyp7a1_30680 | Human Uniprot function (Human CYP7A1): A cytochrome P450 monooxygenase involved in the metabolism of endogenous cholesterol and its oxygenated derivatives (oxysterols) (PubMed:11013305, PubMed:12077124, PubMed:19965590, PubMed:2384150, PubMed:21813643). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (CPR; NADPH-ferrihemoprotein reductase) (PubMed:2384150, PubMed:11013305, PubMed:12077124, PubMed:19965590, PubMed:21813643). Functions as a critical regulatory enzyme of bile acid biosynthesis and cholesterol homeostasis. Catalyzes the hydroxylation of carbon hydrogen bond at 7-alpha position of cholesterol, a rate-limiting step in cholesterol catabolism and bile acid biosynthesis (PubMed:12077124, PubMed:19965590, PubMed:2384150). 7-alpha hydroxylates several oxysterols, including 4beta-hydroxycholesterol and 24-hydroxycholesterol (PubMed:11013305, PubMed:12077124). Catalyzes the oxidation of the 7,8 double bond of 7-dehydrocholesterol and lathosterol with direct and predominant formation of the 7-keto derivatives (PubMed:21813643). \{ECO:0000269\|PubMed:11013305, ECO:0000269\|PubMed:12077124, ECO:0000269\|PubMed:19965590, ECO:0000269\|PubMed:21813643, ECO:0000269\|PubMed:2384150\}.
Dbp | 13170 | Dbp_31391 | Human Uniprot function (Human DBP): This transcriptional activator recognizes and binds to the sequence 5’-RTTAYGTAAY-3’ found in the promoter of genes such as albumin, CYP2A4 and CYP2A5. It is not essential for circadian rhythm generation, but modulates important clock output genes. May be a direct target for regulation by the circadian pacemaker component clock. May affect circadian period and sleep regulation.
Ecm1 | 13601 | Ecm1_29959 | Human Uniprot function (Human ECM1): Involved in endochondral bone formation as negative regulator of bone mineralization. Stimulates the proliferation of endothelial cells and promotes angiogenesis. Inhibits MMP9 proteolytic activity. \{ECO:0000269\|PubMed:11165938, ECO:0000269\|PubMed:11292659, ECO:0000269\|PubMed:16512877\}.
Gnmt | 14711 | Gnmt_32228 | Human Uniprot function (Human GNMT): Catalyzes the methylation of glycine by using S-adenosylmethionine (AdoMet) to form N-methylglycine (sarcosine) with the concomitant production of S-adenosylhomocysteine (AdoHcy). Possible crucial role in the regulation of tissue concentration of AdoMet and of metabolism of methionine. \{ECO:0000269\|PubMed:15340920, ECO:0000269\|PubMed:17660255\}.
Hlf | 217082 | Hlf_30768 | Human Entrez Gene Summary (Human HLF): This gene encodes a member of the proline and acidic-rich (PAR) protein family, a subset of the bZIP transcription factors. The encoded protein forms homodimers or heterodimers with other PAR family members and binds sequence-specific promoter elements to activate transcription. Chromosomal translocations fusing portions of this gene with the E2A gene cause a subset of childhood B-lineage acute lymphoid leukemias. Alternatively spliced transcript variants have been described, but their biological validity has not been determined. [provided by RefSeq, Jul 2008]
Hsd3b1 | 15492 | Hsd3b1_30309 | Human Uniprot function (Human HSD3B1): A bifunctional enzyme responsible for the oxidation and isomerization of 3beta-hydroxy-Delta(5)-steroid precursors to 3-oxo-Delta(4)-steroids, an essential step in steroid hormone biosynthesis. Specifically catalyzes the conversion of pregnenolone to progesterone, 17alpha-hydroxypregnenolone to 17alpha-hydroxyprogesterone, dehydroepiandrosterone (DHEA) to 4-androstenedione, and androstenediol to testosterone. Additionally, catalyzes the interconversion between 3beta-hydroxy and 3-oxo-5alpha-androstane steroids controlling the bioavailability of the active forms. Specifically converts dihydrotestosterone to its inactive form 5alpha-androstanediol, that does not bind androgen receptor/AR. Also converts androstanedione, a precursor of testosterone and estrone, to epiandrosterone (PubMed:1401999, PubMed:2139411). Expected to use NAD(+) as preferred electron donor for the 3beta-hydroxy-steroid dehydrogenase activity and NADPH for the 3-ketosteroid reductase activity (Probable). \{ECO:0000269\|PubMed:1401999, ECO:0000269\|PubMed:2139411, ECO:0000305\|PubMed:1401999\}.
Ifi44 | 99899 | Ifi44_29813 | Human Uniprot function (Human IFI44): This protein aggregates to form microtubular structures. \{ECO:0000250\}.
Ifit3 | 15959 | Ifit3_29860 | Human Uniprot function (Human IFIT3): IFN-induced antiviral protein which acts as an inhibitor of cellular as well as viral processes, cell migration, proliferation, signaling, and viral replication. Enhances MAVS-mediated host antiviral responses by serving as an adapter bridging TBK1 to MAVS which leads to the activation of TBK1 and phosphorylation of IRF3 and phosphorylated IRF3 translocates into nucleus to promote antiviral gene transcription. Exhibits an antiproliferative activity via the up-regulation of cell cycle negative regulators CDKN1A/p21 and CDKN1B/p27. Normally, CDKN1B/p27 turnover is regulated by COPS5, which binds CDKN1B/p27 in the nucleus and exports it to the cytoplasm for ubiquitin-dependent degradation. IFIT3 sequesters COPS5 in the cytoplasm, thereby increasing nuclear CDKN1B/p27 protein levels. Upregulates CDKN1A/p21 by downregulating MYC, a repressor of CDKN1A/p21. Can negatively regulate the apoptotic effects of IFIT2. \{ECO:0000269\|PubMed:17050680, ECO:0000269\|PubMed:20686046, ECO:0000269\|PubMed:21190939, ECO:0000269\|PubMed:21642987, ECO:0000269\|PubMed:21813773\}.
Il1b | 16176 | Il1b_30437 | Human Uniprot function (Human IL1B): Potent proinflammatory cytokine. Initially discovered as the major endogenous pyrogen, induces prostaglandin synthesis, neutrophil influx and activation, T-cell activation and cytokine production, B-cell activation and antibody production, and fibroblast proliferation and collagen production. Promotes Th17 differentiation of T-cells. Synergizes with IL12/ interleukin-12 to induce IFNG synthesis from T-helper 1 (Th1) cells (PubMed:10653850). Plays a role in angiogenesis by inducing VEGF production synergistically with TNF and IL6 (PubMed:12794819). \{ECO:0000269\|PubMed:10653850, ECO:0000269\|PubMed:12794819, ECO:0000269\|PubMed:3920526\}.
Il4 | 16189 | Il4_31858 | Human Uniprot function (Human IL4): Participates in at least several B-cell activation processes as well as of other cell types (PubMed:3016727). It is a costimulator of DNA-synthesis. It induces the expression of class II MHC molecules on resting B-cells. It enhances both secretion and cell surface expression of IgE and IgG1. It also regulates the expression of the low affinity Fc receptor for IgE (CD23) on both lymphocytes and monocytes. Positively regulates IL31RA expression in macrophages (By similarity). Stimulates autophagy in dendritic cells by interfering with mTORC1 signaling and through the induction of RUFY4 (By similarity). \{ECO:0000250\|UniProtKB:P07750, ECO:0000269\|PubMed:3016727\}.
Mthfd1l | 270685 | Mthfd1l_32017 | Human Uniprot function (Human MTHFD1L): May provide the missing metabolic reaction required to link the mitochondria and the cytoplasm in the mammalian model of one-carbon folate metabolism in embryonic an transformed cells complementing thus the enzymatic activities of MTHFD2. \{ECO:0000250, ECO:0000269\|PubMed:16171773\}.
Ndrg1 | 17988 | Ndrg1_31127 | Human Uniprot function (Human NDRG1): Stress-responsive protein involved in hormone responses, cell growth, and differentiation. Acts as a tumor suppressor in many cell types. Necessary but not sufficient for p53/TP53-mediated caspase activation and apoptosis. Has a role in cell trafficking, notably of the Schwann cell, and is necessary for the maintenance and development of the peripheral nerve myelin sheath. Required for vesicular recycling of CDH1 and TF. May also function in lipid trafficking. Protects cells from spindle disruption damage. Functions in p53/TP53-dependent mitotic spindle checkpoint. Regulates microtubule dynamics and maintains euploidy. \{ECO:0000269\|PubMed:15247272, ECO:0000269\|PubMed:15377670, ECO:0000269\|PubMed:17786215, ECO:0000269\|PubMed:9766676\}.
Nfil3 | 18030 | Nfil3_31222 | Human Uniprot function (Human NFIL3): Acts as a transcriptional regulator that recognizes and binds to the sequence 5’-[GA]TTA[CT]GTAA[CT]-3’, a sequence present in many cellular and viral promoters. Represses transcription from promoters with activating transcription factor (ATF) sites. Represses promoter activity in osteoblasts (By similarity). Represses transcriptional activity of PER1 (By similarity). Represses transcriptional activity of PER2 via the B-site on the promoter (By similarity). Activates transcription from the interleukin-3 promoter in T-cells. Competes for the same consensus-binding site with PAR DNA-binding factors (DBP, HLF and TEF) (By similarity). Component of the circadian clock that acts as a negative regulator for the circadian expression of PER2 oscillation in the cell-autonomous core clock (By similarity). Protects pro-B cells from programmed cell death (By similarity). Represses the transcription of CYP2A5 (By similarity). Positively regulates the expression and activity of CES2 by antagonizing the repressive action of NR1D1 on CES2 (By similarity). \{ECO:0000250\|UniProtKB:O08750, ECO:0000269\|PubMed:1620116, ECO:0000269\|PubMed:7565758, ECO:0000269\|PubMed:8836190\}.
Nqo1 | 18104 | Nqo1_29503 | Human Uniprot function (Human NQO1): The enzyme apparently serves as a quinone reductase in connection with conjugation reactions of hydroquinones involved in detoxification pathways as well as in biosynthetic processes such as the vitamin K-dependent gamma-carboxylation of glutamate residues in prothrombin synthesis.
Pcolce | 18542 | Pcolce_31229 | Human Uniprot function (Human PCOLCE): Binds to the C-terminal propeptide of type I procollagen and enhances procollagen C-proteinase activity.; FUNCTION: C-terminal processed part of PCPE (CT-PCPE) may have an metalloproteinase inhibitory activity.
Pecam1 | 18613 | Pecam1_30950 | Human Uniprot function (Human PECAM1): Cell adhesion molecule which is required for leukocyte transendothelial migration (TEM) under most inflammatory conditions (PubMed:19342684, PubMed:17580308). Tyr-690 plays a critical role in TEM and is required for efficient trafficking of PECAM1 to and from the lateral border recycling compartment (LBRC) and is also essential for the LBRC membrane to be targeted around migrating leukocytes (PubMed:19342684). Trans-homophilic interaction may play a role in endothelial cell-cell adhesion via cell junctions (PubMed:27958302). Heterophilic interaction with CD177 plays a role in transendothelial migration of neutrophils (PubMed:17580308). Homophilic ligation of PECAM1 prevents macrophage-mediated phagocytosis of neighboring viable leukocytes by transmitting a detachment signal (PubMed:12110892). Promotes macrophage-mediated phagocytosis of apoptotic
Pecam1 | 18613 | Pecam1_30950 | leukocytes by tethering them to the phagocytic cells; PECAM1-mediated detachment signal appears to be disabled in apoptotic leukocytes (PubMed:12110892). Modulates bradykinin receptor BDKRB2 activation (PubMed:18672896). Regulates bradykinin- and hyperosmotic shock-induced ERK1/2 activation in endothelial cells (PubMed:18672896). Induces susceptibility to atherosclerosis (By similarity). \{ECO:0000250\|UniProtKB:Q08481, ECO:0000269\|PubMed:12110892, ECO:0000269\|PubMed:17580308, ECO:0000269\|PubMed:18672896, ECO:0000269\|PubMed:19342684, ECO:0000269\|PubMed:27958302\}.; FUNCTION: [Isoform Delta15]: Does not protect against apoptosis. \{ECO:0000269\|PubMed:18388311\}.
Por | 18984 | Por_29647 | Human Uniprot function (Human POR): This enzyme is required for electron transfer from NADP to cytochrome P450 in microsomes. It can also provide electron transfer to heme oxygenase and cytochrome B5. \{ECO:0000255\|HAMAP-Rule:MF\_03212\}.
Prc1 | 233406 | Prc1_29718 | Human Uniprot function (Human PRC1): Key regulator of cytokinesis that cross-links antiparallel microtubules at an average distance of 35 nM. Essential for controlling the spatiotemporal formation of the midzone and successful cytokinesis. Required for KIF14 localization to the central spindle and midbody. Required to recruit PLK1 to the spindle. Stimulates PLK1 phosphorylation of RACGAP1 to allow recruitment of ECT2 to the central spindle. Acts as an oncogene for promoting bladder cancer cells proliferation, apoptosis inhibition and carcinogenic progression (PubMed:17409436). \{ECO:0000269\|PubMed:12082078, ECO:0000269\|PubMed:15297875, ECO:0000269\|PubMed:15625105, ECO:0000269\|PubMed:16431929, ECO:0000269\|PubMed:17409436, ECO:0000269\|PubMed:19468300, ECO:0000269\|PubMed:20691902, ECO:0000269\|PubMed:9885575\}.
Rgs2 | 19735 | Rgs2_29422 | Human Uniprot function (Human RGS2): Regulates G protein-coupled receptor signaling cascades. Inhibits signal transduction by increasing the GTPase activity of G protein alpha subunits, thereby driving them into their inactive GDP-bound form (PubMed:11063746, PubMed:19478087). It is involved in the negative regulation of the angiotensin-activated signaling pathway (PubMed:28784619). Plays a role in the regulation of blood pressure in response to signaling via G protein-coupled receptors and GNAQ. Plays a role in regulating the constriction and relaxation of vascular smooth muscle (By similarity). Binds EIF2B5 and blocks its activity, thereby inhibiting the translation of mRNA into protein (PubMed:19736320). \{ECO:0000250\|UniProtKB:O08849, ECO:0000269\|PubMed:11063746, ECO:0000269\|PubMed:11278586, ECO:0000269\|PubMed:17901199, ECO:0000269\|PubMed:19736320, ECO:0000269\|PubMed:28784619, ECO:0000305\|PubMed:7643615\}.
Rsad2 | 58185 | Rsad2_31088 | Human Uniprot function (Human RSAD2): Interferon-inducible iron-sulfur (4FE-4S) cluster-binding antiviral protein which plays a major role in the cell antiviral state induced by type I and type II interferon. Can inhibit a wide range of DNA and RNA viruses, including human cytomegalovirus (HCMV), hepatitis C virus (HCV), west Nile virus (WNV), dengue virus, sindbis virus, influenza A virus, sendai virus, vesicular stomatitis virus (VSV), and human immunodeficiency virus (HIV-1). Displays antiviral activity against influenza A virus by inhibiting the budding of the virus from the plasma membrane by disturbing the lipid rafts. This is accomplished, at least in part, through binding and inhibition of the enzyme farnesyl diphosphate synthase (FPPS), which is essential for the biosynthesis of isoprenoid-derived lipids. Promotes TLR7 and TLR9-dependent production of IFN-beta production in plasmacytoid dendritic cells (pDCs) by facilitating Lys-63’-linked ubiquitination of IRAK1. Plays a role in CD4+ T-cells activation and differentiation. Facilitates T-cell receptor (TCR)-mediated GATA3 activation and optimal T-helper 2 (Th2)
| | | cytokine production by modulating NFKB1 and JUNB activities. Can inhibit secretion of soluble proteins. \{ECO:0000269\|PubMed:11752458, ECO:0000269\|PubMed:16108059, ECO:0000269\|PubMed:16982913, ECO:0000269\|PubMed:17686841, ECO:0000269\|PubMed:18005719, ECO:0000269\|PubMed:19074433\}.
Slc51a | 106407 | Slc51a_29138 | Human Uniprot function (Human SLC51A): Essential component of the Ost-alpha/Ost-beta complex, a heterodimer that acts as the intestinal basolateral transporter responsible for bile acid export from enterocytes into portal blood. Efficiently transports the major species of bile acids. \{ECO:0000269\|PubMed:16317684\}.
Slfn4 | 20558 | Slfn4_31065 | Rat Entrez Gene Summary (Rat Slfn4): Regulates cell growth; involved in T cell development [RGD, Feb 2006]
Syn1 | 20964 | Syn1_30750 | Human Uniprot function (Human SYN1): Neuronal phosphoprotein that coats synaptic vesicles, binds to the cytoskeleton, and is believed to function in the regulation of neurotransmitter release. The complex formed with NOS1 and CAPON proteins is necessary for specific nitric-oxide functions at a presynaptic level.
Tcap | 21393 | Tcap_31038 | Human Uniprot function (Human TCAP): Muscle assembly regulating factor. Mediates the antiparallel assembly of titin (TTN) molecules at the sarcomeric Z-disk.
Tk1 | 21877 | Tk1_29710 | Human Entrez Gene Summary (Human TK1): The protein encoded by this gene is a cytosolic enzyme that catalyzes the addition of a gamma-phosphate group to thymidine. This creates dTMP and is the first step in the biosynthesis of dTTP, which is one component required for DNA replication. The encoded protein, whose levels fluctuate depending on the cell cycle stage, can act as a low activity dimer or a high activity tetramer. High levels of this protein have been used as a biomarker for diagnosing and categorizing many types of cancers. [provided by RefSeq, Oct 2016]
Tmem182 | 381339 | Tmem182_30628 | No description available.
Tsku | 244152 | Tsku_31948,Tsku_29473 | Human Uniprot function (Human TSKU): Contributes to various developmental events and other processes such as wound healing and cholesterol homeostasis through its interactions with multiple signaling pathways. Wnt signaling inhibitor which competes with WNT2B for binding to Wnt receptor FZD4 and represses WNT2B-dependent development of the peripheral eye. Plays a role in regulating the hair cycle by controlling TGFB1 signaling. Required for the development of the anterior commissure in the brain by inhibiting neurite outgrowth. Essential for terminal differentiation of hippocampal neural stem cells. Plays a role in regulating bone elongation and bone mass by modulating growth plate chondrocyte function and overall body size. Required for development of the inner ear through its involvement in stereocilia formation in inner hair cells. Facilitates wound healing by inhibiting secretion of TGFB1 from macrophages which prevents myofibroblast differentiation, maintaining inflammatory cell quiescence. Plays a role in cholesterol homeostasis by reducing circulating high-density lipoprotein cholesterol, lowering cholesterol efflux capacity and decreasing cholesterol-to-bile acid conversion in the liver. In one study, shown to negatively regulate sympathetic innervation in brown fat, leading to reduced energy expenditure. In another study, shown not to affect brown fat thermogenic capacity, body weight gain or glucose homeostasis.
Tspan4 | 64540 | Tspan4_30708,Tspan4_32011 | Human Entrez Gene Summary (Human TSPAN4): The protein encoded by this gene is a member of the transmembrane 4 superfamily, also known as the tetraspanin family. Most of these members are cell-surface proteins that are characterized by the presence of four hydrophobic domains. The proteins mediate signal transduction events that play a role in the regulation of cell development, activation, growth and motility. This encoded protein is a cell surface glycoprotein and is similar in sequence to its family member CD53 antigen. It is known to complex with integrins and other transmembrane 4 superfamily proteins. Alternatively spliced transcript variants encoding different isoforms have been identified. [provided by RefSeq, Jul 2008]

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^37^ and Entrez Gene.^38^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Mouse UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Mouse Entrez Gene was used as the fourth resource.

^b^ In some cases, a probe may map to more than one gene, resulting in duplicate reporting of that probe mapped to different genes.

Gene definition version and retrieval dates: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.