# Appendix D Transcriptomic Quality Control and Empirical False Discovery Rate

## D.1 Gene Expression Quality Control

Figure D-1

A Principal Component Analysis of the Normalized Data from the Heart of Female Rats

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each exposure group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than exposure concentration-related changes, which indicates any technical batch-related effects are minimal.

Figure D-2

A Principal Component Analysis of the Normalized Data from the Kidney of Female Rats

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each exposure group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than exposure concentration-related changes, which indicates any technical batch-related effects are minimal.

Figure D-3

A Principal Component Analysis of the Normalized Data from the Liver of Female Rats

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each exposure group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than exposure concentration-related changes, which indicates any technical batch-related effects are minimal.

Figure D-4

A Principal Component Analysis of the Normalized Data from the Lung of Female Rats

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each exposure group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than exposure concentration-related changes, which indicates any technical batch-related effects are minimal.

Figure D-5

A Principal Component Analysis of the Normalized Data from the Ovary of Female Rats

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each exposure group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than exposure concentration-related changes, which indicates any technical batch-related effects are minimal.

Figure D-6

A Principal Component Analysis of the Normalized Data from the Heart of Female Mice

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each exposure group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than exposure concentration-related changes, which indicates any technical batch-related effects are minimal.

Figure D-7

A Principal Component Analysis of the Normalized Data from the Kidney of Female Mice

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each exposure group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than exposure concentration-related changes, which indicates any technical batch-related effects are minimal.

Figure D-8

A Principal Component Analysis of the Normalized Data from the Liver of Female Mice

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each exposure group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than exposure concentration-related changes, which indicates any technical batch-related effects are minimal.

Figure D-9

A Principal Component Analysis of the Normalized Data from the Lung of Female Mice

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each exposure group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than exposure concentration-related changes, which indicates any technical batch-related effects are minimal.

Figure D-10

A Principal Component Analysis of the Normalized Data from the Ovary of Female Mice

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each exposure group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than exposure concentration-related changes, which indicates any technical batch-related effects are minimal.

## D.2 Empirical False Discovery Rate

### D.2.1 Methods

Synthetic null data were generated using the probe-filtered (i.e., “no 0”) 0 ppm data from each tissue in the 1,2-dichlorobenzene rat and mouse studies. The synthetic null data were generated using the Synthetic and Null Data Generator (SaNDGen; https://rstudio.niehs.nih.gov/sandgen/), which employed the normal distribution method previously described for generating synthetic data.^29^ In short, for each set of tissue/species, 0 ppm data were used to generate a distribution for each probe. This distribution was resampled to generate 1,000 values for each probe. These values were distributed into synthetic samples, which were then organized into 20 different experiments paralleling the distribution of samples in the experimental study, i.e., 10 samples in the 0 ppm group and 5 for each nonzero exposure concentration. Each of the 20 synthetic null experiments was processed through BMDExpress using the identical parameters used to analyze the experimental data. The resultant data were then used to determine the empirical false discovery rates (eFDR), which are reported as percentages of possible genes and Gene Ontology (GO) biological processes. The associated bm2 analysis files that are the basis of the empirical false discovery rate can be found in ‎Appendix G.

### D.2.2 Results

In all species-tissue combinations, the gene-level eFDR was <1%, with a range of 0% to 0.21% (Table D-1). Most gene-level eFDR values were below 0.5%. In all cases, the eFDR for GO biological processes was 0% across all species-tissue combinations.

Table D-1 Empirical False Discovery Results

Species | Tissue | Gene eFDR (%) | | GO Biological Process eFDR (%)
Species | Tissue | Mean | Range | Mean | Range
Mouse | Heart | 0.07 | 0–0.2 | 0 | 0
Mouse | Kidney | 0.03 | 0–0.09 | 0 | 0
Mouse | Liver | 0.05 | 0–0.21 | 0 | 0
Mouse | Lung | 0.06 | 0–0.14 | 0 | 0
Mouse | Ovary | 0.03 | 0–0.09 | 0 | 0
Rat | Heart | 0.04 | 0–0.2 | 0 | 0
Rat | Kidney | 0.02 | 0–0.005 | 0 | 0
Rat | Liver | 0.03 | 0–0.01 | 0 | 0
Rat | Lung | 0.03 | 0–0.007 | 0 | 0
Rat | Ovary | 0.02 | 0–0.005 | 0 | 0

eFDR = empirical false discovery rate; GO = Gene Ontology.