# Appendix C Animal Identifiers

Table C-1 Animal Numbers and FASTQ Data File Names for Female Rats Exposed to 1,2-Dichlorobenzene for Five Days

Animal Number | Selection | Group | Exposure Concentration (ppm) | Survived to Study Termination | Tissue | FASTQ File ID
1 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DR1F1HE_S78_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DR1F1KI_S78_R1_001.fastq.gz^a^
1 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DR1F1LI_S86_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DR1F1LU_S86_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DR1F1OV_S12_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DR1F2HE_S109_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DR1F2KI_S109_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DR1F2LI_S77_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DR1F2LU_S77_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DR1F2OV_S3_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DR1F3HE_S91_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DR1F3KI_S91_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DR1F3LI_S99_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DR1F3LU_S99_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DR1F3OV_S25_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DR1F4HE_S88_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DR1F4KI_S88_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DR1F4LI_S96_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DR1F4LU_S96_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DR1F4OV_S22_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DR1F5HE_S98_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DR1F5KI_S98_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DR1F5LI_S106_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DR1F5LU_S106_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DR1F5OV_S32_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DR1F6HE_S99_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DR1F6KI_S99_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DR1F6LI_S107_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DR1F6LU_S107_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DR1F6OV_S33_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DR1F7HE_S86_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DR1F7KI_S86_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DR1F7LI_S94_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DR1F7LU_S94_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DR1F7OV_S20_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DR1F8HE_S110_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DR1F8KI_S110_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DR1F8LI_S78_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DR1F8LU_S78_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DR1F8OV_S4_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DR1F9HE_S93_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DR1F9KI_S93_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DR1F9LI_S101_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DR1F9LU_S101_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DR1F9OV_S27_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DR1F10HE_S92_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DR1F10KI_S92_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DR1F10LI_S100_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DR1F10LU_S100_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DR1F10OV_S26_R1_001.fastq.gz
11 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
12 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
13 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
101 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Heart | 2DR2F101HE_S100_R1_001.fastq.gz
101 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Kidney | 2DR2F101KI_S100_R1_001.fastq.gz
101 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Liver | 2DR2F101LI_S108_R1_001.fastq.gz
101 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Lung | 2DR2F101LU_S108_R1_001.fastq.gz
101 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Ovary | 2DR2F101OV_S34_R1_001.fastq.gz
102 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Heart | 2DR2F102HE_S112_R1_001.fastq.gz
102 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Kidney | 2DR2F102KI_S112_R1_001.fastq.gz
102 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Liver | 2DR2F102LI_S80_R1_001.fastq.gz
102 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Lung | 2DR2F102LU_S80_R1_001.fastq.gz
102 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Ovary | 2DR2F102OV_S6_R1_001.fastq.gz
103 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Heart | 2DR2F103HE_S104_R1_001.fastq.gz
103 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Kidney | 2DR2F103KI_S104_R1_001.fastq.gz
103 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Liver | 2DR2F103LI_S112_R1_001.fastq.gz
103 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Lung | 2DR2F103LU_S112_R1_001.fastq.gz
103 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Ovary | 2DR2F103OV_S38_R1_001.fastq.gz
104 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Heart | 2DR2F104HE_S79_R1_001.fastq.gz
104 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Kidney | 2DR2F104KI_S79_R1_001.fastq.gz
104 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Liver | 2DR2F104LI_S87_R1_001.fastq.gz
104 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Lung | 2DR2F104LU_S87_R1_001.fastq.gz
104 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Ovary | 2DR2F104OV_S13_R1_001.fastq.gz
105 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Heart | 2DR2F105HE_S73_R1_001.fastq.gz
105 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Kidney | 2DR2F105KI_S73_R1_001.fastq.gz
105 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Liver | 2DR2F105LI_S81_R1_001.fastq.gz
105 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Lung | 2DR2F105LU_S81_R1_001.fastq.gz
105 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Ovary | 2DR2F105OV_S7_R1_001.fastq.gz
106 | ICA Animals | 1,2-Dichlorobenzene | 1 | Yes | None | NA
107 | ICA Animals | 1,2-Dichlorobenzene | 1 | Yes | None | NA
108 | ICA Animals | 1,2-Dichlorobenzene | 1 | Yes | None | NA
201 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Heart | 2DR3F201HE_S89_R1_001.fastq.gz
201 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Kidney | 2DR3F201KI_S89_R1_001.fastq.gz
201 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Liver | 2DR3F201LI_S97_R1_001.fastq.gz
201 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Lung | 2DR3F201LU_S97_R1_001.fastq.gz
201 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Ovary | 2DR3F201OV_S23_R1_001.fastq.gz
202 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Heart | 2DR3F202HE_S83_R1_001.fastq.gz
202 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Kidney | 2DR3F202KI_S83_R1_001.fastq.gz
202 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Liver | 2DR3F202LI_S91_R1_001.fastq.gz
202 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Lung | 2DR3F202LU_S91_R1_001.fastq.gz
202 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Ovary | 2DR3F202OV_S17_R1_001.fastq.gz
203 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Heart | 2DR3F203HE_S94_R1_001.fastq.gz
203 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Kidney | 2DR3F203KI_S94_R1_001.fastq.gz
203 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Liver | 2DR3F203LI_S102_R1_001.fastq.gz
203 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Lung | 2DR3F203LU_S102_R1_001.fastq.gz
203 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Ovary | 2DR3F203OV_S28_R1_001.fastq.gz
204 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Heart | 2DR3F204HE_S111_R1_001.fastq.gz
204 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Kidney | 2DR3F204KI_S111_R1_001.fastq.gz
204 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Liver | 2DR3F204LI_S79_R1_001.fastq.gz
204 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Lung | 2DR3F204LU_S79_R1_001.fastq.gz
204 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Ovary | 2DR3F204OV_S5_R1_001.fastq.gz
205 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Heart | 2DR3F205HE_S90_R1_001.fastq.gz
205 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Kidney | 2DR3F205KI_S90_R1_001.fastq.gz
205 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Liver | 2DR3F205LI_S98_R1_001.fastq.gz
205 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Lung | 2DR3F205LU_S98_R1_001.fastq.gz
205 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Ovary | 2DR3F205OV_S24_R1_001.fastq.gz
206 | ICA Animals | 1,2-Dichlorobenzene | 10 | Yes | None | NA
207 | ICA Animals | 1,2-Dichlorobenzene | 10 | Yes | None | NA
208 | ICA Animals | 1,2-Dichlorobenzene | 10 | Yes | None | NA
301 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Heart | 2DR4F301HE_S95_R1_001.fastq.gz
301 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Kidney | 2DR4F301KI_S95_R1_001.fastq.gz
301 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Liver | 2DR4F301LI_S103_R1_001.fastq.gz
301 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Lung | 2DR4F301LU_S103_R1_001.fastq.gz
301 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Ovary | 2DR4F301OV_S29_R1_001.fastq.gz
302 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Heart | 2DR4F302HE_S74_R1_001.fastq.gz
302 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Kidney | 2DR4F302KI_S74_R1_001.fastq.gz
302 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Liver | 2DR4F302LI_S82_R1_001.fastq.gz
302 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Lung | 2DR4F302LU_S82_R1_001.fastq.gz
302 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Ovary | 2DR4F302OV_S8_R1_001.fastq.gz
303 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Heart | 2DR4F303HE_S103_R1_001.fastq.gz
303 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Kidney | 2DR4F303KI_S103_R1_001.fastq.gz
303 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Liver | 2DR4F303LI_S111_R1_001.fastq.gz
303 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Lung | 2DR4F303LU_S111_R1_001.fastq.gz
303 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Ovary | 2DR4F303OV_S37_R1_001.fastq.gz
304 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Heart | 2DR4F304HE_S76_R1_001.fastq.gz
304 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Kidney | 2DR4F304KI_S76_R1_001.fastq.gz
304 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Liver | 2DR4F304LI_S84_R1_001.fastq.gz
304 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Lung | 2DR4F304LU_S84_R1_001.fastq.gz
304 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Ovary | 2DR4F304OV_S10_R1_001.fastq.gz
305 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Heart | 2DR4F305HE_S81_R1_001.fastq.gz
305 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Kidney | 2DR4F305KI_S81_R1_001.fastq.gz
305 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Liver | 2DR4F305LI_S89_R1_001.fastq.gz
305 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Lung | 2DR4F305LU_S89_R1_001.fastq.gz
305 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Ovary | 2DR4F305OV_S15_R1_001.fastq.gz
306 | ICA Animals | 1,2-Dichlorobenzene | 30 | Yes | None | NA
307 | ICA Animals | 1,2-Dichlorobenzene | 30 | Yes | None | NA
308 | ICA Animals | 1,2-Dichlorobenzene | 30 | Yes | None | NA
401 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Heart | 2DR5F401HE_S106_R1_001.fastq.gz
401 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Kidney | 2DR5F401KI_S106_R1_001.fastq.gz
401 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Liver | 2DR5F401LI_S114_R1_001.fastq.gz
401 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Lung | 2DR5F401LU_S114_R1_001.fastq.gz
401 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Ovary | 2DR5F401OV_S40_R1_001.fastq.gz
402 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Heart | 2DR5F402HE_S108_R1_001.fastq.gz
402 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Kidney | 2DR5F402KI_S108_R1_001.fastq.gz
402 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Liver | 2DR5F402LI_S76_R1_001.fastq.gz
402 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Lung | 2DR5F402LU_S76_R1_001.fastq.gz
402 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Ovary | 2DR5F402OV_S2_R1_001.fastq.gz
403 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Heart | 2DR5F403HE_S97_R1_001.fastq.gz
403 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Kidney | 2DR5F403KI_S97_R1_001.fastq.gz
403 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Liver | 2DR5F403LI_S105_R1_001.fastq.gz
403 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Lung | 2DR5F403LU_S105_R1_001.fastq.gz
403 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Ovary | 2DR5F403OV_S31_R1_001.fastq.gz
404 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Heart | 2DR5F404HE_S77_R1_001.fastq.gz
404 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Kidney | 2DR5F404KI_S77_R1_001.fastq.gz
404 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Liver | 2DR5F404LI_S85_R1_001.fastq.gz
404 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Lung | 2DR5F404LU_S85_R1_001.fastq.gz
404 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Ovary | 2DR5F404OV_S11_R1_001.fastq.gz
405 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Heart | 2DR5F405HE_S87_R1_001.fastq.gz
405 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Kidney | 2DR5F405KI_S87_R1_001.fastq.gz
405 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Liver | 2DR5F405LI_S95_R1_001.fastq.gz
405 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Lung | 2DR5F405LU_S95_R1_001.fastq.gz
405 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Ovary | 2DR5F405OV_S21_R1_001.fastq.gz
406 | ICA Animals | 1,2-Dichlorobenzene | 100 | Yes | None | NA
407 | ICA Animals | 1,2-Dichlorobenzene | 100 | Yes | None | NA
408 | ICA Animals | 1,2-Dichlorobenzene | 100 | Yes | None | NA
501 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DR6F501HE_S105_R1_001.fastq.gz
501 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DR6F501KI_S105_R1_001.fastq.gz
501 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DR6F501LI_S113_R1_001.fastq.gz
501 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DR6F501LU_S113_R1_001.fastq.gz
501 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DR6F501OV_S39_R1_001.fastq.gz
502 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DR6F502HE_S107_R1_001.fastq.gz
502 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DR6F502KI_S107_R1_001.fastq.gz
502 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DR6F502LI_S115_R1_001.fastq.gz
502 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DR6F502LU_S115_R1_001.fastq.gz
502 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DR6F502OV_S41_R1_001.fastq.gz
503 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DR6F503HE_S75_R1_001.fastq.gz
503 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DR6F503KI_S75_R1_001.fastq.gz
503 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DR6F503LI_S83_R1_001.fastq.gz
503 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DR6F503LU_S83_R1_001.fastq.gz
503 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DR6F503OV_S9_R1_001.fastq.gz
504 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DR6F504HE_S101_R1_001.fastq.gz
504 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DR6F504KI_S101_R1_001.fastq.gz
504 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DR6F504LI_S109_R1_001.fastq.gz
504 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DR6F504LU_S109_R1_001.fastq.gz
504 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DR6F504OV_S35_R1_001.fastq.gz
505 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DR6F505HE_S96_R1_001.fastq.gz
505 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DR6F505KI_S96_R1_001.fastq.gz
505 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DR6F505LI_S104_R1_001.fastq.gz
505 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DR6F505LU_S104_R1_001.fastq.gz
505 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DR6F505OV_S30_R1_001.fastq.gz
506 | ICA Animals | 1,2-Dichlorobenzene | 250 | Yes | None | NA
507 | ICA Animals | 1,2-Dichlorobenzene | 250 | Yes | None | NA
508 | ICA Animals | 1,2-Dichlorobenzene | 250 | Yes | None | NA
601 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Heart | 2DR7F601HE_S84_R1_001.fastq.gz
601 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Kidney | 2DR7F601KI_S84_R1_001.fastq.gz
601 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Liver | 2DR7F601LI_S92_R1_001.fastq.gz
601 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Lung | 2DR7F601LU_S92_R1_001.fastq.gz^a^
601 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Ovary | 2DR7F601OV_S18_R1_001.fastq.gz
602 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Heart | 2DR7F602HE_S80_R1_001.fastq.gz
602 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Kidney | 2DR7F602KI_S80_R1_001.fastq.gz
602 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Liver | 2DR7F602LI_S88_R1_001.fastq.gz
602 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Lung | 2DR7F602LU_S88_R1_001.fastq.gz
602 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Ovary | 2DR7F602OV_S14_R1_001.fastq.gz
603 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Heart | 2DR7F603HE_S82_R1_001.fastq.gz
603 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Kidney | 2DR7F603KI_S82_R1_001.fastq.gz
603 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Liver | 2DR7F603LI_S90_R1_001.fastq.gz
603 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Lung | 2DR7F603LU_S90_R1_001.fastq.gz
603 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Ovary | 2DR7F603OV_S16_R1_001.fastq.gz
604 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Heart | 2DR7F604HE_S102_R1_001.fastq.gz
604 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Kidney | 2DR7F604KI_S102_R1_001.fastq.gz
604 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Liver | 2DR7F604LI_S110_R1_001.fastq.gz
604 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Lung | 2DR7F604LU_S110_R1_001.fastq.gz
604 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Ovary | 2DR7F604OV_S36_R1_001.fastq.gz
605 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Heart | 2DR7F605HE_S85_R1_001.fastq.gz
605 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Kidney | 2DR7F605KI_S85_R1_001.fastq.gz
605 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Liver | 2DR7F605LI_S93_R1_001.fastq.gz
605 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Lung | 2DR7F605LU_S93_R1_001.fastq.gz
605 | Core Animals | 1,2-Dichlorobenzene | 500 | Yes | Ovary | 2DR7F605OV_S19_R1_001.fastq.gz
606 | ICA Animals | 1,2-Dichlorobenzene | 500 | Yes | None | NA
607 | ICA Animals | 1,2-Dichlorobenzene | 500 | Yes | None | NA
608 | ICA Animals | 1,2-Dichlorobenzene | 500 | Yes | None | NA

ICA = internal concentration assessment; NA = no transcriptomics data collected for selected animal.

^a^ Removed due to quality control fail.

Table C-2 Animal Numbers and FASTQ Data File Names for Female Mice Exposed to 1,2-Dichlorobenzene for Five Days

Animal Number | Selection | Group | Exposure Concentration (ppm) | Survived to Study Termination | Tissue | FASTQ File ID
1 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DM1F1HE_S6_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DM1F1KI_S6_R1_001.fastq.gz^a^
1 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DM1F1LI_S11_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DM1F1LU_S11_R1_001.fastq.gz
1 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DM1F1OV_S93_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DM1F2HE_S35_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DM1F2KI_S35_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DM1F2LI_S3_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DM1F2LU_S3_R1_001.fastq.gz
2 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DM1F2OV_S85_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DM1F3HE_S14_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DM1F3KI_S14_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DM1F3LI_S19_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DM1F3LU_S19_R1_001.fastq.gz
3 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DM1F3OV_S101_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DM1F4HE_S16_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DM1F4KI_S16_R1_001.fastq.gz^a^
4 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DM1F4LI_S21_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DM1F4LU_S21_R1_001.fastq.gz
4 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DM1F4OV_S103_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DM1F5HE_S26_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DM1F5KI_S26_R1_001.fastq.gz^b^
5 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DM1F5LI_S31_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DM1F5LU_S31_R1_001.fastq.gz
5 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DM1F5OV_S113_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DM1F6HE_S27_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DM1F6KI_S27_R1_001.fastq.gz^a^
6 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DM1F6LI_S32_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DM1F6LU_S32_R1_001.fastq.gz
6 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DM1F6OV_S114_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DM1F7HE_S9_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DM1F7KI_S9_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DM1F7LI_S14_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DM1F7LU_S14_R1_001.fastq.gz
7 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DM1F7OV_S96_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DM1F8HE_S32_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DM1F8KI_S32_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DM1F8LI_S37_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DM1F8LU_S37_R1_001.fastq.gz
8 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DM1F8OV_S119_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DM1F9HE_S21_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DM1F9KI_S21_R1_001.fastq.gz^a^
9 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DM1F9LI_S26_R1_001.fastq.gz^c^
9 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DM1F9LU_S26_R1_001.fastq.gz
9 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DM1F9OV_S108_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Heart | 2DM1F10HE_S15_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Kidney | 2DM1F10KI_S15_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Liver | 2DM1F10LI_S20_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Lung | 2DM1F10LU_S20_R1_001.fastq.gz
10 | Core Animals | Vehicle Control | 0 | Yes | Ovary | 2DM1F10OV_S102_R1_001.fastq.gz
11 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
12 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
13 | ICA Animals | Vehicle Control | 0 | Yes | None | NA
101 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Heart | 2DM2F101HE_S23_R1_001.fastq.gz
101 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Kidney | 2DM2F101KI_S23_R1_001.fastq.gz
101 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Liver | 2DM2F101LI_S28_R1_001.fastq.gz^c^
101 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Lung | 2DM2F101LU_S28_R1_001.fastq.gz
101 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Ovary | 2DM2F101OV_S110_R1_001.fastq.gz
102 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Heart | 2DM2F102HE_S25_R1_001.fastq.gz
102 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Kidney | 2DM2F102KI_S25_R1_001.fastq.gz
102 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Liver | 2DM2F102LI_S30_R1_001.fastq.gz^c^
102 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Lung | 2DM2F102LU_S30_R1_001.fastq.gz
102 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Ovary | 2DM2F102OV_S112_R1_001.fastq.gz
103 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Heart | 2DM2F103HE_S31_R1_001.fastq.gz
103 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Kidney | 2DM2F103KI_S31_R1_001.fastq.gz
103 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Liver | 2DM2F103LI_S36_R1_001.fastq.gz
103 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Lung | 2DM2F103LU_S36_R1_001.fastq.gz
103 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Ovary | 2DM2F103OV_S118_R1_001.fastq.gz
104 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Heart | 2DM2F104HE_S7_R1_001.fastq.gz
104 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Kidney | 2DM2F104KI_S7_R1_001.fastq.gz
104 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Liver | 2DM2F104LI_S12_R1_001.fastq.gz
104 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Lung | 2DM2F104LU_S12_R1_001.fastq.gz^b^
104 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Ovary | 2DM2F104OV_S94_R1_001.fastq.gz
105 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Heart | 2DM2F105HE_S1_R1_001.fastq.gz
105 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Kidney | 2DM2F105KI_S1_R1_001.fastq.gz^c^
105 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Liver | 2DM2F105LI_S6_R1_001.fastq.gz^b^
105 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Lung | 2DM2F105LU_S6_R1_001.fastq.gz
105 | Core Animals | 1,2-Dichlorobenzene | 1 | Yes | Ovary | 2DM2F105OV_S88_R1_001.fastq.gz
106 | ICA Animals | 1,2-Dichlorobenzene | 1 | No | None | NA
107 | ICA Animals | 1,2-Dichlorobenzene | 1 | Yes | None | NA
108 | ICA Animals | 1,2-Dichlorobenzene | 1 | Yes | None | NA
201 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Heart | 2DM3F201HE_S17_R1_001.fastq.gz
201 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Kidney | 2DM3F201KI_S17_R1_001.fastq.gz
201 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Liver | 2DM3F201LI_S22_R1_001.fastq.gz
201 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Lung | 2DM3F201LU_S22_R1_001.fastq.gz
201 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Ovary | 2DM3F201OV_S104_R1_001.fastq.gz
202 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Heart | 2DM3F202HE_S11_R1_001.fastq.gz
202 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Kidney | 2DM3F202KI_S11_R1_001.fastq.gz^a^
202 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Liver | 2DM3F202LI_S16_R1_001.fastq.gz
202 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Lung | 2DM3F202LU_S16_R1_001.fastq.gz
202 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Ovary | 2DM3F202OV_S98_R1_001.fastq.gz
203 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Heart | 2DM3F203HE_S22_R1_001.fastq.gz
203 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Kidney | 2DM3F203KI_S22_R1_001.fastq.gz
203 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Liver | 2DM3F203LI_S27_R1_001.fastq.gz^c^
203 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Lung | 2DM3F203LU_S27_R1_001.fastq.gz
203 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Ovary | 2DM3F203OV_S109_R1_001.fastq.gz
204 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Heart | 2DM3F204HE_S33_R1_001.fastq.gz
204 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Kidney | 2DM3F204KI_S33_R1_001.fastq.gz
204 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Liver | 2DM3F204LI_S38_R1_001.fastq.gz
204 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Lung | 2DM3F204LU_S38_R1_001.fastq.gz
204 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Ovary | 2DM3F204OV_S120_R1_001.fastq.gz
205 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Heart | 2DM3F205HE_S13_R1_001.fastq.gz
205 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Kidney | 2DM3F205KI_S13_R1_001.fastq.gz
205 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Liver | 2DM3F205LI_S18_R1_001.fastq.gz
205 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Lung | 2DM3F205LU_S18_R1_001.fastq.gz
205 | Core Animals | 1,2-Dichlorobenzene | 10 | Yes | Ovary | 2DM3F205OV_S100_R1_001.fastq.gz
206 | ICA Animals | 1,2-Dichlorobenzene | 10 | Yes | None | NA
207 | ICA Animals | 1,2-Dichlorobenzene | 10 | Yes | None | NA
208 | ICA Animals | 1,2-Dichlorobenzene | 10 | Yes | None | NA
301 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Heart | 2DM4F301HE_S18_R1_001.fastq.gz
301 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Kidney | 2DM4F301KI_S18_R1_001.fastq.gz
301 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Liver | 2DM4F301LI_S23_R1_001.fastq.gz
301 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Lung | 2DM4F301LU_S23_R1_001.fastq.gz
301 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Ovary | 2DM4F301OV_S105_R1_001.fastq.gz
302 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Heart | 2DM4F302HE_S2_R1_001.fastq.gz
302 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Kidney | 2DM4F302KI_S2_R1_001.fastq.gz^b^
302 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Liver | 2DM4F302LI_S7_R1_001.fastq.gz
302 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Lung | 2DM4F302LU_S7_R1_001.fastq.gz
302 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Ovary | 2DM4F302OV_S89_R1_001.fastq.gz
303 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Heart | 2DM4F303HE_S30_R1_001.fastq.gz
303 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Kidney | 2DM4F303KI_S30_R1_001.fastq.gz^a^
303 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Liver | 2DM4F303LI_S35_R1_001.fastq.gz
303 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Lung | 2DM4F303LU_S35_R1_001.fastq.gz
303 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Ovary | 2DM4F303OV_S117_R1_001.fastq.gz
304 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Heart | 2DM4F304HE_S36_R1_001.fastq.gz
304 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Kidney | 2DM4F304KI_S36_R1_001.fastq.gz
304 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Liver | 2DM4F304LI_S4_R1_001.fastq.gz
304 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Lung | 2DM4F304LU_S4_R1_001.fastq.gz
304 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Ovary | 2DM4F304OV_S86_R1_001.fastq.gz
305 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Heart | 2DM4F305HE_S4_R1_001.fastq.gz
305 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Kidney | 2DM4F305KI_S4_R1_001.fastq.gz
305 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Liver | 2DM4F305LI_S9_R1_001.fastq.gz
305 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Lung | 2DM4F305LU_S9_R1_001.fastq.gz
305 | Core Animals | 1,2-Dichlorobenzene | 30 | Yes | Ovary | 2DM4F305OV_S91_R1_001.fastq.gz
306 | ICA Animals | 1,2-Dichlorobenzene | 30 | Yes | None | NA
307 | ICA Animals | 1,2-Dichlorobenzene | 30 | Yes | None | NA
308 | ICA Animals | 1,2-Dichlorobenzene | 30 | Yes | None | NA
401 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Heart | 2DM5F401HE_S29_R1_001.fastq.gz
401 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Kidney | 2DM5F401KI_S29_R1_001.fastq.gz^a^
401 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Liver | 2DM5F401LI_S34_R1_001.fastq.gz
401 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Lung | 2DM5F401LU_S34_R1_001.fastq.gz
401 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Ovary | 2DM5F401OV_S116_R1_001.fastq.gz
402 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Heart | 2DM5F402HE_S34_R1_001.fastq.gz
402 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Kidney | 2DM5F402KI_S34_R1_001.fastq.gz^a^
402 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Liver | 2DM5F402LI_S2_R1_001.fastq.gz
402 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Lung | 2DM5F402LU_S2_R1_001.fastq.gz
402 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Ovary | 2DM5F402OV_S84_R1_001.fastq.gz
403 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Heart | 2DM5F403HE_S20_R1_001.fastq.gz
403 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Kidney | 2DM5F403KI_S20_R1_001.fastq.gz^b^
403 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Liver | 2DM5F403LI_S25_R1_001.fastq.gz
403 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Lung | 2DM5F403LU_S25_R1_001.fastq.gz
403 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Ovary | 2DM5F403OV_S107_R1_001.fastq.gz
404 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Heart | 2DM5F404HE_S37_R1_001.fastq.gz
404 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Kidney | 2DM5F404KI_S37_R1_001.fastq.gz
404 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Liver | 2DM5F404LI_S5_R1_001.fastq.gz
404 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Lung | 2DM5F404LU_S5_R1_001.fastq.gz
404 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Ovary | 2DM5F404OV_S87_R1_001.fastq.gz
405 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Heart | 2DM5F405HE_S10_R1_001.fastq.gz
405 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Kidney | 2DM5F405KI_S10_R1_001.fastq.gz
405 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Liver | 2DM5F405LI_S15_R1_001.fastq.gz
405 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Lung | 2DM5F405LU_S15_R1_001.fastq.gz
405 | Core Animals | 1,2-Dichlorobenzene | 100 | Yes | Ovary | 2DM5F405OV_S97_R1_001.fastq.gz
406 | ICA Animals | 1,2-Dichlorobenzene | 100 | Yes | None | NA
407 | ICA Animals | 1,2-Dichlorobenzene | 100 | Yes | None | NA
408 | ICA Animals | 1,2-Dichlorobenzene | 100 | Yes | None | NA
501 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DM6F501HE_S28_R1_001.fastq.gz
501 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DM6F501KI_S28_R1_001.fastq.gz^a^
501 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DM6F501LI_S33_R1_001.fastq.gz
501 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DM6F501LU_S33_R1_001.fastq.gz
501 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DM6F501OV_S115_R1_001.fastq.gz
502 | Core Animals | 1,2-Dichlorobenzene | 250 | No | Heart | NA
502 | Core Animals | 1,2-Dichlorobenzene | 250 | No | Kidney | NA
502 | Core Animals | 1,2-Dichlorobenzene | 250 | No | Liver | NA
502 | Core Animals | 1,2-Dichlorobenzene | 250 | No | Lung | NA
502 | Core Animals | 1,2-Dichlorobenzene | 250 | No | Ovary | NA
503 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DM6F503HE_S3_R1_001.fastq.gz
503 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DM6F503KI_S3_R1_001.fastq.gz
503 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DM6F503LI_S8_R1_001.fastq.gz
503 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DM6F503LU_S8_R1_001.fastq.gz
503 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DM6F503OV_S90_R1_001.fastq.gz
504 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DM6F504HE_S24_R1_001.fastq.gz
504 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DM6F504KI_S24_R1_001.fastq.gz
504 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DM6F504LI_S29_R1_001.fastq.gz^c^
504 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DM6F504LU_S29_R1_001.fastq.gz
504 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DM6F504OV_S111_R1_001.fastq.gz
505 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DM6F505HE_S19_R1_001.fastq.gz
505 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DM6F505KI_S19_R1_001.fastq.gz
505 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DM6F505LI_S24_R1_001.fastq.gz
505 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DM6F505LU_S24_R1_001.fastq.gz^c^
505 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DM6F505OV_S106_R1_001.fastq.gz
506R | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DM6F506RHE_S12_R1_001.fastq.gz
506R | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DM6F506RKI_S12_R1_001.fastq.gz
506R | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DM6F506RLI_S17_R1_001.fastq.gz
506R | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DM6F506RLU_S17_R1_001.fastq.gz
506R | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DM6F506ROV_S99_R1_001.fastq.gz
507 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DM6F507HE_S8_R1_001.fastq.gz
507 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DM6F507KI_S8_R1_001.fastq.gz
507 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DM6F507LI_S13_R1_001.fastq.gz
507 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DM6F507LU_S13_R1_001.fastq.gz
507 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DM6F507OV_S95_R1_001.fastq.gz
508 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Heart | 2DM6F508HE_S5_R1_001.fastq.gz
508 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Kidney | 2DM6F508KI_S5_R1_001.fastq.gz
508 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Liver | 2DM6F508LI_S10_R1_001.fastq.gz
508 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Lung | 2DM6F508LU_S10_R1_001.fastq.gz
508 | Core Animals | 1,2-Dichlorobenzene | 250 | Yes | Ovary | 2DM6F508OV_S92_R1_001.fastq.gz
509 | ICA Animals | 1,2-Dichlorobenzene | 250 | Yes | None | NA
510 | ICA Animals | 1,2-Dichlorobenzene | 250 | Yes | None | NA
511 | ICA Animals | 1,2-Dichlorobenzene | 250 | No | None | NA
512 | ICA Animals | 1,2-Dichlorobenzene | 250 | No | None | NA
513 | ICA Animals | 1,2-Dichlorobenzene | 250 | Yes | None | NA

ICA = internal concentration assessment; NA = no transcriptomics data collected for selected animal.

^a^ Removed due to potential tissue contamination.

^b^ Removed due to principal component analysis/inter-replicate correlation analysis outlier.

^c^ Removed due to quality control fail.