# Appendix B Internal Concentration Assessment

## B.1 Validation of Analytical Method

A method utilizing headspace solid-phase microextraction-gas chromatography mass spectrometry (HS-SPME-GC/MS; Table B-1) was adapted from the literature^33,34^ and validated for simultaneous quantitation of 1,2-dichlorobenzene (1,2-DCB) and 1,4-dichlorobenzene (1,4-DCB) in blood, liver, and lung.

Experiments were designed to demonstrate the linearity, sensitivity, selectivity, intra- and interday accuracy and precision, and reproducibility. Accuracy and precision were evaluated as percent relative error (% RE) and percent relative standard deviation (% RSD), respectively. The lower limit of quantitation (LLOQ) was the lowest calibration standard that could be accurately quantitated for six replicates within 20% RE and reproducible within 20% RSD. The limit of detection (LOD) was defined as 3 times the standard deviation of the LLOQ response, expressed as concentration. The ability to quantitate analyte concentrations above the validated range was also evaluated by preparing samples in respective matrices with concentrations above the upper limit of the validated range and diluting into the validated range using various approaches. The validated method was used to demonstrate the performance of the method to quantify analytes in study matrices (Hsd:Sprague Dawley^®^ SD^®^ [HSD] rat, B6D2F1/Crl mouse and B6C3F1 mouse blood, liver, and lung). HSD rat, B6D2F1/Crl mouse, and B6C3F1 mouse blood, liver, and lung were obtained from various sources, including BioIVT (Westbury, NY), Southern Research (Birmingham, AL), Battelle (Columbus, OH), and/or AmplifyBio (West Jefferson, OH). The stability of analytes in blood and tissues during sample storage to cover the study sample storage duration and under the conditions of the sample analysis was also assessed.

The method was validated in male HSD rat blood over an analyte concentration range of 0.5 to 250 ng/mL using seven concentrations. Quality control (QC) standards were prepared at 1, 25, and 200 ng/mL. 1,2- and 1,4-DCB solvent standards containing both analytes were prepared in acetone. ^13^C_6_ 1,2-DCB (added as a mixture of ^13^C_6_ 1,2-DCB and ^13^C_6_ 1,4-DCB; Cambridge Isotope Laboratories, Inc., Tewksbury, MA) was used as the internal standard (IS). The working IS solution was prepared as 250 ng/mL of ^13^C_6_ 1,4-DCB and ^13^C_6_ 1,2-DCB in acetone.

Blood calibration standards and QC samples were prepared by aliquoting 20 μL analyte spiking solution in acetone into 180 μL HSD rat blood. Then, 100 μL of analyte-spiked blood was transferred into a 2 mL headspace vial, and 25 μL IS solution (250 ng/mL) in acetone was added prior to immediately capping the vials. Method (with IS) and matrix blanks (without IS) were prepared similarly except analyte spiking solution was not added to method and matrix blanks. Liver and lung QC samples were prepared by homogenizing 100 mg tissue in 170 μL phosphate buffered saline (PBS) with one 5 mm stainless-steel bead in the presence of 75 μL IS (or acetone for blanks without IS) and appropriate 30 μL analyte standard spiking solution (or acetone for blanks) using the TissueLyser at 25 Hz for 60 seconds 2 to 3 times until complete homogenization was observed. The final tissue dilution was 1:3. One hundred twenty-five microliters of the processed homogenate was transferred into individual 2 mL headspace vials and immediately capped. Stability of analytes during sample analysis at ambient temperature and during sample storage in ultracold temperature was assessed by preparing QC samples as described above with IS present and comparing to freshly prepared QC samples on day 0. The final IS concentration in all calibration standards, blanks, and QC samples was 50 ng/mL. All samples were analyzed using the HS-SPME-GC/MS method (Table B-1) and quantified as described in section ‎B.3.

Validation data for 1,2-DCB are shown in Table B-2. Calibration curves were linear (r^2^ ≥ 0.99) over the range (0.5 to 250 ng/mL) with an intra- and interday accuracy and precision of ≤ ±8.4% RE and ≤15.0% RSD, respectively. The intra- and interday accuracy and precision for QC standards were ≤ ±14.4% RE and ≤12.8% RSD, respectively. Carryover was assessed by comparing responses from three air blanks that were run immediately following the highest calibration standard of 250 ng/mL and met the acceptance criteria of <30% of the average response of the lowest standard (0.5 ng/mL). Selectivity was assessed by analyzing six replicates of blanks from two different lots of blood, with and without IS. Interference was minimal; the responses were 0.6%–7.4% of the lowest calibration concentration response (0.5 ng/mL). With each analytical batch, two air blanks were also analyzed to assess carryover. The air blanks were empty, 2 mL screw-top vials that did not go through sample processing. There was no appreciable carryover.

Dilution verification was conducted using different dilution schemes (i.e., using blood or blood diluted with acetone with or without IS) to determine if concentrations above the validated range could be quantified after diluting into the validated range. Because the blood sample collection during the study included the addition of IS, the data for blood prepared with IS and then diluted with blood containing IS are reported (Table B-3). In blood, 1,2-DCB concentrations up to 100,000 ng/mL can be quantified with good precision (≤0.5% RSD). The RE was £ ±7.1% for up to 20,000 ng/mL, demonstrating that 1,2-DCB can be quantified with good accuracy up to 20,000 ng/mL after dilution. Estimated RE was higher, approximately ±34%, for concentrations >20,000 ng/mL.

The validated method was used to assess the performance in secondary (study) matrices with QC samples prepared as described above. The estimated RSD in all secondary matrices was ≤6.6% (Table B-4). Estimated RE in B6D2F1/Crl mouse blood was ≤ ±11.2%, whereas the RE in all other tissues was 23.0%–33.0%. Overall data showed that the method is acceptable for quantitation of 1,2-DCB in secondary matrices, with the caveat that there is higher variability in some matrices. Dilution verification was also conducted for rat liver QC samples prepared at 150,000 ng/g and diluted using blood after homogenization (Table B-4). The accuracy of the dilutions was 15.3% and precision was 9.4%, demonstrating that liver samples could be diluted into the validated range for analysis. Because lung and liver homogenates behaved similarly, this assessment was not conducted for lung.

Analyte stability in blood and tissues was evaluated after storing QC samples under analysis conditions for 21 days or at –70°C for 100 or 149 days and then analyzing with freshly prepared samples on day 0 (Table B-5). When samples were prepared with IS present, 1,2-DCB showed acceptable stability in blood for up to 21 days at ambient temperature and for up to 149 days when frozen. 1,2-DCB was stable in liver at –70°C for up to 100 days. Stability of 1,2-DCB in lung was not evaluated and was expected to be similar to the liver.

## B.2 Study Sample Collection

Blood, lung, and liver samples were collected from the internal concentration assessment animals immediately following the last exposure on study day 4 (once chamber concentrations were at or below the regulatory limit of 12 ppm without additional health and safety considerations). Blood, lung, and liver samples were also collected from core animals designated for internal concentration assessment on study day 5 (approximately 18 hours following the last exposure).

### B.2.1 Blood

On study day 4, blood was collected from the internal concentration assessment animals via cardiac puncture for all surviving rats and mice (up to 3/exposure group) while animals were anesthetized with CO_2_/O_2_ (70%/30%). On study day 5, blood samples from designated core animals (3/exposure group) were taken via retro orbital plexus (rats) or retro orbital sinus (mice) while animals were anesthetized with CO_2_/O_2_ (70%/30%). All blood samples were collected within a 2-hour window. Blood was collected into tubes containing tripotassium ethylenediaminetetraacetic acid (K_3_ EDTA) and three aliquots of 100 µL were transferred into headspace vials and kept on wet ice. To aliquoted blood, IS (25 μL of 250 ng/mL of combined ^13^C_6_ 1,4-DCB and ^13^C_6_ 1,2-DCB in acetone) was added and kept on wet ice until transferred to frozen storage (−85°C to −60°C). The final IS concentration in samples was 50 ng/mL.

All samples were frozen within 1 hour of collection. QC samples were also prepared at the analytical chemistry laboratory to track the impacts of storage and shipping, if any, by spiking 0.1 mL blank blood aliquots with 25 ng/mL 1,2- and 1,4-DCB. At the testing facility, these blood aliquots were spiked with IS and processed similarly to study samples.

### B.2.2 Lung and Liver

After blood collection, animals were euthanized by exsanguination and lung and liver tissues were collected (following organ weight measurements for core animals designated for internal concentration assessment) from each animal within 1 hour of each other. Up to three aliquots of approximately 100 mg (rats) or 50 mg (mice) (exact weights were recorded) lung and liver tissue were collected from each animal and flash frozen. Samples were stored frozen (−85°C to −60°C) until analyzed.

### B.2.3 Study Sample Preparation

One blood aliquot from each animal was directly analyzed for 1,2-DCB using the validated method using conditions given in Table B-1. Calibration standards, QC samples (1 and 100 ng/mL), matrix blanks, method blanks, and tracking QC samples prepared in HSD rat blood were run with each analytical batch. Blood samples with 1,2-DCB concentrations above the validated method were reanalyzed after diluting into the validated range using blood diluent with IS present at the same concentration as study samples such that the final IS concentration in the sample was 50 ng/mL.

Rat lung and liver study samples were homogenized as described above under section ‎B.1. Mouse liver and lung study samples were prepared by homogenizing 50 mg of tissue with 100 μL of PBS and 37.5 μL IS as described for rat but with one 3 mm stainless-steel bead. The final IS concentration in tissues was 50 ng/mL. After homogenization, samples were centrifuged at approximately 20,800 rcf for approximately 10 minutes. One hundred twenty-five microliters of the supernatant was transferred to individual 2 mL headspace vials, immediately sealed, and analyzed by HS-SPME-GC/MS (Table B-1). Lung and liver samples with concentrations above the validated method were reanalyzed after diluting with HSD rat blood without IS into the validated range and IS at a final concentration of 50 ng/mL was added following dilution.

## B.3 Instrumentation and Quantitation

All samples were analyzed using the HS-SPME-GC/MS method (Table B-1) and quantified using blood calibration curves. The peak area response ratio (analyte/IS) was calculated in each injection for 1,2-DCB. A linear regression equation with 1/x weighting was calculated relating the peak area response ratio (y) to the nominal concentration (x) in blood calibration standards for 1,2-DCB.

The concentration of each calibration standard, QC standard, and blank was calculated in nanograms per milliliter using its individual response ratio and the regression equation. Tissue concentration was converted to ng/g using the tissue weight and homogenization parameters (1 part tissue to 2 parts PBS/acetone).

Data from the study samples were considered valid if they were bracketed by valid QC sets. In general, each sample set, method blank, and control was bracketed by two QC sets, which consisted of a calibration blank and two concentrations of calibration standards. A QC set passed when the measured concentration for QC standards was ≤15% of its nominal value for at least 67% of all QC standards and at least 50% of the QC standards at each concentration level (high or low) having determined concentrations ≤15% of the nominal value. All QC standard sets met these acceptance criteria.

Twenty-nine tracking blood QC standards were analyzed with the study samples. Estimated REs for the tracking QC standards ranged from 8% to 23.6%, demonstrating that there was no appreciable analyte loss during sample collection and storage.

Table B-1 Analytical System and Parameters Used in the Internal Concentration Assessment of 1,2-Dichlorobenzene

Instrument and Parameter | System A
System | Agilent GC 7890B plus Agilent MS 5977B
Sampling
Headspace Autosampler | PAL RSI 85 Autosampler (CTC Analytics AG, Zwingen, Switzerland)
Solid Phase Microextraction | Topaz inlet liner (0.75 mm × 6.35 mm × 78.5 mm) and 100% polydimethylsiloxane fiber
Sample Incubation Temperature | 40°C
Sample Incubation Time | 10 minutes
Fiber Conditioning Temperature | 300°C
Pre-desorption Conditioning Time | 5 minutes
Sampling Time | 15 minutes
Sample Vial Penetration Speed | 20 mm/sec
Inlet Penetration Speed | 100 mm/sec
Sample Desorption Time | 2 minutes
Post-desorption Conditioning Time | 15 minutes
Column and Program
Column | Restek Rtx-5 (30 m × 0.25 mm ID, 0.25 µm film thickness)
Carrier Gas | Helium at 1 mL/min
Oven Temperature Program | 80°C for 2 minutes, then 5°C/min to 100°C, then 25°C/min to 250°C, 5-minute hold
Inlet Temperature | 250°C
Inlet Purge Flow, Time | 50.0 mL/min at 0.2 minutes
GC Cycle Time | 22 minutes
Solvent Delay | 3.5 to 4 minutes
Retention Time | ~5.3 minutes
Auxiliary Temperature | 250°C
MS Detector
Source Temperature | 230°C
Quadrupole Temperature | 150°C
Ionization Mode | Electron Ionization Positive (EI+)
Acquisition Mode | SIM for 30 minutes m/z 146 (1,2-DCB quantitation ion) m/z 111(1,2-DCB confirmation ion) m/z 152 (^13^C_6_ 1,2-DCB quantitation ion) m/z 117 (^13^C_6_ 1,2-DCB confirmation ion)

GC = gas chromatography; MS = mass spectrometry; ID = internal diameter; EI = electron ionization; SIM = single ion monitoring.

Table B-2 Method Validation Data for 1,2-Dichlorobenzene in Rat Blood

Parameter | Male Sprague Dawley Rat
Matrix Concentration Range (ng/mL) | 0.5–250^a^
Sensitivity
LLOQ (ng/mL) | 0.5
LOD (ng/mL) | 0.157
Coefficient of determination (r^2^) | >0.99
Accuracy (% RE)
Calibration standards intraday | ≤ ±8.4
Calibration standards interday | ≤ ±3.2
QC standards intraday^b^ | ≤ ±14.4
QC standards interday^b^ | ≤ ±3.2
Precision (% RSD)
Calibration standards intraday | ≤15.0
Calibration standards interday | ≤10.3
QC standards intraday^b^ | ≤6.9
QC standards interday^b^ | ≤12.8

LLOQ = lower limit of quantitation; LOD = limit of detection; RE = relative error; QC = quality control; RSD = relative standard deviation.

^a^ Range validated with seven matrix calibration standards.

^b^ Quality control standards prepared at 1, 25, and 200 ng/mL. n = 4 for intraday and n = 12 for interday except for 1 ng/mL where n = 1.

Table B-3 Method Dilution Verification Data for 1,2-Dichlorobenzene in Male Sprague Dawley Rat Blood

Parameter^a^ | 9,900 ng/mL^b^ | 19,600 ng/mL^c^ | 47,600 ng/mL^d^ | 90,900 ng/mL^e^
Accuracy (% RE) | 7.1 | 5.1 | 34.7 | –33.9
Precision (% RSD) | 0.5 | 0.5 | 0.4 | 0.1

RE = relative error; RSD = relative standard deviation.

^a^ All values are a result of three replicate quality control standards.

^b^ 50-fold dilution with blood containing internal standard (IS).

^c^ 100-fold dilution with blood containing IS.

^d^ 250-fold dilution with blood containing IS.

^e^ 500-fold dilution with blood containing IS.

Table B-4 Secondary Matrix Evaluation Data for 1,2-Dichlorobenzene

Matrix | Accuracy (%RE) | Precision (%RSD)
Harlan Sprague Dawley Rat Blood^a^ | ≤ ±23.0 | ≤5.4
Harlan Sprague Dawley Rat Liver^b^ | 25.8 | 2.8
Harlan Sprague Dawley Rat Liver, Dilution Verification^c^ | 15.3 | 9.4
Harlan Sprague Dawley Rat Lung^b^ | 25.3 | 3.3
B6C3F1 Mouse Blood^d^ | ≤ ±33.0 | ≤6.6
B6C3F1 Mouse Liver^b^ | 24.7 | 2.6
B6C3F1 Mouse Lung^b^ | 26.0 | 3.0
B6D2F1 Mouse Blood^e^ | ≤ ±11.2 | ≤1.5

RE = relative error; RSD = relative standard deviation.

^a^ Results from one analysis of six 1 ng/mL quality control (QC) standards and one analysis of three 1 ng/mL and three 25 ng/mL QC standards.

^b^ Results from one analysis of six 3.0 ng/g QC standards (1 part tissue:2 parts water).

^c^ Results from one analysis of four 150,000 ng/g samples diluted with blood at a 250-fold dilution.

^d^ Results from two analyses of six 1 ng/mL QC standards.

^e^ Results from one analysis of three 1 ng/mL and one analysis of three 25 ng/mL QC standards.

Table B-5 Storage Stability of 1,2-Dichlorobenzene in Sample Matrices

Matrix | Environment | Percent of Day 0
Sprague Dawley Rat Blood^a^ | Ambient, light | 80.5 to 102.1
Sprague Dawley Rat Blood^b^ | –70°C, dark | 74.3 to 79.3
Harlan Sprague Dawley Rat Liver^c^ | –70°C, dark | 98.7 to 108.3

^a^ Four replicate quality control (QC) standards at three concentrations (1, 25, and 200 ng/mL); processed with internal standard (IS), stored at ambient temperature in the light for 21 days, and injected with freshly processed matrix calibration standards.

^b^ Four replicate QC standards at three concentrations (1, 25, and 200 ng/mL); processed with IS, stored at –70°C for 149 days, and injected with freshly processed matrix calibration standards.

^c^ Four replicate QC standards at three concentrations (3, 75, and 600 ng/g); stored at –70°C for 100 days and injected with freshly processed matrix calibration standards.