# ACKNOWLEDGMENTS

The National Healthcare Quality and Disparities Report (NHQDR) is the product of collaboration among agencies from the U.S. Department of Health and Human Services (HHS), other Federal departments, and the private sector. Many individuals guided and contributed to this effort. Without their magnanimous support, the report would not have been possible. Specifically, we thank:

- Authors: Barbara Barton (AHRQ), Romsai Tony Boonyasai (AHRQ), Cecilia Hahn (AHRQ)
- Primary AHRQ Staff: David Meyers, Jeff Brady, Erin Grace, Karen Chaves, Irim Azam, Barbara Barton, Doreen Bonnett, Romsai Tony Boonyasai, Darryl Gray, and Cecilia Hahn.
- HHS Interagency Workgroup (IWG) for the NHQDR: Girma Alemu (HRSA), Irim Azam (AHRQ), Andreea Balan-Cohen (IMPAQ), Barbara Barton (AHRQ), Doreen Bonnett (AHRQ), Deron Burton (CDC), Victoria Chau (SAMHSA), Karen Chaves (AHRQ), Xiuhua Chen (Atlas Research), Deborah Duran (NIH-NIMHD), Melissa Evans (CMS), Camille Fabiyi (AHRQ), Darryl Gray (AHRQ), Kirk Greenway (IHS), Sarah Heppner (HRSA), Ed Huff (CMS), DeLoris Hunter (NIH-NIMHD), Susan Jenkins (ACL), Christine Lee (FDA), Doris Lefkowitz (AHRQ), Jesse Lichstein (HRSA), Lan Liang (AHRQ), Shari Ling (CMS), Iris Mabry-Hernandez (AHRQ), Marlene Matosky (HRSA), Tracy Matthews (HRSA), Christine Merenda (FDA), Kamila Mistry (AHRQ), Ernest Moy (VHA), Samia Noursi (NIH-NIDA), Kathy O’Connor (CDC), Rajasri Roy (NIH-OD-ORWH), Dianne Rucinski (OASH), Asel Ryskulova (CDC), Michelle Schreiber (CMS), Adelle Simmons (ASPE), Robin Streeter (HRSA), Loida Tamayo (CMS), Caroline Taplin (ASPE), Emmanuel Taylor (NIH-NCI), Anjel Vahratian (CDC), Michelle Washko (HRSA), and Ying Zhang (HIS).
- Data Support Contractors: Atlas Research, IMPAQ International.