# ACKNOWLEDGMENTS

The National Healthcare Quality and Disparities Report (NHQDR) is the product of collaboration among agencies across the U.S. Department of Health and Human Services (HHS). Many individuals guided and contributed to this effort. Without their magnanimous support, this chartbook would not have been possible. Specifically, we thank:

Authors:

- AHRQ: Irim Azam, Darryl Gray, Doreen Bonnett, and Cecilia Hahn.
- Health Services Advisory Group (HSAG): Rob Fornango, Gosia Skinner, Paul Niemann, David Carnell, Cindy Strickland, Fredericka Thompson, Michael Lichter, and Mitchell Keener.

Primary AHRQ Staff: David Meyers, Jeff Brady, Erin Grace, Margie Shofer, Karen Chaves, Barbara Barton, Doreen Bonnett, Irim Azam, Darryl Gray, Romsai (Tony) Boonyasai, Cecilia Hahn, Lan Liang, Pradip Muhuri, Tahleah Chappel, Caren Ginsburg, Elma Chowdhury, Jim Cleeman, and Noel Eldridge.

AHRQ Patient Safety Team Reviewers: Cindy Brach, Emily Chew, Jim Cleeman, Paula DiStable, Noel Eldridge, Camille Fabiyi, Caren Ginsburg, Monika Haugstetter, Lawrence Reid, Margie Shofer, Tselote Tilahun, Andrea Timashenka.

HHS Interagency Workgroup (IWG) for the NHQDR: Girma Alemu (HRSA), Irim Azam (AHRQ), Andreea Balan-Cohen (IMPAQ), Barbara Barton (AHRQ), Doreen Bonnett (AHRQ), Deron Burton (CDC), Victoria Chau (SAMHSA), Karen Chaves (AHRQ), Xiuhua Chen (Atlas Research), Deborah Duran (NIH-NIMHD), Melissa Evans (CMS), Camille Fabiyi (AHRQ), Darryl Gray (AHRQ), Kirk Greenway (IHS), Sarah Heppner (HRSA), Ed Huff (CMS), DeLoris Hunter (NIH-NIMHD), Susan Jenkins (ACL), Christine Lee (FDA), Doris Lefkowitz (AHRQ), Jesse Lichstein (HRSA), Lan Liang (AHRQ), Shari Ling (CMS), Iris Mabry-Hernandez (AHRQ), Marlene Matosky (HRSA), Tracy Matthews (HRSA), Christine Merenda (FDA), Kamila Mistry (AHRQ), Ernest Moy (VHA), Samia Noursi (NIH-NIDA), Kathy O’Connor (CDC), Dianne Rucinski (OASH), Asel Ryskulova (CDC), Yahtyng Sheu (HRSA), Adelle Simmons (ASPE), Loida Tamayo (CMS), Caroline Taplin (ASPE), Emmanuel Taylor (NIH-NCI), Michelle Washko (HRSA), and Ying Zhang (IHS).

Data Support Contractors:

- ActioNet: Tomas Montgomery, Robyn Thomas
- HSAG: Rob Fornango, Gosia Skinner, Paul Niemann, David Carnell, Cindy Strickland, Fredericka Thompson, Michael Lichter, Mitchell Keener
- Atlas: Xiuhua Chen
- Westat: Theresa Famolaro, Naomi Yount