# ACKNOWLEDGMENTS

The National Healthcare Quality and Disparities Report (NHQDR) is the product of collaboration among agencies across the U.S. Department of Health and Human Services (HHS). Many individuals guided and contributed to this effort. Without their magnanimous support, this chartbook C not have been possible. We also appreciate the collaboration of the Veterans Health Administration, Department of Veterans Affairs. Specifically, we thank:

Authors:

- IMPAQ: Abigail Woodroffe, Andreea Balan-Cohen, Ben DeWinkle, Fan Huang, Colleen McLelland, Mary Nishioka
- Veterans Health Administration, Office of Health Equity: Ernest Moy, Lauren Korshak, Kenneth Jones
- AHRQ: Karen Chaves, Irim Azam, Doreen Bonnett, Cecilia Hahn

Special Data Analyses:

- National Center for Health Statistics: Carla Zelaya, Peter Boersma
- VHA OHE/QUERI National Partnered Evaluation Initiative: Donna Washington

Primary AHRQ Staff: Gopal Khanna, David Meyers, Jeff Brady, Francis Chesley, Erin Grace, Karen Chaves, Barbara Barton, Cecilia Hahn, Irim Azam, Doreen Bonnett.

HHS Interagency Workgroup for the NHQDR: Irim Azam (AHRQ/CQuIPS), Girma Alemu HRSA), Doreen Bonnett (AHRQ/OC), Deron Burton (CDC/DDID/NCHHSTP/OD), Victoria Chau (SAMHSA), Karen H. Chaves (AHRQ), Christine Lee (FDA), Deborah Duran NIH/NIMHD), Ernest Moy (VA), Melissa Evans (CMS/CCSQ), Camille Fabiyi (AHRQ/OEREP), Darryl Gray (AHRQ/CQuIPS), Kirk Greenway (IHS/HQ), Sarah Heppner HRSA), Edwin D. Huff (CMS/CCSQ), DeLoris Hunter (NIH/NIMHD), Susan M. Jenkins ACL), Doris C. Lefkowitz (AHRQ/CFACT), Lan Liang (AHRQ/CFACT), Jesse Lichstein HRSA), Shari Ling (CMS/CCSQ), Iris Mabry-Hernandez (AHRQ/CEPI), Marlene Matosky HRSA), Tracy Matthews (HRSA), Christine Merenda (FDA), Kamila Mistry (AHRQ/OEREP), Pradip Muhuri (AHRQ/CFACT), Samia Noursi (NIH/NIDA), Kathy O’Connor CDC/DDPHSS/NCHS/DHCS), Paul Gorrell (Atlas Research), Rajasri Roy (NIH/NCI), Dianne Rucinski (OS/OASH), Asel Ryskulova (CDC/DDPHSS/NCHS/DAE), Adelle Simmons (HHS/ASPE), Robin Streeter (HRSA), Loida Tamayo (CMS/OMH), Caroline Taplin (HHS/ASPE), Emmanuel Taylor (NIH/NCI), Michelle Washko (HRSA), Ellen Werner NIH/NHLBI), Xiuhua Chen (Atlas Research), Ying Zhang (IHS/HQ).

Data Support Contractors:

- IMPAQ: Abigail Woodroffe, Andreea Balan-Cohen, Ben DeWinkle, Fan Huang, Colleen McLelland, Mary Nishioka
- Atlas Research: Paul Gorrell, Xiuhua Chen