# CONTRAST 2 FINDINGS: DISPARITIES WITHIN THE VETERAN POPULATION

## Disparities in the Veteran Population by Age, Gender, and Ethnicity

Bar graph. Veterans age 45-64 experienced better care than Veterans age 18-44 on 6 measures (30%), similar on 13 measures (65%), and worse on 1 measure (5%). Veterans age 65+ experienced better care than Veterans age 18-44 on 8 measures (50%), similar on 5 measures (31%), and worse on 3 measures (19%). Female Veterans experienced better care than male Veterans on 1 measure (6%) and similar on 17 measures (94%). Hispanic Veterans experienced better care than non-Hispanic white Veterans on 1 measure (5%) and similar on 20 measures (95%). Non-Hispanic black Veterans experienced better care than non-Hispanic white Veterans on 1 measure (5%), similar on 18 measures (82%), and worse on 3 measures (14%). Key: y.o. = years old; NH = non-Hispanic. Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017; and Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018. Note: For the nine National Health Interview Survey measures, the youngest age category was 20-49 years old and the middle age category was 50-64 years old.

- Importance: The goal of quality improvement is to produce better quality of and access to care, and ultimately improved patient outcomes, regardless of Veteran characteristics.
- Findings: For the most recent 4-year period of data (2014–2017 or 2015–2018), findings show that some age, gender, and racial/ethnic disparities persist.
  ■ Age
    ⧫ Veterans ages 45–64 (ages 49–64 for National Health Interview Survey [NHIS] measures) experienced better care than Veterans ages 18–44 (ages 20–49 for NHIS measures) on 6 measures (30%), similar care on 13 measures (65%), and worse care on 1 measure (5%).
    ⧫ Veterans age 65+ experienced better care than Veterans ages 18–44 (ages 20–49 for NHIS measures) on 8 measures (50%), similar care on 5 measures (31%), and worse care on 3 measures (19%).
  ■ Gender
    ⧫ Female Veterans experienced better care than male Veterans on 1 measure (6%) and similar care on 17 measures (94%).
  ■ Race/Ethnicity
    ⧫ Hispanic Veterans experienced better care than non-Hispanic White Veterans on 1 measure (5%) and similar care on 20 measures (95%).
    ⧫ Non-Hispanic Black Veterans experienced better care than non-Hispanic White Veterans on 1 measure (5%), similar care on 18 measures (82%), and worse care on 3 measures (14%).

## Disparities in the Veteran Population by Various Demographic Categories

Stacked bar chart For the most 2014-2017 or 2015-2018: Rural Veterans experienced similar care as urban Veterans on 7 measures (78%) and worse on 2 measures (22%). Veterans with limited activity experienced better care than Veterans without limited activity on 3 measures (13%), similar on 11 measures (48%), and worse on 9 measures (39%). Veterans with a high school degree or less education experienced similar care as Veterans with at least some college on 20 measures (83%) and worse on 4 measures (17%). Veterans with incomes below the poverty line experienced similar care as Veterans with middle or high incomes on 9 measures (69%) and worse on 4 measures (31%). Veterans with incomes just above the poverty line experienced similar care as Veterans with middle or high incomes on 15 measures (75%) and worse on 5 measures (25%). Veterans with public insurance experienced similar care as Veterans with private insurance on 4 measures (100%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017; and Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: The goal of quality improvement is to produce better quality of and access to care, and ultimately improved patient outcomes, regardless of Veteran characteristics.
- Findings: For the most recent 4-year period of data (2014–2017 or 2015–2018), findings show that some location, disability status, educational, and income disparities persist.
  ■ Location
    ⧫ Rural Veterans experienced care similar to urban Veterans on 7 measures (78%) and worse care on 2 measures (22%).
  ■ Disability Status
    ⧫ Veterans with limited activity experienced better care than Veterans without limited activity on 3 measures (13%), similar care on 11 measures (48%), and worse care on 9 measures (39%).
  ■ Education
    ⧫ Veterans with a high school degree or less education experienced care similar to Veterans with at least some college on 20 measures (83%) and worse care on 4 measures (17%).
  ■ Income
    ⧫ Veterans with incomes below the poverty line experienced care similar to Veterans with middle or high incomes on 9 measures (69%) and worse care on 4 measures (31%).
    ⧫ Veterans with incomes just above the poverty line experienced care similar to Veterans with middle or high incomes on 15 measures (75%) and worse care on 5 measures (25%).
  ■ Insurance
    ⧫ Veterans with public insurance experienced care similar to Veterans with private insurance on 4 measures (100%).

## Usual Primary Care Provider

Usual Primary Care Provider, by Age, Gender, and Ethnicity

Bar Graph. Veterans 18 to 44 years old had 63.2%, Veterans 45-64 years of age had 80.1%, and vetrans aged 65 or older had 90.7%. Female Veterans had 83.6% and male veterans had 82.5%. Hispanic veterans had 72.6%, non hispanic Black veterans had 81.8%, and non hispanic white veterans had 84.2% Key: y.o. = years old; NH = non-Hispanic. Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017.

- Importance: Having a usual source of care can decrease the probability of inpatient admissions and readmissions and decrease expenditures on emergency department visits for physical health, 30-day readmissions, and behavioral health inpatient admissions. It also has a positive effect on several quality measures (Fullerton, et al., 2019).
- Overall Rate: In 2014–2017, 82.6% of Veterans ages 18+ had a usual source of care (data not shown).
- Groups With Disparities: In 2014–2017, findings show significant disparities by age but not gender or race/ethnicity.
  ■ Age
    ⧫ Veterans ages 45–64 were significantly more likely to have a primary care provider compared with Veterans ages 18–44 (80.1% vs. 63.2%).
    ⧫ Veterans age 65+ were significantly more likely to have a primary care provider compared with Veterans ages 18–44 (90.7% vs. 63.2%).
  ■ Gender
    ⧫ There were no statistically significant differences between female Veterans and male Veterans in the percentage with a primary care provider (83.6% vs. 82.5%).
  ■ Race/Ethnicity
    ⧫ There were no statistically significant differences between Hispanic Veterans and non-Hispanic White Veterans in the percentage with a primary care provider (72.6% vs. 84.2%).
    ⧫ There were no statistically significant differences between non-Hispanic Black Veterans and non-Hispanic White Veterans in the percentage with a primary care provider (81.8% vs. 84.2%).

Usual Primary Care Provider, by Disability, Education, and Income

Key: y.o. = years old; NH = non-Hispanic. Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017. Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017. Note: The data for rural vs. urban location and private vs. public insurance did not meet criterial for statistical reliability and are not included.

- Importance: Having a usual source of care can decrease the probability of inpatient admissions and readmissions and decrease expenditures on emergency department visits for physical health, 30-day readmissions, and behavioral health inpatient admissions. It also has a positive effect on several quality measures (Fullerton, et al., 2019).
- Overall Rate: In 2014–2017, 82.6% of Veterans age 18+ had a usual source of care (data not shown).
- Groups With Disparities: In 2014–2017, findings do not show significant disparities by activity status, education, or income.
  ■ Activity Status
    ⧫ There were no statistically significant differences between Veterans with limited activity and Veterans without limited activity in the percentage with a primary care provider (88.6% vs. 81.2%).
  ■ Education
    ⧫ There were no statistically significant differences between Veterans with high school or less education and Veterans with at least some college education in the percentage with a primary care provider (80.5% vs. 82.6%).
  ■ Income
    ⧫ There were no statistically significant differences between Veterans who were poor and Veterans with middle or high income in the percentage with a primary care provider (78.4% vs. 82.8%).
    ⧫ There were no statistically significant differences between Veterans with near poverty income and Veterans with middle or high income in the percentage with a primary care provider (83.2% vs. 82.8%).

Usual Primary Care Provider, Trends by Age and Gender

Line Graph. Percent of Veterans with a usual primary care provider, 2014-2017: Female Veterans age 18-44 (71.0% vs. 80.1%) Female Veterans age 45-64 (81.4% vs. 81.7%). Female Veterans age 65+ (89.4% vs. 90.8%). Male Veterans age 18-44 (63.3% vs. 58.4%). Male Veterans age 45-64 (82.4% vs. 79.0%). Male Veterans age 65+ (91.6% vs. 89.9%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017. Note: The data for female Veterans age 65+ in 2014 did not meet criterial for statistical reliability and are not included.

- Importance: Having a usual source of care can decrease the probability of inpatient admissions and readmissions and decrease expenditures on emergency department visits for physical health, 30-day readmissions, and behavioral health inpatient admissions. It also has a positive effect on several quality measures (Fullerton, et al., 2019).
- Overall Rate: In 2014–2017, 82.6% of Veterans had a usual primary care provider (data not shown).
- Trends: From 2014–2017, findings show varying trends across Veterans of different age/gender categories:
  ■ Female Veterans ages 18–44 had an increase in the percentage with a usual primary care provider from 2014 to 2017 (71.0% to 80.1%).
  ■ Female Veterans ages 45–64 had an increase in the percentage with a usual primary care provider from 2014 to 2017 (81.4% to 81.7%).
  ■ Female Veterans age 65+ had an increase in the percentage with a usual primary care provider from 2015 to 2017 (89.4% to 90.8%).
  ■ Male Veterans ages 18–44 had a decrease in the percentage with a usual primary care provider from 2014 to 2017 (63.3% to 58.4%).
  ■ Male Veterans ages 45–64 had a decrease in the percentage with a usual primary care provider from 2014 to 2017 (82.4% to 79.0%).
  ■ Male Veterans age 65+ had a decrease in the percentage with a usual primary care provider from 2014 to 2017 (91.6% to 89.9%).

## Dental Visits

Dental Visits, by Age, Gender, and Ethnicity

Bar Graph. Percent of Veterans who indicated a dental visit in the past calendar year, 2014-2017: Veterans age 45-64 compared to Veterans age 18-44 (42.1% vs. 32.1%);Veterans age 65+ compared to Veterans age 18-44 (48.7% vs. 32.1%); Female Veterans compared to male Veterans (49.4% vs. 43.2%); Hispanic Veterans compared to non-Hispanic white Veterans (39.9% vs. 45.4%); Non-Hispanic black Veterans compared to non-Hispanic white Veterans (31.1% vs. 45.4%). Key: y.o. = years old; NH = non-Hispanic. Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017.

- Importance: Oral health is important to an individual’s overall health and well-being. While advances in oral health have benefited most Americans, some cannot afford all the care they need, resulting in needless pain and suffering, complications that may devastate overall health and well-being, and social costs that diminish quality of life (National Institute of Dental and Craniofacial Research, 2000).
- Overall Rate: In 2014–2017, 43.8% of Veterans had a dental visit in the past year (data not shown).
- Groups With Disparities: In 2014–2017, findings show significant disparities by age but not gender or race/ethnicity.
  ■ Age
    ⧫ Veterans ages 45–64 were significantly more likely to have a dental visit compared with Veterans ages 18–44 (42.1% vs. 32.1%).
    ⧫ Veterans age 65+ were significantly more likely to have a dental visit compared with Veterans ages 18–44 (48.7% vs. 32.1%).
  ■ Gender
    ⧫ There were no statistically significant differences between female Veterans and male Veterans in the percentage who had a dental visit (49.4% vs. 43.2%).
  ■ Race/Ethnicity
    ⧫ There were no statistically significant differences between Hispanic Veterans and non-Hispanic White Veterans in the percentage who had a dental visit (39.9% vs. 45.4%).
    ⧫ There were no statistically significant differences between non-Hispanic Black Veterans and non-Hispanic White Veterans in the percentage who had a dental visit (31.1% vs. 45.4%).

Dental Visits, by Disability, Education, and Income

Bar Graph. Percent of Veterans who indicated a dental visit in the past calendar year, 2014-2017 Veterans with limited activity compared to Veterans without limited activity (31.4% vs. 45.9%); Veterans with a high school degree or less compared to Veterans with at least some college (31.5% vs. 51.3%); Veterans with incomes just above the poverty compared to Veterans with middle or high incomes (28.9% vs. 46.3%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017. Note: The data for poor vs. middle/high income, rural vs. urban location, and private vs. public insurance did not meet criterial for statistical reliability and are not included.

- Importance: Oral health is important to an individual’s overall health and well-being. While advances in oral health have benefited most Americans, some cannot afford all the care they need, resulting in needless pain and suffering, complications that may devastate overall health and well-being, and social costs that diminish quality of life (National Institute of Dental and Craniofacial Research, 2000).
- Overall Rate: In 2014–2017, 43.8% of Veterans had a dental visit in the past year (data not shown).
- Groups With Disparities: In 2014–2017, findings show significant disparities by activity status, education, and income.
  ■ Activity Status
    ⧫ Veterans with limited activity were significantly less likely to have a dental visit compared with Veterans without limited activity (31.4% vs. 45.9%).
  ■ Education
    ⧫ Veterans with a high school degree or less education were significantly less likely to have a dental visit compared with Veterans with at least some college (31.5% vs. 51.3%).
  ■ Income
    ⧫ Veterans with incomes just above the poverty line (i.e., near poverty) were significantly less likely to have a dental visit compared with Veterans with middle or high incomes (28.9% vs. 46.3%).

Dental Visits, Trends by Age and Gender

Line Graph. Percent of Veterans who indicated a dental visit in the past calendar year, 2014-2017: Female Veterans age 18-44 (42.9% vs. 59.1%); Female Veterans age 45-64 (39.6% vs. 53.9%); Female Veterans age 65+ (43.1% vs. 67.7%); Male Veterans age 18-44 (33.3% vs. 26.7%); Male Veterans age 45-64 (46.9% vs. 37.9%); Male Veterans age 65+ (48.8% vs. 48.1%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017. Note: The data for female Veterans age 65+ in 2014 did not meet criterial for statistical reliability and are not included.

- Importance: Oral health is important to an individual’s overall health and well-being. While advances in oral health have benefited most Americans, some cannot afford all the care they need, resulting in needless pain and suffering, complications that may devastate overall health and well-being, and social costs that diminish quality of life (National Institute of Dental and Craniofacial Research, 2000).
- Overall Rate: In 2014–2017, 43.8% of Veterans had a dental visit in the past year (data not shown).
- Trends: From 2014–2017, findings show varying trends across Veterans of different age/gender categories.
  ■ Female Veterans ages 18–44 had an increase in the percentage with a dental visit from 2014 to 2017 (42.9% to 59.1%).
  ■ Female Veterans ages 45–64 had an increase in the percentage with a dental visit from 2014 to 2017 (39.6% to 53.9%).
  ■ Female Veterans age 65+ had an increase in the percentage with a dental visit from 2015 to 2017 (43.1% to 67.7%).
  ■ Male Veterans ages 18–44 had a decrease in the percentage with a dental visit from 2014 to 2017 (33.3% to 26.7%).
  ■ Male Veterans ages 45–64 had a decrease in the percentage with a dental visit from 2014 to 2017 (46.9% to 37.9%).
  ■ Male Veterans age 65+ had a decrease in the percentage with a dental visit from 2014 to 2017 (48.8% to 48.1%).

## Receipt of Influenza Vaccination

Receipt of Influenza Vaccination, by Age, Gender, and Ethnicity

Bar Graph. Percent of Veterans who received an influenza vaccination in the past 12 months, 2015-2018: Veterans age 50-64 compared to Veterans age 20-49 (49.0% vs. 44.8%). Veterans age 65+ compared to Veterans age 20-49 (71.5% vs. 44.8%). Female Veterans compared to male Veterans (57.3% vs. 49.1%); Hispanic Veterans compared to non-Hispanic white Veterans (51.4% vs. 49.9%); Non-Hispanic black Veterans compared to non-Hispanic white Veterans (49.2% vs. 49.9%). Ke: y.o. = years old; NH = non-Hispanic. Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: Each year, millions of Americans get sick with influenza. Sometimes it causes mild illness but it can also be serious or even deadly, especially for people over 65, newborn babies, and people with certain chronic illnesses (NLM, 2020). Vaccination can prevent influenza and reduce influenza-related morbidity and mortality (CDC, 2019).
- Overall Rate: In 2015–2018, 50.2% of Veterans age 20+ had an influenza vaccination in the past 12 months (data not shown).
- Groups With Disparities: In 2015–2018, findings show significant disparities by age and gender but not race/ethnicity.
  ■ Age
    ⧫ There were no statistically significant differences between Veterans ages 50–64 and Veterans ages 20–49 in the percentage who received an influenza vaccination (49.0% vs. 44.8%).
    ⧫ Veterans age 65+ were significantly more likely to have an influenza vaccination compared with Veterans ages 20–49 (71.5% vs. 44.8%).
  ■ Gender
    ⧫ Female Veterans were significantly more likely to have an influenza vaccination compared with male Veterans (57.3% vs. 49.1%).
  ■ Race/Ethnicity
    ⧫ There were no statistically significant differences between Hispanic Veterans and non-Hispanic White Veterans in the percentage who received an influenza vaccination (51.4% vs. 49.9%).
    ⧫ There were no statistically significant differences between non-Hispanic Black Veterans and non-Hispanic White Veterans in the percentage who received an influenza vaccination (49.2% vs. 49.9%).

Receipt of Influenza Vaccination, by Residence Location, Disability, Education, and Income

Bar Graph: Percent of Veterans who received an influenza vaccination in the past 12 months, 2015-2018: Rural Veterans compared to urban Veterans (44.4% vs. 51.1%). Veterans with limited activity compared to Veterans without limited activity (50.5% vs. 48.9%). Veterans with a high school degree or less education compared to Veterans with at least some college (42.7% vs. 55.0%). Veterans with incomes below the poverty line compared to Veterans with middle or high incomes (45.6% vs. 51.9%). Veterans with incomes just above the poverty line compared to Veterans with middle or high incomes (41.9% vs. 51.9%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018. Note: The data for private vs. public insurance did not meet criterial for statistical reliability and are not included.

- Importance: Each year, millions of Americans get sick with influenza. Sometimes it causes mild illness but it can also be serious or even deadly, especially for people over 65, newborn babies, and people with certain chronic illnesses (NLM, 2020). Vaccination can prevent influenza and reduce influenza-related morbidity and mortality (CDC, 2019).
- Overall Rate: In 2015–2018, 50.2% of Veterans age 20+ had an influenza vaccination in the past 12 months (data not shown).
- Groups With Disparities: In 2015–2018, findings show significant disparities by location, education, and income but not activity status.
  ■ Location
    ⧫ Rural Veterans were significantly less likely to have an influenza vaccination compared with urban Veterans (44.4% vs. 51.1%).
  ■ Activity Status
    ⧫ There were no statistically significant differences between Veterans with limited activity and Veterans without limited activity in the percentage who received an influenza vaccination (50.5% vs. 48.9%).
  ■ Education
    ⧫ Veterans with a high school degree or less education were significantly less likely to have an influenza vaccination compared with Veterans with at least some college (42.7% vs. 55.0%).
  ■ Income
    ⧫ There were no statistically significant differences between Veterans with incomes below the poverty line and Veterans with middle or high incomes in the percentage who received an influenza vaccination (45.6% vs. 51.9%).
    ⧫ Veterans with incomes just above the poverty line were significantly less likely to have an influenza vaccination compared with Veterans with middle or high incomes (41.9% vs. 51.9%).

## Receipt of Shingles Vaccination

Receipt of Shingles Vaccination, by Age, Gender, and Ethnicity

Bar chart Percent of Veterans who received a shingles vaccination in the past 12 months, 2015-2018: Veterans age 65+ compared to Veterans age 50-64 (41.0% vs. 11.1%). Female Veterans compared to male Veterans (28.5% vs. 24.4%). Hispanic Veterans compared to non-Hispanic white Veterans (21.2% vs. 25.9%). Non-Hispanic black Veterans compared to non-Hispanic white Veterans (15.5% vs. 25.9%). Key: y.o. = years old; NH = non-Hispanic. Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: Shingles is a painful rash that usually develops on one side of the body, often the face or torso. For some people, long-lasting pain, which can last for months or even years after the rash goes away, is the most common complication of shingles. The risk of getting shingles increases with age (CDC, 2016) but decreases with vaccination (CDC, 2018).
- Overall Rate: In 2015–2018, 24.8% of Veterans age 50+ had a shingles vaccination in the past 12 months (data not shown).
- Groups With Disparities: In 2015–2018, findings show significant disparities by age and race/ethnicity but not gender.
  ■ Age
    ⧫ Veterans age 65+ were significantly more likely to have a shingles vaccination compared with Veterans ages 50–64 (41.0% vs. 11.1%).
  ■ Gender
    ⧫ There were no statistically significant differences between female Veterans and male Veterans in the percentage who received a shingles vaccination (28.5% vs. 24.4%).
  ■ Race/Ethnicity
    ⧫ There were no statistically significant differences between Hispanic Veterans and non-Hispanic White Veterans in the percentage who received a shingles vaccination (21.2% vs. 25.9%).
    ⧫ Non-Hispanic Black Veterans were significantly less likely to have a shingles vaccination compared with non-Hispanic White Veterans (15.5% vs. 25.9%).

Receipt of Shingles Vaccination, by Residence Location, Disability, Education, and Income

Bar Graph. Percent of Veterans who received a shingles vaccination in the past 12 months, 2015-2018: Rural Veterans compared to urban Veterans (23.6% vs. 25.0%). Veterans with limited activity compared to Veterans without limited activity (22.8% vs. 25.4%). Veterans with a high school degree or less education compared to Veterans with at least some college (19.1% vs. 29.3%). Veterans with incomes below the poverty line compared to Veterans with middle or high incomes (19.6% vs. 26.3%). Veterans with incomes just above the poverty compared to Veterans with middle or high incomes (17.8% vs. 26.3%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018. Note: The data for private vs. public insurance did not meet criterial for statistical reliability and are not included.

- Importance: Shingles is a painful rash that usually develops on one side of the body, often the face or torso. For some people, long-lasting pain, which can last for months or even years after the rash goes away, is the most common complication of shingles. The risk of getting shingles increases with age (CDC, 2016) but decreases with vaccination (CDC, 2018).
- Overall Rate: In 2015–2018, 24.8% of Veterans age 50+ had a shingles vaccination in the past 12 months (data not shown).
- Groups With Disparities: In 2015–2018, findings show significant disparities by education and income but not location or activity status.
  ■ Location
    ⧫ There were no statistically significant differences between rural Veterans and urban Veterans in the percentage who received a shingles vaccination (23.6% vs. 25.0%).
  ■ Activity Status
    ⧫ There were no statistically significant differences between Veterans with limited activity and Veterans without limited activity in the percentage who received a shingles vaccination (22.8% vs. 25.4%).
  ■ Education
    ⧫ Veterans with a high school degree or less education were significantly less likely to have a shingles vaccination compared with Veterans with at least some college (19.1% vs. 29.3%).
  ■ Income
    ⧫ Veterans with incomes below the poverty line were significantly less likely to have a shingles vaccination compared with Veterans with middle or high incomes (19.6% vs. 26.3%).
    ⧫ Veterans with incomes just above the poverty line were significantly less likely to have a shingles vaccination compared with Veterans with middle or high incomes (17.8% vs. 26.3%).

## Cholesterol Screening

Receipt of Cholesterol Screening, by Age, Gender, and Ethnicity

Bar Graph. Percent of Veterans who received a cholesterol screening in the past 12 months, 2015-2018: Veterans age 50-64 compared better to Veterans age 20-49 (81.1% vs. 61.1%). Veterans age 65+ compared better to Veterans age 20-49 (91.1% vs. 61.1%). Female Veterans compared the same to male Veterans (73.4% vs. 70.7%). Hispanic Veterans compared the same to non-Hispanic white Veterans (74.1% vs. 68.8%). Non-Hispanic Black Veterans compared better to non-Hispanic white Veterans (80.9% vs. 68.8%). Key: y.o. = years old; NH = non-Hispanic. Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: About 95 million Americans age 20 and older have total cholesterol levels higher than 200 mg/dL and nearly 29 million have total cholesterol levels higher than 240 mg/dL. High cholesterol raises the risk of heart disease, the leading cause of death, and stroke, the fifth leading cause of death (CDC, 2020).
- Overall Rate: In 2015–2018, 71.3% of Veterans age 20+ had a cholesterol screening (data not shown).
- Groups With Disparities: In 2015–2018, findings show significant disparities by age and race/ethnicity but not gender.
  ■ Age
    ⧫ Veterans ages 50–64 were significantly more likely to have a cholesterol screening compared with Veterans ages 20–49 (81.1% vs. 61.1%).
    ⧫ Veterans age 65+ were significantly more likely to have a cholesterol screening compared with Veterans ages 20–49 (91.1% vs. 61.1%).
  ■ Gender
    ⧫ There were no statistically significant differences between female Veterans and male Veterans in the percentage who received a cholesterol screening (73.4% vs. 70.7%).
  ■ Race/Ethnicity
    ⧫ There were no statistically significant differences between Hispanic Veterans and non-Hispanic White Veterans in the percentage who received a cholesterol screening (74.1% vs. 68.8%).
    ⧫ Non-Hispanic Black Veterans were significantly more likely to have a cholesterol screening compared with non-Hispanic White Veterans (80.9% vs. 68.8%).

Receipt of Cholesterol Screening, by Residence Location, Disability, Education, and Income

Bar Graph. Percent of Veterans who received a cholesterol screening in the past 12 months, 2015-2018: Rural Veterans compared the same to urban Veterans (68.1% vs. 71.9%). Veterans with limited activity compared better to Veterans without limited activity (81.8% vs. 69.8%). Veterans with a high school degree or less education compared the same to Veterans with at least some college (70.4% vs. 75.9%). Veterans with incomes below the poverty line compared the same to Veterans with middle or high incomes (70.3% vs. 71.9%). Veterans with incomes just above the poverty line compared the same to Veterans with middle or high incomes (67.6% vs. 71.9%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018. Note: The data for private vs. public insurance did not meet criterial for statistical reliability and are not included.

- Importance: About 95 million Americans age 20 and older have total cholesterol levels higher than 200 mg/dL and nearly 29 million have total cholesterol levels higher than 240 mg/dL. High cholesterol raises the risk of heart disease, the leading cause of death, and stroke, the fifth leading cause of death (CDC, 2020).
- Overall Rate: In 2015–2018, 71.3% of Veterans age 20+ had a cholesterol screening (data not shown).
- Groups With Disparities: In 2015–2018, findings show significant disparities by activity status but not location, education, or income.
  ■ Location
    ⧫ There were no statistically significant differences between rural Veterans and urban Veterans in the percentage who received a cholesterol screening (68.1% vs. 71.9%).
  ■ Activity Status
    ⧫ Veterans with limited activity were significantly more likely to have a cholesterol screening compared with Veterans without limited activity (81.8% vs. 69.8%).
  ■ Education
    ⧫ There were no statistically significant differences between Veterans with a high school degree or less education and Veterans with at least some college in the percentage who received a cholesterol screening (70.4% vs. 75.9%).
  ■ Income
    ⧫ There were no statistically significant differences between Veterans with incomes below the poverty line and Veterans with middle or high incomes in the percentage who received a cholesterol screening (70.3% vs. 71.9%).
    ⧫ There were no statistically significant differences between Veterans with incomes just above the poverty line and Veterans with middle or high incomes in the percentage who received a cholesterol screening (67.6% vs. 71.9%).

## Glucose Screening

Receipt of Glucose Screening, by Age, Gender, and Ethnicity

Bar Graph. Percent of Veterans who received a glucose screening in the past 12 months, 2015-2018: Veterans age 50-64 compared better to Veterans age 20-49 (65.3% vs. 44.4%). Veterans age 65+ compared better to Veterans age 20-49 (71.6% vs. 44.4%). Female Veterans compared the same to male Veterans (56.2% vs. 53.7%). Hispanic Veterans compared better to non-Hispanic White Veterans (59.1% vs. 53.3%). Non-Hispanic black compared the same to non-Hispanic White Veterans (56.8% vs. 53.3%). Key: y.o. = years old; NH = non-Hispanic. Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: Glucose screening is a test used to diagnose prediabetes and type 1, type 2, or gestational diabetes. Diabetes is a chronic health condition in which the body either does not make enough insulin or cannot use the insulin it makes as well as it should. Diabetes is a leading cause of morbidity and mortality in the United States (CDC, 2019, 2020).
- Overall Rate: In 2015–2018, 54.3% of Veterans age 20+ had a glucose screening (data not shown).
- Groups With Disparities: In 2015–2018, findings show significant disparities by age and race/ethnicity but not gender.
  ■ Age
    ⧫ Veterans ages 50–64 were significantly more likely to have a glucose screening compared with Veterans ages 20–49 (65.3% vs. 44.4%).
    ⧫ Veterans age 65+ were significantly more likely to have a glucose screening compared with Veterans ages 20–49 (71.6% vs. 44.4%).
  ■ Gender
    ⧫ There were no statistically significant differences between female Veterans and male Veterans in the percentage who received a glucose screening (56.2% vs. 53.7%).
  ■ Race/Ethnicity
    ⧫ Hispanic Veterans were significantly more likely to have a glucose screening compared with non-Hispanic White Veterans (59.1% vs. 53.3%).
    ⧫ There were no statistically significant differences between non-Hispanic Black Veterans and non-Hispanic White Veterans in the percentage who received a glucose screening (56.8% vs. 53.3%).

Receipt of Glucose Screening, by Residence Location, Disability, Education, and Income

Bar Graph. Percent of Veterans who received a glucose screening in the past 12 months, 2015-2018: Rural Veterans compared the same to urban Veterans (52.3% vs. 54.7%). Veterans with limited activity compared the same to Veterans without limited activity (60.0% vs. 52.8%). Veterans with a high school degree or less compared worse to Veterans with at least some college (51.2% vs. 59.9%). Veterans with incomes below the poverty compared the same to Veterans with middle or high incomes (51.3% vs. 56.0%). Veterans with incomes just above the poverty line compared worse to Veterans with middle or high incomes (46.9% vs. 56.0%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018. Note: The data for private vs. public insurance did not meet criterial for statistical reliability and are not included.

- Importance: Glucose screening is a test used to diagnose prediabetes and type 1, type 2, or gestational diabetes. Diabetes is a chronic health condition in which the body either does not make enough insulin or cannot use the insulin it makes as well as it should. Diabetes is a leading cause of morbidity and mortality in the United States (CDC, 2019, 2020).
- Overall Rate: In 2015–2018, 54.3% of Veterans age 20+ had a glucose screening (data not shown).
- Groups With Disparities: In 2015–2018, findings show significant disparities by education and income but not location or activity status.
  ■ Location
    ⧫ There were no statistically significant differences between rural Veterans and urban Veterans in the percentage who received a glucose screening (52.3% vs. 54.7%).
  ■ Activity Status
    ⧫ There were no statistically significant differences between Veterans with limited activity and Veterans without limited activity in the percentage who received a glucose screening (60.0% vs. 52.8%).
  ■ Education
    ⧫ Veterans with a high school degree or less education were significantly less likely to have a glucose screening compared with Veterans with at least some college (51.2% vs. 59.9%).
  ■ Income
    ⧫ There were no statistically significant differences between Veterans with incomes below the poverty line and Veterans with middle or high incomes in the percentage who received a glucose screening (51.3% vs. 56.0%).
    ⧫ Veterans with incomes just above the poverty line were significantly less likely to have a glucose screening compared with Veterans with middle or high incomes (46.9% vs. 56.0%).

## Doctor’s Office or HMO as Usual Source of Care

Veterans Whose Usual Source of Care Was a Doctor’s Office or HMO, by Age, Gender, and Ethnicity

Bar Graph. Percent of Veterans with a usual source of care who indicated their usual source of care is a doctor’s office or HMO, 2015-2018: Veterans age 50-64 with a usual source of care compared better to Veterans age 20-49 with a usual source of care (63.9% vs. 57.7%). Veterans age 65+ with a usual source of care compared better to Veterans age 20-49 with a usual source of care (74.7% vs. 57.7%). Female Veterans with a usual source of care compared the same to male Veterans with a usual source of care (66.1% vs. 61.3%). Hispanic Veterans with a usual source of care compared the same to non-Hispanic white Veterans with a usual source of care (61.0% vs. 62.6%). Non-Hispanic black Veterans with a usual source of care compared the same to non-Hispanic white Veterans with a usual source of care (62.7% vs. 62.6%). Key: y.o. = years old; NH = non-Hispanic. Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: Having a usual source of care can decrease the probability of inpatient admissions and readmissions and decrease expenditures on emergency department visits for physical health, 30-day readmissions, and behavioral health inpatient admissions. It also had a positive effect on several quality measures (Fullerton, et al., 2019). Veterans may consider a Veterans Affairs Medical Center or community-based outpatient clinic (VAMC/CBOC) as a usual source of care.
- Overall Rate: In 2015–2018, 62.5% of Veterans age 20+ with a usual source of care indicated their usual source was a doctor’s office or health maintenance organization (HMO) (data not shown).
- Groups With Disparities: In 2015–2018, findings show significant disparities by age but not gender or race/ethnicity.
  ■ Age
    ⧫ Veterans ages 50–64 with a usual source of care were significantly more likely to indicate their usual source was a doctor’s office or HMO compared with Veterans ages 20–49 with a usual source of care (63.9% vs. 57.7%).
    ⧫ Veterans age 65+ with a usual source of care were significantly more likely to indicate their usual source was a doctor’s office or HMO compared with Veterans ages 20–49 with a usual source of care (74.7% vs. 57.7%).
  ■ Gender
    ⧫ There were no statistically significant differences between female Veterans and male Veterans with a usual source of care who indicated their usual source was a doctor’s office or HMO (66.1% vs. 61.3%).
  ■ Race/Ethnicity
    ⧫ There were no statistically significant differences between Hispanic Veterans and non-Hispanic White Veterans with a usual source of care who indicated their usual source was a doctor’s office or HMO (61.0% vs. 62.6%).
    ⧫ There were no statistically significant differences between non-Hispanic Black Veterans and non-Hispanic White Veterans with a usual source of care who indicated their usual source was a doctor’s office or HMO (62.7% vs. 62.6%).

Veterans Whose Usual Source of Care Was a Doctor’s Office or HMO, by Residence Location, Disability, Education, and Income

Bar Graph. Percent of Veterans with a usual source of care who indicated their usual source of care is a doctor’s office or HMO, 2015-2018: Rural compared to urban (47.1% vs. 65.2%). Veterans with limited activity to Veterans without limited activity (48.5% vs. 63.9%). Veterans with a high school degree or less education compared to Veterans with at least some college (60.8% vs. 66.7%). Veterans with incomes below the poverty line compared to Veterans with middle or high incomes (42.1% vs. 66.4%). Veterans with incomes just above the poverty line compared to Veterans with middle or high incomes (50.1% vs. 66.4%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018. Note: The data for private vs. public insurance did not meet criterial for statistical reliability and are not included.

- Importance: Having a usual source of care can decrease the probability of inpatient admissions and readmissions and decrease expenditures on emergency department visits for physical health, 30-day readmissions, and behavioral health inpatient admissions. It also had a positive effect on several quality measures (Fullerton, et al., 2019). Veterans may consider a Veterans Affairs Medical Center or community-based outpatient clinic (VAMC/CBOC) as a usual source of care.
- Overall Rate: In 2015–2018, 62.5% of Veterans age 20+ with a usual source of care indicated their usual source was a doctor’s office or health maintenance organization (HMO) (data not shown).
- Groups With Disparities: In 2015–2018, findings show significant disparities by location, activity status, and income but not education.
  ■ Location
    ⧫ Rural Veterans with a usual source of care were significantly less likely to indicate their usual source was a doctor’s office or HMO compared with urban Veterans with a usual source of care (47.1% vs. 65.2%).
  ■ Activity Status
    ⧫ Veterans with limited activity and a usual source of care were significantly less likely to indicate their usual source was a doctor’s office or HMO compared with Veterans without limited activity and a usual source of care (48.5% vs. 63.9%).
  ■ Education
    ⧫ There were no statistically significant differences between Veterans with a high school degree or less education and Veterans with at least some college in the percentage with a usual source of care who indicated their usual source was a doctor’s office or HMO (60.8% vs. 66.7%).
  ■ Income
    ⧫ Veterans with incomes below the poverty line and a usual source of care were significantly less likely to indicate their usual source was a doctor’s office or HMO compared with Veterans with middle or high incomes and a usual source of care (42.1% vs. 66.4%).
    ⧫ Veterans with incomes just above the poverty line and a usual source of care were significantly less likely to indicate their usual source was a doctor’s office or HMO compared with Veterans with middle or high incomes and a usual source of care (50.1% vs. 66.4%).

## Opioid Prescriptions Among Veterans

Line Graph. Percent of Veterans who filled an outpatient opioid prescription in the calendar year, 2014-2017: Female Veterans age 18-44 (25.5% vs. 8.6%). Female Veterans age 45-64 (21.3% vs. 30.3%). Female Veterans age 65+ (41.9% vs. 33.2%). Male Veterans age 18-44 (13.3% vs. 8.6%). Male Veterans age 45- (25.7% vs. 19.4%). Male Veterans age 65+ (24.5% vs. 21.2%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017. Note: The data for female Veterans age 65+ in 2014 did not meet criterial for statistical reliability and are not included.

- Importance: Prescription opioids are often used to treat chronic and acute pain and, when used appropriately, can be an important component of treatment. However, serious risks are associated with their use, and it is essential to carefully consider the risks of using prescription opioids alongside their benefits. These risks include misuse, opioid use disorder (addiction), overdoses, and death (CDC, 2020).
- Overall Rate: In 2014–2017, 21.7% of Veterans filled an outpatient opioid prescription (data not shown).
- Trends: From 2014–2017, findings show varying trends across female and male Veterans in different age categories.
  ■ Female Veterans ages 18–44 had a decrease in outpatient opioid prescriptions from 2014 to 2017 (25.5% to 8.6%).
  ■ Female Veterans ages 45–64 had an increase in outpatient opioid prescriptions from 2014 to 2017 (21.3% to 30.3%).
  ■ Female Veterans age 65+ had a decrease in outpatient opioid prescriptions from 2015 to 2017 (41.9% to 33.2%).
  ■ Male Veterans ages 18–44 had a decrease in outpatient opioid prescriptions from 2014 to 2017 (13.3% to 8.6%).
  ■ Male Veterans ages 45–64 had a decrease in outpatient opioid prescriptions from 2014 to 2017 (25.7% to 19.4%).
  ■ Male Veterans age 65+ had a decrease in outpatient opioid prescriptions from 2014 to 2017 (24.5% to 21.2%).