# CONTRAST 1 FINDINGS: DISPARITIES BETWEEN VETERANS AND NON-VETERANS

## Number of Measures With Differences Between Veterans and Non-Veterans

Bar Graph. For the most recent 4-year period of data year (2014-2017 or 2015-2018), Veterans experience better care than non-Veterans on 8 measures (22%), similar care on 24 measures (67%), and worse care on 4 measures (11%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017; and Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: The goal of quality improvement is to produce better quality of and access to care, and ultimately improved patient outcomes, regardless of Veteran status.
- Findings:
  ■ For the most recent 4-year period of data (2014–2017 or 2015–2018), findings show that some disparities persist.
  ■ Veterans experienced better care than non-Veterans on 8 measures (22%), similar care on 24 measures (67%), and worse care on 4 measures (11%).

## Differences Between Veterans and Non-Veterans by Priority Area

Bar Graph. Veterans were most likely to experience better care than non-Veterans for Healthy Living measures (8 of 13 measures [62% of measures]). Veterans were most likely to experience worse care than non-Veterans for Effective Treatment and Patient Safety measures (2 of 2 measures [100% of measures]. Veterans had the same access on 9 and worse on 2 measures. The same on 1 measure for care coordination, and the same on 9 measures for person centered care. Key: y.o. = years old; NH = non-Hispanic. Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017; and Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018. Note: There were insufficient data for Affordable Care measures, so they are not included.

- Importance: The goal of quality improvement is to produce better quality of and access to care across all dimensions of care, and ultimately improved patient outcomes, regardless of Veteran status.
- Findings:
  ■ Veterans experienced worse access to care than non-Veterans on 2 measures (18%) and the same access on 9 measures (82%).
  ■ Veterans were most likely to experience better care than non-Veterans for Healthy Living measures (8 of 13 measures [62%]).
  ■ Veterans were most likely to experience worse care than non-Veterans for Effective Treatment and Patient Safety measures (2 of 2 measures [100%]).

## Receipt of Vaccinations

Four charts First chart: Bar Graph. Female Veterans age 20+ were significantly more likely to receive an influenza immunization compared to female non-Veterans age 20+ (57.3% vs. 45.3%). Male Veterans age 20+ were significantly more likely to receive an influenza immunization compared to male non-Veterans age 20+ (49.1% vs. 37.5%). Second chart: Bar Graph. Female Veterans age 65+ were significantly more likely to receive a pneumococcal immunization compared to female non-Veterans age 65+ (77.5% vs. 68.2%). Male Veterans age 65+ were significantly more likely to receive a pneumococcal immunization compared to male non-Veterans age 65+ (73.1% vs. 60.2%). Third chart: Bar Graph. Female Veterans age 50+ were not significantly more likely to receive a shingles immunization compared to female non-Veterans age 50+ (28.5% vs. 24.5%). Male Veterans age 50+ were significantly more likely to receive a shingles immunization compared to male non-Veterans age 50+ (24.4% vs. 20.0%). Fourth chart: Bar Graph. Female Veterans age 20+ were significantly more likely to receive a tetanus immunization compared to female non-Veterans age 20+ (75.7% vs. 61.1%). Male Veterans age 20+ were significantly more likely to receive a tetanus immunization compared to male non-Veterans age 20+ (74.2% vs. 61.9%). Source for all charts: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance:
  ■ Each year, millions of Americans get sick with influenza. Sometimes it causes mild illness but it can also be serious or even deadly, especially for people over 65, newborn babies, and people with certain chronic illnesses (National Library of Medicine [NLM], 2020). Vaccination can prevent influenza and reduce influenza-related morbidity and mortality (Centers for Disease Control and Prevention [CDC], 2019).
  ■ Pneumococcal disease is caused by bacteria and can result in a range of ailments, from mild ear infection to meningitis, sepsis, and fatal pneumonia (NIAID, 2014). Adults over age 65 and individuals of any age with chronic illness are at increased risk for pneumococcal disease and death. The best way to prevent pneumococcal disease is by getting vaccinated (CDC, 2019).
  ■ Shingles is a painful rash that usually develops on one side of the body, often the face or torso. For some people, long-lasting pain, which can last for months or even years after the rash goes away, is the most common complication of shingles. The risk of getting shingles increases with age (CDC, 2016) but decreases with vaccination (CDC, 2018).
  ■ Tetanus is an infection caused by tetanus bacteria spores that get into the body through broken skin, usually through injuries from contaminated objects. Tetanus infection can lead to serious health problems, including being unable to open the mouth and having trouble swallowing and breathing (CDC, 2019). Nearly all cases of tetanus are in people who never got a tetanus vaccine, did not receive a complete course of tetanus vaccines, or did not stay up to date on their 10-year booster shots (CDC, 2020).
- Overall Rate:
  ■ In 2015–2018,
    ⧫ 50.2% of Veterans and 41.7% of non-Veterans received an influenza vaccination;
    ⧫ 73.4% of Veterans and 65.8% of non-Veterans age 65 years and over received a pneumococcal vaccination;
    ⧫ 24.8% of Veterans and 22.9% of non-Veterans age 50 years and over received a shingles vaccination; and
    ⧫ 74.6% of Veterans and 61.4% of non-Veterans received a tetanus vaccination in the past 10 years (data not shown).
- Groups With Disparities: In 2015–2018:
  ■ Female Veterans age 20+ were significantly more likely to receive an influenza vaccination compared with female non-Veterans age 20+ (57.3% vs. 45.3%).
  ■ Male Veterans age 20+ were significantly more likely to receive an influenza vaccination compared with male non-Veterans age 20+ (49.1% vs. 37.5%).
  ■ Female Veterans age 65+ were significantly more likely to receive a pneumococcal vaccination compared with female non-Veterans age 65+ (77.5% vs. 68.2%).
  ■ Male Veterans age 65+ were significantly more likely to receive a pneumococcal vaccination compared with male non-Veterans age 65+ (73.1% vs. 60.2%).
  ■ There were no statistically significant differences between female Veterans age 50+ and female non-Veterans age 50+ in receipt of a shingles vaccination (28.5% vs. 24.5%).
  ■ Male Veterans age 50+ were significantly more likely to receive a shingles vaccination compared with male non-Veterans age 50+ (24.4% vs. 20.0%).
  ■ Female Veterans age 20+ were significantly more likely to receive a tetanus vaccination compared with female non-Veterans age 20+ (75.7% vs. 61.1%).
  ■ Male Veterans age 20+ were significantly more likely to receive a tetanus vaccination compared with male non-Veterans age 20+ (74.2% vs. 61.9%).

## Receipt of Screenings

Three charts First chart: Bar Graph. Female Veterans were not significantly more likely to receive a blood pressure screening compared with female non-Veterans (91.2% vs. 88.3%). Male Veterans were significantly more likely to receive a blood pressure screening compared with male non-Veterans (86.0% vs. 78.1%). Second chart: Bar Graph. Female Veterans were not significantly more likely to receive a cholesterol screening compared with female non-Veterans (73.4% vs. 69.4%). Male Veterans were significantly more likely to receive a cholesterol screening compared with male non-Veterans (70.7% vs. 61.9%). Third chart: Bar Graph. Female Veterans were not significantly more likely to receive a glucose screening compared with female non-Veterans (56.2% vs. 51.2%). Male Veterans were significantly more likely to receive a glucose screening compared with male non-Veterans (53.7% vs. 44.9%). Source for all charts: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance:
  ■ Nearly half of all adults in the United States, or about 103 million people, have high blood pressure (American Heart Association [AHA], 2018). High blood pressure increases the risk for heart disease and stroke, two leading causes of death for Americans (CDC, 2020).
  ■ About 95 million Americans age 20 and over have total cholesterol levels higher than 200 mg/dL and nearly 29 million have total cholesterol levels higher than 240 mg/dL. High cholesterol raises the risk of heart disease, the leading cause of death, and stroke, the fifth leading cause of death (CDC, 2020).
  ■ Glucose screening is used to diagnose prediabetes and type 1, type 2, or gestational diabetes. Diabetes is a chronic health condition in which the body either does not make enough insulin or cannot use the insulin it makes as well as it should. Diabetes is a leading cause of morbidity and mortality in the United States (CDC, 2019, 2020).
- Overall Rate: In 2015–2018, 86.9% of Veterans and 83.5% of non-Veterans received a blood pressure screening; 71.3% of Veterans and 65.8% of non-Veterans received a cholesterol screening; and 54.3% of Veterans and 48.1% of non-Veterans received a glucose screening (data not shown).
- Groups With Disparities: In 2015–2018, among adults age 20 years and over:
  ■ There were no statistically significant differences between female Veterans and female non-Veterans in receipt of a blood pressure screening (91.2% vs. 88.3%).
  ■ Male Veterans were significantly more likely to receive a blood pressure screening compared with male non-Veterans (86.0% vs. 78.1%).
  ■ There were no statistically significant differences between female Veterans and female non-Veterans in receipt of a cholesterol screening (73.4% vs. 69.4%).
  ■ Male Veterans were significantly more likely to receive a cholesterol screening compared with male non-Veterans (70.7% vs. 61.9%).
  ■ There were no statistically significant differences between female Veterans and female non-Veterans in receipt of a glucose screening (56.2% vs. 51.2%).
  ■ Male Veterans were significantly more likely to receive a glucose screening compared with male non-Veterans (53.7% vs. 44.9%).

## Usual Source of Care

Bar Graph. Percent of respondents with a usual source of care who indicated their usual source of care is a doctor’s office or HMO, 2015-2018: Female Veterans age 20-49 compared to female non-Veterans age 20-49 (65.1% vs. 70.4%). Female Veterans age 50-64 compared to female non-Veterans age 50-64 (64.5% vs. 78.5%). Female Veterans age 65+ compared to female non-Veterans age 65+ (71.2% vs. 82.5%). Male Veterans age 20-49 compared to male non-Veterans age 20-49 (55.3% vs. 68.1%). Male Veterans age 50-64 compared to male non-Veterans age 50-64 (63.8% vs. 77.4%). Male Veterans age 65+ compared to male non-Veterans age 65+ (74.5% vs. 81.4%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: Having a usual source of care can decrease the probability of inpatient admissions and readmissions and decrease expenditures on emergency department visits for physical health, 30-day readmissions, and behavioral health inpatient admissions. It also has a positive effect on several quality measures (Fullerton, et al., 2019). Veterans may consider a Veterans Affairs Medical Center or community-based outpatient clinic (VAMC/CBOC) as a usual source of care.
- Overall Rate: In 2015–2018, 62.5% of Veterans and 73.8% of non-Veterans with a usual source of care indicated their usual source was a doctor’s office or health maintenance organization (HMO) (data not shown).
- Groups With Disparities: In 2015–2018, among adults age 20 years and over:
  ■ There were no statistically significant differences between female Veterans ages 20–49 and female non-Veterans ages 20–49 with a usual source of care in the percentage who indicated their usual source was a doctor’s office or HMO (65.1% vs. 70.4%).
  ■ Female Veterans ages 50–64 with a usual source of care were significantly less likely to indicate their usual source was a doctor’s office or HMO compared with female non-Veterans ages 50–64 with a usual source of care (64.5% vs. 78.5%).
  ■ There were no statistically significant differences between female Veterans age 65+ and female non-Veterans age 65+ with a usual source of care in the percentage who indicated their usual source was a doctor’s office or HMO (71.2% vs. 82.5%).
  ■ Male Veterans ages 20–49 with a usual source of care were significantly less likely to indicate their usual source was a doctor’s office or HMO compared with male non-Veterans ages 20–49 with a usual source of care (55.3% vs. 68.1%).
  ■ Male Veterans ages 50–64 with a usual source of care were significantly less likely to indicate their usual source was a doctor’s office or HMO compared with male non-Veterans ages 50–64 with a usual source of care (63.8% vs. 77.4%).
  ■ There were no statistically significant differences between male Veterans age 65+ and male non-Veterans age 65+ with a usual source of care in the percentage who indicated their usual source was a doctor’s office or HMO (74.5% vs. 81.4%).

## Usual Primary Care Provider, Trends by Gender

Line Graph. Percent of respondents with a usual primary care provider, 2014-2017: Female Veterans had an increase from 2015 to 2017 (78.6% vs. 83.0%). Female non-Veterans had a decrease from 2014 to 2017 (76.3% vs. 75.4%). Male Veterans had a decrease from 2014 to 2017 (73.7% vs. 69.8%). Male non-Veterans had a decrease from 2015 to 2017 (66.4% vs. 65.4%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017. Note: The data for female Veterans in 2014 did not meet criterial for statistical reliability and are not included.

- Importance: Having a usual source of care can decrease the probability of inpatient admissions and readmissions and can decrease expenditures on emergency department visits for physical health, 30-day readmissions, and behavioral health inpatient admissions. It also has a positive effect on several quality measures (Fullerton, et al., 2019).
- Overall Rate: In 2014–2017, 82.6% of Veterans and 71.0% of non-Veterans had a usual primary care provider (data not shown).
- Trends: From 2014–2017, findings show varying trends across female and male Veterans and non-Veterans.
  ■ The percentage of female Veterans with a usual primary care provider increased from 2015 to 2017 (78.6% to 83.0%).
  ■ The percentage of female non-Veterans with a usual primary care provider decreased from 2014 to 2017 (76.3% to 75.4%).
  ■ The percentage of male Veterans with a usual primary care provider decreased from 2014 to 2017 (73.7% to 69.8%).
  ■ The percentage of male non-Veterans with a usual primary care provider decreased from 2014 to 2017 (66.4% to 65.4%).

## Difficulty Contacting Usual Source of Care by Telephone

Bar Graph. Percent of respondents who indicated their usual source of care is somewhat to very difficult to contact during regular business hours over the telephone, 2014-2017: Female Veterans age 18-44 compared to female non-Veterans age 18-44 (26.6% vs. 15.2%). Female Veterans age 45-64 compared to female non-Veterans age 45-64 (22.9% vs. 15.7%). Female Veterans age 65+ compared to female non-Veterans age 65+ (18.8% vs. 15.1%). Male Veterans age 18-44 compared to male non-Veterans age 18-44 (23.1% vs. 13.4%). Male Veterans age 45-64 compared to male non-Veterans age 45-64 (19.9% vs. 15.6%). Male Veterans age 65+ compared to male non-Veterans age 65+ (17.5% vs. 16.0%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017.

- Importance: Timely delivery of appropriate care can help reduce mortality and morbidity for chronic conditions (Smart and Titus, 2011). Ease of contact is a measure of the healthcare system’s capacity to provide care quickly once a need is recognized (Blewett, et al., 2008).
- Overall Rate: In 2014–2017, 19.3% of Veterans and 15.1% of non-Veterans indicated their usual source of care was somewhat to very difficult to contact during regular business hours over the phone (data not shown).
- Groups With Disparities: In 2014–2017, among adults age 18 years and over:
  ■ Female Veterans ages 18–44 were significantly more likely to indicate their usual source of care was somewhat to very difficult to contact during regular business hours over the phone compared with female non-Veterans ages 18–44 (26.6% vs. 15.2%).
  ■ Female Veterans ages 45–64 were significantly more likely to indicate their usual source of care was somewhat to very difficult to contact during regular business hours over the phone compared with female non-Veterans ages 45–64 (22.9% vs. 15.7%).
  ■ There were no statistically significant differences between female Veterans age 65+ and female non-Veterans age 65+ in the percentage who indicated their usual source of care was somewhat to very difficult to contact during regular business hours over the phone (18.8% vs. 15.1%).
  ■ Male Veterans ages 18–44 were significantly more likely to indicate their usual source of care was somewhat to very difficult to contact during regular business hours over the phone compared with male non-Veterans ages 18–44 (23.1% vs. 13.4%).
  ■ Male Veterans ages 45–64 were significantly more likely to indicate their usual source of care was somewhat to very difficult to contact during regular business hours over the phone compared with male non-Veterans ages 45–64 (19.9% vs. 15.6%).
  ■ There were no statistically significant differences between male Veterans age 65+ and male non-Veterans age 65+ in the percentage who indicated their usual source of care was somewhat to very difficult to contact during regular business hours over the phone (17.5% vs. 16.0%).

## Advice To Quit Smoking

Bar Graph : In 2014-2017, adults age 18 years and over: Female Veteran smokers age 45-64 compared to female non-Veteran smokers age 45-64 (70.0% vs. 73.0%). Male Veteran smokers age 18-44 compared to male non-Veteran smokers age 18-44 (57.8% vs. 43.9%). Male Veteran smokers age 45-64 compared to male non-Veteran smokers age 45-64 (74.1% vs. 65.8%). Male Veteran smokers age 65+ compared to male non-Veteran smokers age 65+ (80.5% vs. 76.2%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017. Note: There were insufficient data for female Veterans ages 18-44 and 65+, so they are not included.

- Importance: Quitting smoking greatly reduces the risk of developing smoking-related diseases. Even brief advice to quit (<3 minutes) from a physician improves cessation rates and is highly cost-effective (CDC, 2020).
- Overall Rate: In 2014–2017, 73.5% of Veterans who smoked and 63.3% of non-Veterans who smoked received advice to quit smoking (data not shown).
- Groups With Disparities: In 2014–2017, among adults age 18 years and over who were current smokers:
  ■ There were no statistically significant differences between female Veterans ages 45–64 and female non-Veterans ages 45–64 in the percentage who received advice to quit smoking (70.0% vs. 73.0%).
  ■ Male Veterans ages 18–44 were significantly more likely to receive advice to quit smoking compared with male non-Veterans ages 18–44 (57.8% vs. 43.9%).
  ■ Male Veterans ages 45–64 were significantly more likely to receive advice to quit smoking compared with male non-Veterans ages 45–64 (74.1% vs. 65.8%).
  ■ There were no statistically significant differences between male Veterans age 65+ and male non-Veterans age 65+ in the percentage who received advice to quit smoking (80.5% vs. 76.2%).

## Inappropriate Medications for Older Adults

Bar Graph. Percent of respondents who received in the calendar year at least 1 of 33 potentially inappropriate prescription medications for older adults, 2014-2017: Female Veterans age 18-44 compared with female non-Veterans age 18-44 (11.2% vs. 7.6%). Female Veterans age 45-64 compared with female non-Veterans age 45-64 (19.1% vs. 12.6%). Female Veterans age 65+ compared with female non-Veterans age 65+ (13.5% vs. 11.4%). Male Veterans age 18-44 compared with male non-Veterans age 18-44 (8.6% vs. 3.6%). Male Veterans age 45-64 compared with male non-Veterans age 45-64 (10.8% vs. 7.7%). Male Veterans age 65+ with male non-Veterans age 65+ (8.6% vs. 8.3%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017.

- Importance: Some drugs prescribed for older adults are known to be potentially harmful and can lead to adverse drug events that are both expensive and associated with poor health outcomes. While these drugs are potentially most harmful to older adults, they should be monitored for all ages, especially with certain conditions such as reduced kidney function (American Geriatrics Society, 2015).
- Overall Rate: In 2014–2017, 9.9% of Veterans and 8.1% of non-Veterans received inappropriate prescription medications for older adults (data not shown).
- Groups With Disparities: In 2014–2017, among adults age 18 years and over:
  ■ There were no statistically significant differences between female Veterans ages 18–44 and female non-Veterans ages 18–44 in the percentage who received inappropriate prescription medications for older adults (11.2% vs. 7.6%).
  ■ There were no statistically significant differences between female Veterans ages 45–64 and female non-Veterans ages 45–64 in the percentage who received inappropriate prescription medications for older adults (19.1% vs. 12.6%).
  ■ There were no statistically significant differences between female Veterans age 65+ and female non-Veterans age 65+ in the percentage who received inappropriate prescription medications for older adults (13.5% vs. 11.4%).
  ■ Male Veterans ages 18–44 were significantly more likely to receive inappropriate prescription medications for older adults compared with male non-Veterans ages 18–44 (8.6% vs. 3.6%).
  ■ Male Veterans ages 45–64 were significantly more likely to receive inappropriate prescription medications for older adults compared with male non-Veterans ages 45–64 (10.8% vs. 7.7%).
  ■ There were no statistically significant differences between male Veterans age 65+ and male non-Veterans age 65+ in the percentage who received inappropriate prescription medications for older adults (8.6% vs. 8.3%).

## Outpatient Opioid Prescriptions

Outpatient Opioid Prescriptions, by Age and Gender

Bar Graph. Percent of respondents who filled an outpatient opioid prescription in the calendar year, 2014-2017: Female Veterans age 18-44 compared with female non-Veterans age 18-44 (14.1% vs. 13.2%). Female Veterans age 45-64 compared with female non-Veterans age 45-64 (27.9% vs. 19.3%). Female Veterans age 65+ compared with female non-Veterans age 65+ (35.4% vs. 23.7%). Male Veterans age 18-44 compared with male non-Veterans age 18-44 (12.8% vs. 7.8%). Male Veterans age 45-64 with male non-Veterans age 45-64 (22.2% vs. 15.4%). Male Veterans age 65+ compared with male non-Veterans age 65+ (23.1% vs. 20.5%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017.

- Importance: Prescription opioids are often used to treat chronic and acute pain and, when used appropriately, can be an important component of treatment. However, serious risks are associated with their use, and it is essential to carefully consider the risks of using prescription opioids alongside their benefits. These risks include misuse, opioid use disorder (addiction), overdoses, and death (CDC, 2020).
- Overall Rate: In 2014–2017, 21.7% of Veterans and 14.9% of non-Veterans filled an outpatient opioid prescription (data not shown).
- Groups With Disparities: In 2014–2017, among adults age 18 years and over:
  ■ There were no statistically significant differences between female Veterans ages 18–44 and female non-Veterans ages 18–44 in the percentage who filled an outpatient opioid prescription (14.1% vs. 13.2%).
  ■ Female Veterans ages 45–64 were significantly more likely to fill an outpatient opioid prescription compared with female non-Veterans ages 45–64 (27.9% vs. 19.3%).
  ■ Female Veterans age 65+ were significantly more likely to fill an outpatient opioid prescription compared with female non-Veterans age 65+ (35.4% vs. 23.7%).
  ■ Male Veterans ages 18–44 were significantly more likely to fill an outpatient opioid prescription compared with male non-Veterans ages 18–44 (12.8% vs. 7.8%).
  ■ Male Veterans ages 45–64 were significantly more likely to fill an outpatient opioid prescription compared with male non-Veterans ages 45–64 (22.2% vs. 15.4%).
  ■ There were no statistically significant differences between male Veterans age 65+ and male non-Veterans age 65+ in the percentage who filled an outpatient opioid prescription (23.1% vs. 20.5%).

Outpatient Opioid Prescriptions, Trends by Gender

Line Graph. Percent of respondents who filled an outpatient opioid prescription in the calendar year, 2014-2017: Female Veterans (24.0% vs. 21.3%). Female non-Veterans (20.0% vs. 14.5%). Male Veterans (19.1% vs. 14.0%). Male non-Veterans (13.8% vs. 9.9%). Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017. Note: The data for female Veterans in 2014 did not meet criterial for statistical reliability and are not included.

- Importance: Prescription opioids are often used to treat chronic and acute pain and, when used appropriately, can be an important component of treatment. However, serious risks are associated with their use, and it is essential to carefully consider the risks of using prescription opioids alongside their benefits. These risks include misuse, opioid use disorder (addiction), overdoses, and death (CDC, 2020).
- Overall Rate: In 2014–2017, 21.7% of Veterans and 14.9% of non-Veterans filled an outpatient opioid prescription (data not shown).
- Trends: From 2014–2017, findings show varying trends across female and male Veterans and non-Veterans.
  ■ Female Veterans had a decrease in the percentage who filled an outpatient opioid prescription from 2015 to 2017 (24.0% to 21.3%).
  ■ Female non-Veterans had a decrease in the percentage who filled an outpatient opioid prescription from 2014 to 2017 (20.0% to 14.5%).
  ■ Male Veterans had a decrease in the percentage who filled an outpatient opioid prescription from 2014 to 2017 (19.1% to 14.0%).
  ■ Male non-Veterans had a decrease in the percentage who filled an outpatient opioid prescription from 2014 to 2017 (13.8% to 9.9%).