# OVERVIEW OF VHA PATIENT, VETERAN, AND NON-VETERAN POPULATIONS AND CHARACTERISTICS

Veteran Population by State

Map showing percentage of veterans in each state by quartile; data for states are in the text after the map

Source: U.S. Census Bureau, 2017 American Community Survey 5-Year Estimates.

- Importance: The percentage and number of Veterans varies by state. New York has the lowest percentage of Veterans relative to the state’s population and Alaska has the highest percentage.
- Data: State and number of Veterans per state (percentage of Veterans):

- Puerto Rico 83,641 (3.1%); - New York 757,900 (4.9%); - District of Columbia 27,695 (5.0%); - New Jersey 351,542 (5.1%); - California 1,661,433 (5.6%); - Wisconsin 350,330 (7.8%); - Indiana 397,715 (7.9%); - Pennsylvania 803,420 (8.0%); - Vermont 40,145 (8.0%); - Iowa 193,451 (8.1%); - Kentucky 279,153 (8.2%); - Maryland 380,555 (8.2%); - North Dakota 47,228 (8.3%); - Georgia 646,350 (8.4%); - Ohio 752,153 (8.4%); - Kansas 185,292 (8.6%); - Nebraska 122,311 (8.6%); - North Carolina 670,326 (8.7%) | - Massachusetts 325,299 (6.0%); - Utah 125,074 (6.0%); - Illinois 614,725 (6.2%); - Connecticut 180,111 (6.4%); - Rhode Island 59,535 (7.1%); - Tennessee 441,554 (8.7%); - Florida 1,454,632 (9.0%); - Alabama 341,642 (9.1%); - Arkansas 206,796 (9.1%); - Colorado 376,336 (9.1%); - Delaware 66,854 (9.1%); - Missouri 424,605 (9.1%); - Oregon 291,153 (9.2%); - Arizona 486,760 (9.4%); - New Hampshire 100,474 (9.4%); - South Dakota 60,330 (9.4%); - Idaho 115,437 (9.5%); - Nevada 210,461 (9.5%) | - Louisiana 254,920 (7.2%); - Texas 1,482,871 (7.4%); - Michigan 581,527 (7.5%); - Minnesota 319,438 (7.6%); - Mississippi 172,587 (7.7%); - New Mexico 150,650 (9.5%); - Oklahoma 276,948 (9.5%); - West Virginia 138,508 (9.5%); - South Carolina 367,921 (9.8%); - Washington 541,122 (9.8%); - Hawaii 106,630 (9.9%); - Maine 110,362 (10.3%); - Wyoming 46,540 (10.5%); - Montana 84,878 (10.6%); - Virginia 688,536 (10.8%); - Alaska 67,004 (12.5%)

Veteran Population – by VISN

US map showing the number of Veterans within each VISN varies. VISN 15,23,12,9, 5, and 1 have 700,00 - 899,999. VISN 6 and 21 have 1,100,000 - 1,299,999. VISN 20,19, 16, 4, and 2 have 900,000-1,099,999. The Veteran population is lowest in VISN 15 which is KS and MO, and highest in VISN 10 which is IN, MI, and OH.

Source: Department of Veterans Affairs, 2016 Veteran Population Model data.

- Importance: The number of Veterans within each VISN varies. The Veteran population is lowest in VISN 15 and highest in VISN 10.
- Data: VISN, name, and population
  ■ 1 VA New England Healthcare System 833,407
  ■ 2 NY/NJ VA Health Care Network 1,014,031
  ■ 4 VA Healthcare - VISN 4 1,025,705
  ■ 5 VA Capitol Health Care Network 785,107
  ■ 6 VA Mid-Atlantic Health Care Network 1,243,752
  ■ 7 VA Southeast Network 1,356,446
  ■ 8 VA Sunshine Healthcare Network 1,513,361
  ■ 9 VA Mid South Healthcare Network 816,898
  ■ 10 VA Healthcare System 1,630,604
  ■ 12 VA Great Lakes Health Care System 880,288
  ■ 15 VA Heartland Network 752,934
  ■ 16 South Central VA Health Care Network 917,434
  ■ 17 VA Heart of Texas Health Care Network 1,568,097
  ■ 19 Rocky Mountain Network 996,509
  ■ 20 Northwest Network 1,038,985
  ■ 21 Sierra Pacific Network 1,118,873
  ■ 22 Desert Pacific Healthcare Network 1,639,110
  ■ 23 VA Midwest Health Care Network 867,259

## Demographics

Gender

Bar graph. Percent distribution of gender among VHA Patient, Veteran, and Non-Veteran Populations, Shows the percentage distribution of gender: VHA Populations is 6.7% women 93.3% men, the Veteran Population is 8.9% women 91.1% men, and 54.8% women, 45.2% Men in the non-Veteran population. Source: U.S. Census Bureau, 2017 (Veterans and non-Veterans) and VHA administrative data, 2017 (VHA patients).

- Importance: In terms of gender, the VHA patient population is fairly consistent with the general Veteran population (6.7% vs. 8.9% women). Both the VHA patient and Veteran populations have a lower percentage of women than the non-Veteran population (54.8% women).

Age

Bar Graph. Percent Distribution of Age Among VHA Patient, veteran, and non-veteran populations: The VHA patient population is 15.9% age 18-44, 37.8% age 45-64, and 46.3% age 65+. The Veteran Population is 14.2% age 18-44, 31.8% age 45-64, and 54.0% age 65+. The non-Veteran population is 48.2% age 18-44, 33.6% age 45-64, and 18.2% age 65+. Source: U.S. Census Bureau, 2017 (Veterans and non-Veterans) and VHA administrative data, 2017 (VHA patients).

- Importance: In terms of age, the VHA patient population is fairly consistent with the general Veteran population (15.9% vs.14.2% ages 18–44, 37.8% vs. 31.8% ages 45–64, and 46.3% vs. 54.0% age 65+). However, the VHA and Veteran populations have a lower percentage of younger individuals and higher percentage of older individuals than the non-Veteran population (48.2% ages 18–44, 33.6% ages 45–64, and 18.2% age 65+).

Race and Ethnicity

Bar Graph. Percent distribution of race among veteran and non-veteran populations: In terms of race, Veteran population has a lower percentage of minority individuals and higher percentage of white individuals than the non-Veteran population (e.g., .2% vs. .2% NHOPI, .8% vs .8% AIAN, 2.0% vs. 2.3%multi-race, 1.4% vs. 4.9% other race, 1.6% vs. 6.1% Asian, 11.8% vs. 12.4% black, 82.2% vs. 73.3% white). Bar Graph. Percent distribution of Ethnicity among veteran and non-veteran populations In terms of ethnicity, Veteran population has a lower percentage of Hispanic individuals than the non-Veteran population (6.9% vs. 16.7% Hispanics). Key: NHOPI = Native Hawaiian and Other Pacific Islander; AIAN = American Indian or Alaska Native. Source: U.S. Census Bureau, 2017.

- Importance:
  ■ In terms of race, the Veteran population has a lower percentage of minority individuals and higher percentage of White individuals than the non-Veteran population (e.g., 1.6% vs. 6.1% Asian, 11.8% vs. 12.4% Black, 82.2% vs. 73.3% White).
  ■ In terms of ethnicity, the Veteran population has a lower percentage of Hispanic individuals than the non-Veteran population (6.9% vs. 16.7% Hispanic).

Urban/Rural Location

Bar Graph. Percent distribution of rural and urban status among VHA patient, veteran, and non-veteran, populations: In terms of urban or rural location, the VHA patient population has a higher percentage of Veterans living in rural areas compared to the general Veteran population (37.4% rural and 62.6% urban vs. 24.1% rural and 75.9% urban). Both the VHA and Veteran populations have a higher percentage of individuals living in rural areas than the non-Veteran population (18.9% rural vs. 81.1% urban). Source: U.S. Census Bureau, 2017 (Veterans and non-Veterans) and VHA administrative data, 2017 (VHA patients).

- Importance: In terms of urban/rural location, the VHA patient population has a higher percentage of Veterans living in rural areas compared with the general Veteran population (37.4% vs. 24.1% rural). Both the VHA patient and Veteran populations have a higher percentage of individuals living in rural areas than the non-Veteran population (18.9% rural).

Note: Census and VHA administrative data use slightly different urban/rural definitions. Census defines rural at the county level. VHA uses the census tract.

Income and Education

Two charts First chart: Bar graph. percent distibution of income among veteran and non veteran populations: Veteran population has a lower percentage of individuals below the poverty line than the non-Veteran population (6.9% below and 93.1% above vs. 12.3% below 87.7% above the poverty line). Second chart: Bar graph. percent distibution of educational attainment among veteran and non veteran populations. Veteran population has 5.8% that are less than a high school graduate, 28.2% that are high school graduates, 37.2% with some college or an associate's degree, 28.8% with a bachelors degree or higher. Non-Veteran population has 12.6% that are less than a high school graduate, 27.1% that are high school graduates, 28.1% with some college or an associate's degree, 32.2% with a bachelors degree or higher. Source for both charts: U.S. Census Bureau, 2017.

- Importance:
  ■ In terms of income, the Veteran population has a lower percentage of individuals below the poverty line than the non-Veteran population (6.9% vs. 12.3% below the poverty line).
  ■ In terms of education, the Veteran population has a lower percentage of individuals with a high school diploma or less education than the non-Veteran population (34.0% vs. 39.7% with a high school diploma or less).

Disabilities

Two charts First chart: Bar Graph. Percent distribution of disabilities and limitations among veteran and non veteran populations, Veteran population has a higher percentage of individuals with a disability than the non-Veteran population (29.5% vs. 14.2% with a disability, 70.5% vs. 85.8% without a disability) Second chart: Bar Graph. Percent distribution of service-connected disability rating among veteran and non veteran populations: within the VHA population, 51.4% have no service-connected disability, 23.3% have a service-connected disability rating of 0 to 49%, 18.6% have a service-connected disability rating of 50-99%, and 6.8% have a service-connected disability rating of 100%. For both charts: Key: SCD = Service-connected disability. Source: U.S. Census Bureau, 2017 (Veterans and non-Veterans) and VHA administrative data, 2017 (VHA patients). Note: Service-connected disabilities are disabilities incurred or aggravated during active military service.

- Importance:
  ■ In terms of disability, the Veteran population has a higher percentage of individuals with a disability than the non-Veteran population (29.5% vs. 14.2% with a disability).
  ■ In terms of service-connected disability, within the VHA patient population, 51.4% of Veterans have no service-connected disability, 23.3% have a service-connected disability rating of 0 to 49%, 18.6% have a service-connected disability rating of 50–99%, and 6.8% have a service-connected disability rating of 100%.

## Health and Lifestyle

Health and Lifestyle, Ages 20–49

Two charts First chart: Bar Graph. Prevalence of overall health and lifestyle patterns among veterans and non veterans: female Veterans age 20-49 have lower rates of very good or excellent health (57.6% vs. 67.8%) and no physical activity (35.6% vs. 43.2%) and higher rates of current smoking (18.7% vs. 14%), not rested (51.2% vs. 46.3%), and chronic pain (27.3% vs. 14.6%), compared to non-Veterans age 50-64. Second chart: Bar Graph. Prevalence overall health and lifestyle patterns among veterans and non veterans: male Veterans age 20-49 have lower rates of very good or excellent health (61.4% vs. 70.8%) and no physical activity (28.4% vs. 34.5%) and higher rates of current smoking (24.0% vs. 18%), not rested (41.4% vs. 35.6%), and chronic pain (25.1% vs. 11.1%), compared to non-Veterans age 20-49. Source for both charts: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- Importance: In terms of overall health and lifestyle patterns, female and male Veterans ages 20–49 have lower rates of very good or excellent health and no physical activity and higher rates of current smoking, not rested, and chronic pain, compared with non-Veterans ages 20–49.

Health and Lifestyle, Ages 50–64

Two charts First chart: Bar Graph. Prevalence of lifestyle patterns amoung female Veterans age 50-64: Veterans have lower rates of very good or excellent health (45.9% vs. 52%) and no physical activity (41.2% vs. 50.5%) and higher rates of current smoking (23.8% vs. 15.6%), are not as rested (47.5% vs. 41.1%), and have more chronic pain (35.9% vs. 27.8%), compared to non-Veterans age 50-64. Second chart: Bar Graph. Prevalence of lifestyle patterns amoung male Veterans age 50-64: Veterans have lower rates of very good or excellent health (48.4% vs. 54.4%) and no physical activity (45.3% vs. 45.5%) and higher rates of current smoking (24.9% vs. 17%), are not as rested (38.7% vs. 33.7%), and have more chronic pain (33.9% vs. 23.4%), compared to non-Veterans age 50-64. Source for both charts: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- Importance: In terms of overall health and lifestyle patterns, female and male Veterans ages 50–64 have lower rates of very good or excellent health and no physical activity and higher rates of current smoking, not rested, and chronic pain, compared with non-Veterans ages 50–64.

Health and Lifestyle, Ages 65

Two charts First chart: Bar Graph. Prevalence of overall health and lifestyle patterns among female Veterans age 65-79: Veterans age 65-79 have lower rates of very good or excellent health (45.1% vs. 48.8%) and no physical activity (54.8% vs. 55.8%) and higher rates of current smoking (14.7% vs. 8.9%), are not as rested (33.8% vs. 29.3%), and have more chronic pain (32% vs. 29.9%), compared to non-Veterans age 65-79. Second chart: Bar Graph. Prevalence of overall health and lifestyle patterns among male Veterans age 65-79: Veterans have lower rates of very good or excellent health (47.5% vs. 47.6%) and no physical activity (48.1% vs. 48.5%) and higher rates of current smoking (11.4% vs. 11.1%), are not as rested (25.1% vs. 24.3%), and have more chronic pain (30.6% vs. 25.2%), compared to non-Veterans age 65-79. Source for both charts: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- Importance: In terms of overall health and lifestyle patterns, female and male Veterans ages 65–79 have lower rates of very good or excellent health and no physical activity and higher rates of current smoking, not rested, and chronic pain, compared with non-Veterans ages 65–79.

## Physical Health Conditions

Physical Health Conditions, Ages 18–44

Two charts First chart: Bar graph. Prevalence physical health disorders Among Veterans and Non-Veterans, Females Age 18-44. Hypertension: Veteran Population (V) 10.6%, Non-Veteran Population (NV) 9.5%; high cholesterol: V 17.8%, NV 8%; heart disease: V 15.6%, NV 4.7%; diabetes V 2.8%, NV 2.9%; cancer: V 4.3%, NV 2.6%; asthma V 11%, NV 15.1%; arthritis 21.6%, NV 8%. Second chart: Bar graph. Prevalence physical health disorders Among Veterans and Non-Veterans, Males Age 18-44. Hypertension: Veteran Population (V) 23.1%, Non-Veteran Population (NV) 13.6%; high cholesterol: V 17.4%, NV 10.6%; heart disease: V 4.9%, NV 4.6%; diabetes V 1.9%, NV 2.5%; cancer: V 1.9%, NV 2.5%; asthma V 11.3%, NV 12.1%; arthritis 19.8%, NV 4.6%. Source for both charts: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- Importance: In terms of physical health conditions, female and male Veterans ages 18–44 have higher rates of hypertension, high cholesterol, heart disease, cancer, and arthritis and lower rates of diabetes and asthma, compared with non-Veterans ages 18–44.

Physical Health Conditions, Ages 45–64

Two charts First chart: Bar graph. Prevalence physical health disorders Among Veterans and Non-Veterans, females Age 45-64. Hypertension: Veteran Population (V) 49.7%, Non-Veteran Population (NV) 36.2%; high cholesterol: V 43%, NV 33.5%; heart disease: V 24.5%, NV 13.3%; diabetes V 9.3%, NV 12.6%; cancer: V 11.1%, NV 12.4 %; asthma V 12.1%, NV 13.6%; arthritis 47.6%, NV 36.6%. Second chart: Bar graph. Prevalence physical health disorders Among Veterans and Non-Veterans, males Age 45-64. Hypertension: Veteran Population (V) 56%, Non-Veteran Population (NV) 43.5%; high cholesterol: V 54.3%, NV 39.2%; heart disease: V 19.3%, NV 14.5%; diabetes V 20.2%, NV 14.3%; cancer: V 12%, NV 8.3%; asthma V 8.6%, NV 8.9%; arthritis 41.8%, NV 24.2%. Source for both charts: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- Importance: In terms of physical health conditions:
  ■ Female Veterans ages 45–64 have higher rates of hypertension, high cholesterol, heart disease, and arthritis and lower rates of diabetes, cancer, and asthma, compared with female non-Veterans ages 45–64.
  ■ Male Veterans ages 45–64 have higher rates of hypertension, high cholesterol, heart disease, diabetes, cancer, and arthritis and lower rates of asthma, compared with male non-Veterans ages 45–64.

Physical Health Conditions, Ages 65–79

Two charts First chart: Bar graph. Prevalence physical health disorders Among Veterans and Non-Veterans, females Age 65-79. Hypertension: Veteran Population (V) 55.2%, Non-Veteran Population (NV) 64%; high cholesterol: V 57.8%, NV 59.3%; heart disease: V 26.4%, NV 29.4%; diabetes V 7.2%, NV 20.7%; cancer: V 25.7%, NV 28.1%; asthma V 23.9%, NV 13.1%; arthritis 64.4%, NV 63.9%. Second chart: Bar graph. Prevalence physical health disorders Among Veterans and Non-Veterans, males Age 65-79. Hypertension: Veteran Population (V) 55.2%, Non-Veteran Population (NV) 64%; high cholesterol: V 57.8%, NV 59.3%; heart disease: V 26.4%, NV 29.4%; diabetes V 7.2%, NV 20.7%; cancer: V 25.7%, NV 28.1%; asthma V 23.9%, NV 13.1%; arthritis 64.4%, NV 63.9%. Source for both charts: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- Importance: In terms of physical health conditions:
  ■ Female Veterans ages 65–79 have higher rates of asthma and arthritis and lower rates of hypertension, high cholesterol, heart disease, diabetes, and cancer, compared with female non-Veterans ages 65–79.
  ■ Male Veterans ages 65–79 have higher rates of hypertension, high cholesterol, heart disease, diabetes, cancer, asthma, and arthritis, compared with male non-Veterans ages 65–79.

## Mental Health Conditions

Bar graph. Prevalence mental health disorders Among VHA Patients and General Population. PTSD: VHA Patients (VHAP) 12.1%, General Population (GP) 6.8%; Alcohol Use Disorder: VHAP 7.1%, GP 6.4%; Major depressive disorder: VHAP 5.9%, GP 7.1%; Drug use disorder: VHAP 4.4%, GP 2.7%; Bipolar Disorder: VHAP 2.3%, GP 4.4%; Schizophrenia: VHAP 1.6%, GP .5%. Key: PTSD = Post-traumatic stress disorder. Source: National Institute of Mental Health, 2019 (general population) and VHA administrative data, 2017 (VHA patients).

- Importance: In terms of mental health conditions, the VHA patient population has higher rates of post-traumatic stress disorder (PTSD), alcohol use disorder, drug use disorder, and schizophrenia and lower rates of major depressive disorder and bipolar disorder, compared with the general U.S. population.