# CHARTBOOK METHODOLOGY

## Comparison Populations and Contrasts

- Analyses included three populations: Veterans, non-Veterans, and Veterans who use VHA services.
- Analyses were organized into three types of comparison (i.e., contrasts).

Contrast | Population | Comparison
#1 | Veterans and non-Veterans | Assessed disparities by comparing Veterans with non-Veterans, standardizing by age and gender
#2 | All Veterans | Assessed disparities across characteristics such as age, gender, race, ethnicity, urban/rural location, education, income, disabilities/limitations, physical health status, and mental health status
#3 | Veterans who use VHA services (i.e., VHA users) | Assessed disparities across characteristics such as age, gender, race, ethnicity, urban/rural location, socioeconomic status, period of service, service-connected disability, physical health status, and mental health status

## Data Sources

### National Surveys

- Used for Contrasts 1 and 2.
- National Health Interview Survey (NHIS)
  ■ National in-person interview survey providing detailed information about health status, access to care, and receipt of services.
  ■ Self-reported data.
- Medicare Expenditure Panel Survey (MEPS)
  ■ Set of national panel surveys of individuals and providers collecting and reporting comprehensive information about access, use, quality, and cost of healthcare.
  ■ MEPS panels derived from NHIS sampling frames.
  ■ Self-reported data.

### VHA Data

- Used for Contrast 3.
- Survey of Healthcare Experience of Patients (SHEP)
  ■ Customer experience survey used to evaluate and improve the experience of care among users of VHA facilities.
  ■ Self-reported data.
- VHA administrative mortality data
  ■ Data collected for administrative purposes.

### Data Sources by Dimension, Priority Area, and Contrast

Data sources varied by NHQDR dimension, NHQDR priority area, and contrast.

NHQDR Dimension | NHQDR Priority Area | Data Sources for Contrasts 1 & 2 | Data Sources for Contrast 3
Access | N/A | MEPS; NHIS | SHEP
Quality | Patient Safety | MEPS | N/A
Quality | Person-Centered Care | MEPS | SHEP
Quality | Care Coordination | MEPS | SHEP
Quality | Effective Treatment | MEPS; NHIS | SHEP
Quality | Healthy Living | MEPS; NHIS | N/A
Quality | Mortality | N/A | VHA Administrative

Note: There were insufficient data for Affordable Care measures, so they are not included.

## Characteristics and Measure Summary

- Background analyses of demographics, location, and other characteristics are based on 2017 data, where possible.
- The chartbook includes 65 healthcare quality, access, and mortality measures.
  ■ Access and quality measures reflect care provided in 2014–2018.
    ⧫ NHIS measures are from pooled 2015–2018 data.
    ⧫ Most MEPS measures are from pooled 2014–2017 data.
    ⧫ SHEP measures are from 2015 data.
  ■ Mortality measures are based on first visit in fiscal year 2009 and followup through 2016.
  ■ One MEPS measure, Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, is from pooled 2014–2016 data.

### Data Preparation

- Metrics were aligned so that a higher rate is “better” (i.e., higher rate implies a healthier status).
- Reference groups were determined.
- Measures were categorized by NHQDR dimension, NHQDR priority area, and contrast.

Variable | Reference Group
Veteran Status | Non-Veterans
Age | Younger age (i.e., 18–44 or 20–49 years)
Gender | Male
Race/Ethnicity | White, non-Hispanic
Income | Middle or high income
Education | College education
Insurance | Any private insurance
Activity Limitations | No activity limitation

### Number of Measures by Dimension, Priority Area, and Contrast

The number of measures varied by NHQDR dimension, NHQDR priority area, and contrast.

NHQDR Dimension | NHQDR Priority Area | Measures for Contrasts 1 & 2 | Measures for Contrast 3 | Total Measures
Access | N/A | 11 | 6 | 17
Quality | Patient Safety | 1 | 0 | 1
Quality | Person-Centered Care | 9 | 9 | 18
Quality | Care Coordination | 1 | 11 | 12
Quality | Effective Treatment | 1 | 2 | 3
Quality | Healthy Living | 9 | 0 | 9
Quality | Mortality | 0 | 5 | 5
Total | N/A | 32 | 33 | 65

Note: There were insufficient data for Affordable Care measures, so they are not included.

## Analysis Summary

- Measure values for Veterans were compared using age and gender strata, age-adjusted gender strata, or age-gender adjusted values.
- Comparisons were made between priority and reference groups.
- Meaningful differences between two groups were determined based on two criteria:
  ■ Absolute difference was statistically significant with p < 0.05 on a two-tailed test.
  ■ The relative difference was at least 10%, where relative difference is defined as the difference between priority group and reference group, divided by reference group value.

## Limitations

- Not all characteristics (e.g., education, disability status) were available from all data sources, so comparisons were limited.
- Due to small numbers of Veterans in the survey sample, particularly female Veterans, few trend analyses were feasible.
  ■ Estimates with fewer than 30 individuals per group or a relative standard error more than 30% were excluded (or suppressed).
- Most measures were derived from survey data and may reflect response biases, including:
  ■ Nonresponse bias - individuals with poorer health may be less likely to respond to the survey.
  ■ Social desirability bias - individuals who do respond may provide responses they believe are more socially desirable than the truth.
- Only aggregate data were provided, so multivariate analyses were not performed for this chartbook.