# INTRODUCTION TO CHARTBOOK ON HEALTHCARE FOR VETERANS

## National Healthcare Quality and Disparities Report Chartbooks

The NHQDR is supported by a series of related chartbooks that:

- Cover various topics, such as access to care, healthcare priority areas, and priority populations.
- Are posted online at https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/index.html.

The Chartbook on Healthcare for Veterans:

- Uses NHQDR methodology for assessing disparities.
- Uses NHQDR and non-NHQDR measures to present novel comparisons between Veterans and non-Veterans and within Veteran populations.

## Background on Chartbook

- Veterans are individuals who have served in the armed forces: Army, Marine Corps, Navy, Air Force, or Coast Guard.
- Veterans differ from non-Veterans.
- Veterans are more likely to be older, White, and male.
- Veterans are more likely to have a disability, as well as certain physical and mental health conditions.
- Some Veterans receive healthcare through VHA.
- VHA users differ from Veterans who do not use VHA.
- Evidence suggests that disparities in healthcare access and quality exist between Veterans and non-Veterans, within the Veteran population, and within the VHA patient population.

Note: Information regarding VHA, its structure, and eligibility is provided in the “Veterans Health Administration” section below. Comparisons of non-Veterans, all Veterans, and VHA users are provided in the “Veteran population” section below.

### Office of Health Equity

- The VHA Office of Health Equity (OHE) was created in 2012 to promote the advancement of health equity and reduction of health disparities among Veterans.
- Health equity is the attainment of the highest level of health for all people.
- Health disparities are health differences closely linked with social or economic disadvantage.

### Health Equity Action Plan

- The Health Equity Action Plan (HEAP) is produced by OHE in conjunction with the Health Equity Coalition (HEC) to outline how to accomplish OHE’s vision.
- The HEC is a committee that works collaboratively with executive VHA and VA members and external organizations with expertise in health equity.
- The HEAP is organized around five aims to match the goals of the National Partnership for Action to End Health Disparities National Stakeholder Strategy, the HHS-led federal strategy for eliminating disparities. The aims are:
  ■ Awareness.
  ■ Leadership.
  ■ Health system and life experience.
  ■ Cultural and linguistic competency.
  ■ Data, research, and evaluation.

### Chartbook on Healthcare for Veterans

- The Chartbook on Healthcare for Veterans aligns with the HEAP’s awareness, data, research, and evaluation activities:
  ■ Increase awareness of health disparities, their impact, and actions needed to improve health outcomes.
  ■ Improve data availability and coordination, utilization, and diffusion of research and evaluation outcomes.
- It is a collaboration between the AHRQ NHQDR team, the VHA OHE, and the Interagency Work Group.