# BACKGROUND ON NATIONAL HEALTHCARE QUALITY AND DISPARITIES REPORT

The National Healthcare Quality and Disparities Report (NHQDR) is an annual report to Congress mandated in the Healthcare Research and Quality Act of 1999 (P.L. 106–129). The report provides a comprehensive overview of:

- Quality of healthcare received by the general U.S. population.
- Disparities in care experienced by different racial and socioeconomic groups.

In addition, the report assesses the performance of the U.S. healthcare system and identifies areas of strength and weakness along three main axes:

- Access to healthcare
- Quality of healthcare
- NHQDR priorities

The NHQDR is based on more than 250 measures of access, quality, and disparities covering a broad array of healthcare services and settings and health conditions. It includes data from 2000 through 2018. The report is produced with the help of an Interagency Work Group led by the Agency for Healthcare Research and Quality (AHRQ) and submitted on behalf of the Secretary of the Department of Health and Human Services (HHS). To access the most recent National Healthcare Quality and Disparities Report, including methodologies and measure lists, go to https://www.ahrq.gov/research/findings/nhqrdr/index.html.

The NHQDR assesses access to and quality of healthcare. Quality is organized by NHQDR priority area.

NHQDR Priority | Description
Patient Safety | Making care safer by reducing harm caused in the delivery of care
Person-Centered Care | Ensuring that each person and family is engaged as partners in their care
Care Coordination | Promoting effective communication and coordination of care
Effective Treatment | Promoting the most effective prevention and treatment practices for the leading causes of mortality, starting with cardiovascular disease
Healthy Living | Working with communities to promote wide use of best practices to enable healthy living
Affordable Care | Making quality care more affordable for individuals, families, employers, and governments by developing and spreading new healthcare delivery models