# CHARTBOOK SECTIONS

- Background on National Healthcare Quality and Disparities Report (NHQDR)
- Introduction to Chartbook on Healthcare for Veterans
- Veterans Health Administration (VHA)
- Methodology
- Veteran Population
- Quality Measures
  ■ Contrast 1: Disparities Between Veterans and Non-Veterans
  ■ Contrast 2: Disparities Within the Veteran Population
  ■ Contrast 3: Disparities Within VHA Users
- Resources and References
- Appendix