# RESOURCES AND REFERENCES

## Resources

- The National Healthcare Quality and Disparities Reports website features annual reports on healthcare quality and disparities and chartbooks on multiple quality topics. https://nhqrnet.ahrq.gov/inhqrdr/
- The VA Office of Health Equity aims to increase access to high-quality healthcare for all Veterans by creating reports and tools to assess health conditions and provide comparative information. https://www.va.gov/healthequity/
- The VA Office of Research and Development conducts research and provides analytics on topics such as reducing inequality in healthcare for Veterans. https://www.research.va.gov/topics/health_equity.cfm

## References

Note: All web pages noted here were accessed November 3, 2020.

Advanced Data Systems Corporation. 4 Things That Improve Patient Experience in the Doctor’s Office. 2019. https://www.adsc.com/blog/4-things-all-patients-want-in-their-doctors-office.
Agency for Healthcare Research and Quality. Chartbook on the Healthcare for Asians and Native Hawaiians/Pacific Islanders. 2020. https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/asian-nhpi/index.html
Agency for Healthcare Research and Quality. Prevention, Diagnosis, and Management of Opioids, Opioid Misuse, and Opioid Use Disorder in Older Adults. 2019. https://effectivehealthcare.ahrq.gov/products/opioids-older-adults/protocol
American Geriatrics Society. For older people, medications are common; updated AGS Beers Criteria^®^ aims to make sure they’re appropriate, too [press release]. 2019. https://www.americangeriatrics.org/media-center/news/older-people-medications-are-common-updated-ags-beers-criteriar-aims-make-sure
American Heart Association. More than 100 million Americans have high blood pressure, AHA says. 2018. https://www.heart.org/en/news/2018/05/01/more-than-100-million-americans-have-high-blood-pressure-aha-says
Bible JE, Shau DN, Kay HF, . Are low patient satisfaction scores always due to the provider?: determinants of patient satisfaction scores during spine clinic visits. Spine 2018;43(1):58–64. https://pubmed.ncbi.nlm.nih.gov/26780613/ 26780613
Blewett LA, Johnson PJ, Lee B, . When a usual source of care and usual provider matter: adult prevention and screening services. J Gen Intern Med 2008;23(9):1354–60. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2518015/.18506542
Centers for Disease Control and Prevention. About Tetanus - Causes and Transmission. 2019. https://www.cdc.gov/tetanus/about/causes-transmission.html
Centers for Disease Control and Prevention. About Tetanus - Symptoms and Complications. 2019. https://www.cdc.gov/tetanus/about/symptoms-complications.html
Centers for Disease Control and Prevention. Diabetes Tests. 2019. https://www.cdc.gov/diabetes/basics/getting-tested.html
Centers for Disease Control and Prevention. Diphtheria, Tetanus, and Whooping Cough Vaccination: What Everyone Should Know. 2020. https://www.cdc.gov/vaccines/vpd/dtap-tdap-td/public/index.html
Centers for Disease Control and Prevention. Flu Vaccination Coverage, the United States, 2018–19 Influenza Season. https://www.cdc.gov/flu/fluvaxview/coverage-1819estimates.htm
Centers for Disease Control and Prevention. Getting Your Cholesterol Checked. 2020. https://www.cdc.gov/cholesterol/cholesterol_screening.htm
Centers for Disease Control and Prevention. High Blood Pressure. 2020. https://www.cdc.gov/blood-pressure/
Centers for Disease Control and Prevention. High Cholesterol Facts. 2020. https://www.cdc.gov/cholesterol/facts.htm
Centers for Disease Control and Prevention. National Diabetes Statistics Report. 2020. https://www.cdc.gov/diabetes/pdfs/data/statistics/national-diabetes-statistics-report.pdf
Centers for Disease Control and Prevention. Oral and Dental Health. 2017. https://www.cdc.gov/nchs/fastats/dental.htm
Centers for Disease Control and Prevention. Pneumococcal Disease. Types of Infection. 2017. https://www.cdc.gov/pneumococcal/about/infection-types.html
Centers for Disease Control and Prevention. Pneumococcal Vaccination: What Everyone Should Know. 2019. https://www.cdc.gov/vaccines/vpd/pneumo/public/index.html
Centers for Disease Control and Prevention. Preventing Suicide. 2020. https://www.cdc.gov/violenceprevention/suicide/fastfact.html
Centers for Disease Control and Prevention. Shingles (Herpes Zoster) Vaccination. 2016. https://www.cdc.gov/vaccines/vpd/shingles/index.html
Centers for Disease Control and Prevention. Smoking & Tobacco Use. Smoking Cessation: Fast Facts. 2020. https://www.cdc.gov/tobacco/data_statistics/fact_sheets/cessation/smoking-cessation-fastfacts/index.html
Centers for Disease Control and Prevention. Smoking Cessation: A Report of the Surgeon General. 2020. https://www.cdc.gov/tobacco/data_statistics/sgr/2020-smoking-cessation/index.html
Centers for Disease Control and Prevention. Vaccination Coverage Among Adults in the United States, National Health Interview Survey, 2016. 2018. https://www.cdc.gov/vaccines/imzmanagers/coverage/adultvaxview/pubs-resources/NHIS-2016.html
Centers for Disease Control and Prevention. What Is Diabetes? 2020. https://www.cdc.gov/diabetes/basics/diabetes.html
Chou SC, Rothenberg C, Agnoli A, . Patient centered medical homes did not improve access to timely follow-up after ED visit. American J Emerg Med 2018;36(5):854–58. https://pubmed.ncbi.nlm.nih.gov/29452920/
Fullerton CA, Witt WP, Chow CM, . Impact of a usual source of care on health care use, spending, and quality among adults with mental health conditions. Admin Pol Mental Health. 2018 May;45(3):462–71. https://pubmed.ncbi.nlm.nih.gov/29189994/
National Cancer Institute. Cancer Stat Facts: Colorectal Cancer. 2020. https://seer.cancer.gov/statfacts/html/colorect.html
National Cancer Institute, Cancer Stat Facts: Female Breast Cancer. 2020. https://seer.cancer.gov/statfacts/html/breast.html
National Cancer Institute. Cancer Stat Facts: Lung and Bronchus Cancer. 2020. https://seer.cancer.gov/statfacts/html/lungb.html
National Conference on State Legislators. Managed Care, Market Reports and the States. 2017. https://www.ncsl.org/research/health/managed-care-and-the-states.aspx
Smart NA, Titus TT. Outcomes of early versus late nephrology referral in chronic kidney disease: a systematic review. Am J Med 2011;124(11):1073–80e2. https://pubmed.ncbi.nlm.nih.gov/22017785/.22017785
U.S. Preventive Services Task Force. Screening for High Blood Pressure in Adults: Recommendation Statement. 2016. https://www.aafp.org/afp/2016/0215/p300.html