# CONTRAST 3 FINDINGS: DISPARITIES WITHIN VHA USERS

## Access and Quality Measures

Disparities in Access or Quality Within VHA Users, by Age, Gender, and Education

Bar Graph. For 2015: VHA users age 45-64 experienced better care than VHA users age 18-44 on 18 measures (64%) and similar on 10 measures (36%). VHA users age 65+ experienced better care than VHA users age 18-44 on 22 measures (79%), similar on 4 measures (14%), and worse on 2 measures (7%). VHA users with less than high school education experienced better care than VHA users with a Bachelor’s degree on 10 measures (36%), similar on 15 measures (54%), and worse on 3 measures (11%). VHA users with a high school education experienced better care than VHA users with a Bachelor’s degree on 7 measures (25%) and similar on 21 measures (75%). VHA users with some college education experienced similar care to VHA users with a Bachelor’s degree on 28 measures (100%). Female VHA users experienced better care than male VHA users on 1 measure (4%), similar on 16 measures (57%), and worse on 11 measures (39%). Key: y.o. = years old. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: The goal of quality improvement is to produce better quality of and access to care, and ultimately improved patient outcomes, regardless of VHA user characteristics.
- Findings: For the most recent data year (2015), findings show that age, education, and gender disparities persist.
  ■ Age
    ⧫ VHA users ages 45–64 experienced better care than VHA users ages 18–44 on 18 measures (64%) and similar care on 10 measures (36%).
    ⧫ VHA users age 65+ experienced better care than VHA users ages 18–44 on 22 measures (79%), similar care on 4 measures (14%), and worse care on 2 measures (7%).
  ■ Gender
    ⧫ Female VHA users experienced better care than male VHA users on 1 measure (4%), similar care on 16 measures (57%), and worse care on 11 measures (39%).
  ■ Education
    ⧫ VHA users with less than a high school education experienced better care than VHA users with a bachelor’s degree on 10 measures (36%), similar care on 15 measures (54%), and worse care on 3 measures (11%).
    ⧫ VHA users with a high school education experienced better care than VHA users with a bachelor’s degree on 7 measures (25%) and similar care on 21 measures (75%).
    ⧫ VHA users with some college education experienced care similar to VHA users with a bachelor’s degree on 28 measures (100%).

Disparities in Access Within VHA Users, by Age, Gender, and Education

Bar Graph. For 2015: VHA users age 45-64 experienced better care than VHA users age 18-44 on 5 measures (83%) and similar on 1 measure (17%). VHA users age 65+ experienced better care than VHA users age 18-44 on 6 measures (100%). VHA users with less than high school education experienced better care than VHA users with a Bachelor’s degree on 4 measures (67%) and similar on 2 measures (33%). VHA users with a high school education experienced better care than VHA users with a Bachelor’s degree on 4 measures (67%) and similar on 2 measures (33%). VHA users with some college education experienced similar care to VHA users with a Bachelor’s degree on 6 measures (100%). Female VHA users experienced similar care to male VHA users on 1 measure (17%) and worse on 5 measures (83%). Key: y.o. = years old. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: The goal of quality improvement is to produce better quality of and access to care, and ultimately improved patient outcomes, regardless of VHA user characteristics.
- Findings: For the most recent data year (2015), findings show that age, education, and gender disparities persist across ACCESS measures.
  ■ Age
    ⧫ VHA users ages 45–64 experienced better care than VHA users ages 18–44 on 5 measures (83%) and similar care on 1 measure (17%).
    ⧫ VHA users age 65+ experienced better care than VHA users ages 18–44 on 6 measures (100%).
  ■ Gender
    ⧫ Female VHA users experienced care similar to male VHA users on 1 measure (17%) and worse care on 5 measures (83%).
  ■ Education
    ⧫ VHA users with less than a high school education experienced better care than VHA users with a bachelor’s degree on 4 measures (67%) and similar care on 2 measures (33%).
    ⧫ VHA users with a high school education experienced better care than VHA users with a bachelor’s degree on 4 measures (67%) and similar care on 2 measures (33%).
    ⧫ VHA users with some college education experienced care similar to VHA users with a bachelor’s degree on 6 measures (100%).

Disparities in Quality Within VHA Users, by Age, Gender, and Education

Bar Graph. For 2015: VHA users age 45-64 experienced better care than VHA users age 18-44 on 13 measures (59%) and similar on 9 measures (41%). VHA users age 65+ experienced better care than VHA users age 18-44 on 16 measures (73%), similar on 4 measures (18%), and worse on 2 measures (9%). VHA users with less than high school education experienced better care than VHA users with a Bachelor’s degree on 6 measures (27%), similar on 13 measures (59%), and worse on 3 measures (14%). VHA users with a high school education experienced better care than VHA users with a Bachelor’s degree on 3 measures (14%) and similar on 19 measures (86%). VHA users with some college education experienced similar care to VHA users with a Bachelor’s degree on 22 measures (100%). Female VHA users experienced better care than male VHA users on 1 measure (4%), similar on 15 measures (68%), and worse on 6 measures (27%). Key: y.o. = years old. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: The goal of quality improvement is to produce better quality of and access to care, and ultimately improved patient outcomes, regardless of VHA user characteristics.
- Findings: For the most recent data year (2015), findings show that age, education, and gender disparities persist across QUALITY measures.
  ■ Age
    ⧫ VHA users ages 45–64 experienced better care than VHA users ages 18–44 on 13 measures (59%) and similar care on 9 measures (41%).
    ⧫ VHA users age 65+ experienced better care than VHA users ages 18–44 on 16 measures (73%), similar care on 4 measures (18%), and worse care on 2 measures (9%).
  ■ Gender
    ⧫ Female VHA users experienced better care than male VHA users on 1 measure (4%), similar care on 15 measures (68%), and worse care on 6 measures (27%).
  ■ Education
    ⧫ VHA users with less than a high school education experienced better care than VHA users with a bachelor’s degree on 6 measures (27%), similar care on 13 measures (59%), and worse care on 3 measures (14%).
    ⧫ VHA users with a high school education experienced better care than VHA users with a bachelor’s degree on 3 measures (14%) and similar care on 19 measures (86%).
    ⧫ VHA users with some college education experienced care similar to VHA users with a bachelor’s degree on 22 measures (100%).

Disparities in Access or Quality Within VHA Users, by Race/Ethnicity

Bar Graph. For 2015: Hispanic VHA users experienced better care than non-Hispanic white VHA users on 2 measures (7%), similar on 20 measures (71%), and worse on 6 measures (21%). Non-Hispanic American Indian Alaska Native VHA users experienced better care than non-Hispanic white VHA users on 1 measure (4%), similar on 21 measures (75%), and worse on 6 measures (21%). Non-Hispanic Asian VHA users experienced better care than non-Hispanic white VHA users on 1 measure (4%), similar on 22 measures (79%), and worse on 5 measures (18%). Non-Hispanic black VHA users experienced better care than non-Hispanic white VHA users on 3 measures (11%), similar on 23 measures (82%), and worse on 2 measures (7%). Non-Hispanic multirace VHA users experienced better care than non-Hispanic white VHA users on 1 measure (4%), similar on 23 measures (82%), and worse on 4 measures (14%). Non-Hispanic Native Hawaiian/other Pacific Islander VHA users experienced better care than non-Hispanic white VHA users on 2 measures (7%), similar on 22 measures (79%), and worse on 4 measures (14%). Key: NH = Non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: The goal of quality improvement is to produce better quality of and access to care, and ultimately improved patient outcomes, regardless of VHA user characteristics.
- Findings: For the most recent data year (2015), findings show that racial/ethnic disparities persist.
  ■ Hispanic VHA users experienced better care than non-Hispanic White VHA users on 2 measures (7%), similar care on 20 measures (71%), and worse care on 6 measures (21%).
  ■ Non-Hispanic American Indian/Alaska Native VHA users experienced better care than non-Hispanic White VHA users on 1 measure (4%), similar care on 21 measures (75%), and worse care on 6 measures (21%).
  ■ Non-Hispanic Asian VHA users experienced better care than non-Hispanic White VHA users on 1 measure (4%), similar care on 22 measures (79%), and worse care on 5 measures (18%).
  ■ Non-Hispanic Black VHA users experienced better care than non-Hispanic White VHA users on 3 measures (11%), similar care on 23 measures (82%), and worse care on 2 measures (7%).
  ■ Non-Hispanic multirace VHA users experienced better care than non-Hispanic White VHA users on 1 measure (4%), similar care on 23 measures (82%), and worse care on 4 measures (14%).
  ■ Non-Hispanic Native Hawaiian/Other Pacific Islander VHA users experienced better care than non-Hispanic White VHA users on 2 measures (7%), similar care on 22 measures (79%), and worse care on 4 measures (14%).

Disparities in Access Within VHA Users, by Race/Ethnicity

Bar Graph. For 2015: Hispanic VHA users experienced similar care to non-Hispanic white VHA users on 2 measures (33%) and worse on 4 measures (67%). Non-Hispanic American Indian Alaska Native VHA users experienced similar care to non-Hispanic white VHA users on 3 measures (50%) and worse on 3 measures (50%). Non-Hispanic Asian VHA users experienced similar care to non-Hispanic white VHA users on 5 measures (83%) and worse on 1 measure (17%). Non-Hispanic black VHA users experienced better care than non-Hispanic white VHA users on 1 measure (17%), similar on 3 measures (50%), and worse on 2 measures (33%). Non-Hispanic multi race VHA users experienced similar care to non-Hispanic white VHA users on 3 measures (50%) and worse on 3 measures (50%). Non-Hispanic Native Hawaiian/other Pacific Islander VHA users experienced similar care to non-Hispanic white VHA users on 5 measures (83%) and worse on 1 measure (17%). Key: NH = Non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: The goal of quality improvement is to produce better quality of and access to care, and ultimately improved patient outcomes, regardless of VHA user characteristics.
- Findings: For the most recent data year (2015), findings show that racial/ethnic disparities persist across ACCESS measures.
  ■ Hispanic VHA users experienced care similar to non-Hispanic White VHA users on 2 measures (33%) and worse care on 4 measures (67%).
  ■ Non-Hispanic American Indian/Alaska Native VHA users experienced care similar to non-Hispanic White VHA users on 3 measures (50%) and worse care on 3 measures (50%).
  ■ Non-Hispanic Asian VHA users experienced care similar to non-Hispanic White VHA users on 5 measures (83%) and worse care on 1 measure (17%).
  ■ Non-Hispanic Black VHA users experienced better care than non-Hispanic White VHA users on 1 measure (17%), similar care on 3 measures (50%), and worse care on 2 measures (33%).
  ■ Non-Hispanic multirace VHA users experienced care similar to non-Hispanic White VHA users on 3 measures (50%) and worse care on 3 measures (50%).
  ■ Non-Hispanic Native Hawaiian/Other Pacific Islander VHA users experienced care similar to non-Hispanic White VHA users on 5 measures (83%) and worse care on 1 measure (17%).

Disparities in Quality Within VHA Users, by Race/Ethnicity

Bar Graph. For 2015: Hispanic VHA users experienced better care than non-Hispanic white VHA users on 2 measures (9%), similar on 18 measures (82%), and worse on 2 measures (9%). Non-Hispanic American Indian Alaska Native VHA users experienced better care than non-Hispanic white VHA users on 1 measure (4%), similar on 18 measures (82%), and worse on 3 measures (14%). Non-Hispanic Asian VHA users experienced better care than non-Hispanic white VHA users on 1 measure (4%), similar on 17 measures (77%), and worse on 4 measures (18%). Non-Hispanic black VHA users experienced better care than non-Hispanic white VHA users on 2 measures (9%) and similar on 20 measures (91%). Non-Hispanic multirace VHA users experienced better care than non-Hispanic white VHA users on 1 measure (4%), similar on 20 measures (91%), and worse on 1 measure (4%). Non-Hispanic Native Hawaiian/other Pacific Islander VHA users experienced better care than non-Hispanic white VHA users on 2 measures (9%), similar on 17 measures (77%), and worse on 3 measures (14%) Key: NH = Non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: The goal of quality improvement is to produce better quality of and access to care, and ultimately improved patient outcomes, regardless of VHA user characteristics.
- Findings: For the most recent data year (2015), findings show that racial/ethnic disparities persist across QUALITY measures.
  ■ Hispanic VHA users experienced better care than non-Hispanic White VHA users on 2 measures (9%), similar care on 18 measures (82%), and worse care on 2 measures (9%).
  ■ Non-Hispanic American Indian/Alaska Native VHA users experienced better care than non-Hispanic White VHA users on 1 measure (4%), similar care on 18 measures (82%), and worse care on 3 measures (14%).
  ■ Non-Hispanic Asian VHA users experienced better care than non-Hispanic White VHA users on 1 measure (4%), similar care on 17 measures (77%), and worse care on 4 measures (18%).
  ■ Non-Hispanic Black VHA users experienced better care than non-Hispanic White VHA users on 2 measures (9%) and similar care on 20 measures (91%).
  ■ Non-Hispanic multirace VHA users experienced better care than non-Hispanic White VHA users on 1 measure (4%), similar care on 20 measures (91%), and worse care on 1 measure (4%).
  ■ Non-Hispanic Native Hawaiian/Other Pacific Islander VHA users experienced better care than non-Hispanic White VHA users on 2 measures (9%), similar care on 17 measures (77%), and worse care on 3 measures (14%).

## Timely Access to Care

VHA Users Who Got an Appointment for Routine Care As Soon as Needed, by Age, Gender, and Education

Bar graph. Percent of VHA users who indicated that in the last 12 months, when making an appointment for a check-up or routine care, they got an appointment as soon as needed, 2015: when compared to VHA users age 18-44 VHA users age 45-64 were significantly more likely to indicate they got a routine care appointment as soon as needed (49.2% vs. 37.8%); VHA users age 65+ were significantly more likely to indicate they got a routine care appointment as soon as needed (59.1% vs. 37.8%). Female VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed compared to male VHA users (43.0% vs. 53.4%). VHA users with less than a high school degree was not significantly more likely to indicate they got a routine care appointment as soon as needed (56.9% vs. 52.4%). VHA users with a high school degree were not significantly more likely to indicate they got a routine care appointment as soon as needed (55.6% vs. 52.4%). VHA users with some college education were not significantly less likely to indicate they got a routine care appointment as soon as needed (49.6% vs. 52.4%), compared to VHA users with a Bachelor’s degree. Key: y.o. = years old. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: Timely delivery of appropriate care is a measure of the healthcare system’s capacity to provide care quickly after a need is recognized (Smart and Titus, 2011).
- Overall Rate: In 2015, 52.4% of VHA users, when making an appointment for a checkup or routine care, got an appointment as soon as needed (data not shown).
- Groups With Disparities: In 2015, findings show significant disparities by age and gender but not education.
  ■ Age
    ⧫ VHA users ages 45–64 were significantly more likely to indicate they got a routine care appointment as soon as needed compared with VHA users ages 18–44 (49.2% vs. 37.8%).
    ⧫ VHA users age 65+ were significantly more likely to indicate they got a routine care appointment as soon as needed compared with VHA users ages 18–44 (59.1% vs. 37.8%).
  ■ Gender
    ⧫ Female VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed compared with male VHA users (43.0% vs. 53.4%).
  ■ Education
    ⧫ There were no statistically significant differences between VHA users with less than a high school degree and VHA users with a bachelor’s degree in the percentage who indicated they got a routine care appointment as soon as needed (56.9% vs. 52.4%).
    ⧫ There were no statistically significant differences between VHA users with a high school degree and VHA users with a bachelor’s degree in the percentage who indicated they got a routine care appointment as soon as needed (55.6% vs. 52.4%).
    ⧫ There were no statistically significant differences between VHA users with some college education and VHA users with a bachelor’s degree in the percentage who indicated they got a routine care appointment as soon as needed (49.6% vs. 52.4%).

VHA Users Who Got an Appointment for Routine Care As Soon as Needed, by Race/Ethnicity

Bar Graph. For 2015: When compared to non-Hispanic white VHA users: Hispanic VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed (44.8% vs. 55.0%). Non-Hispanic American Indian/Alaska Native VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed (46.2% vs. 55.0%). Non-Hispanic Asian VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed (42.9% vs. 55.0%). Non-Hispanic black VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed (48.1% vs. 55.0%). Non-Hispanic multiracial VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed (47.5% vs. 55.0%). Non-Hispanic Native Hawaiian/other Pacific Islander VHA users were significantly less likely to indicate they got a routine care appointment as soon as (46.4% vs. 55.0%). Key: NH = Non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: Timely delivery of appropriate care is a measure of the healthcare system’s capacity to provide care quickly after a need is recognized (Smart and Titus, 2011).
- Overall Rate: In 2015, 52.4% of VHA users, when making an appointment for a checkup or routine care, got an appointment as soon as needed (data not shown).
- Groups With Disparities: In 2015, findings show significant racial/ethnic disparities.
  ■ Hispanic VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed compared with non-Hispanic White VHA users (44.8% vs. 55.0%).
  ■ Non-Hispanic American Indian/Alaska Native VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed compared with non-Hispanic White VHA users (46.2% vs. 55.0%).
  ■ Non-Hispanic Asian VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed compared with non-Hispanic White VHA users (42.9% vs. 55.0%).
  ■ Non-Hispanic Black VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed compared with non-Hispanic White VHA users (48.1% vs. 55.0%).
  ■ Non-Hispanic multirace VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed compared with non-Hispanic White VHA users (47.5% vs. 55.0%).
  ■ Non-Hispanic Native Hawaiian/Other Pacific Islander VHA users were significantly less likely to indicate they got a routine care appointment as soon as needed compared with non-Hispanic White VHA users (46.4% vs. 55.0%).

VHA Users Who Got Care Evenings, Weekends, or Holidays, by Age, Gender, and Education

Bar Graph. During evenings, weekends, or holidays when compared to compared to VHA users age 18-44: VHA users age 45-64 were (18.6% vs. 13.5%). VHA users age 65+ were (22.0% vs. 13.5%). When compared to male VHA users: Female VHA users were significantly less likely to receive care they needed (11.9% vs. 19.9%). VHA users with less than a high school degree were significantly more likely to receive care they needed (25.1% vs. 17.1%). VHA users with a high school degree were (21.9% vs. 17.1%). VHA users with some college education were not significantly more likely receive care they needed (17.2% vs. 17.1%). Key: y.o. = years old. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: An analysis of the 2010 Health Tracking Household Survey found that among people with a usual source of primary care, 40.2% reported that their practice offered extended hours, such as at night or on weekends. The analysis also found that one in five people who attempted after-hours contact with their primary care provider reported it was “very difficult” or “somewhat difficult” to reach a clinician. Those who reported less difficulty contacting a clinician after hours had significantly fewer emergency department visits (30.4% compared with 37.7%) and lower rates of unmet medical need (6.1% compared with 13.7%) than people who experienced more difficulty (O’Malley, 2013).
- Overall Rate: In 2015, 18.9% of VHA users received care they needed during evenings, weekends, or holidays (data not shown).
- Groups With Disparities: In 2015, findings show significant disparities by age, gender, and education.
  ■ Age
    ⧫ VHA users ages 45–64 were significantly more likely to receive care they needed during evenings, weekends, or holidays compared with VHA users ages 18–44 (18.6% vs. 13.5%).
    ⧫ VHA users age 65+ were significantly more likely to receive care they needed during evenings, weekends, or holidays compared with VHA users ages 18–44 (22.0% vs. 13.5%).
  ■ Gender
    ⧫ Female VHA users were significantly less likely to receive care they needed during evenings, weekends, or holidays compared with male VHA users (11.9% vs. 19.9%).
  ■ Education
    ⧫ VHA users with less than a high school degree were significantly more likely to receive care they needed during evenings, weekends, or holidays compared with VHA users with a bachelor’s degree (25.1% vs. 17.1%).
    ⧫ VHA users with a high school degree were significantly more likely to receive care they needed during evenings, weekends, or holidays compared with VHA users with a bachelor’s degree (21.9% vs. 17.1%).
    ⧫ There were no statistically significant differences between VHA users with some college education and VHA users with a bachelor’s degree who received care they needed during evenings, weekends, or holidays (17.2% vs. 17.1%).

VHA Users Who Got Care Evenings, Weekends, or Holidays, by Race/Ethnicity

Bar Graph. In 2015 Percentage of VHA users who received the care they needed from their provider during evenings, weekends, or holidays within the last 12 months, 2015: Hispanic (16.2%); NH AIAN (14.9%); NH Asian (17.3%); NH Black (22.8); NH Multi Race (18.1%); NH NHOPI (21.6%) NH White (18.3%). Key: NH = Non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: An analysis of the 2010 Health Tracking Household Survey found that among people with a usual source of primary care, 40.2% reported that their practice offered extended hours, such as at night or on weekends. The analysis also found that one in five people who attempted after-hours contact with their primary care provider reported it was “very difficult” or “somewhat difficult” to reach a clinician. Those who reported less difficulty contacting a clinician after hours had significantly fewer emergency department visits (30.4% compared with 37.7%) and lower rates of unmet medical need (6.1% compared with 13.7%) than people who experienced more difficulty (O’Malley, 2013).
- Overall Rate: In 2015, 18.9% of VHA users received care they needed during evenings, weekends, or holidays (data not shown).
- Groups With Disparities: In 2015, findings show significant racial/ethnic disparities.
  ■ Hispanic VHA users were significantly less likely to receive care they needed during evenings, weekends, or holidays compared with non-Hispanic White VHA users (16.2% vs. 18.3%).
  ■ There were no statistically significant differences between non-Hispanic American Indian/Alaska Native VHA users and non-Hispanic White VHA users in the percentage who received care they needed during evenings, weekends, or holidays (14.9% vs. 18.3%).
  ■ There were no statistically significant differences between non-Hispanic Asian VHA users and non-Hispanic White VHA users in the percentage who received care they needed during evenings, weekends, or holidays (17.3% vs. 18.3%).
  ■ Non-Hispanic Black VHA users were significantly more likely to receive care they needed during evenings, weekends, or holidays compared with non-Hispanic White VHA users (22.8% vs. 18.3%).
  ■ There were no statistically significant differences between non-Hispanic multirace VHA users and non-Hispanic White VHA users in the percentage who received care they needed during evenings, weekends, or holidays (18.1% vs. 18.3%).
  ■ There were no statistically significant differences between non-Hispanic Native Hawaiian/Other Pacific Islander VHA users and non-Hispanic White VHA users in the percentage who received care they needed during evenings, weekends, or holidays (21.6% vs. 18.3%).

VHA Users Who Phoned Their Provider’s Office and Got an Appointment As Soon As Needed, by Age, Gender, and Education

Bar Graph. In 2015 Percentage of VHA users who phoned their provider’s office and received an appointment for care as soon as they needed within the last 12 months: 18-44 years old 31%, 45-64 Years old 42%, 65 plus 50.3%; Female 35.7%, Male 44.6%; Who had some high school 48.4%, a high school degree 47.3%; Some College 41.4%, a bachelor’s degree 42%. Key: y.o. = years old. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: Timely delivery of appropriate care is a measure of the healthcare system’s capacity to provide care quickly after a need is recognized (Healthy People 2020). One study examined patient followup care at primary care practices and patient-centered medical homes following emergency department discharge. The study found that only 31% of patients using primary care practices were able to obtain an appointment in 7 days while practices with a patient-centered medical home designation were less likely to offer appointments within 7 days than those without the designation (23.4% vs. 33.1%) (Chou, et. al., 2018).
- Overall Rate: In 2015, 43.7% of VHA users, when phoning their provider’s office, got an appointment as soon as needed (data not shown).
- Groups With Disparities: In 2015, findings show significant disparities by age, gender, and education.
  ■ Age
    ⧫ VHA users ages 45–64 were significantly more likely to indicate they got an appointment as soon as needed compared with VHA users ages 18–44 (42.0% vs. 31.0%).
    ⧫ VHA users age 65+ were significantly more likely to indicate they got an appointment as soon as needed compared with VHA users ages 18–44 (50.3% vs. 31.0%).
  ■ Gender
    ⧫ Female VHA users were significantly less likely to indicate they got an appointment as soon as needed compared with male VHA users (35.7% vs. 44.6%).
  ■ Education
    ⧫ VHA users with less than a high school degree were significantly more likely to indicate they got an appointment as soon as needed compared with VHA users with a bachelor’s degree (48.4% vs. 42.0%).
    ⧫ VHA users with a high school degree were significantly more likely to indicate they got an appointment as soon as needed compared with VHA users with a bachelor’s degree (47.3% vs. 42.0%).
    ⧫ There were no statistically significant differences between VHA users with some college education and VHA users with a bachelor’s degree in the percentage who indicated they got an appointment as soon as needed (41.4% vs. 42.0%).

VHA Users Who Phoned Their Provider’s Office and Got an Appointment As Soon As Needed, by Race/Ethnicity

Bar Graph. In 2015 Percentage of VHA users who phoned their provider’s office and received an appointment for care as soon as they needed within the last 12 months, 2015 Hispanic 39.1%, NH AIAN 40.5%, NH Asian 45.1%, NH Black 42.9%, NH Multi racial 39.9%, NH NHOPI 44.5%, and NH White 44.9%. Key: NH = Non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: Timely delivery of appropriate care is a measure of the healthcare system’s capacity to provide care quickly after a need is recognized (Healthy People 2020). One study examined patient followup care at primary care practices and patient-centered medical homes following emergency department discharge. The study found that only 31% of patients using primary care practices were able to obtain an appointment in 7 days while practices with a patient-centered medical home designation were less likely to offer appointments within 7 days than those without the designation (23.4% vs. 33.1%) (Chou, et. al., 2018).
- Overall Rate: In 2015, 43.7% of VHA users, when phoning their provider’s office, got an appointment as soon as needed (data not shown).
- Groups With Disparities: In 2015, findings show significant racial/ethnic disparities.
  ■ Hispanic VHA users were significantly less likely to indicate they got an appointment as soon as needed compared with non-Hispanic White VHA users (39.1% vs. 44.9%).
  ■ There were no statistically significant differences between non-Hispanic American Indian/Alaska Native VHA users and non-Hispanic White VHA users who indicated they got an appointment as soon as needed (40.5% vs. 44.9%).
  ■ There were no statistically significant differences between non-Hispanic Asian VHA users and non-Hispanic White VHA users who indicated they got an appointment as soon as needed (45.1% vs. 44.9%).
  ■ There were no statistically significant differences between non-Hispanic Black VHA users and non-Hispanic White VHA users who indicated they got an appointment as soon as needed (42.9% vs. 44.9%).
  ■ Non-Hispanic multirace VHA users were significantly less likely to indicate they got an appointment as soon as needed compared with non-Hispanic White VHA users (39.9% vs. 44.9%).
  ■ There were no statistically significant differences between non-Hispanic Native Hawaiian/Other Pacific Islander VHA users and non-Hispanic White VHA users who indicated they got an appointment as soon as needed (44.5% vs. 44.9%).

## Receipt of Followup

Receipt of Followup From Provider’s Office After Tests, by Age, Gender, and Education

Bar Graph. In 2015 Percentage of VHA users who received a follow-up from their provider’s office after the provider ordered a blood test, x-ray, or other test within the last 12 months. 18 to 44 years old 47.3%, 45-64 years old 57%, 65 plus years old 63.7%; Female 50.2%, Male 59.8%; Those with some High School 63.2%, a High School Degree 62.3%, Some college 56.7%, a bachelor’s degree 57.4%. Key: y.o. = years old. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: Failure to follow up on test results is an important safety concern that requires urgent attention. In one review of studies quantifying the extent of failure to follow up test results among ambulatory patients, the impact on patient outcomes included missed cancer diagnoses (Callen, 2012). Among hospitalized patients, another systematic review of studies investigated the failure to follow up for inpatients. The review found that the lack of followup of test results for inpatients ranged from 20.0% to 61.6% (Callen, 2011). The consequences of missed test results for patient care included delayed diagnoses such as malignancies, hypothyroidism, hyperthyroidism, and osteoporosis (Callen, 2015).
- Overall Rate: In 2015, 58.9% of VHA users received a followup from their provider’s office after the provider ordered a blood test, x ray, or other test within the last 12 months (data not shown).
- Groups With Disparities: In 2015, findings show significant disparities by age, gender, and education.
  ■ Age
    ⧫ VHA users ages 45–64 were significantly more likely to receive followup compared with VHA users ages 18–44 (57.0% vs. 47.3%).
    ⧫ VHA users age 65+ were significantly more likely to receive followup compared with VHA users ages 18–44 (63.7% vs. 47.3%).
  ■ Gender
    ⧫ Female VHA users were significantly less likely to receive followup compared with male VHA users (50.2% vs. 59.8%).
  ■ Education
    ⧫ VHA users with less than a high school degree were significantly more likely to receive followup compared with VHA users with a bachelor’s degree (63.2% vs. 57.4%).
    ⧫ There were no statistically significant differences between VHA users with a high school degree and VHA users with a bachelor’s degree in the percentage who received followup (62.3% vs. 57.4%).
    ⧫ There were no statistically significant differences between VHA users with some college education and VHA users with a bachelor’s degree in the percentage who received followup (56.7% vs. 57.4%).

Receipt of Followup From Provider’s Office After Tests, by Race/Ethnicity

Bar Graph. Within the last 12 months of 2015, the Percentage of VHA users who received a follow-up from their provider’s office after the provider ordered a blood test, x-ray, or other test: Hispanic 51.2%, Non-Hispanic American Indian/Alaska Native 51.1%, Non-Hispanic Asian 48.5%, Non-Hispanic black 59.6%, Non-Hispanic multirace 55.0%, Non-Hispanic Native Hawaiian/other Pacific Islander 47.6%, 60.3% non-hispanic white. Key: NH = Non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: Failure to follow up on test results is an important safety concern that requires urgent attention. In one review of studies quantifying the extent of failure to follow up test results among ambulatory patients, the impact on patient outcomes included missed cancer diagnoses (Callen, 2012). Among hospitalized patients, another systematic review of studies investigated the failure to follow up for inpatients. The review found that the lack of followup of test results for inpatients ranged from 20.0% to 61.6% (Callen, 2011). The consequences of missed test results for patient care included delayed diagnoses such as malignancies, hypothyroidism, hyperthyroidism, and osteoporosis (Callen, 2015).
- Overall Rate: In 2015, 58.9% of VHA users received a followup from their provider’s office after the provider ordered a blood test, x-ray, or other test within the last 12 months (data not shown).
- Groups With Disparities: In 2015, findings show significant racial/ethnic disparities.
  ■ Hispanic VHA users were significantly less likely to receive followup compared with non-Hispanic White VHA users (51.2% vs. 60.3%).
  ■ Non-Hispanic American Indian/Alaska Native VHA users were significantly less likely to receive followup compared with non-Hispanic White VHA users (51.1% vs. 60.3%).
  ■ Non-Hispanic Asian VHA users were significantly less likely to receive followup compared with non-Hispanic White VHA users (48.5% vs. 60.3%).
  ■ There were no statistically significant differences between non-Hispanic Black VHA users and non-Hispanic White VHA users in the percentage who received followup (59.6% vs. 60.3%).
  ■ There were no statistically significant differences between non-Hispanic multirace VHA users and non-Hispanic White VHA users in the percentage who received followup (55.0% vs. 60.3%).
  ■ Non-Hispanic Native Hawaiian/Other Pacific Islander VHA users were significantly less likely to receive followup compared with non-Hispanic White VHA users (47.6% vs. 60.3%).

## Provider Discussions About Personal Problems, Substance Use, or Mental Illness

VHA Users Who Had Someone From Their Provider’s Office Talk to Them About a Personal Problem, Substance Use, or Mental Illness, by Age, Gender, and Education

Bar Graph. Percentage of VHA users who had someone from their provider?s office talk to them about a personal problem, family problem, alcohol use, drug use, or mental or emotional illness within the last 12 months, 2015: age 45-64 57.7%, age 65+ 45.0%; Female users 56.3%, male 51.3%; with less than a high school degree 44.6%, with a high school degree 51.5%, some college education 53.9%, a Bachelor’s degree 50.4%. Key: y.o. = years old. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance:
  ■ Team-based care offers many potential advantages, including more effective and efficient delivery of additional services that are essential to providing high-quality care, such as patient education, behavioral health, self-management support, and care coordination (Schottenfield, 2016).
  ■ It is common for patients to see a primary care provider because of behavioral health issues, including mental illnesses such as depression, anxiety, or problems with alcohol use. On January 1, 2017, the Centers for Medicare & Medicaid Services began paying primary care clinicians separately for collaborative care services they provide to patients being treated for a mental or behavioral health condition. Collaborative care is when a behavioral healthcare manager becomes part of the patient’s treatment team and helps the primary care provider evaluate the patient’s mental health. If the patient receives a diagnosis of a mental health disorder and wants treatment, the care manager, primary care provider, and patient work together to develop a treatment plan (NIMH, 2016).
- Overall Rate: In 2015, 51.9% of VHA users had someone talk to them about a personal problem, family problem, alcohol use, drug use, or mental or emotional illness within the last 12 months (data not shown).
- Groups With Disparities: In 2015, findings show significant disparities by age and education but not gender.
  ■ Age
    ⧫ There were no statistically significant differences between VHA users ages 4564 and VHA users ages 18–44 in the percentage who had someone talk about personal issues (57.7% vs. 60.8%).
    ⧫ VHA users age 65+ were significantly less likely to have someone talk about personal issues compared with VHA users ages 18–44 (45.0% vs. 60.8%).
  ■ Gender
    ⧫ There were no statistically significant differences between female VHA users and male VHA users in the percentage who had someone talk about personal issues (56.3% vs. 51.3%).
  ■ Education
    ⧫ VHA users with less than a high school degree were significantly less likely to have someone talk about personal issues compared with VHA users with a bachelor’s degree (44.6% vs. 50.4%).
    ⧫ There were no statistically significant differences between VHA users with a high school degree and VHA users with a bachelor’s degree in the percentage who had someone talk about personal issues (51.5% vs. 50.4%).
    ⧫ There were no statistically significant differences between VHA users with some college education and VHA users with a bachelor’s degree in the percentage who had someone talk about personal issues (53.9% vs. 50.4%).

VHA Users Who Someone From Their Provider’s Office Talk to Them About a Personal Problem, Substance Use, or Mental Illness, by Race/Ethnicity

Bar Graph. Percentage of VHA users who had someone from their provider?s office talk to them about a personal problem, family problem, alcohol use, drug use, or mental or emotional illness within the last 12 months, 2015. Hispanic 55.3%, Non-Hispanic American Indian/Alaska Native 55.3%, Non-Hispanic Asian 55.4%, Non-Hispanic black 59.7%, Non-Hispanic multirace 55.1%, Non-Hispanic Native Hawaiian/other Pacific Islander 61.8%, non-Hispanic white 49.2%. Key: NH = Non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance:
  ■ Team-based care offers many potential advantages, including more effective and efficient delivery of additional services that are essential to providing high-quality care, such as patient education, behavioral health, self-management support, and care coordination (Schottenfield, 2016).
  ■ It is common for patients to see a primary care provider because of behavioral health issues, including mental illnesses such as depression, anxiety, or problems with alcohol use. On January 1, 2017, the Centers for Medicare & Medicaid Services began paying primary care clinicians separately for collaborative care services they provide to patients being treated for a mental or behavioral health condition. Collaborative care is when a behavioral healthcare manager becomes part of the patient’s treatment team and helps the primary care provider evaluate the patient’s mental health. If the patient receives a diagnosis of a mental health disorder and wants treatment, the care manager, primary care provider, and patient work together to develop a treatment plan (NIMH, 2016).
- Overall Rate: In 2015, 51.9% of VHA users had someone talk to them about a personal problem, family problem, alcohol use, drug use, or mental or emotional illness within the last 12 months (data not shown).
- Groups With Disparities: In 2015, findings show significant racial/ethnic disparities.
  ■ Hispanic VHA users were significantly more likely to have someone talk about personal issues compared with non-Hispanic White VHA users (55.3% vs. 49.2%).
  ■ Non-Hispanic American Indian/Alaska Native VHA users were significantly more likely to have someone talk about personal issues compared with non-Hispanic White VHA users (55.3% vs. 49.2%).
  ■ Non-Hispanic Asian VHA users were significantly more likely to have someone talk about personal issues compared with non-Hispanic White VHA users (55.4% vs. 49.2%).
  ■ Non-Hispanic Black VHA users were significantly more likely to have someone talk about personal issues compared with non-Hispanic White VHA users (59.7% vs. 49.2%).
  ■ Non-Hispanic multirace VHA users were significantly more likely to have someone talk about personal issues compared with non-Hispanic White VHA users (55.1% vs. 49.2%).
  ■ Non-Hispanic Native Hawaiian/Other Pacific Islander VHA users were significantly more likely to have someone talk about personal issues compared with non-Hispanic White VHA users (61.8% vs. 49.2%).

## Quality of Service by Clerks and Receptionists

VHA Users Who Indicated That Clerks and Receptionists at Their Provider’s Office Were as Helpful as They Should Be, by Age, Gender, and Education

Bar Graph. Percent of VHA users who indicated that in the last 12 months, clerks and receptionists at their provider's office were as helpful as they should be, 2015: age 45-64 56.3%, users age 65+ 63.1%; Female 51.3%; Male 59.2; less than a high school degree 65.3%, with a high school degree 63.3%, some college education 56.3%, a Bachelor’s degree 54.2%. Key: y.o. = years old. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: Courtesy and respect go a long way toward maintaining a positive relationship between staff and patient. The more comfortable patients are, the more likely they are to bring up issues the doctor needs to know about and discuss with them during diagnosis (Advanced Data Systems Corporation, 2019). In a study of patient satisfaction during spine clinic visits, patients’ perception of teamwork between staff and providers along with reliable followup communication were found to be significant determinants of overall patient satisfaction and perceived quality of care (Bible, et al., 2018).
- Overall Rate: In 2015, 58.5% of VHA users indicated clerks and receptionists at their provider’s office were as helpful as they should be (data not shown).
- Groups With Disparities: In 2015, findings show significant disparities by age, gender, and education.
  ■ Age
    ⧫ VHA users ages 45–64 were significantly more likely to indicate clerks and receptionists at their provider’s office were as helpful as they should be compared with VHA users ages 18–44 (56.3% vs. 47.8%).
    ⧫ VHA users age 65+ were significantly more likely to indicate clerks and receptionists at their provider’s office were as helpful as they should be compared with VHA users ages 18–44 (63.1% vs. 47.8%).
  ■ Gender
    ⧫ Female VHA users were significantly less likely to indicate clerks and receptionists at their provider’s office were as helpful as they should be compared with male VHA users (51.3% vs. 59.2%).
  ■ Education
    ⧫ VHA users with less than a high school degree were significantly more likely to indicate clerks and receptionists at their provider’s office were as helpful as they should be compared with VHA users with a bachelor’s degree (65.3% vs. 54.2%).
    ⧫ VHA users with a high school degree were significantly more likely to indicate clerks and receptionists at their provider’s office were as helpful as they should be compared with VHA users with a bachelor’s degree (63.3% vs. 54.2%).
    ⧫ There were no statistically significant differences between VHA users with some college education and VHA users with a bachelor’s degree in the percentage who indicated clerks and receptionists at their provider’s office were as helpful as they should be (56.3% vs. 54.2%).

VHA Users Who Indicated That Clerks and Receptionists at Their Provider’s Office Were as Helpful as They Should Be, by Race/Ethnicity

Bar Graph. Percent of VHA users who indicated that in the last 12 months, clerks and receptionists at their provider's office were as helpful as they should be, 2015: Hispanic 53.8%, Non-Hispanic American Indian/Alaska Native 54.4%, Non-Hispanic Asian 50.3%, Non-Hispanic black 57.0%, Non-Hispanic multiracial 53.1%, Non-Hispanic Native Hawaiian/other Pacific Islander 49.3%, non-Hispanic white 60.1%. Key: NH = Non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: Courtesy and respect go a long way toward maintaining a positive relationship between staff and patient. The more comfortable patients are, the more likely they are to bring up issues the doctor needs to know about and discuss with them during diagnosis (Advanced Data Systems Corporation, 2019). In a study of patient satisfaction during spine clinic visits, patients’ perception of teamwork between staff and providers along with reliable followup communication were found to be significant determinants of overall patient satisfaction and perceived quality of care (Bible, et al., 2018).
- Overall Rate: In 2015, 58.5% of VHA users indicated clerks and receptionists at their provider’s office were as helpful as they should be (data not shown).
- Groups With Disparities: In 2015, findings show significant racial/ethnic disparities.
  ■ Hispanic VHA users were significantly less likely to indicate clerks and receptionists at their provider’s office were as helpful as they should be compared with non-Hispanic White VHA users (53.8% vs. 60.1%).
  ■ There were no statistically significant differences between non-Hispanic American Indian/Alaska Native VHA users and non-Hispanic White VHA users in the percentage who indicated clerks and receptionists at their provider’s office were as helpful as they should be (54.4% vs. 60.1%).
  ■ Non-Hispanic Asian VHA users were significantly less likely to indicate clerks and receptionists at their provider’s office were as helpful as they should be compared with non-Hispanic White VHA users (50.3% vs. 60.1%).
  ■ There were no statistically significant differences between non-Hispanic Black VHA users and non-Hispanic White VHA users in the percentage who indicated clerks and receptionists at their provider’s office were as helpful as they should be (57.0% vs 60.1%).
  ■ Non-Hispanic multirace VHA users were significantly less likely to indicate clerks and receptionists at their provider’s office were as helpful as they should be compared with non-Hispanic White VHA users (53.1% vs. 60.1%).
  ■ Non-Hispanic Native Hawaiian/Other Pacific Islander VHA users were significantly less likely to indicate clerks and receptionists at their provider’s office were as helpful as they should be compared with non-Hispanic White VHA users (49.3% vs. 60.1%).

VHA Users Who Indicated That Clerks and Receptionists at Their Provider’s Office Treated Them With Courtesy and Respect, by Age, Gender, and Education

Bar Graph. Percent of VHA users who indicated that in the last 12 months, clerks and receptionists at their provider's office were as helpful as they should be, 2015: Hispanic 53.8%, Non-Hispanic American Indian/Alaska Native 54.4%, Non-Hispanic Asian 50.3%, Non-Hispanic black 57.0%, Non-Hispanic multiracial 53.1%, Non-Hispanic Native Hawaiian/other Pacific Islander 49.3%, non-Hispanic white 60.1%. Key: y.o. = years old. Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: Courtesy and respect go a long way toward maintaining a positive relationship between staff and patient. The more comfortable patients are, the more likely they are to bring up issues the doctor needs to know about and discuss with them during diagnosis (Advanced Data Systems Corporation, 2019). In a study of patient satisfaction during spine clinic visits, patients’ perception of teamwork between staff and providers along with reliable followup communication were found to be significant determinants of overall patient satisfaction and perceived quality of care (Bible, et al., 2018).
- Overall Rate: In 2015, 73.8% of VHA users indicated clerks and receptionists at their provider’s office treated them with courtesy and respect (data not shown).
- Groups With Disparities: In 2015, findings show significant disparities by age, gender, and education.
  ■ Age
    ⧫ VHA users ages 45–64 were significantly more likely to indicate clerks and receptionists at their provider’s office treated them with respect compared with VHA users ages 18–44 (71.6% vs. 63.7%).
    ⧫ VHA users age 65+ were significantly more likely to indicate clerks and receptionists at their provider’s office treated them with respect compared with VHA users ages 18–44 (78.3% vs. 63.7%).
  ■ Gender
    ⧫ Female VHA users were significantly less likely to indicate clerks and receptionists at their provider’s office treated them with respect compared with male VHA users (67.3% vs. 74.5%).
  ■ Education
    ⧫ VHA users with less than a high school degree were significantly more likely to indicate clerks and receptionists at their provider’s office treated them with respect compared with VHA users with a bachelor’s degree (79.5% vs. 70.2%).
    ⧫ VHA users with a high school degree were significantly more likely to indicate clerks and receptionists at their provider’s office treated them with respect compared with VHA users with a bachelor’s degree (77.9% vs. 70.2%).
    ⧫ There were no statistically significant differences between VHA users with some college education and VHA users with a bachelor’s degree in the percentage who indicated clerks and receptionists at their provider’s office treated them with respect (72.0% vs. 70.2%).

VHA Users Who Indicated That Clerks and Receptionists at Their Provider’s Office Treated Them With Courtesy and Respect, by Race/Ethnicity

Bar Graph. Percent of VHA users who indicated that in the last 12 months, clerks and receptionists at their provider's office treated them with courtesy and respect, 2015: non-Hispanic white 75.4%, Hispanic 70.1%, Non-Hispanic American Indian/Alaska Native 66.7%, Non-Hispanic Asian 64.8%, Non-Hispanic black 72.1%, Non-Hispanic multirace 70.3%, Non-Hispanic Native Hawaiian/other Pacific Islander 60.8%. Key: NH = Non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander Source: Veterans Health Administration, Survey of Healthcare Experience of Patients, 2015.

- Importance: Courtesy and respect go a long way toward maintaining a positive relationship between staff and patient. The more comfortable patients are, the more likely they are to bring up issues the doctor needs to know about and discuss with them during diagnosis (Advanced Data Systems Corporation, 2019). In a study of patient satisfaction during spine clinic visits, patients’ perception of teamwork between staff and providers along with reliable followup communication were found to be significant determinants of overall patient satisfaction and perceived quality of care (Bible, et al., 2018).
- Overall Rate: In 2015, 73.8% of VHA users indicated clerks and receptionists at their provider’s office treated them with courtesy and respect (data not shown).
- Groups With Disparities: In 2015, findings show significant racial/ethnic disparities.
  ■ There were no statistically significant differences between Hispanic VHA users and non-Hispanic White VHA users in the percentage who indicated clerks and receptionists at their provider’s office treated them with respect (70.1% vs. 75.4%).
  ■ Non-Hispanic American Indian/Alaska Native VHA users were significantly less likely to indicate clerks and receptionists at their provider’s office treated them with respect compared with non-Hispanic White VHA users (66.7% vs. 75.4%).
  ■ Non-Hispanic Asian VHA users were significantly less likely to indicate clerks and receptionists at their provider’s office treated them with respect compared with non-Hispanic White VHA users (64.8% vs. 75.4%).
  ■ There were no statistically significant differences between non-Hispanic Black VHA users and non-Hispanic White VHA users in the percentage who indicated clerks and receptionists at their provider’s office treated them with respect (72.1% vs 75.4%).
  ■ There were no statistically significant differences between non-Hispanic multirace VHA users and non-Hispanic White VHA users in the percentage who indicated clerks and receptionists at their provider’s office treated them with respect (70.3% vs. 75.4%).
  ■ Non-Hispanic Native Hawaiian/Other Pacific Islander VHA users were significantly less likely to indicate clerks and receptionists at their provider’s office treated them with respect compared with non-Hispanic White VHA users (60.8% vs. 75.4%).

## Mortality Measures

Number of Mortality Measures With Disparities Within VHA Users, by Age, Gender, and Residence Location

Bar Graph. Number and percent of mortality measures for which VHA users of selected groups experienced better, same, or worse mortality rates compared with reference group VHA users, 2009-2016 * Based on Veterans’ initial FY2009 VHA visit: VHA users age 45-64, lower mortality rate than VHA users age 18-44 on 1 measure (20%) and higher rates on 4 measures (80%). VHA users age 65+ experienced lower mortality rates than VHA users age 18-44 on 2 measures (40%) and higher rates on 3 measures (60%). Female experienced lower mortality rates than male on 4 measures (80%) and a higher rate on 1 measure (20%). Rural experienced a lower mortality rate than urban on 1 measure (20%), similar rates on 3 measures (60%), and a higher rate on 1 measure (20%) Key: y.o. = years old. Source: Veterans Health Administration, administrative data, 2009-2016 . Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: Many factors, including quality of and access to care, play a role in mortality rates for common conditions (breast cancer, colorectal cancer, HIV, lung cancer, and suicide).
- Findings: For VHA users seen in fiscal year 2009 and followed until 2016, findings show that age, gender, and location disparities persist in mortality rates.
  ■ Age
    ⧫ VHA users ages 45–64 experienced a lower mortality rate than VHA users ages 18–44 on 1 measure (20%) and higher rates on 4 measures (80%).
    ⧫ VHA users age 65+ experienced lower mortality rates than VHA users ages 18–44 on 2 measures (40%) and higher rates on 3 measures (60%).
  ■ Gender
    ⧫ Female VHA users experienced lower mortality rates than male VHA users on 4 measures (80%) and a higher rate on 1 measure (20%).
  ■ Location
    ⧫ Rural VHA users experienced a lower mortality rate than urban VHA users on 1 measure (20%), similar rates on 3 measures (60%), and a higher rate on 1 measure (20%).

Number of Mortality Measures With Disparities Within VHA Users, by Race/Ethnicity

Bar Graph. Number and percent of mortality measures for which VHA users of race/ethnicity groups experienced better, same, or worse mortality rates compared with non-Hispanic white VHA users, 2009-2016: Hispanic had a lower mortality rates on 2 measures (40%), a similar on 1 measure (20%), and higher on 2 measures (40%). Non-Hispanic American Indian/Alaska Native experienced lower on 1 measure (33%) and similar on 2 measures (67%). Non-Hispanic Asian had lower on 4 measures (80%) and similar on 1 measure (20%). Non-Hispanic black had lower on 1 measures (20%), a similar rate on 1 measure (20%), and higher rates on 3 measures (60%). Non-Hispanic multirace experienced a lower on 1 measure (20%), similar rates on 3 measures (60%), and a higher rate on 1 measure (20%). Non-Hispanic Native Hawaiian/other Pacific Islander had lower on 1 measure (20%) and similar on 4 measures (80%). Key: NH = non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, administrative data, 2009-2016 . Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: Many factors, including quality of and access to care, play a role in mortality rates for common conditions (breast cancer, colorectal cancer, HIV, lung cancer, and suicide).
- Findings: For VHA users seen in fiscal year 2009 and followed until 2016, findings show that racial/ethnic disparities persist in mortality rates.
  ■ Hispanic VHA users experienced lower mortality rates than non-Hispanic White VHA users on 2 measures (40%), a similar rate on 1 measure (20%), and higher rates on 2 measures (40%).
  ■ Non-Hispanic American Indian/Alaska Native VHA users experienced a lower mortality rate than non-Hispanic White VHA users on 1 measure (33%) and similar rates on 2 measures (67%).
  ■ Non-Hispanic Asian VHA users experienced lower mortality rates than non-Hispanic White VHA users on 4 measures (80%) and a similar rate on 1 measure (20%).
  ■ Non-Hispanic Black VHA users experienced a lower mortality rate than non-Hispanic White VHA users on 1 measure (20%), a similar rate on 1 measure (20%), and higher rates on 3 measures (60%).
  ■ Non-Hispanic multirace VHA users experienced a lower mortality rate than non-Hispanic White VHA users on 1 measure (20%), similar rates on 3 measures (60%), and a higher rate on 1 measure (20%).
  ■ Non-Hispanic Native Hawaiian/Other Pacific Islander VHA users experienced a lower mortality rate than non-Hispanic White VHA users on 1 measure (20%) and similar rates on 4 measures (80%).

## Breast Cancer Mortality

Breast Cancer Mortality per 100,000 VHA User Person-Years, by Age, Gender, and Residence Location

Bar Graph. Rate of breast cancer mortality per 100,000 VHA user person-years, comparing members of selected groups with reference group, 2009-2016: age 18-44 had 0.30; users age 45-64 had 1.64, age 65 plus had 4.55, Female users had 91.91; male users had 1.32, Rural users had 4.19; urban users had 4.18. Key: y.o. = years old. Source: Veterans Health Administration, administrative data, 2009-2016. Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: Breast cancer is the second leading cause of cancer death in women (only lung cancer kills more women each year). The chance that a woman will die from breast cancer is about 1 in 38 (2.6%). It is estimated that in 2020, approximately 42,170 women will die from breast cancer in the United States (NCI, 2020).
- Overall Rate: For VHA users seen in fiscal year 2009 and followed until 2016, the breast cancer mortality rate was 4.18 per 100,000 VHA user person-years (data not shown).
- Groups With Disparities: For VHA users seen in fiscal year 2009 and followed until 2016, findings show significant disparities by age and gender but not location.
  ■ Age
    ⧫ VHA users ages 45–64 had a significantly higher breast cancer mortality rate compared with VHA users ages 18–44 (1.64 vs. 0.30 per 100,000 VHA person-years).
    ⧫ VHA users age 65+ had a significantly higher breast cancer mortality rate compared with VHA users ages 18–44 (4.55 vs. 0.30 per 100,000 VHA person-years).
  ■ Gender
    ⧫ Female VHA users had a significantly higher breast cancer mortality rate compared with male VHA users (91.91 vs. 1.32 per 100,000 VHA person-years).
  ■ Location
    ⧫ There were no statistically significant differences between rural VHA users and urban VHA users in breast cancer mortality rates (4.19 vs. 4.18 per 100,000 VHA person-years).

Breast Cancer Mortality per 100,000 VHA User Person-Years, by Race/Ethnicity

Bar Graph. Rate of breast cancer mortality per 100,000 VHA user person-years, comparing members of race/ethnicity groups with reference group, 2009-2016: Hispanic VHA 3.02, Non-Hispanic Asian 3.84; Non-Hispanic black 5.23; Non-Hispanic multi race 5.86; Non-Hispanic Native Hawaiian/other Pacific Islander 5.40; non-Hispanic white VHA 3.86. Key: NH = non-Hispanic; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, administrative data, 2009-2016. Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: Breast cancer is the second leading cause of cancer death in women (only lung cancer kills more women each year). The chance that a woman will die from breast cancer is about 1 in 38 (2.6%). It is estimated that in 2020, approximately 42,170 women will die from breast cancer in the United States (NCI, 2020).
- Overall Rate: For VHA users seen in fiscal year 2009 and followed until 2016, the breast cancer mortality rate was 4.18 per 100,000 VHA user person-years (data not shown).
- Groups With Disparities: For VHA users seen in fiscal year 2009 and followed until 2016, findings show significant racial/ethnic disparities.
  ■ There were no statistically significant differences between Hispanic VHA users and non-Hispanic White VHA users in breast cancer mortality rates (3.02 vs. 3.86 per 100,000 VHA person-years).
  ■ There were no statistically significant differences between non-Hispanic Asian VHA users and non-Hispanic White VHA users in breast cancer mortality rates (3.84 vs. 3.86 per 100,000 VHA person-years).
  ■ Non-Hispanic Black VHA users had a significantly higher breast cancer mortality rate compared with non-Hispanic White VHA users (5.23 vs. 3.86 per 100,000 VHA person-years).
  ■ There were no statistically significant differences between non-Hispanic multirace VHA users and non-Hispanic White VHA users in breast cancer mortality rates (5.86 vs. 3.86 per 100,000 VHA person-years).
  ■ There were no statistically significant differences between non-Hispanic Native Hawaiian/Other Pacific Islander VHA users and non-Hispanic White VHA users in breast cancer mortality rates (5.40 vs. 3.86 per 100,000 VHA person-years).

## Colorectal Cancer Mortality

Colorectal Cancer Mortality per 100,000 VHA User Person-Years, by Age, Gender, and Residence Location

Bar Graph. Rate of colorectal cancer mortality per 100,000 VHA user person-years, comparing members of selected groups with reference group, 2009-2016: age 45-64 41.22; age 65 plus 123.21; Female 62.63; users age 18-44 4.49. Female 62.63; Male 77.47. Rural 75.24; Urban 73.18. Key: y.o. = years old. Source: Veterans Health Administration, administrative data, 2009-2016. Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: Colorectal cancer is more common in men than women and among those of African American descent. It is estimated that in 2020, approximately 53,200 people will die from colorectal cancer in the United States (NCI, 2020).
- Overall Rate: For VHA users seen in fiscal year 2009 and followed until 2016, the colorectal cancer mortality rate was 74.06 per 100,000 VHA user person-years (data not shown).
- Groups With Disparities: For VHA users seen in fiscal year 2009 and followed until 2016, findings show significant disparities by age and gender but not location.
  ■ Age
    ⧫ VHA users ages 45–64 had a significantly higher colorectal cancer mortality rate compared with VHA users ages 18–44 (41.22 vs. 4.49 per 100,000 VHA person-years).
    ⧫ VHA users age 65+ had a significantly higher colorectal cancer mortality rate compared with VHA users ages 18–44 (123.21 vs. 4.49 per 100,000 VHA person-years).
  ■ Gender
    ⧫ Female VHA users had a significantly lower colorectal cancer mortality rate compared with male VHA users (62.63 vs. 77.47 per 100,000 VHA person-years).
  ■ Location
    ⧫ There were no statistically significant differences between rural VHA users and urban VHA users in colorectal cancer mortality rates (75.24 vs. 73.18 per 100,000 VHA person-years).

Colorectal Cancer Mortality per 100,000 VHA User Person-Years, by Race/Ethnicity

Bar Graph. Rate of colorectal cancer mortality per 100,000 VHA user person-years, comparing members of race/ethnicity groups with reference group, 2009-2016: Hispanic VHA 92.20; non-Hispanic white 80.43; Non-Hispanic American Indian/Alaska Native 98.15; Non-Hispanic Asian 53.23; Non-Hispanic black 110.79; Non-Hispanic multi race 104.86; Non-Hispanic Native Hawaiian/other Pacific Islander 87.20. Key: NH = non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, administrative data, 2009-2016. Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: Colorectal cancer is more common in men than women and among those of African American descent. It is estimated that in 2020, approximately 53,200 people will die from colorectal cancer in the United States (NCI, 2020).
- Overall Rate: For VHA users seen in fiscal year 2009 and followed until 2016, the colorectal cancer mortality rate was 74.06 per 100,000 VHA user person-years (data not shown).
- Groups With Disparities: For VHA users seen in fiscal year 2009 and followed until 2016, findings show significant racial/ethnic disparities.
  ■ Hispanic VHA users had a significantly higher colorectal cancer mortality rate compared with non-Hispanic White VHA users (92.20 vs. 80.43 per 100,000 VHA person-years).
  ■ There were no statistically significant differences between non-Hispanic American Indian/Alaska Native VHA users and non-Hispanic White VHA users in colorectal cancer mortality rates (98.15 vs. 80.43 per 100,000 VHA person-years).
  ■ Non-Hispanic Asian VHA users had a significantly lower colorectal cancer mortality rate compared with non-Hispanic White VHA users (53.23 vs. 80.43 per 100,000 VHA person-years).
  ■ Non-Hispanic Black VHA users had a significantly higher colorectal cancer mortality rate compared with non-Hispanic White VHA users (110.79 vs. 80.43 per 100,000 VHA person-years).
  ■ Non-Hispanic multirace VHA users had a significantly higher colorectal cancer mortality rate compared with non-Hispanic White VHA users (104.86 vs. 80.43 per 100,000 VHA person-years).
  ■ There were no statistically significant differences between non-Hispanic Native Hawaiian/Other Pacific Islander VHA users and non-Hispanic White VHA users in colorectal cancer mortality rates (87.20 vs. 80.43 per 100,000 VHA person-years).

## Lung Cancer Mortality

Lung Cancer Mortality per 100,000 VHA User Person-Years, by Age, Gender, and Residence Location

Bar Graph. Rate of lung cancer mortality per 100,000 VHA user person-years, comparing members of selected groups with reference group, 2009-2016: age 18-44 5.33; age 45-64 214.28; age 65+ 506.02; Female 223.36; male 327.61; Rural 322.85; urban 294.91. Key: y.o. = years old. Source: Veterans Health Administration, administrative data, 2009-2016. Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: Lung cancer is more common in men than women, particularly African American men. Smoking is widely recognized as the leading cause of lung cancer. It is estimated that in 2020, approximately 135,720 people will die from lung/bronchus cancer in the United States (NCI, 2020).
- Overall Rate: For VHA users seen in fiscal year 2009 and followed until 2016, the lung cancer mortality rate was 306.92 per 100,000 VHA user person-years (data not shown).
- Groups With Disparities: For VHA users seen in fiscal year 2009 and followed until 2016, findings show significant disparities by age and gender but not location.
  ■ Age
    ⧫ VHA users ages 45–64 had a significantly higher lung cancer mortality rate compared with VHA users ages 18–44 (214.28 vs. 5.33 per 100,000 VHA person-years).
    ⧫ VHA users age 65+ had a significantly higher lung cancer mortality rate compared with VHA users ages 18–44 (506.02 vs. 5.33 per 100,000 VHA person-years).
  ■ Gender
    ⧫ Female VHA users had a significantly lower lung cancer mortality rate compared with male VHA users (223.36 vs. 327.61 per 100,000 VHA person-years).
  ■ Location
    ⧫ There were no statistically significant differences between rural VHA users and urban VHA users in lung cancer mortality rates (322.85 vs. 294.91 per 100,000 VHA person-years).

Lung Cancer Mortality per 100,000 VHA User Person-Years, by Race/Ethnicity

Bar Graph. Rate of lung cancer mortality per 100,000 VHA user person-years, comparing members of race/ethnicity groups with reference group, 2009-2016: Hispanic 157.6; non-Hispanic white 357.89; Non-Hispanic American Indian/Alaska Native 370.12; Non-Hispanic Asian 199.52; Non-Hispanic black 359.04; Non-Hispanic multi race 386.72; Non-Hispanic Native Hawaiian/other Pacific Islander 352.85. Key: NH = non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, administrative data, 2009-2016. Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: Lung cancer is more common in men than women, particularly African American men. Smoking is widely recognized as the leading cause of lung cancer. It is estimated that in 2020, approximately 135,720 people will die from lung/bronchus cancer in the United States (NCI, 2020).
- Overall Rate: For VHA users seen in fiscal year 2009 and followed until 2016, the lung cancer mortality rate was 306.92 per 100,000 VHA user person-years (data not shown).
- Groups With Disparities: For VHA users seen in fiscal year 2009 and followed until 2016, findings show significant racial/ethnic disparities.
  ■ Hispanic VHA users had a significantly lower lung cancer mortality rate compared with non-Hispanic White VHA users (157.66 vs. 357.89 per 100,000 VHA person-years).
  ■ There were no statistically significant differences between non-Hispanic American Indian/Alaska Native VHA users and non-Hispanic White VHA users in lung cancer mortality rates (370.12 vs. 357.89 per 100,000 VHA person-years).
  ■ Non-Hispanic Asian VHA users had a significantly lower lung cancer mortality rate compared with non-Hispanic White VHA users (199.52 vs. 357.89 per 100,000 VHA person-years).
  ■ There were no statistically significant differences between non-Hispanic Black VHA users and non-Hispanic White VHA users in lung cancer mortality rates (359.04 vs. 357.89 per 100,000 VHA person-years).
  ■ There were no statistically significant differences between non-Hispanic multirace VHA users and non-Hispanic White VHA users in lung cancer mortality rates (386.72 vs. 357.89 per 100,000 VHA person-years).
  ■ There were no statistically significant differences between non-Hispanic Native Hawaiian/Other Pacific Islander VHA users and non-Hispanic White VHA users in lung cancer mortality rates (352.85 vs. 357.89 per 100,000 VHA person-years).

## HIV Disease Mortality

HIV Disease Mortality per 100,000 VHA User Person-Years, by Age, Gender, and Residence Location

Bar Graph. Rate of HIV disease mortality per 100,000 VHA user person-years, comparing members of selected groups with reference group, 2009-2016: 18-44 4.21; age 45-64 10.75; VHA users age 65 plus 2.52. Female 1.31; male 6.24. Rural 2.74; urban 8.50. Key: y.o. = years old. Source: Veterans Health Administration, administrative data, 2009-2016. Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: People with HIV who get and stay virally suppressed or undetectable can stay healthy and have a significantly low risk of transmitting HIV. Taking HIV medicine as prescribed can make the level of virus in their body very low or even undetectable. People with HIV need to know they are HIV positive so they can take medicine to treat HIV (CDC, 2019, 2019).
- Overall Rate: For VHA users seen in fiscal year 2009 and followed until 2016, the HIV disease mortality rate was 6.02 per 100,000 VHA user person-years (data not shown).
- Groups With Disparities: For VHA users seen in fiscal year 2009 and followed until 2016, findings show significant disparities by age, gender, and location.
  ■ Age
    ⧫ VHA users ages 45–64 had a significantly higher HIV disease mortality rate compared with VHA users ages 18–44 (10.75 vs. 4.21 per 100,000 VHA person-years).
    ⧫ VHA users age 65+ had a significantly lower HIV disease mortality rate compared with VHA users ages 18–44 (2.52 vs. 4.21 per 100,000 VHA person-years).
  ■ Gender
    ⧫ Female VHA users had a significantly lower HIV disease mortality rate compared with male VHA users (1.31 vs. 6.24 per 100,000 VHA person-years).
  ■ Location
    ⧫ Rural VHA users had a significantly lower HIV disease mortality rate compared with urban VHA users (2.74 vs. 8.50 per 100,000 VHA person-years).

HIV Disease Mortality per 100,000 VHA User Person-Years, by Race/Ethnicity

Bar Graph. Rate of HIV disease mortality per 100,000 VHA user person-years, comparing members of race/ethnicity groups with reference group, 2009-2016: Hispanic 7.38; non-Hispanic white 2.97; Non-Hispanic Asian 0.54; Non-Hispanic black 18.39; Non-Hispanic multirace 6.22; Non-Hispanic Native Hawaiian/other Pacific Islander 4.31 Key: NH = non-Hispanic; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, administrative data, 2009-2016. Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: People with HIV who get and stay virally suppressed or undetectable can stay healthy and have a significantly low risk of transmitting HIV. Taking HIV medicine as prescribed can make the level of virus in their body very low or even undetectable. People with HIV need to know they are HIV positive so they can take medicine to treat HIV (CDC, 2019, 2019).
- Overall Rate: For VHA users seen in fiscal year 2009 and followed until 2016, the HIV disease mortality rate was 6.02 per 100,000 VHA user person-years (data not shown).
- Groups With Disparities: For VHA users seen in fiscal year 2009 and followed until 2016, findings show significant racial/ethnic disparities.
  ■ Hispanic VHA users had a significantly higher HIV disease mortality rate compared with non-Hispanic White VHA users (7.38 vs. 2.97 per 100,000 VHA person-years).
  ■ Non-Hispanic Asian VHA users had a significantly lower HIV disease mortality rate compared with non-Hispanic White VHA users (0.54 vs. 2.97 per 100,000 VHA person-years).
  ■ Non-Hispanic Black VHA users had a significantly higher HIV disease mortality rate compared with non-Hispanic White VHA users (18.39 vs. 2.97 per 100,000 VHA person-years).
  ■ There were no statistically significant differences between non-Hispanic multirace VHA users and non-Hispanic White VHA users in HIV disease mortality rates (6.22 vs. 2.97 per 100,000 VHA person-years).
  ■ There were no statistically significant differences between non-Hispanic Native Hawaiian/Other Pacific Islander VHA users and non-Hispanic White VHA users in HIV disease mortality rates (4.31 vs. 2.97 per 100,000 VHA person-years).

## Suicide Mortality

Suicide Mortality per 100,000 VHA User Person-Years, by Age, Gender, and Residence Location

Bar Graph. Rate of suicide mortality per 100,000 VHA user person-years, comparing members of selected groups with reference group, 2009-2016: age 18-44 48.51; age 45-64 37.49; age 65+ 39.65; Female 13.64; male 40.42; Rural 43.21, urban 36.57. Key: y.o. = years old. Source: Veterans Health Administration, administrative data, 2009-2016. Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: Suicide is the 10th leading cause of death in the United States. It was responsible for more than 48,000 deaths in 2018, resulting in one death every 11 minutes. Suicide death rates vary by race/ethnicity, age, and other population characteristics, with the highest rates across the lifespan occurring among non-Hispanic American Indian/Alaska Native and non-Hispanic White populations (CDC, 2020).
- Overall Rate: For VHA users seen in fiscal year 2009 and followed until 2016, the suicide mortality rate was 39.42 per 100,000 VHA user person-years (data not shown).
- Groups With Disparities: For VHA users seen in fiscal year 2009 and followed until 2016, findings show significant disparities by age, gender, and location.
  ■ Age
    ⧫ VHA users ages 45–64 had a significantly lower suicide mortality rate compared with VHA users ages 18–44 (37.49 vs. 48.51 per 100,000 VHA person-years).
    ⧫ VHA users age 65+ had a significantly lower suicide mortality rate compared with VHA users ages 18–44 (39.65 vs. 48.51 per 100,000 VHA person-years).
  ■ Gender
    ⧫ Female VHA users had a significantly lower suicide mortality rate compared with male VHA users (13.64 vs. 40.42 per 100,000 VHA person-years).
  ■ Location
    ⧫ Rural VHA users had a significantly higher suicide mortality rate compared with urban VHA users (43.21 vs. 36.57 per 100,000 VHA person-years).

Suicide Mortality per 100,000 VHA User Person-Years, by Race/Ethnicity

Bar Graph. Rate of suicide mortality per 100,000 VHA user person-years, comparing members of race/ethnicity groups with reference group, 2009-2016: Hispanic VHA 22.12; Non-Hispanic American Indian/Alaska Native 34.87; Non-Hispanic Asian 16.16; Non-Hispanic black 12.81; Non-Hispanic multi race 34.77; Non-Hispanic Native Hawaiian/other Pacific Islander 32.51; non-Hispanic white 45.80. Key: NH = non-Hispanic; AIAN = American Indian or Alaska Native; NHOPI = Native Hawaiian or Other Pacific Islander. Source: Veterans Health Administration, administrative data, 2009-2016. Note: Data are based on Veterans’ initial fiscal year 2009 VHA visit.

- Importance: Suicide is the 10th leading cause of death in the United States. It was responsible for more than 48,000 deaths in 2018, resulting in one death every 11 minutes. Suicide death rates vary by race/ethnicity, age, and other population characteristics, with the highest rates across the lifespan occurring among non-Hispanic American Indian/Alaska Native and non-Hispanic White populations (CDC, 2020).
- Overall Rate: For VHA users seen in fiscal year 2009 and followed until 2016, the suicide mortality rate was 39.42 per 100,000 VHA user person-years (data not shown).
- Groups With Disparities: For VHA users seen in fiscal year 2009 and followed until 2016, findings show significant racial/ethnic disparities.
  ■ Hispanic VHA users had a significantly lower suicide mortality rate compared with non-Hispanic White VHA users (22.12 vs. 45.80 per 100,000 VHA person-years).
  ■ Non-Hispanic American Indian/Alaska Native VHA users had a significantly lower suicide mortality rate compared with non-Hispanic White VHA users (34.87 vs. 45.80 per 100,000 VHA person-years).
  ■ Non-Hispanic Asian VHA users had a significantly lower suicide mortality rate compared with non-Hispanic White VHA users (16.16 vs. 45.80 per 100,000 VHA person-years).
  ■ Non-Hispanic Black VHA users had a significantly lower suicide mortality rate compared with non-Hispanic White VHA users (12.81 vs. 45.80 per 100,000 VHA person-years).
  ■ Non-Hispanic multirace VHA users had a significantly lower suicide mortality rate compared with non-Hispanic White VHA users (34.77 vs. 45.80 per 100,000 VHA person-years).
  ■ Non-Hispanic Native Hawaiian/Other Pacific Islander VHA users had a significantly lower suicide mortality rate compared with non-Hispanic White VHA users (32.51 vs. 45.80 per 100,000 VHA person-years).