# EXECUTIVE SUMMARY

This chartbook provides information regarding disparities in access to and quality of healthcare received by Veterans. Data on disparities are presented:

- Contrast 1: Between Veterans and non-Veterans.
- Contrast 2: Between all Veterans, regardless of provider and payer of healthcare, with different characteristics (e.g., age, gender).
- Contrast 3: Between Veterans Health Administration (VHA) users with different characteristics (e.g., age, gender).

Note: Data in this chartbook are from the 2014–2017 Medical Expenditure Panel Survey (MEPS), 2015–2018 National Health Interview Survey (NHIS), 2015 Survey of Healthcare Experience of Patients (SHEP), and fiscal year 2009–2016 VHA administrative data.

## Executive Summary: Contrast 1 Key Findings

- Contrast 1: Assessing disparities in access to and quality of care for Veterans vs. non-Veterans.
  ■ Veterans reported better care for 22% of measures, which often related to vaccinations and health screening.
  ■ Veterans reported similar care for 67% of measures.
  ■ Veterans reported worse care for 11% of measures, which often were for access to care or related to inappropriate medications for older adults.

Notes:

- Results are cross-sectional (for a static point in time). Trends over time were conducted for a limited number of measures where sufficient data were available.
- These findings are based on 2014–2017 MEPS and 2015–2018 NHIS data.

## Executive Summary: Contrast 2 Key Findings

- Contrast 2: Assessing disparities in access to and quality of care for Veterans with different characteristics.
  ■ Disparities occurred most often across age and disability status.
  ■ Compared with younger Veterans, middle-aged Veterans had better care for 30% of measures, similar care for 65% of measures, and worse care for 5% of measures.
  ■ Compared with younger Veterans, older Veterans had better care for 50% of measures, similar care for 31% of measures, and worse care for 19% of measures.
  ■ Compared with Veterans with no activity limitations, Veterans with activity limitations had better care for 13% of measures, similar care for 48% of measures, and worse care for 39% of measures.
  ■ Fewer disparities occurred across the following groups:
    ⧫ Gender: female vs. male
    ⧫ Race/ethnicity: Hispanic vs. non-Hispanic White and non-Hispanic Black vs. non-Hispanic White
    ⧫ Location: rural vs. urban
    ⧫ Education: high school degree or less education vs. at least some college education
    ⧫ Income: below poverty line (poor) income vs. middle/high income and just above (near) poverty income vs. middle/high income
    ⧫ Insurance: public insurance vs. private insurance

Notes:

- Results are cross-sectional (for a static point in time). Trends over time were conducted for a limited number of measures where sufficient data were available.
- These findings are based on 2014–2017 MEPS and 2015–2018 NHIS data.

## Executive Summary: Contrast 3 Key Findings

- Contrast 3: Assessing disparities in access to and quality of care for VHA users with different characteristics.
  ■ Disparities in access to and quality of care occurred most often across age and gender categories.
  ■ Compared with younger VHA users, middle-aged VHA users had better care for 64% of measures and similar care for 36% of measures.
  ■ Compared with younger VHA users, older VHA users had better care for 79% of measures, similar care for 14% of measures, and worse care for 7% of measures.
  ■ Compared with male VHA users, females had better care for 4% of measures, similar care for 57% of measures, and worse care for 39% of measures.
  ■ In access to care, disparities occurred frequently across racial/ethnic categories.
  ■ Compared with non-Hispanic White VHA users, VHA users of racial and ethnic minority groups had better access to care for 3% of measures, similar access to care for 58% of measures, and worse access to care for 39% of measures.
  ■ Fewer disparities occurred across education, less than a high school degree vs. bachelor’s degree, high school degree vs. bachelor’s degree, and some college education vs. bachelor’s degree.

Notes:

- Results are cross-sectional (for a static point in time). Trends over time were not available for this contrast.
- These findings are based on 2015 SHEP data.

Disparities in mortality rates occurred most often across age, gender, and racial/ethnic categories:

- Compared with younger VHA users, middle-aged VHA users had, as expected, higher mortality rates for 80% of measures and lower rates for 20% of measures.
- Compared with younger VHA users, older VHA users had, as expected, higher mortality rates for 60% of measures and lower rates for 40% of measures.
- Compared with male VHA users, females had higher mortality rates for 20% of measures and lower rates for 80% of measures.
- Compared with non-Hispanic White VHA users, VHA users of racial and ethnic minority groups had higher mortality rates for 21% of measures, similar rates for 43% of measures, and lower rates for 36% of measures.
- Fewer disparities occurred across rural vs. urban location.

Notes:

- Results are cross-sectional (for a static point in time). Trends over time were not available for this contrast.
- These findings are based on fiscal year 2009–2016 VHA administrative data.