# APPENDIX

## Appendix Slides

- The Contrast 1 data show age-adjusted gender strata percentages to compare Veterans and non-Veterans.
- The following data provide percentages by age and gender strata for the same measures, which allows comparisons of specific age-gender groups among Veterans and non-Veterans.
- Sources for the data are the Medical Expenditure Panel Survey (MEPS), 2014–2017; National Health Interview Survey (NHIS), 2015–2018; Survey of Healthcare Experience of Patients (SHEP), 2015; and Veterans Health Administration (VHA) Administrative Fiscal year (FY) 2009–2016.

## Vaccinations

Receipt of Influenza Vaccination, by Age and Gender

Bar Graph. Percent of respondents who reported receiving influenza vaccination(s), 2015-2018: Female Veterans age 20-49 compared better to female non-Veterans age 20-49 (52.3% vs. 37.3%). Female Veterans age 50-64 compared to better female non-Veterans age 50-64 (57.7% vs. 48.7%). Female Veterans age 65+ compared the same to female non-Veterans age 65+ (75.1% vs. 68.2%). Male Veterans age 20-49 compared better to male non-Veterans age 20-49 (43.3% vs. 26.9%). Male Veterans age 50-64 compared better to male non-Veterans age 50-64 (47.9% vs. 42.7%). Male Veterans age 65+ compared the same to male non-Veterans age 65+ (71.0% vs. 65.9% Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: Each year, millions of Americans get sick with influenza. Sometimes it causes mild illness but it can also be serious or even deadly, especially for people over 65, newborn babies, and people with certain chronic illnesses (NLM, 2020). Vaccination can prevent influenza and reduce influenza-related morbidity and mortality (CDC, 2019).
- Overall Rate: In 2015–2018, 50.2% of Veterans and 41.7% of non-Veterans received an influenza vaccination (data not shown).
- Groups With Disparities: In 2015–2018, among adults age 20 years and over:
  ■ Female Veterans ages 20–49 were significantly more likely to receive an influenza vaccination compared with female non-Veterans ages 20–49 (52.3% vs. 37.3%).
  ■ Female Veterans ages 50–64 were significantly more likely to receive an influenza vaccination compared with female non-Veterans ages 50–64 (57.7% vs. 48.7%).
  ■ There were no statistically significant differences between female Veterans age 65+ and female non-Veterans age 65+ in the percentage who received an influenza vaccination (75.1% vs. 68.2%).
  ■ Male Veterans ages 20–49 were significantly more likely to receive an influenza vaccination compared with male non-Veterans ages 20–49 (43.3% vs. 26.9%).
  ■ Male Veterans ages 50–64 were significantly more likely to receive an influenza vaccination compared with male non-Veterans ages 50–64 (47.9% vs. 42.7%).
  ■ There were no statistically significant differences between male Veterans age 65+ and male non-Veterans age 65+ in the percentage who received an influenza vaccination (71.0% vs. 65.9%).

Receipt of Pneumococcal Vaccination, by Gender, Age 65+

Bar Graph. Percent of respondents who reported receiving pneumococcal vaccination(s), 2015-2018: Female Veterans were compared to female non-Veterans (77.6% vs. 68.2%). Male Veterans compared to male non-Veterans (72.6% vs. 59.9%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: Pneumococcal disease is caused by bacteria and can result in a range of ailments, from mild ear infection to meningitis, sepsis, and fatal pneumonia (NIAID, 2014). Adults over age 65 and individuals of any age with chronic illness are at increased risk for pneumococcal disease and death. The best way to prevent pneumococcal disease is by getting vaccinated (CDC, 2019).
- Overall Rate: In 2015–2018, 73.4% of Veterans and 65.8% of non-Veterans age 65 years and over received pneumococcal vaccination (data not shown).
- Groups With Disparities: In 2015–2018, among adults age 65 years and over:
  ■ There were no statistically significant differences between female Veterans and female non-Veterans in the percentage who received a pneumococcal vaccination (77.6% vs. 68.2%).
  ■ Male Veterans were significantly more likely to receive a pneumococcal vaccination compared with male non-Veterans (72.6% vs. 59.9%).

Receipt of Shingles Vaccination, by Gender, Ages 50–79

Bar Graph. Percent of respondents who reported receiving shingles vaccination(s), 2015-2018: Female Veterans age 50-64 compared to female non-Veterans age 50-64 (16.4% vs. 12.5%). Female. Veterans age 65+ compared to female non-Veterans age 65+ (44.1% vs. 40.3%). Male Veterans age 50-64 compared to male non-Veterans age 50-64 (10.4% vs. 9.6%). Male Veterans age 65+ were compared to male non-Veterans age 65+ (41.2% vs. 33.8%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: Shingles is a painful rash that usually develops on one side of the body, often the face or torso. For some people, long-lasting pain, which can last for months or even years after the rash goes away, is the most common complication of shingles. The risk of getting shingles increases with age (CDC, 2016) but decreases with vaccination (CDC, 2018).
- Overall Rate: In 2015–2018, 24.8% of Veterans and 22.9% of non-Veterans received a shingles vaccination (data not shown).
- Groups With Disparities: In 2015–2018, among adults age 50 years and over:
  ■ There were no statistically significant differences between female Veterans ages 50–64 and female non-Veterans ages 50–64 in the percentage who received a shingles vaccination (16.4% vs. 12.5%).
  ■ There were no statistically significant differences between female Veterans age 65+ and female non-Veterans age 65+ in the percentage who received a shingles vaccination (44.1% vs. 40.3%).
  ■ There were no statistically significant differences between male Veterans ages 50–64 and male non-Veterans ages 50–64 in the percentage who received a shingles vaccination (10.4% vs. 9.6%).
  ■ Male Veterans age 65+ were significantly more likely to receive a shingles vaccination compared with male non-Veterans age 65+ (41.2% vs. 33.8%).

Receipt of Tetanus Vaccinations, by Age and Gender

Bar Graph. Percent of respondents who reported receiving tetanus vaccination(s), 2015-2018: Female Veterans age 20-49 compared better to female non-Veterans age 20-49 (79.7% vs. 62.6%). Female Veterans age 50-64 compared better to female non-Veterans age 50-64 (77.3% vs. 62.1%). Female Veterans age 65+ compared the same to female non-Veterans age 65+ (60.3% vs. 58.5%). Male Veterans age 20-49 compared better to male non-Veterans age 20-49 (77.2% vs. 62.7%). Male Veterans age 50-64 compared better to male non-Veterans age 50-64 (72.4% vs. 64.3%). Male Veterans age 65+ compared better to male non-Veterans age 65+ (69.3% vs. 59.5%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: Tetanus is an infection caused by tetanus bacteria spores that get into the body through broken skin, usually through injuries from contaminated objects. Tetanus infection can lead to serious health problems, including being unable to open the mouth and having trouble swallowing and breathing (CDC, 2019). Nearly all cases of tetanus are in people who never got a tetanus vaccine or did not receive a complete course of tetanus vaccines, or adults who did not stay up to date on their 10-year booster shots (CDC, 2020).
- Overall Rate: In 2015–2018, 74.6% of Veterans and 61.4% of non-Veterans received a tetanus vaccination in the past 10 years (data not shown).
- Groups With Disparities: In 2015–2018, among adults age 20 years and over:
  ■ Female Veterans ages 20–49 were significantly more likely to receive a tetanus vaccination compared with female non-Veterans ages 20–49 (79.7% vs. 62.6%).
  ■ Female Veterans ages 50–64 were significantly more likely to receive a tetanus vaccination compared with female non-Veterans ages 50–64 (77.3% vs. 62.1%).
  ■ There were no statistically significant differences between female Veterans age 65+ and female non-Veterans age 65+ in the percentage who received a tetanus vaccination (60.3% vs. 58.5%).
  ■ Male Veterans ages 20–49 were significantly more likely to receive a tetanus vaccination compared with male non-Veterans ages 20–49 (77.2% vs. 62.7%).
  ■ Male Veterans ages 50–64 were significantly more likely to receive a tetanus vaccination compared with male non-Veterans ages 50–64 (72.4% vs. 64.3%).
  ■ Male Veterans age 65+ were significantly more likely to receive a tetanus vaccination compared with male non-Veterans age 65+ (69.3% vs. 59.5%). Screenings

## Screenings

Receipt of Blood Pressure Screening, by Age and Gender

Bar Graph. Percent of respondents who reported receiving blood pressure screening(s) in the past 12 months, 2015-2018: Female Veterans age 20-49 compared to female non-Veterans age 20-49 (90.5% vs. 85.2%). Female Veterans age 50-64 compared to female non-Veterans age 50-64 (90.2% vs. 91.2%). Female Veterans age 65+ compared to female non-Veterans age 65+ (95.7% vs. 95.5%). Male Veterans age 20-49 compared to male non-Veterans age 20-49 (81.4% vs. 70.1%). Male Veterans age 50-64 compared to male non-Veterans age 50-64 (89.5% vs. 86.2%). Male Veterans age 65+ compared to male non-Veterans age 65+ (95.2% vs. 93.9%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: Nearly half of all adults in the United States, about 103 million people, have high blood pressure (AHA, 2018). High blood pressure increases the risk for heart disease and stroke, two leading causes of death for Americans (CDC, 2020).
- Overall Rate: In 2015–2018, 86.9% of Veterans and 83.5% of non-Veterans received a blood pressure screening (data not shown).
- Groups With Disparities: In 2015–2018, among adults age 20 years and over:
  ■ There were no statistically significant differences between female Veterans ages 20–49 and female non-Veterans ages 20–49 in the percentage who received a blood pressure screening (90.5% vs. 85.2%).
  ■ There were no statistically significant differences between female Veterans ages 50–64 and female non-Veterans ages 50–64 in the percentage who received a blood pressure screening (90.2% vs. 91.2%).
  ■ There were no statistically significant differences between female Veterans age 65+ and female non-Veterans age 65+ in the percentage who received a blood pressure screening (95.7% vs. 95.5%).
  ■ Male Veterans ages 20–49 were significantly more likely to receive a blood pressure screening compared with male non-Veterans ages 20–49 (81.4% vs. 70.1%).
  ■ There were no statistically significant differences between male Veterans ages 50–64 and male non-Veterans ages 50–64 in the percentage who received a blood pressure screening (89.5% vs. 86.2%).
  ■ There were no statistically significant differences between male Veterans age 65+ and male non-Veterans age 65+ in the percentage who received a blood pressure screening (95.2% vs. 93.9%).

Receipt of Cholesterol Screening, by Age and Gender

Bar Graph. Percent of respondents who reported receiving cholesterol screening(s) in the past 12 months, 2015-2018: Female Veterans age 20-49 compared to female non-Veterans age 20-49 (65.9% vs. 59.1%). Female Veterans age 50-64 compared to female non-Veterans age 50-64 (80.8% vs. 80.6%). Female Veterans age 65+ compared to female non-Veterans age 65+ (89.1% vs. 88.5%). Male Veterans age 20-49 compared to male non-Veterans age 20-49 (59.9% vs. 47.8%). Male Veterans age 50-64 compared to male non-Veterans age 50-64 (81.1% vs. 75.9%). Male Veterans age 65+ compared to male non-Veterans age 65+ (91.2% vs. 88.8%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: About 95 million Americans age 20 and older have total cholesterol levels higher than 200 mg/dL and nearly 29 million have total cholesterol levels higher than 240 mg/dL. High cholesterol raises the risk of heart disease, the leading cause of death, and stroke, the fifth leading cause of death (CDC, 2020).
- Overall Rate: In 2015–2018, 71.3% of Veterans and 65.8% of non-Veterans received a cholesterol screening (data not shown).
- Groups With Disparities: In 2015–2018, among adults age 20 years and over:
  ■ There were no statistically significant differences between female Veterans ages 20–49 and female non-Veterans ages 20–49 in the percentage who received a cholesterol screening (65.9% vs. 59.1%).
  ■ There were no statistically significant differences between female Veterans ages 50–64 and female non-Veterans ages 50–64 in the percentage who received a cholesterol screening (80.8% vs. 80.6%).
  ■ There were no statistically significant differences between female Veterans age 65+ and female non-Veterans age 65+ in the percentage who received a cholesterol screening (89.1% vs. 88.5%).
  ■ Male Veterans ages 20–49 were significantly more likely to receive a cholesterol screening compared with male non-Veterans ages 20–49 (59.9% vs. 47.8%).
  ■ There were no statistically significant differences between male Veterans ages 50–64 and male non-Veterans ages 50–64 in the percentage who received a cholesterol screening (81.1% vs. 75.9%).
  ■ There were no statistically significant differences between male Veterans age 65+ and male non-Veterans age 65+ in the percentage who received a cholesterol screening (91.2% vs. 88.8%).

Receipt of Glucose Screening, by Age and Gender

Bar Graph. Percent of respondents who reported receiving glucose screening(s) in the past 12 months, 2015-2018: Female Veterans age 20-49 compared to female non-Veterans age 20-49 (49.6% vs. 42.4%). Female Veterans age 50-64 compared to female non-Veterans age 50-64 (61.0% vs. 61.7%). Female Veterans age 65+ compared to female non-Veterans age 65+ (73.2% vs. 67.0%). Male Veterans age 20-49 compared to male non-Veterans age 20-49 (42.9% vs. 31.8%). Male Veterans age 50-64 compared to male non-Veterans age 50-64 (65.9% vs. 59.0%). Male Veterans age 65+ compared to male non-Veterans age 65+ (71.8% vs. 69.2%). Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2015-2018.

- Importance: Glucose screening is a test used to diagnose prediabetes and type 1, type 2, or gestational diabetes. Diabetes is a chronic health condition in which the body either does not make enough insulin or cannot use the insulin it makes as well as it should. Diabetes is a leading cause of morbidity and mortality in the United States (CDC, 2019, 2020).
- Overall Rate: In 2015–2018, 54.3% of Veterans and 48.1% of non-Veterans received a glucose screening (data not shown).
- Groups With Disparities: In 2015–2018, among adults age 20 years and over:
  ■ There were no statistically significant differences between female Veterans ages 20–49 and female non-Veterans ages 20–49 in the percentage who received a glucose screening (49.6% vs. 42.4%).
  ■ There were no statistically significant differences between female Veterans ages 50–64 and female non-Veterans ages 50–64 in the percentage who received a glucose screening (61.0% vs. 61.7%).
  ■ There were no statistically significant differences between female Veterans age 65+ and female non-Veterans age 65+ in the percentage who received a glucose screening (73.2% vs. 67.0%).
  ■ Male Veterans ages 20–49 were significantly more likely to receive a glucose screening compared with male non-Veterans ages 20–49 (42.9% vs. 31.8%).
  ■ Male Veterans ages 50–64 were significantly more likely to receive a glucose screening compared with male non-Veterans ages 50–64 (65.9% vs. 59.0%).
  ■ There were no statistically significant differences between male Veterans age 65+ and male non-Veterans age 65+ in the percentage who received a glucose screening (71.8% vs. 69.2%).