# Acknowledgments

The National Healthcare Quality and Disparities Report (NHQDR) is the product of collaboration among agencies from the U.S. Department of Health and Human Services (HHS), other federal departments, and the private sector. Many individuals guided and contributed to this effort. Without their magnanimous support, the report would not have been possible. Specifically, we thank:

Primary AHRQ Staff: Robert Valdez, Craig Umscheid, Erin Grace, Karen Chaves, Darryl Gray, Barbara Barton, Romsai Tony Boonyasai, Cecilia Hahn, and Doreen Bonnett.

HHS Interagency Workgroup (IWG) for the NHQDR:, Girma Alemu (HRSA), Anne-Marie Gomes (SAMHSA), Jill Ashman (CDC), Elizabeth Barfield (NIH), Barbara Barton (AHRQ), Doreen Bonnett (AHRQ), Romsai Tony Boonyasai (AHRQ), Christopher Cairns (CDC), Victoria Chau (SAMHSA), Karen Chaves (AHRQ), Xiuhua Chen (CVP), Robin Cohen (CDC), Nathan Donnelly (SAMHSA), Deborah Duran (NIH), Melissa Evans (CMS), William Freeman (AHRQ), Sabrina Frost (HRSA), Darryl Gray (AHRQ), Kirk Greenway (IHS), Monika Haugstetter (AHRQ), Rebecca Hawes (NIH), Kirk Henry (CDC), Sarah Heppner (HRSA), Trevor Hsu (SAMHSA), Heydy Juarez (SAMHSA), Christine Lee (FDA), Doris Lefkowitz (AHRQ), Lan Liang (AHRQ), Jesse Lichstein (HRSA), Shari Ling (CMS), Iris Mabry-Hernandez (AHRQ), Marlene Matosky (HRSA), Tracy Matthews (HRSA), Donna McCree (CDC), Christine Merenda (FDA), Kamila Mistry (AHRQ), Dawn Morales (NIH), Ernest Moy (VHA), Pradip Muhuri (AHRQ), Sarada Pyda (ASPE), Mary Roary (SAMHSA), Rajasri Roy (NIH), Dianne Rucinski (CMS), Asel Ryskulova (CDC), Michelle Schreiber (CMS), Yahtyng Sheu (HRSA), Adelle Simmons (ASPE), LaQuanta Smalley (HRSA), Loida Tamayo (CMS), Caroline Taplin (ASPE), Anjel Vahratian (CDC), Michelle Washko (HRSA), Tracy Wolff (AHRQ), Abigail Woodroffe (AIR), Ying Zhang (IHS), and Rachael Zuckerman (ASPE).

NHQDR Team: Barbara Barton (CQuIPS), Doreen Bonnett (OC), Romsai Tony Boonyasai (CQuIPS), Xiuhua Chen, (CVP), William Freeman (OEREP), Erin Grace (CQuIPS), Darryl Gray (CQuIPS), Cecilia Hahn (CQuIPS), Lan Liang (CFACT), Kamila Mistry (OEREP), Margie Shofer (CQuIPS), Andrea Timaskenka (CQuIPS), Tselote Tilahun (CQuIPS), and Abigail Woodroffe (AIR).

HHS Data Experts: Cuong Bui (HRSA), Lara Bull-Otterson (CDC), Christopher Cairns (CDC), Robin Cohen (CDC-NCHS), Joann Fitzell (CMS), Elizabeth Goldstein (CMS), Irene Hall (CDC-HIV), Katrina Hoadley (CMS), Jessica King (CDC), Amanda Lankford (CDC), Lan Liang (AHRQ), Lori Luria (CMS), Marlene Matosky (HRSA), Anthony Oliver (CMS), Tracy Matthews (HRSA), Robert Morgan (CMS), Richard Moser (NIH-NCI), Pradip Muhuri (AHRQ), Robert Pratt (CDC), Asel Ryskulova (CDC-NCHS), LaQuanta Smalley (HRSA), Alek Sripipatana (HRSA), Rita Wilson (EPA), and Xiaohong (Julia) Zhu (HRSA).

Other Data Experts: Valarie Ashby (University of Michigan), Mark Cohen (ACS NSQIP), Sheila Eckenrode (MPSMS-Yale), Clifford Ko (ACS NSQIP), Jill McCarty (IBM), Joe Messana (University of Michigan), Tammie Nahra (University of Michigan), Leticia Nogueira (American Cancer Society), Robin Padilla (University of Michigan), Rebecca Anhang Price (RAND), Jennifer Sardone (University of Michigan), Yun Wang (MPSMS-Yale), and Robin Yabroff (American Cancer Society).

Other AHRQ Contributors: Ashley Allman, Cindy Brach, Howard Holland, Edwin Lomotan, Corey Mackison, Karen Migdail, Milli O’Brien, Pamela Owens, Mary Rolston, Ruby Sachdeva, Bruce Seeman, and Michele Valentine.

Data Support Contractors: AIR, CVP Corp.