# Growth of Telehealthcare During the COVID-19 Pandemic

Telehealthcare is the delivery of healthcare services through telecommunication technologies and can be conducted via synchronous services (i.e., live interaction via audio or video) or asynchronous services such as messaging, file sharing, and remote monitoring. This section of the NHQDR focuses on telehealthcare services provided via synchronous video-plus-audio (referred to in this section as “video”) or audio-only visits between a provider and patient.^1^

As in-person services were limited during the COVID-19 pandemic, policymakers, healthcare systems, providers, and patients pivoted to increase the use of telehealthcare services. This section provides a brief history of telehealthcare services, how they changed during the COVID-19 pandemic, and disparities in telehealthcare services. It also presents findings from analyses of data obtained for the NHQDR, including:

- Use of telehealthcare services before the pandemic was very low, due in part to policy restrictions, but rates increased in the first few months of the pandemic due to waivers and policy flexibilities by the federal and state governments. Although telehealthcare use waned as the pandemic progressed, despite continued federal flexibilities, its use remains higher than before the pandemic.
- Provider use of telehealthcare services was not consistent. Practices with fewer providers were less likely to report telehealthcare service use.
- Telehealthcare services were most often provided for mental health care.
- People living in areas with lower internet access or in rural areas and older adults were less likely to have a telehealthcare visit.
  ■ Of people with a telehealthcare visit, older and lower income individuals were less likely to have a telehealthcare visit that included video technology.
- Practices that used telehealthcare services most often reported that patient difficulty using telehealthcare technology and limitations in patient access to technology affected the practices’ use of telehealthcare.
  ■ Although limited provider internet access or speed issues were less commonly reported overall, this limitation more often affected providers in non-metropolitan statistical areas (MSAs) and areas with a higher percentage of non-Hispanic (NH) White individuals.
- About one-third of practices indicated that quality was fully or to a great extent the same as in-person visits.
  ■ About 60% of practices were very or somewhat satisfied with telehealthcare technology and about 70% were planning to continue providing telehealthcare services after the pandemic ended.

Lastly, this section discusses the findings, presents conclusions based on findings and current telehealthcare practices, and provides resources for additional information about telehealthcare.

## Background

### Telehealthcare Service Use Before the COVID-19 Pandemic Was Limited

❖ Although there was healthcare community and patient interest in telehealthcare before the COVID-19 pandemic, the use of telehealthcare services was infrequent, partly because of payer- and policy-related obstacles.

Communication technology has long been touted as a useful tool for improving access to quality healthcare. More than 20 years ago, the Institute of Medicine, now the National Academy of Medicine, promoted innovative and expanded use of telehealthcare.^2^ With the passage of the Affordable Care Act in 2010 and its focus on improving efficiency in healthcare delivery, policymakers and providers further increased interest in telehealthcare.^3^

Although telehealthcare use was low before the COVID-19 pandemic, patients and providers showed interest.^4^ In a 2019 study, 69% of physicians and 66% of patients reported being willing to use telehealthcare. However, less than 10% of them reported receiving telehealthcare services.5 The study also found that use varied by age and geography; telehealthcare users were more likely to be younger and living in the South.^5^ Of consumers who had used telehealthcare services, experiences were generally positive, with at least two-thirds of recipients reporting satisfaction using telehealthcare services.^Error! Bookmark not defined.,6,7,8^

Before the COVID-19 pandemic, low use was often due to payer- and policy-related barriers. For example, reimbursement for telehealthcare services was limited, modes of technology were restricted, and limitations were placed on patient (originating) and provider (distant) sites eligible for telehealthcare, with Medicare excluding urban locations.^9^

Additional barriers for patients included lack of reliable internet access, limited patient awareness, and patient discomfort with use of technology.^10,11,12^ For example, older adults, low-income individuals, and rural residents have lower rates of owning a smart phone or having home broadband internet access.^13,14,15^

## Findings

The figures in this section of the NHQDR provide insight on the use of synchronous telehealthcare services during the COVID-19 pandemic. The findings section is divided into subsections: overall use of telehealthcare services, variation in telehealthcare service use, variation in mode of telehealthcare used (video and audio only), barriers to use of telehealthcare services, and perceptions of care for telehealthcare services. The measures present findings for the most recent data year.

### Telehealthcare Service Use Increased During the COVID-19 Pandemic

❖ Because of policies enabling telehealthcare service use and provider, staff, and patient desire to minimize in-person contacts, telehealthcare service use became more common during the COVID-19 pandemic. Some specialties provided services via telehealthcare technology more than others.

Early in the COVID-19 public health emergency (PHE), government and healthcare facility regulations limited in-person care for noncritical health conditions. However, providers and policymakers recognized that delaying care could result in worse long-term outcomes, as noted in the Ambulatory Care section of the NHQDR.

The Centers for Disease Control and Prevention (CDC) noted excess deaths in 2020 not due directly to COVID-19. These deaths may have been due to individuals not receiving needed or timely care. Evidence also showed that individuals in poorer health were more likely to delay care than those in good health, which could have put them at risk for poor long-term health outcomes.^16^

To minimize the spread of COVID-19 and limit in-person interaction with medical providers and staff while still providing needed healthcare, policies were enacted to encourage greater use of telehealthcare services. These federal and state policies included:

- Providing the same rates of reimbursement for virtual visits as for in-office appointments.
- Using more types of mobile devices for virtual visits and not enforcing certain HIPAA Rules^i^ that include the good faith provision of telehealth using a non-public-facing remote communication technology.
- Allowing audio-only telehealthcare reimbursement for certain services.
- Relaxing rules around telehealthcare patient (originating) and provider (distant) sites eligible for telehealthcare.
- Expanding the types of services and providers covered by telehealthcare (e.g., physical and occupational therapists).
- Permitting telehealthcare across state lines, with some state-specific provisions, including waivers of state licensure requirements.
- Using first-dollar coverage for telehealthcare services without first meeting a minimum deductible, or no patient cost sharing.

In addition to changes in federal and state regulations, hospital systems and providers implemented additional rules for COVID-19 safety, such as requiring virtual appointments only for certain office visits and deferring elective visits.

Due to factors such as COVID-19 pandemic-related policies and fear of COVID-19 contagion, the rate of telehealthcare visits increased noticeably.^17^ The number of telehealthcare visits increased 154% in the last week of March 2020 compared with the same week in March 2019.^18^

The peak of telehealthcare use for Medicare fee-for-service and Medicare Advantage plans occurred in April 2020.^19,20^

The level of telehealthcare visits decreased after April 2020 but remained higher than before the pandemic, particularly for specialist behavioral health care (Figure 1). In 2021, 81% of adults and 80% of children who had a virtual medical appointment said it was because of COVID-19 (data not shown).^ii^

Figure 1 Outpatient telehealthcare services for Medicare fee-for-service beneficiaries, per week, by type of healthcare, 2020-2021

Source: Office of the Assistant Secretary for Planning and Evaluation analysis of Medicare fee-for-service claims, 2020-2021, in Samson LW, Couture SJ, Jacobus-Kantor L, Creedon TB, Sheingold S. Updated Medicare FFS Telehealth Trends by Beneficiary Characteristics, Visit Specialty, and State, 2019-2021. Issue Brief No. HP-2023-18. Washington, DC: U.S. Department of Health and Human Services, July 2023.

Although telehealthcare increased substantially during the pandemic, the decrease in in-person care was so large that telehealthcare services did not fully make up for the lack of in-person services. For example, individuals with Medicare coverage still had more total healthcare visits in the year before the pandemic (March 2019-February 2020) than in the first year of the pandemic (March 2020-February 2021).^19,20^

As shown above, use of telehealthcare varied by medical specialty. Practices that require physical contact to examine or treat people may not have been able to leverage telehealthcare technology as effectively as other specialties. Studies found that, similar to prepandemic patterns, most telehealthcare visits during the pandemic were for behavioral health.^21,22,23,24^

In addition, the rate of telehealthcare use for advanced practice registered nurses (APRNs), who commonly practice primary care, increased during the pandemic. A study found that 12% of APRNs surveyed used telehealthcare at least once a week before the pandemic compared with 70% of APRNs surveyed who used it at least weekly during the pandemic, a nearly sixfold increase.^25^

In contrast, specialties such as ophthalmology, obstetrics/gynecology, and surgery had few telehealthcare visits before and during the pandemic.^21^ Analyses of NHQDR data also showed that behavioral health and primary care were more likely than other specialties to provide telehealthcare during the COVID-19 pandemic.

In 2020 and 2021, about a third of in-person outpatient visits were for general practice/internal medicine, but fewer than 5% of visits were for psychiatry/psychology (Figure 2). During the same period, more than a third of telehealthcare outpatient visits were for psychiatry/psychology and another third were for general practice/internal medicine.

Figure 2 Medical specialty of outpatient medical visits, by in person or telehealthcare visit, 2020 and 2021

Note: Outpatient medical appointments include office-based and hospital-based outpatient visits. The 2020 data include visits occurring July-December 2020. The 2021 data are for visits occurring anytime during 2021.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2020 and 2021.

- In 2020, 33.0% of in-person outpatient visits were for general practice/internal medicine, 9.8% were for ophthalmology, 7.9% were for pediatrics, 3.7% were for psychiatry/psychology, and 45.6% were for other types of care (Figure 2).
- In 2021, 32.3% of in-person outpatient visits were for general practice/internal medicine, 9.3% were for ophthalmology, 8.2% were for pediatrics, 4.7% were for psychiatry/psychology, and 45.5% were for other types of care.
- In 2020, 37.2% of telehealthcare outpatient visits were for general practice/internal medicine, 0.2% were for ophthalmology, 5.1% were for pediatrics, 36.2% were for psychiatry/psychology, and 21.3% were for other types of care.
- In 2021, 31.4% of telehealthcare outpatient visits were for general practice/internal medicine, 0.2% were for ophthalmology, 2.9% were for pediatrics, 46.2% were for psychiatry/psychology, and 19.3% were for other types of care.

### Use of Telehealthcare Services Varied by Provider and Patient Characteristics

❖ Most practices reported use of some telehealthcare services, but a small percentage of all healthcare visits were via telehealthcare. Telehealthcare services were less frequently used by surgical practices and practices with fewer physicians. Rates of telehealthcare use were often lower in populations that may benefit the most from telehealthcare services, such as older individuals, individuals living in areas with less internet access, and individuals in more rural areas.

Disparities exist in access to care and care provided via telehealthcare may address some historical barriers that disproportionately affect rural and low-income individuals. Since patients and providers may not need transportation, they may face fewer cost, logistic, and timing issues. Telehealthcare visits also have fewer childcare barriers.^26,27,28^ Telehealthcare may also decrease burden on providers, particularly in rural areas.^26^

Findings from the NHQDR show that the percentage of practices that used telehealthcare increased more than fourfold during the COVID-19 pandemic, from 16.0% in 2019 to 86.5% in 2021 (2019 data not shown).^iii^ In 2021, the use of telehealthcare services varied across practice characteristics.

As noted above, some variation, such as by specialty, may be related to appropriateness of care. However, other variations in telehealthcare use may indicate that the potential of telehealthcare has not been realized and disparities exist in resources and supports available to some practices.

As shown in Figure 3, practices with fewer providers and surgical practices were less likely to provide any telehealthcare services compared with larger practices and primary care practices, respectively.

Figure 3 Any use of any telehealthcare technology by practice size, specialty, percentage of non-Hispanic White individuals, and practice location, 2021

Key: NHW = non-Hispanic White; MSA = metropolitan statistical area.

Note: Telehealthcare includes audio-only and video services.

Source: Centers for Disease Control and Prevention, National Electronic Health Records Survey, 2021.

- In 2021, 86.5% of practices reported any use of telehealthcare technology (Figure 3).
- In 2021, the rate of practices reporting any use of telehealthcare technology was significantly^iv^ lower for practices with 1 physician (76.3%) and practices with 2-3 physicians (77.9%) compared with practices with 51+ physicians (97.9%).
- In 2021, the rate of practices reporting any use of telehealthcare technology was significantly lower for surgical practices (74.8%) compared with primary care practices (91.5%).
- In 2021, there were no statistically significant differences by NH-White population or practice location in the rate of practices reporting any use of telehealthcare technology.

The literature indicates that use of telehealthcare services varies notably by individuals’ geographic location and sociodemographic characteristics. Although telehealthcare services can benefit people in rural areas who have to travel long distances to receive healthcare, evidence shows that telehealthcare use is often more common in urban areas than in rural areas.^23,26,29,30^

Studies of telehealthcare use during the pandemic often showed that younger individuals and those with higher incomes use telehealthcare services at higher rates than older individuals and those with lower incomes.^28,31,32,33,34^ Studies also indicate women use telehealthcare services marginally more often than men.^18,22,28,30,33,35,36^

Rates by race and ethnicity have been less definitive. Telehealthcare service use by Black individuals for some medical care may be lower for some medical specialties (e.g., telehealthcare visits among those receiving behavioral health care), technologies used (e.g., video, audio only), and geographic areas.^22,28,30,33,34,36^ Evidence is inconclusive regarding whether Asian and Hispanic people use telehealthcare services more or less than White individuals.^22,23,28,34^

Findings from the NHQDR are similar to the literature showing that rates of audio-only or video telehealthcare use for office-based providers (i.e., not in a hospital setting) were lower for older individuals, individuals living in areas with less internet access, and individuals from more rural areas. These groups may especially benefit from telehealthcare services.

Figure 4 Office-based provider visits that were telehealthcare visits, by county-level internet access and geographic location, 2021

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2021.

- In 2021, 8.8% of doctor’s office visits were telehealthcare visits (Figure 4).
- In 2021, the rate of doctor’s office visits that were telehealthcare visits was significantly lower for individuals living in counties with 50-79% of households with internet access (5.6%) and 80-89% of households with internet access (7.0%) than for individuals living in counties with 90-100% of households with internet access (12.0%).
- In 2021, the rate of doctor’s office visits that were telehealthcare visits was significantly lower for individuals living in medium metro (6.3%), small metro (4.8%), micropolitan (5.7%), and noncore (3.7%) areas than for individuals living in large fringe metro areas (11.0%).

Figure 5 Office-based provider visits that were telehealthcare visits, by patient age, patient race/ethnicity, and family income, 2021

Key: NH = non-Hispanic; PG = federal poverty guideline.

Note: Sample sizes for American Indian or Alaska Native and Native Hawaiian/Pacific Islander groups were too small to produce statistically reliable data.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2021.

- In 2021, the rate of doctor’s office visits that were telehealthcare visits was significantly lower for individuals under age 18 years (9.0%), ages 45-64 years (7.4%), and age 65 years and over (3.1%) than for individuals ages 18-44 years (15.8%) (Figure 5).
- In 2021, there were no statistically significant differences by race/ethnicity or family income in the rate of doctor’s office visits that were telehealthcare visits.

Studies indicate individuals using telehealthcare visits had higher rates of attended visits and adherence to therapy and medications. However, they may have had lower rates of up-to-date lab tests, paraclinical assessment, and care resolution in initial visit (i.e., higher rates of followup visits). The findings varied by medical specialty and across studies.^27^

### Mode of Telehealthcare Use Varied by Patient Characteristics

❖ Audio-only technology was frequently used by providers and patients. The rates of video technology use varied across populations and were less common for people with lower incomes and older people.

Between July 2021 and August 2022, about half (49% to 56%, depending on the month) of the telehealthcare appointments were video telehealthcare visits, while the remaining were audio-only visits.37 Audio-only services are effective in many cases. However, in some cases, video is preferred so the provider can view the patient’s physical appearance, note the patient’s living conditions, and observe nonverbal cues (e.g., body language). Telehealthcare, whether it is provided via video or audio only, is better than no care.^38^

The most salient barrier to video telehealthcare visits is that visits require internet access and a supporting device. From 2015 to 2020, about 20% of adults in the United States did not have access to a smart phone and about 15% did not have broadband internet access at home.^39^ The rates are even higher among older, lower income, rural, and less-educated individuals. Video telehealthcare use also requires comfort using the technology.^37^

Limited English proficiency also poses a barrier to video telehealthcare. Although routine provision of interpreter services is not yet the standard for telehealthcare platforms, a trained medical interpreter may need to join the visit remotely, requiring interpreters to have video capabilities and providers to have three-way communication technology.^27^ Therefore, audio-only technology has been used more often by older and lower income individuals and those who require an interpreter.^37,40^

NHQDR data also indicate similar rates and variations in the use of audio only and video for individuals who have telehealthcare visits. In 2021, practices were more likely to report using telephone audio than video technology for telehealthcare.

Figure 6 Practices that use various modes of telehealthcare technology for telehealthcare visits, 2021

Key: EHR = electronic health record.

Source: Centers for Disease Control and Prevention, National Electronic Health Records Survey, 2021.

- Of practices that use telehealthcare technology:
  ■ 67.0% of practices reported using telephone audio for telehealthcare visits,
  ■ 56.4% reported using video software with audio,
  ■ 44.7% reported using telehealthcare platforms that were not integrated with electronic health records (EHRs), and
  ■ 28.6% reported using telehealthcare platforms that were integrated with EHRs (Figure 6).

NHQDR findings also indicated that, of telehealthcare visits with office-based providers, video technology was used less often by people with lower incomes and older people. This finding is particularly notable since older individuals were less likely to have care provided via telehealthcare and when they did have telehealthcare visits, the visits were more likely to be with audio only.

Figure 7 Telehealthcare visits for office-based providers that included video in the past 12 months, by county-level internet access and geographic location, 2021

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2021.

- In 2021, 66.7% of telehealthcare visits to doctors’ offices included video (Figure 7).
- In 2021, the rate of telehealthcare visits to doctor’s offices that included video was significantly lower for individuals living in small metro areas (48.0%) than for individuals living in large fringe metro areas (67.3%).
- In 2021, there were no statistically significant differences by percentage of households in the county with internet access in the rate of telehealthcare visits to doctors’ offices that included video.

Figure 8 Telehealthcare visits for office-based providers that included video in the past 12 months, by patient age, patient race/ethnicity, and family income, 2021

Key: NH = non-Hispanic; PG = federal poverty guideline.

Note: Sample sizes for American Indian or Alaska Native and Native Hawaiian/Pacific Islander groups were too small to produce statistically reliable data.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2021.

- In 2021, the rate of telehealthcare visits to doctors’ offices that included video was significantly lower for individuals ages 45-64 (60.7%) and age 65 years and over (42.2%) than for individuals ages 18-44 years (71.7%) (Figure 8).
- In 2021, the rate of telehealthcare visits to doctors’ offices that included video was significantly lower for individuals with family incomes less than 100% of the poverty guideline (50.1%) and 100% to 199% of the poverty guideline (53.7%) than for individuals with family incomes 400% or more of the poverty guideline (71.5%).
- In 2021, there were no statistically significant differences by race/ethnicity in the rate of telehealthcare visits to doctors’ offices that included video.

### Barriers to Telehealthcare Use Are Common

❖ Patient difficulty using telehealthcare technology and limitations in patient access to technology were the most often reported barriers to telehealthcare use, affecting more than half the practices reporting. Although limited provider internet access or speed issues were less commonly reported overall, this limitation more often affected providers in non-MSAs (i.e., rural areas) and areas with a higher percentage of non-Hispanic White individuals.

Practices reported on factors that affected their use of telehealthcare services.

Figure 9 Practice-reported factors affecting use of telehealthcare technology, 2021

Note: Telehealthcare includes audio-only and video services.

Source: Centers for Disease Control and Prevention, National Electronic Health Records Survey, 2021.

• In 2021, of practices that use audio-only or video telehealthcare technology:

■ 70.4% of physicians reported patients’ difficulty using technology as a factor affecting use of telehealthcare,
■ 64.3% reported limitations in patients’ access to technology,
■ 41.6% reported improved reimbursement and relaxation of rules,
■ 33.0% reported limited physician internet access or speed issues,
■ 25.5% reported telehealthcare inappropriate for specialty/type of patients, and
■ 16.8% reported telehealthcare platform not easy to use or not meeting needs (Figure 9).

The rate at which the factors affected practices varied by practice characteristics. Surgical practices that provided telehealthcare services were less likely to report factors affecting their use of telehealthcare technology compared with primary care practices that provided telehealthcare services. Practices in non-MSAs were more likely to report factors affecting their use of telehealthcare technology compared with MSAs.

The barrier related to limited internet access or speed showed the most variation and was more problematic for primary care practices, practices in areas with 80-100% NH-White population, and practices in non-MSAs.

Figure 10 Practices that reported patients’ difficulty using technology/platform as affecting their use of telehealthcare for office visits, by practice size, specialty, percentage of non-Hispanic White individuals, and practice location, 2021

Key: NHW = non-Hispanic White; MSA = metropolitan statistical area.

Note: Telehealthcare includes audio-only and video services.

Source: Centers for Disease Control and Prevention, National Electronic Health Records Survey, 2021.

- In 2021, of practices that use telehealthcare technology, the rate of practices that reported patients’ difficulty using technology/platform as affecting their use of telehealthcare for office visits was significantly lower for surgical practices (55.9%) compared with primary care practices (71.0%) (Figure 10).
- In 2021, of practices that use telehealthcare technology, there were no statistically significant differences by practice size, NH-White population, or practice location in the rate of practices that reported patients’ difficulty using technology/platform as affecting their use of telehealthcare for office visits.

Figure 11 Practices that reported limitations in patients’ access to technology as affecting their use of telehealthcare for office visits, by practice size, specialty, percentage of non-Hispanic White individuals, and practice location, 2021

Key: NHW = non-Hispanic White; MSA = metropolitan statistical area.

Note: Telehealthcare includes audio-only and video services.

Source: Centers for Disease Control and Prevention, National Electronic Health Records Survey, 2021.

- In 2021, of practices that use telehealthcare technology, the rate of practices that reported limitations in patients’ access to technology as affecting their use of telehealthcare for office visits was significantly higher for practices with 11-50 physicians (74.8%) compared with practices with 51+ physicians (59.2%) (Figure 11).
- In 2021, of practices that use telehealthcare technology, there were no statistically significant differences by specialty, NH-White population, or practice location in the rate of practices that reported limitations in patients’ access to technology as affecting their use of telehealthcare for office visits.

Figure 12 Practices that reported improved reimbursement and relaxation of rules related to use of telehealthcare visits as affecting their use of telehealthcare for office visits, by practice size, specialty, percentage of non-Hispanic White individuals, and practice location, 2021

Key: NHW = non-Hispanic White; MSA = metropolitan statistical area.

Note: Telehealthcare includes audio-only and video services.

Source: Centers for Disease Control and Prevention, National Electronic Health Records Survey, 2021.

- In 2021, of practices that use telehealthcare technology, the rate of practices that reported improved reimbursement and relaxation of rules related to use of telehealthcare visits as affecting their use of telehealthcare for office visits was significantly lower for surgical practices (23.4%) compared with primary care practices (46.2%) (Figure 12).
- In 2021, of practices that use telehealthcare technology, the rate of practices that reported improved reimbursement and relaxation of rules related to use of telehealthcare visits as affecting their use of telehealthcare for office visits was significantly higher for practices located in non-MSAs (53.8%) compared with practices located in MSAs (40.8%).
- In 2021, of practices that use telehealthcare technology, there were no statistically significant differences by practice size or NH-White population in the rate of practices that reported improved reimbursement and relaxation of rules related to use of telehealthcare visits as affecting their use of telehealthcare for office visits.

Figure 13 Practices that reported limited internet access or speed as affecting their use of telehealthcare for office visits, by practice size, specialty, percentage of non-Hispanic White individuals, and practice location, 2021

Key: NHW = non-Hispanic White; MSA = metropolitan statistical area.

Note: Telehealthcare includes audio-only and video services.

Source: Centers for Disease Control and Prevention, National Electronic Health Records Survey, 2021.

- In 2021, of practices that use telehealthcare technology, the rate of practices that reported limited internet access or speed as affecting their use of telehealthcare for office visits was significantly lower for surgical practices (18.2%) compared with primary care practices (35.7%) (Figure 13).
- In 2021, of practices that use telehealthcare technology, the rate of practices that reported limited internet access as affecting their use of telehealthcare for office visits was significantly lower for practices in areas with less than 50% NH-White population (27.3%) and practices in areas with 50-69.99% NH-White population (33.5%) compared with practices in areas with 80-100% NH-White population (43.4%).
- In 2021, of practices that use telehealthcare technology, the rate of practices that reported limited internet access as affecting their use of telehealthcare for office visits was significantly higher for practices located in non-MSAs (47.4%) compared with practices located in MSAs (32.0%).
- In 2021, of practices that use telehealthcare technology, there were no statistically significant differences by practice size in the rate of practices that reported limited internet access as affecting their use of telehealthcare for office visits.

### Findings on Perception of Care Provided via Telehealthcare Are Mixed

❖ Although few practices reported being able to provide similar care via telehealthcare services compared with in-person services, most practices were satisfied with the technology and intended to continue using telehealthcare services after the pandemic ended. Relative to primary care and medical practices, surgical practices were significantly less satisfied with telehealthcare and less likely to continue using it when the pandemic was over.

While telehealthcare can improve access to care, it is imperative that the quality of care provided via telehealthcare is similar to the quality of in-person care and that providers are confident in their ability to provide needed care. The following figures provide measures of provider perceptions of quality of care, provider satisfaction with the technology, and provider intentions to continue providing care via telehealthcare.

Figure 14 Practices that described being able to provide similar quality care during telehealthcare visits as during in-person visits, by practice size, specialty, percentage of non-Hispanic White individuals, and practice location, 2021

Key: NHW = non-Hispanic White; MSA = metropolitan statistical area.

Note: Telehealthcare includes audio-only and video services.

Source: Centers for Disease Control and Prevention, National Electronic Health Records Survey, 2021.

- In 2021, of practices that use telehealthcare technology, 31.0% of practices described being able to provide similar quality care during telehealthcare visits as during in-person visits (Figure 14).
- In 2021, of practices that use telehealthcare technology, the rate of practices that described being able to provide similar quality care during telehealthcare visits as during in-person visits was significantly higher for practices in areas with 50-69.99% NH-White population (34.8%) compared with practices in areas with 80%-100% NH-White population (26.3%).
- In 2021, there were no statistically significant differences by practice size, specialty, or practice location in the rate of practices that described being able to provide similar quality care during telehealthcare visits as during in-person visits.

Figure 15 Practices very or somewhat satisfied with using telehealthcare technology for patient visits, by practice size, specialty, percentage of non-Hispanic White individuals, and practice location, 2021

Key: NHW = non-Hispanic White; MSA = metropolitan statistical area.

Note: Telehealthcare includes audio-only and video services.

Source: Centers for Disease Control and Prevention, National Electronic Health Records Survey, 2021.

- In 2021, of practices that use telehealthcare technology, 62.0% of practices were very or somewhat satisfied with using telehealthcare technology for patient visits (Figure 15).
- In 2021, of practices that use telehealthcare technology, the rate of practices very or somewhat satisfied with using telehealthcare technology for patient visits was significantly lower for practices with 2-3 physicians (53.6%) compared with practices with 51+ physicians (69.0%).
- In 2021, of practices that use telehealthcare technology, the rate of practices very or somewhat satisfied with using telehealthcare technology for patient visits was significantly lower for surgical practices (49.5%) compared with primary care practices (65.5%).
- In 2021, of practices that use telehealthcare technology, the rate of practices very or somewhat satisfied with using telehealthcare technology for patient visits was significantly higher for practices in areas with less than 50% NH-White population (64.7%) compared with practices in areas with 80-100% NH-White population (54.4%).
- In 2021, there were no statistically significant differences by practice location in the rate of practices very or somewhat satisfied with using telehealthcare technology for patient visits.

Figure 16 Practices planning to continue using telehealthcare visits when appropriate once the COVID-19 pandemic is over, by practice size, specialty, percentage of non-Hispanic White individuals, and practice location, 2021

Key: NHW = non-Hispanic White; MSA = metropolitan statistical area.

Note: Telehealthcare includes audio-only and video services.

Source: Centers for Disease Control and Prevention, National Electronic Health Records Survey, 2021.

- In 2021, of practices that use telehealthcare technology, 70.8% of practices planned to continue using telehealthcare visits when appropriate once the COVID-19 pandemic was over (Figure 16).
- In 2021, of practices that use telehealthcare technology, the rate of practices planning to continue using telehealthcare visits when appropriate once the COVID-19 pandemic was over was significantly higher for practices with 11-50 physicians (84.1%) compared with practices with 51+ physicians (72.0%).
- In 2021, of practices that use telehealthcare technology, the rate of practices planning to continue using telehealthcare visits when appropriate once the COVID-19 pandemic was over was significantly lower for surgical (63.9%) practices compared with primary care practices (77.1%).
- In 2021, there were no statistically significant differences by NH-White population or practice location in the rate of practices planning to continue using telehealthcare visits when appropriate once the COVID-19 pandemic was over.

## Discussion and Conclusions

Telehealthcare has the potential to reduce disparities and improve access to healthcare. The COVID-19 pandemic increased the interest in and use of telehealthcare. As the pandemic waned, the rate of telehealthcare use decreased but remains higher than before the pandemic, especially for behavioral health care.

However, barriers remain for providers and patients. As noted above, more than half of practices reported patients’ difficulty using technology and limitations in patients’ access to technology. These barriers were reflected in variations in telehealthcare use. The NHQDR findings indicate use of audio-only or video telehealthcare was higher in areas with higher rates of internet access and in large central and large fringe metropolitan areas. Use also varied by age, with older people less likely to use telehealthcare services and when they did use telehealthcare, less likely to use video software.

Innovative programs aimed to expand reliable internet access, loan hardware to individuals, identify or create Wi-Fi hotspots for telehealthcare use, and provide training and technical assistance have received attention.^41,42,43,44^ For example, libraries and library staff are exploring support of telehealthcare by providing broadband access and portable hotspots, laptops, and private spaces, as well as staff who can facilitate their use.^45,46,47^

Provider and staff engagement and patient outreach are also important to reach the most vulnerable individuals.^48^ For example, some clinics in rural areas were less likely to add telehealthcare services during the pandemic.^49^ Therefore, to expand telehealthcare to individuals in rural areas, more effort may be needed to support rural providers in setting up telehealthcare technology within their practices and working with individuals who have less access to or are less adept at telehealthcare technology.

Even if some of the barriers mentioned here are addressed, additional concerns about the future of telehealthcare policies remain now that the PHE has ended. For Medicare, some telehealthcare policies have been made permanent, most notably for behavioral health care, while other Medicare policies have been only temporarily extended (e.g., originating site flexibility, acceptance of additional providers and services). Other policies have ended (e.g., payment parity, state PHE waivers on licensure requirements).

The policies supporting telehealthcare are particularly important given that more than one-third of practices indicated that improved reimbursement and relaxation of rules affected their use of telehealthcare services. Since payers may revert their telehealthcare coverage to pre-COVID standards (e.g., reduce reimbursement rates for telehealthcare relative to in-person visits, limit coverage of specific interventions via telehealthcare), recommendations have been made to make virtual visit reimbursement permanent. The recommendations include fewer restrictions on audio-only visit reimbursement, to protect vulnerable groups without internet access and technology skills.^36,40,50^

Given the rapid expansion of telehealthcare use, it is critical to assess what is working well and what can be improved. The NHQDR measures assessing perceptions of care show that only 31% of practices indicated that quality was fully or to a great extent the same as in-person visits. However, 62% of practices were very or somewhat satisfied with telehealthcare technology and 71% were planning to continue providing telehealthcare services after the pandemic ended. Therefore, additional studies are needed to track use, disparities, and outcomes over time.^48^

Testing and evaluation of innovations are also needed, particularly innovations related to reliable internet availability, rural access, application in specific communities, interoperability of data, and the optimal balance of in-person and virtual care.^40^

In addition, the appropriateness and quality of telehealthcare, as measured by metrics such as rates of ED visits and hospitalizations, outcomes, and patient and provider satisfaction, vary across modes of telehealthcare, populations, specialties, services, and care complexity.^27,51^ Therefore, AHRQ and other entities are assessing how to measure quality of telehealthcare services and develop a new generation of quality measures for telehealthcare and other care sites besides hospitals and physicians’ offices.^31^

Standardized and validated measures related to telehealthcare will provide additional insight into the patient and caregiver experience and the quality and disparities of the nation’s healthcare systems. Finally, with the end of the PHE, policies should be evaluated to determine which should remain and which should be removed, revised, or updated.

## Resources

The Department of Health and Human Services has identified telehealthcare services as a key component in healthcare delivery. As such, resources such as the following are available for providers and patients to learn more about telehealthcare services:

- Telehealth.HHS.gov information hub (https://telehealth.hhs.gov/).
- AHRQ’s Telehealth resource page (https://www.ahrq.gov/topics/telehealth.html).
- AHRQ’s Evidence-based Practice Center evaluations of telehealth (https://effectivehealthcare.ahrq.gov/products/collections/evaluates-telehealth).
- Health Resources and Services Administration (HRSA) Office for the Advancement of Telehealth (https://www.hrsa.gov/about/organization/bureaus/oat).
- HRSA’s Telehealth Resource Center Program (https://www.hrsa.gov/telehealth/telehealth-resource-centers).
- White House Office of National Drug Control Policy’s Telehealth and Substance Use Disorder Services in the Era of COVID-19: Review and Recommendations (https://www.whitehouse.gov/wp-content/uploads/2022/06/Telehealth-and-Substance-Use-Disorder-Services-in-the-Era-of-COVID-19-FINAL.pdf).
- Affordable Connectivity Program (https://www.whitehouse.gov/getinternet/) for discounted internet service plans.
- Office of the Assistant Secretary for Planning and Evaluation Advances in Telehealth (https://aspe.hhs.gov/topics/health-health-care/advances-telehealth) web page, products, and reports.
- Network of the National Library of Medicine Bridging the Digital Divide: Telehealth and Libraries Webinar Series (https://www.nnlm.gov/training/class-catalog/bridging-digital-divide-telehealth-and-libraries-webinar-series).

i HIPAA Rules = Health Insurance Portability and Accountability Act of 1996 Privacy, Security, and Breach Notification Rules.

ii Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

iii Source: Centers for Disease Control and Prevention, National Electronic Health Records Survey, 2019.

iv Unless noted otherwise, for trend analyses, data points under each figure only report differences that are statistically significant (i.e., p value less than 0.1) and show an average annual percentage change greater than 1% per year. For comparisons between two populations, data points under each figure only report differences that are statistically significant (i.e., p value less than 0.05) and have a relative difference between the populations of at least 10%, unless noted otherwise. Readers may learn more about NHQDR’s reporting methodology in Appendix A at https://www.ahrq.gov/research/findings/nhqrdr/nhqdr23/index.html.

## References

1 U.S. Department of Health and Human Services. Getting Started With Telehealth. Last updated July 2023. https://telehealth.hhs.gov/providers/getting-started. Accessed October 30, 2023.
2 Institute of Medicine Committee on Quality of Health Care in America. Crossing the Quality Chasm: A New Health System for the 21st Century. Washington, DC: National Academies Press; 2001. https://www.nap.edu/catalog/10027/crossing-the-quality-chasm-a-newhealth-system-for-the. Accessed October 30, 2023.
3 Weinstein RS, Lopez AM, Joseph BA, Erps KA, Holcomb M, Barker GP, Krupinski EA. Telemedicine, telehealth, and mobile health applications that work: opportunities and barriers. Am J Med. 2014;127(3):183–187. https://doi.org/10.1016/j.amjmed.2013.09.032. Accessed October 30, 2023.24384059
4 Bashshur RL, Howell JD, Krupinski EA, Harms KM, Bashshur N, Doarn DR. The empirical foundations of telemedicine interventions in primary care. Telemed J E Health. 2016;22(5):342–375. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4860623/. Accessed October 30, 2023.27128779
5 Amwell. Telehealth Index: 2019 Consumer Survey. https://resources.amwell.com/white-papers/millennials-are-the-most-likely-age-group-to-use-telehealth-especially-for-mental-health (registration required for full report). Accessed October 30, 2023.
6 Becevic M, Boren S, Mutrux R, Shah Z, Banerjee S. User satisfaction with telehealth: study of patients, providers, and coordinators. Health Care Manag (Frederick). 2015;34(4):337–349. https://pubmed.ncbi.nlm.nih.gov/26506296/. Accessed October 30, 2023.26506296
7 Polinski JM, Barker T, Gagliano N, Sussman A, Brennan TA, Shrank WH. Patients’ satisfaction with and preference for telehealth visits. J Gen Intern Med. 2016 Mar;31:269–275. https://doi.org/10.1007/s11606-015-3489-x. Accessed October 30, 2023.26269131
8 Orlando JF, Beard M, Kumar S. Systematic review of patient and caregivers’ satisfaction with telehealth videoconferencing as a mode of service delivery in managing patients’ health. PLoS One. 2019 Aug 30;14(8):e0221848. https://doi.org/10.1371/journal.pone.0221848. Accessed October 30, 2023.31469865
9 Shaver J. The state of telehealth before and after the COVID-19 pandemic. Prim Care. 2022 Dec;49(4):517–530. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9035352/. Accessed October 30, 2023.36357058
10 Weinstein RS, Lopez AM, Krupinski EA. Telemedicine: news from the front lines. Am J Med. 2014 Mar;127(3):172–173. https://doi.org/10.1016/j.amjmed.2013.09.033. Accessed October 30, 2023.24365166
11 Ellimoottil C, An L, Moyer M, Sossong S, Hollander JE. Challenges and opportunities faced by large health systems implementing telehealth. Health Aff (Millwood). 2018;37(12):1955–1959. https://www.healthaffairs.org/doi/10.1377/hlthaff.2018.05099. Accessed October 30, 2023.30633667
12 Harris J, Newell B, Serafini WB, Hoagland GW, Ruff J. The Future of Telehealth After COVID-19: New Opportunities and Challenges. Bipartisan Policy Center. 2022. https://bipartisanpolicy.org/report/future-oftelehealth/. Accessed October 30, 2023.
13 Pew Research Center. Mobile Fact Sheet. April 7, 2021. http://www.pewinternet.org/fact-sheet/mobile/.Accessed November 21, 2023.
14 Pew Research Center. Mobile Technology and Home Broadband 2021. June 3, 2021.: https://www.pewresearch.org/internet/2021/06/03/mobile-technology-and-home-broadband-2021/. Accessed November 21, 2023.
15 Vogels E. Some digital divides persist between rural, urban and suburban America. Washington, DC: Pew Research Center; August 2021. https://pewresearch-org-preprod.go-vip.co/fact-tank/2021/08/19/some-digital-divides-persist-between-rural-urban-and-suburban-america/. Accessed October 30, 2023.
16 Gertz AH, Pollack CC, Schultheiss MD, Brownstein JS. Delayed medical care and underlying health in the United States during the COVID-19 pandemic: a cross-sectional study. Prev Med Rep. 2022 Aug;28:101882. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9254505/. Accessed October 30, 2023.35813398
17 Bosworth A, Ruhter J, Samson LW, Sheingold S, Taplin C, Tarazi W, Zuckerman R. Medicare Beneficiary Use of Telehealth Visits: Early Data From the Start of COVID-19 Pandemic. Washington, DC: U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation; July 28, 2020. https://aspe.hhs.gov/sites/default/files/migrated_legacy_files/198331/hp-issue-brief-medicare-telehealth.pdf.Accessed October 30, 2023.
18 Koonin LM, Hoots B, Tsang CA, Leroy Z, Farris K, Jolly T, Antall P, McCabe B, Zelis CB R, Tong I, Harris AM. Trends in the use of telehealth during the emergence of the COVID-19 pandemic - United States, January-March 2020. MMWR Morb Mortal Wkly Rep. 2020 Oct 30;69(43):1595–1599. https://www.cdc.gov/mmwr/volumes/69/wr/mm6943a3.htm?s_cid=mm6943a3_w. Accessed October 30, 2023.33119561
19 U.S. Department of Health and Human Services, Office of the Inspector General. Data Brief: Telehealth Was Critical for Providing Services to Medicare Beneficiaries During the First Year of the COVID-19 Pandemic. March 2022, OEI-02-20-00520. https://oig.hhs.gov/oei/reports/OEI-02-20-00520.pdf. Accessed October 30, 2023.
20 Ellimoottil C, Zhu Z, Dunn RL, Thompson MP. Trends in telehealth use by Medicare fee-for-service beneficiaries and its impact on overall volume of healthcare services. medRxiv. 2022 Jun 15;22276468. https://doi.org/10.1101/2022.06.15.22276468. Accessed October 30, 2023.
21 Mehrotra A, Chernew ME, Linetsky D, Hatch H, Cutler DM, Schneider EC. The Impact of COVID-19 on Outpatient Visits in 2020: Visits Remained Stable, Despite a Late Surge in Cases. New York, NY: The Commonwealth Fund; February 2021. https://www.commonwealthfund.org/publications/2021/feb/impact-covid-19-outpatient-visits-2020-visits-stable-despite-late-surge. Accessed October 30, 2023.
22 Mulia N, Ye Y, Greenfield TK, Martinez P, Patterson D, Kerr WC, Karriker-Jaffe KJ. Inequitable access to general and behavioral healthcare in the U.S. during the COVID-19 pandemic: a role for telehealth? Prev Med. 2023;169:107426. https://doi.org/10.1016/j.ypmed.2023.107426. Accessed October 30, 2023.36709864
23 Samson L, Tarazi W, Turrini G, Sheingold S. Medicare Beneficiaries’ Use of Telehealth Services in 2020 – Trends by Beneficiary Characteristics and Location. Issue Brief No. HP-2021-27. U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation; December 3, 2021. https://aspe.hhs.gov/reports/medicare-beneficiaries-use-telehealth-2020. Accessed October 30, 2023.
24 Samson LW, Couture SJ, Jacobus-Kantor L, Creedon TB, Sheingold S. Updated Medicare FFS Telehealth Trends by Beneficiary Characteristics, Visit Specialty and State, 2019-2021. Issue Brief No. HP-2023-18. U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation; July 20, 2023. https://aspe.hhs.gov/reports/updated-medicare-ffs-telehealth-trends. Accessed October 30, 2023.
25 Schorn MN, Myers CR, Barroso J, Hande K, Hudson T, Kim J, Kleinpell R. Changes in telehealth experienced by advanced practice RNs during COVID-19: US survey results. Comput Inform Nurs. 2023 Jul 1;41(7):507–513. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC10332511/. Accessed November 21, 2023.36730718
26 Lo J, Rae M, Amin K, Cox C, Panchal N, Miller BF. Telehealth Has Played an Outsized Role Meeting Mental Health Needs During the COVID-19 Pandemic. Washington, DC: KFF; 2022. https://www.kff.org/coronavirus-covid-19/issue-brief/telehealth-has-played-an-outsized-role-meeting-mental-health-needs-during-the-covid-19-pandemic/. Accessed October 30, 2023.
27 Hatef E, Wilson RF, Hannum SM, Zhang A, Kharrazi H, Weiner JP, Davis SA, Robinson KA. Use of Telehealth During the COVID-19 Era. Systematic Review. Rockville, MD: Agency for Healthcare Research and Quality; January 2023. AHRQ Publication No. 23-EHC005. https://effectivehealthcare.ahrq.gov/products/virtual-health-covid/research. Accessed October 30, 2023.
28 Katzow MW, Steinway C, Jan S. Telemedicine and health disparities during COVID-19. Pediatrics. 2020;146(2): e20201586. https://publications.aap.org/pediatrics/article/146/2/e20201586/36919/Telemedicine-and-Health-Disparities-During-COVID. Accessed October 30, 2023.32747592
29 Reed ME, Huang J, Graetz I, Lee C, Muelly E, Kennedy C, Kim E. Patient characteristics associated with choosing a telemedicine visit vs. office visit with the same primary care clinicians. JAMA Netw Open. 2020;3:e205873. https://doi.org/10.1001/jamanetworkopen.2020.5873. Accessed October 30, 2023.32585018
30 Weiner JP, Bandeian S, Hatef E, Lans D, Liu A, Lemke KW. In-person and telehealth ambulatory contacts and costs in a large U.S. insured cohort before and during the COVID-19 pandemic. JAMA Netw Open. 2021 Mar 1;4(3):e212618. https://doi.org/10.1001/jamanetworkopen.2021.2618. Accessed October 30, 2023.33755167
31 Creating a Framework To Support Measure Development for Telehealth (funded by the Department of Health and Human Services under contract HHSM-500-2012-00009I, Task Order HHSM-500-T0022). Washington, DC: National Quality Forum; 2017. https://www.qualityforum.org/Publications/2017/08/Creating_a_Framework_to_Support_Measure_Development_for_Telehealth.aspx. Accessed October 30, 2023.
32 Hatef E, Lans D, Bandeian S, Lasser EC, Goldsack J, Weiner JP. Outcomes of in-person and telehealth ambulatory encounters during COVID-19 within a large commercially insured cohort. JAMA Netw Open. 2022 Apr 1;5(4):e228954. https://doi.org/10.1001/jamanetworkopen.2022.8954. Accessed October 30, 2023.35471570
33 Koonin LM, Hoots B, Tsang CA, Leroy Z, Farris K, Jolly T, Antall P, McCabe B, Zelis CB R, Tong I, Harris AM. Trends in the use of telehealth during the emergence of the COVID-19 pandemic – United States, January-March 2020. MMWR Morb Mortal Wkly Rep. 2020 Oct 30;69(43):1595–1599. https://www.cdc.gov/mmwr/volumes/69/wr/mm6943a3.htm?s_cid=mm6943a3_w. Accessed October 30, 2023.33119561
34 Mansour O, Tajanlangit M, Heyward J, Mojtabai R, Alexander GC. Telemedicine and office-based care for behavioral and psychiatric conditions during the COVID-19 pandemic in the United States. Ann Intern Med. 2021 Mar;174(3):428–430. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7711651/. Accessed October 30, 2023.33197214
35 Ferguson JM, Jacobs J, Yefimova M, Greene L, Heyworth L, Zulman DM. Virtual care expansion in the Veterans Health Administration during the COVID-19 pandemic: clinical services and patient characteristics associated with utilization. J Am Med Inform Assoc. 2021 Mar 1;28(3):453–462. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7665538/. Accessed October 30, 2023.33125032
36 Gilson SF, Umscheid CA, Laiteerapong N, Ossey G, Nunes KJ, Shah SD. Growth of ambulatory virtual visits and differential use by patient sociodemographics at one urban academic medical center during the COVID-19 pandemic: retrospective analysis. JMIR Med Inform. 2020;8(12):e24544. https://medinform.jmir.org/2020/12/e24544/. Accessed October 30, 2023.33191247
37 Lee EC, Grigorescu V, Enogieru I, Smith SR, Samson LW, Conmy A, De Lew N. Updated National Survey Trends in Telehealth Utilization and Modality: 2021-2022. Issue Brief No. HP-2023-09. Washington, DC: U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation; April 2023. https://aspe.hhs.gov/sites/default/files/documents/7d6b4989431f4c70144f209622975116/household-pulse-survey-telehealth-covid-ib.pdf (https://aspe.hhs.gov/sites/default/files/documents/7d6b4989431f4c70144f209622975116/household). Accessed October 30, 2023.
38 O’Konnor K. CMS Issues New Rule Allowing Billing for Audio-Only Telehealth. Psychiatric News. 2020 May 28. https://doi.org/10.1176/appi.pn.2020.6a21. Accessed October 30, 2023.
39 United States Census Bureau. Table S2801 Types of Computers and Internet Subscriptions. 2015-2020. https://data.census.gov/table/ACSST5Y2020.S2801?q=internet. Accessed November 21, 2023.
40 Chen J, Li KY, Andino J, Hill CE, Ng S, Steppe E, Ellimoottil C. Predictors of audio-only versus video telehealth visits during the COVID-19 pandemic. J Gen Intern Med. 2022;37(5):1138–1144. https://doi.org/10.1007/s11606-021-07172-y. Accessed October 30, 2023.34791589
41 Broadband: Observations on Past and Ongoing Efforts To Expand Access and Improve Mapping Data. GAO-20-535. Washington, DC: U.S. Government Accountability Office; June 25, 2020. https://www.gao.gov/products/gao-20-535. Accessed October 30, 2023.
42 Eyrich NW, Andino JJ, Fessell DP. Bridging the digital divide to avoid leaving the most vulnerable behind. JAMA Surg. 2021;156(8):703–704. https://doi.org/10.1001/jamasurg.2021.1143. Accessed October 30, 2023.33769441
43 Chen A, Ayub MH, Mishuris RG, Rodriguez JA, Gwynn K, Lo MC, Noronha C, Henry TL, Jones D, Lee WW, Varma M, Cuevas E, Onumah C, Gupta R, Goodson J, Lu AD, Syed Q, Suen LW, Heiman E, Salhi BA, Khoong EC, Schmidt S. Telehealth Policy, Practice, and Education: a Position Statement of the Society of General Internal Medicine. J Gen Intern Med. 2023 Aug;38:2613–2620. https://doi.org/10.1007/s11606-023-08190-8 (https://doi.org/10.1007/s11606-023). Accessed October 30, 2023.37095331
44 Federal Communications Commission. Emergency Broadband Benefit. https://www.fcc.gov/broadbandbenefit.Accessed November 21, 2023.
45 DeGuzman PB, Jain N, Loureiro CG. Public Libraries as Partners in Telemedicine Delivery: A Review and Research Agenda, Public Library Quarterly. 2022. 41:3, 294–304, DOI: 10.1080/01616846.2021.1877080
46 Chiricuzio S. Public Libraries Tackle Telehealth Challenges. Library Journal. 2022. https://www.libraryjournal.com/story/Public-Libraries-Tackle-Telehealth-Challenges
47 Settles C. Telehealth Services and Public Libraries: Life-Changing and Life-Saving Opportunities for Libraries to Power Telehealth Solutions in the Communities. Every Library Institute. 2021. https://www.everylibraryinstitute.org/teleheath_and_libraries_report. Accessed November 27, 2023.
48 Haque SN. Telehealth beyond COVID-19. Psychiatr Serv. 2021;72:100–103. https://doi.org/10.1176/appi.ps.202000368. Accessed October 30, 2023.32811284
49 Larson AE, Zahnd WE, Davis MM, Stange KC, Yoon J, Heintzman JD, Harvey SM. Before and during pandemic telemedicine use: an analysis of rural and urban safety-net clinics. Am J Prev Med. 2022 Dec;63(6):1031–1036. https://doi.org/10.1016/j.amepre.2022.06.012. Accessed October 30, 2023.36096960
50 Hicks L. Public Comments on CONNECT for Health Act. Alexandria, VA: Society of General Internal Medicine; January 30, 2023. https://www.sgim.org/File%20Library/SGIM/Communities/Advocacy/Legislative%20Endorsements/CONNECT-118th-Comments_FINAL.pdf (https://www.sgim.org/File%20Library/SGIM/Communities/Advocacy/Legislative%20Endorsements/CONNECT). Accessed October 30, 2023.
51 Totten AM, Womack DM, Eden KB, McDonagh MS, Griffin JC, Grusing S, Hersh WR. Telehealth: Mapping the Evidence for Patient Outcomes From Systematic Reviews. Technical Brief No. 26. Rockville, MD: Agency for Healthcare Research and Quality; June 2016. AHRQ Publication No.16-EHC034-EF. https://effectivehealthcare.ahrq.gov/sites/default/files/pdf/telehealth_technical-brief.pdf. Accessed October 30, 2023.