# Impact of COVID-19 on Nursing Homes

As the COVID-19 pandemic progressed, nursing homes drew attention due to high infection and death rates. Advanced age, underlying frailty, and communal living conditions make nursing home residents especially vulnerable.^1^ Nursing home residents include older adults and people under age 65 with physical or intellectual/developmental disabilities. Their reliance on nursing home staff for daily routines put the staff at high risk for COVID-19 infection and spread. As a result, as of June 12, 2022, more than 209,000 COVID-19 deaths (21%) have been in a long-term care facility,2 including nursing homes, assisted living facilities, intermediate care facilities for individuals with intellectual disability, and other settings.

Nursing home residents were among the first eligible populations for COVID-19 vaccine, because they are the most vulnerable age group due to chronic health conditions and communal living. COVID-19 negatively affected nursing home staff because missed workdays due to COVID-19 infection led to staff shortages and burnout, which affected the care provided to residents. Therefore, evaluation of quality measures in nursing homes is crucial to evaluate healthcare services provided during the COVID-19 pandemic.

Different types of postacute and long-term care were already described in the “Portrait of U.S. Healthcare” section. For Centers for Medicare & Medicaid Services (CMS) measures discussed in this section,” long-stay” and “short-stay” nursing homes are defined as follows:

- Long-stay nursing homes provide chronic care services, typically for patients or residents who choose to enter a nursing facility typically because they can no longer care for themselves at home. These residents tend to remain in the nursing facility anywhere from several months to several years. They may be referred to as “long-stay residents.”
- Short-stay nursing homes provide services for residents who stay fewer than 30 days. These admissions typically follow an acute care hospitalization and involve high-intensity rehabilitation or clinically complex care. These residents may be referred to as “short-stay residents.”

This section of the NHQDR will focus on the impact of COVID-19 on nursing homes. Based on analyses conducted for the NHQDR, this section provides findings such as:

- Confirmed COVID-19 cases among resident and staff were similar, but COVID-19 deaths among residents were much higher than among staff.
- Nursing home residents are more likely to receive recommended vaccines than older adults in the general population. Nursing homes overcame initial resistance to COVID-19 vaccination and had vaccination rates higher than the general population until the end of 2022.
- The COVID-19 pandemic exacerbated nursing home staff shortages, which may have negatively affected quality:
  ■ Long-stay and short-stay nursing home measures, which relied on care provided by nursing home healthcare personnel, showed changes in 2020. The rates cannot be compared with 2019, however, due to temporary changes in CMS reporting requirements.
  ■ Long-stay nursing home measures for urinary tract infection and falls, which are indicators of care, had no statistically significant changes in 2020.

## COVID-19 Cases and Deaths in Nursing Homes

❖ Confirmed COVID-19 cases among residents and staff were similar.

All nursing homes experienced high rates of COVID-19 infections, and more than 1,000 nursing homes had infection rates of 75% or higher during surge periods.^3^

The median age of nursing home workers in 2022 was 43.9 years and only 7.3% were age 65 and over.^4^ In contrast, 84.6% of long-stay and 81.1% of short-stay nursing home residents were age 65 years and over in 2017-2018.^5^ Despite the wide difference in ages among these groups, data from the Centers for Disease Control and Prevention (CDC) COVID Tracker show that surge patterns for COVID-19 infection rates were similar for nursing home staff and residents. This finding suggests that these groups shared interdependent risks for COVID-19.

CDC data, reported earlier in the NHQDR (see “Impact of COVID-19 on the Population”), show that younger adults experienced higher rates of infection than older adults, but older adults and people with disabilities were at greater risk of death from COVID-19.^6^ Younger adults contributed disproportionately to COVID-19 spread because they are active, mobile, and employed and thus in most contact with other adults, including those in nursing homes.

Figure 1 Confirmed COVID-19 cases per 1,000 resident-weeks among residents and staff, by week, May 2020-December 2022

Note: Case rates in the first half of 2020 may underestimate actual infections due to limited testing capacity then.

Source: Centers for Disease Control and Prevention, National Healthcare Safety Network, Nursing Home Covid-19 Data Dashboard, May 2020-December 2022, https://www.cdc.gov/nhsn/covid19/ltc-report-overview.html.

- The peak for COVID-19 confirmed cases occurred in late January 2022 for both residents and staff with the emergence of the Omicron variant (Figure 1).
- For residents, the highest weekly number of confirmed cases during the COVID-19 pandemic was 50,540, and the highest weekly rate of confirmed cases was 43.6 per 1,000 residents.
- For staff, the highest weekly number of confirmed cases was 71,198, and the highest weekly rate of confirmed cases was 61.4 per 1,000 resident-weeks.

❖ COVID-19 deaths among residents were much higher than deaths among staff.

Figure 2 shows COVID-19 mortality rates for nursing home residents and staff among all nursing homes. They show that COVID-19 deaths among nursing home residents exceeded deaths among staff, especially during the first year of the public health emergency (PHE) and during variant-associated surges. The relative magnitude of deaths per 1,000 residents compared with case rates was higher in December 2020 when vaccines were less widely available than in January 2022 when most nursing home residents and staff had received a vaccine.

Significant disparities in COVID-19 deaths also existed among residents in nursing homes with different facility characteristics and locations. A study of 13,312 nursing homes found that facilities with the highest percentages of non-White residents had COVID-19 death counts in 2020 that were 3.3 times higher than those with the highest percentages of White residents.^7^

These racial and ethnic disparities were also linked with characteristics of nursing homes that were more likely to have non-White residents. Such characteristics include larger nursing home size and higher local prevalence of COVID-19, signaling that some nursing homes may have had greater need for resources than others.^7^

Figure 2 COVID-19 deaths per 1,000 resident-weeks among residents and staff, by week, May 2020-December 2022

Source: Centers for Disease Control and Prevention, National Healthcare Safety Network, Nursing Home Covid-19 Data Dashboard, May 2020-December 2022, https://www.cdc.gov/nhsn/covid19/ltc-report-overview.html.

- The peak for COVID-19 deaths occurred the week ending December 20, 2020, for residents, but for staff, the peak occurred much earlier, the week ending June 21, 2020 (data not shown). Although staff had higher infection rates, residents had higher death rates due to their health conditions (Figure 2).
- For residents, the highest death count was 6,167 the week ending December 20, 2020. The highest death rate, 5.5 per 1,000 resident-weeks, also occurred that week.
- For staff, the highest death count was 69 the week ending June 21, 2020. The highest death rate, 0.1 per 1,000 resident-weeks, also occurred that week.

## Vaccines in Nursing Homes During the COVID-19 Pandemic

❖ Nursing home residents are more likely to receive recommended vaccines than older adults in the general population.

Since 2005, CMS has required nursing homes to vaccinate residents against influenza and pneumococcal disease in order to participate in Medicare and Medicaid.^8^ Thus, vaccination rates are typically higher for long- and short-stay nursing home residents than in the overall population. In addition, disparities among racial and ethnic groups in long-stay and short-stay nursing homes are narrower than in the overall population. For long-stay nursing homes, vaccination rates for pneumococcal and seasonal flu vaccines have been close to or above 90% in recent years.

Figure 3 Long-stay and short-stay nursing home residents who were assessed and appropriately given the pneumococcal vaccination and the seasonal influenza vaccine, 2013-2019, 2020, and 2021 (left) and all adults age 65 years and over who ever received pneumococcal vaccine or received influenza vaccine in the last flu season, 2019-2021 (right)

Note: Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submissions to the SNF QRP were optional. Influenza vaccination rates for adults age 65 and over use data from 2019-2020 and 2020-2021 surveys, so only two data points are shown.

Source: Centers for Medicare & Medicaid Services (CMS), Skilled Nursing Facility Quality Reporting Program (SNF QRP), Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2019, 2020, and 2021; and Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2019-2021.

- The percentage of long-stay nursing home residents who were assessed and appropriately given the seasonal influenza vaccine increased from 90.0% in 2013 to 92.4% in 2019^i^ (Figure 3). The percentage was 93% in 2020 and 90.8.% in 2021.
- The percentage of short-stay nursing home residents who were assessed and appropriately given the pneumococcal vaccination increased from 85.6% in 2013 to 86.3% in 2019. The percentage was 83.7% in 2020 and 81.2% in 2021.
- Short-stay nursing homes had lower rates than long-stay nursing homes for both pneumococcal and seasonal influenza vaccines.
- Seasonal influenza vaccine for long-stay nursing home residents was the only measure out of four vaccine measures that did not show a statistically significant change in 2020.
- Short-stay and long-stay nursing homes had higher rates than all adults age 65 years and over for both pneumococcal and seasonal influenza vaccines.

Figure 4 Long-stay nursing home residents who were assessed and appropriately given the seasonal influenza vaccine by race/ethnicity, 2019 and 2020 (left) and all adults age 65 years and over who received influenza vaccine in the last flu season, by race/ethnicity, 2019-2020 (right)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submissions to the SNF QRP were optional. Influenza vaccination rates for adults age 65 and over use data from 2019-2020 and 2020-2021 surveys.

Source: Centers for Medicare & Medicaid Services (CMS), Skilled Nursing Facility Quality Reporting Program (SNF QRP), Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2019 and 2020; and Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2019-2020.

- Overall, the percentage of long-stay nursing home residents who received an influenza vaccine was much higher than the percentage of all adults age 65 years and over who received an influenza vaccine in the last flu season (Figure 4).
- In 2019 and 2020, the percentage of long-stay nursing home residents who received an influenza vaccine was highest for non-Hispanic (NH)-Asian people. The percentage of adults age 65 and over who received an influenza vaccine in the last flu season was also highest for NH-Asian people in 2020.
- In 2020, the percentages were lowest for NH-Black long-stay nursing home residents and NH-Black adults age 65 and over.
- The percentage of NH-American Indian or Alaska Native (AI/AN) adults age 65 and over who received an influenza vaccination in the last flu season increased 54% from 49.8% in 2019 to 76.6% in 2020.

Figure 5 Short-stay nursing home residents who had flu vaccination appropriately given, by race/ethnicity, 2019 and 2020 (left) and all adults age 65 years and over who received influenza vaccine in the last flu season, by race/ethnicity, 2019-2020 (right)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submissions to the SNF QRP were optional. Influenza vaccination rates for adults age 65 and over use data from 2019-2020 and 2020-2021 surveys.

Source: Centers for Medicare & Medicaid Services (CMS), Skilled Nursing Facility Quality Reporting Program (SNF QRP), Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2019 and 2020; and Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2019-2020.

- Overall, the percentage of short-stay nursing home residents who received an influenza vaccine in the last flu season was much higher than the percentage of all adults age 65 years and over who received an influenza vaccine in the last flu season (Figure 5).
- In 2020, the percentage of short-stay nursing home residents who received an influenza vaccine in the last flu season was highest for NH-Asian people. The percentage of adults age 65 and over who had an influenza vaccine in the last flu season was also highest for NH-Asian people.
- In 2020, the percentages were lowest for NH-Black short-stay nursing home residents and for NH-Black adults age 65 years and over.

Figure 6 Long-stay nursing home residents who were assessed and appropriately given the pneumococcal vaccination, by race/ethnicity, 2019, 2020, and 2021 (left) and all adults age 65 years and over who ever received pneumococcal vaccine, by race/ethnicity, 2019-2021 (right)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submissions to the SNF QRP were optional.

Source: Centers for Medicare & Medicaid Services (CMS), Skilled Nursing Facility Quality Reporting Program (SNF QRP), Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2019, 2020, and 2021; and Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2019-2021.

- In 2019, 2020, and 2021, the percentage of long-stay nursing home residents who were assessed and appropriately given the pneumococcal vaccination was highest for NH-Asian residents and lowest for NH-Black residents (Figure 6).
- In 2019, 2020, and 2021, the percentage of adults age 65 and over who were assessed and appropriately given the pneumococcal vaccination was highest for NH-White people. In 2020 and 2021, the percentage was lowest for Hispanic people.

Figure 7 Short-stay nursing home residents who were assessed and appropriately given the pneumococcal vaccination by race/ethnicity, 2019, 2020, and 2021 (left) and all adults age 65 years and over who ever received pneumococcal vaccine, by race/ethnicity, 2019-2021 (right)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submissions to the SNF QRP were optional.

Source: Centers for Medicare & Medicaid Services (CMS), Skilled Nursing Facility Quality Reporting Program (SNF QRP), Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2019, 2020, and 2021; and Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2019-2021.

- In 2021, the percentage of short-stay nursing home residents who were assessed and appropriately given the pneumococcal vaccination was highest for Hispanic people and lowest for NH-Black people (Figure 7).
- From 2019 to 2021, the percentage of adults age 65 and over who ever received pneumococcal vaccination was highest for NH-White people.
- In 2021, the percentage of short-stay nursing home residents who were assessed and appropriately given the pneumococcal vaccination was highest for Hispanic people while the percentage of adults age 65 and over who were given the vaccine was lowest for Hispanic people.

❖ Nursing homes overcame initial resistance to COVID-19 vaccination and had vaccination rates higher than the general population until the end of 2022.

The COVID-19 vaccine became available in December 2020, and older people were advised to receive vaccines to protect themselves and others.^9^ CDC also recommended that people who live and work in long-term care settings receive and stay up to date with COVID-19 vaccines.^10^ Some people questioned the safety and effectiveness of the vaccines and, in some cases, residents and staff of nursing homes initially resisted getting the vaccination.^11^

While nursing homes made significant progress in vaccinating their residents in the months after COVID-19 vaccines became available, approximately one in five nursing home staff were not vaccinated at the end of 2021. In response, CMS amended federal regulations at 42 CFR §483.80 to require that nursing home personnel be fully vaccinated against COVID-19.^12^

The regulations allowed nursing homes to grant staff exemptions from the vaccination requirements based on federal law (e.g., for specific medical and religious reasons). But they required nursing homes to track and securely document the vaccination status of staff, exemptions requested, and exemptions granted.

The effective date of the regulations varied by state, but all states had to comply by March 21, 2022.13 As of March 2022, 12% of nursing facilities nationally reported 100% staff vaccination rates, and 39% of facilities reported rates over 90% but less than 100%. The remaining 49% of facilities reported rates of 90% or below.^14^ Vaccination, along with other infection control measures, is credited with a decrease in COVID-19 risk in nursing homes.^15^

Figure 8 Weekly rate of nursing home residents and healthcare personnel who received a completed COVID-19 vaccination at any time, May 2021-December 2022

Source: Centers for Medicare & Medicaid Services, COVID-19 Nursing Home Data, May 2021-December 2022. https://data.cms.gov/covid-19/covid-19-nursing-home-data.

- In the first week of June 2021, shortly after COVID-19 vaccines became available for all adults in the United States, 79% of nursing home residents had received a completed COVID-19 vaccination at any time. The percentage of nursing home healthcare personnel who had received a completed COVID-19 vaccination was 57% (Figure 8).
- In mid-August 2021, during the surge associated with the Delta variant, 83% of nursing home residents were vaccinated and 63% of nursing home healthcare personnel were vaccinated.
- In the first week of November 2021, after CMS mandated COVID vaccination, 86% of nursing home residents were vaccinated and 76% of nursing home healthcare personnel were vaccinated.
- In mid-January 2022, during the surge associated with the Omicron variant, 87% of nursing home residents were vaccinated and 84% of nursing home healthcare personnel were vaccinated.
- During the last week of December 2022, by the end of the analytic period shown in Figure 8, 86% of nursing home residents were vaccinated and 88% of nursing home healthcare personnel were vaccinated.

## Staff Shortages During the COVID-19 Pandemic

❖ The COVID-19 pandemic exacerbated nursing home staff shortages.

Figure 9 Number of workers employed and at work in nursing and residential care facilities, January 2016-January 2023

Source: Bureau of Labor Statistics, Current Employment Statistics (National), January 2016-January 2023. Accessed at https://www.bls.gov/ces/data/ on August 2, 2023.

- In January 2023, the nursing home and residential care workforce had 3.1 million workers, down 8.4% from levels reported in January 2020 (Figure 9).

Nursing homes were challenged by staffing concerns before the pandemic,^16^ and COVID-19 exacerbated staffing shortages. Infections led nursing home workers to leave the workplace for multiple weeks to avoid infecting residents or their colleagues. Some died because of their infections, permanently removing them from the workforce.

Among other nursing home workers, fear of infection, competing demands outside the workplace, and burnout resulting from staff shortages led to further workforce attrition. To fill the gap, nursing home staff may not have been adequately trained. Poorly trained staff are more likely to neglect important resident needs and cause harm due to their lack of knowledge.^17^

Adequate staffing is critical to providing safe and high-quality healthcare services, especially for people with chronic conditions. Yet more than one in four (28%) nursing facilities nationally reported staffing shortages as of March 2022, ranging from 63% in Alaska to 3% in California.^14^

Figure 10 Monthly percentage of nursing homes with nursing staff, clinical staff, aide, and other staff shortages (top) and monthly sum of staff weekly confirmed COVID-19 cases (bottom), May 2020-April 2023

Note: “Other Staff” refers to staff not included in the other categories, regardless of clinical responsibility or resident contact, such as environmental services staff.

Source: Centers for Medicare & Medicaid Services, COVID-19 Nursing Home Data, May 2020-April 2023. https://data.cms.gov/covid-19/covid-19-nursing-home-data.

- Between May 2020 and April 2023, nursing home staff shortages were smallest among clinical staff, including physicians, physician assistants, and advanced practice nurses, and were largest among nursing staff and aides (Figure 10). Nursing staff include registered nurses, licensed practical nurses, and licensed vocational nurses. Aides include certified nursing assistants, nursing aides, medication aides, and medication technicians.
- Although shortages were highest among aides and nursing staff, people usually associate staff shortages with physicians and nurses.
- The peak of the shortage occurred in January 2022, especially for nursing staff and aides, which was also the peak for COVID-19 confirmed cases.

Women historically account for 80% of all employees in nursing and residential care facilities. Starting in September 2021, the percentage of women working in nursing and residential care decreased to 79%, as more women left the workplace than men. Closing of daycare facilities and schools may have contributed to more women leaving the labor market and accelerating the staff shortages in nursing homes and residential care facilities.^18^

Figure 11 Number of employees working in nursing and residential care facilities, overall and by gender, 2013-2022

Source: Bureau of Labor Statistics, Employment, Hours, and Earnings from the Current Employment Statistics Survey (national), nursing and residential care facilities, 2013-2022.

- The total number of employees of nursing and residential care facilities continuously increased until 2019 (Figure 11).
- The total number of employees dropped 11% from 3,374.1 in thousands in 2019 to 3,012.7 in thousands in 2022, and the number of female employees dropped 12% from 2,705.0 in thousands in 2019 to 2,391.1 in thousands in 2022. The number of male employees dropped 7% from 669.1 in thousands in 2019 to 621.6 in thousands in 2022.

## Impact of Nursing Home Staff Shortages one Quality

❖ Nursing home staff shortages may have negatively affected quality.

Staffing shortages can affect the care provided to nursing home residents, as many residents depend on other people for assistance with essential tasks such as meals, personal hygiene, and emotional support. Although family/caregiver visitors and volunteers often provide additional support, as well as advocacy for residents, federal guidance restricted visitor access during the COVID-19 PHE to limit virus transmission.^19^ When support from family and friends was lost, the effect of understaffing in nursing homes became apparent in quality of care.

Between 2013 and 2019, in the years leading up to the COVID-19 pandemic, long- and short-stay nursing homes had been improving on many measures. Some measures assessed tasks that require sustained attention from nursing home staff, such as:

- Percentage of staff who had moderate to severe pain (which assesses periodically reviewing and attending to residents’ symptoms).
- Percentage of residents who report needing help with daily activities; and
- Percentage of residents who report worsening ability to move independently.

Other measures assess avoidance of potentially harmful interventions, such as percentage of residents with urinary tract infections, which can be modified by avoiding unnecessary urinary catheters. Other measures assess avoidance of unsupervised activity, such as percentage of residents with serious falls.

NHQDR data suggest that limited nursing home staffing may have adversely affected nursing home quality, as measures of tasks requiring sustained attention from staff worsened during the COVID-19 PHE. However, measures involving either avoidance of interventions (such as urinary tract infection rates) or limiting resident mobility (such as serious falls) did not change.

The data also show continued healthcare disparities between nursing home residents in nonmetropolitan communities and those in metropolitan areas, as well as disparities among nursing home residents of different races and ethnicities. But relative disparities among groups remained stable, suggesting that staffing-related concerns had similar effects on quality of care delivered to people in different urban/rural settings and of different races and ethnicities.

## Findings

❖ Long-stay and short-stay nursing home measures, which reflect care provided by nursing home healthcare personnel, showed changes in 2020 but cannot be compared with 2019 due to the temporary change in CMS reporting requirements.

For the nursing home quality measures in this year’s NHQDR, 2020 rates cannot be compared with prior years. Due to COVID-19, CMS temporarily exempted providers from submitting Minimum Data Set (MDS) Assessment Data for quarter 1 and quarter 2, 2020. In general, total sample size decreased about 20% from 2019 to 2020.

NH-Asian sample size decreased more than any other racial/ethnic group. For example, the sample size for long-stay nursing home residents with a urinary tract infection decreased 26% for NH-Asian, 20% for NH-White and multiracial, 16% for NH-Native Hawaiian/Pacific Islander (NHPI), 15% for NH-American Indian or Alaska Native (AI/AN) and Black, and 10% for Hispanic, all races.

Disparities among racial/ethnic groups are not discussed indepth because most (70%-75%) of the nursing home population is NH-White.

Figure 12 Long-stay nursing home residents with moderate to severe pain, by location of facility, 2013-2017, 2019, 2020, and 2021 (lower rates are better)

Note: Data for 2018 have not been analyzed. Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submissions were optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2019 and 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2017, 2019, 2020, and 2021.

- The overall percentage of long-stay nursing home residents with moderate to severe pain decreased 33% from 9.2% in 2013 to 6.2% in 2017. The percentage was 7.0% in 2019, 7.6% in 2020, and 8.0% in 2021 (Figure 12).
- The percentage of metropolitan long-stay nursing home residents with moderate to severe pain decreased 33% from 8.4% in 2013 to 5.6% in 2017. The percentage was 6.1% in 2019, 6.7% in 2020, and 7.1% in 2021.
- The percentage of nonmetropolitan long-stay nursing home residents with moderate to severe pain decreased 28% from 11.4% in 2013 to 8.2% in 2017. The percentage was 10.0% in 2019, 10.9% in 2020, and 11.5% in 2021.

Figure 13 Long-stay nursing home residents with moderate to severe pain, by race/ethnicity, 2013-2017, 2019, 2020, and 2021 (lower rates are better)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Data for 2018 have not been analyzed. Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submissions were optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2019 and 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS 3.0), 2013-2017, 2019, 2020, and 2021.

- The percentage of NH-AI/AN long-stay nursing home residents with moderate to severe pain decreased 19% from 12.9% in 2013 to 10.5% in 2017 (Figure 13). The percentage of NH-AI/AN long-stay nursing home residents with moderate to severe pain was 11.9% in 2019, 12.5% in 2020, and 13.2% in 2021.
- The percentage of NH-Asian long-stay nursing home residents with moderate to severe pain decreased 50% from 3.0% in 2013 to 1.5% in 2017. The percentage was 1.7% in 2019, 1.5% in 2020, and 1.5% in 2021.
- The percentage of NH-White long-stay nursing home residents with moderate to severe pain was 8.1% in 2019, 8.9% in 2020, and 9.4% in 2021.

Figure 14 Short-stay nursing home residents with moderate to severe pain, by location of facilities, 2013-2017, 2019, 2020, and 2021 (lower rates are better)

Note: Data for 2018 have not been analyzed. Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submissions were optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2019 and 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2017, 2019, 2020, and 2021.

- The overall percentage of short-stay nursing home residents with moderate to severe pain decreased 36% from 17.7% in 2013 to 11.3% in 2017 (Figure 14).
- The percentage of metropolitan short-stay nursing home residents with moderate to severe pain decreased 37% from 17.4% in 2013 to 10.9% in 2017. The percentage was 14.5% in 2019, 14.6% in 2020, and 14.4% in 2021.
- The percentage of nonmetropolitan short-stay nursing home residents with moderate to severe pain decreased 31% from 19.6% in 2013 to 13.6% in 2017. The percentage was 18.6% in 2019 and 19.4% in 2020 and 2021.

Figure 15 Short-stay nursing home residents with moderate to severe pain, by race/ethnicity, 2013-2017, 2019, 2020, and 2021 (lower rates are better)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Data for 2018 have not been analyzed. Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submissions were optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2019 and 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2017, 2019, 2020, and 2021.

- The percentage of NH-AI/AN short-stay nursing home residents with moderate to severe pain decreased 29% from 21.7% in 2013 to 15.4% in 2017 (Figure 15). The percentage was 19.8% in 2019, 20.6% in 2020, and 21.4% in 2021.
- The percentage of NH-Asian short-stay nursing home residents with moderate to severe pain decreased 52% from 9.3% in 2013 to 4.5% in 2017.
- The percentage of NH-Native Hawaiian/Pacific Islander (NHPI) short-stay nursing home residents with moderate to severe pain was 9.1% in 2019, 10.5% in 2020, and 9.6% in 2021.

Figure 16 Long-stay nursing home residents whose need for help with daily activities increased, by location of facility, 2013-2019, 2020, and 2021 (lower rates are better)

Note: Data reflect care for the latest episode of a beneficiary in the calendar year. Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submission was optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2019, 2020, and 2021.

- The overall percentage of long-stay nursing home residents with an increased need for help with daily activities decreased 13% from 22.8% in 2013 to 19.9% in 2019. The percentage was 23.7% in 2020 and 19.6% in 2021 (Figure 16).
- The percentage of metropolitan long-stay nursing home residents with an increased need for help with daily activities decreased 13% from 22.4% in 2013 to 19.5% in 2019. The percentage was 23.4% in 2020, and 19.3% in 2021.
- The percentage of nonmetropolitan long-stay nursing home residents with an increased need for help with daily activities decreased 12% from 24.1% in 2013 to 21.2% in 2019. The percentage was 24.9% in 2020 and 20.5% in 2021.

Figure 17 Long-stay nursing home residents whose need for help with daily activities increased, by race/ethnicity, 2013-2019, 2020, and 2021 (lower rates are better)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Data reflect care for the latest episode of a beneficiary in the calendar year. Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submission was optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2019, 2020, and 2021.

- The percentage of NH-White long-stay nursing home residents with an increased need for help with daily activities decreased 13% from 23.1% in 2013 to 20.2% in 2019. The percentage was 24.0% in 2020 and 19.9% in 2021 (Figure 17).
- The percentage of NH-Asian long-stay nursing home residents with an increased need for help with daily activities decreased 13% from 19.5% in 2013 to 16.9% in 2019. The percentage was 21.6% in 2020 and 15.1% in 2021.
- The percentage of NH-NHPI long-stay nursing home residents with an increased need for help with daily activities decreased 16% from 20.6% in 2013 to 17.3% in 2019. The percentage was 20.2% in 2020 and 16.2% in 2021.

Figure 18 Long-stay nursing home residents whose ability to move independently worsened, by location of facility, 2013-2019, 2020, and 2021 (lower rates are better)

Note: Data reflect care for the latest episode of a beneficiary in the calendar year. Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submission was optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2019, 2020, and 2021.

- The overall percentage of long-stay nursing home residents whose ability to move independently worsened decreased 5% from 24.5% in 2013 to 23.2% in 2019. The percentage was 30.3% in 2020 and 24.1% in 2021 (Figure 18).
- The percentage of metropolitan long-stay nursing home residents whose ability to move independently worsened decreased 6% from 24.5% in 2013 to 23.1% in 2019. The percentage was 30.5% in 2020 and 24.0% in 2021.
- The percentage of nonmetropolitan long-stay nursing home residents whose ability to move independently worsened decreased 5% from 24.7% in 2013 to 23.5% in 2019. The percentage was 29.7% in 2020 and 24.8% in 2021.

Figure 19 Long-stay nursing home residents whose ability to move independently worsened, by race/ethnicity, 2013-2019, 2020, and 2021 (lower rates are better)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Data reflect care for the latest episode of a beneficiary in the calendar year. Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submission was optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2019, 2020, and 2021.

- The percentage of NH-White long-stay nursing home residents whose ability to move independently worsened decreased 5% from 25.1% in 2013 to 23.8% in 2019. The percentage was 30.6% in 2020 and 25.0% in 2021 (Figure 19).
- The percentage of Hispanic long-stay nursing home residents whose ability to move independently worsened decreased 8% from 22.3% in 2013 to 20.6% in 2019. The percentage was 26.4% in 2020 and 19.8% in 2021.
- The percentage of NH-Asian long-stay nursing home residents whose ability to move independently worsened decreased 6% from 20.1% in 2013 to 18.9% in 2019. The percentage was 27.1% in 2020 and 19.3% in 2021.
- The percentage of NH-NHPI long-stay nursing home residents whose ability to move independently worsened increased 6% from 19.8% in 2013 to 20.9% in 2019. The percentage was 29.6% in 2020 and 21.0% in 2021.

❖ Critical long-stay nursing home measures for urinary tract infection and falls, which are indicators of care provided in nursing homes, had no statistically significant changes in 2020.

Figure 20 Long-stay nursing home residents with a urinary tract infection, by location of facility, 2013-2019, 2020, and 2021 (lower rates are better)

Note: Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submission was optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2019, 2020, and 2021.

- The overall percentage of long-stay nursing home residents with a urinary tract infection decreased 63% from 4.9% in 2013 to 1.8% in 2019. The percentage was 1.9% in 2020 and 1.7% in 2021 (Figure 20).
- The percentage of metropolitan long-stay nursing home residents with a urinary tract infection decreased 66% from 4.7% in 2013 to 1.6% in 2019. The percentage was 1.7% in 2020 and 1.5% in 2021.
- The percentage of nonmetropolitan long-stay nursing home residents with a urinary tract infection decreased 56% from 5.5% in 2013 to 2.4% in 2019. The percentage was 2.5% in 2020 and 2.3% in 2021.

Figure 21 Long-stay nursing home residents with a urinary tract infection, by race/ethnicity, 2013-2019, 2020, and 2021 (lower rates are better)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submission was optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2019, 2020, and 2021.

- The percentage of NH-NHPI long-stay nursing home residents with a urinary tract infection decreased 80% from 4.3% in 2013 to 0.87% in 2019. The percentage was 1.5% in 2020 and 1.1% in 2021 (Figure 21).
- The percentage of Hispanic long-stay nursing home residents with a urinary tract infection decreased 72% from 4.3% in 2013 to 1.2% in 2019. The percentage was also 1.2% in 2020 and 1.0% in 2021.

Figure 22 Long-stay nursing home patients experiencing one or more falls with major injury, by location of facilities, 2013-2019, 2020, and 2021 (lower rates are better)

Note: Data reflect care for the latest episode of a beneficiary in the calendar year. Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submission was optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2019, 2020, and 2021.

- The overall percentage of long-stay nursing home patients experiencing one or more falls with major injury showed no statistically significant changes from 2013 to 2019, remaining at 0.6%. The percentage was 0.55% in 2020 and 0.58% in 2021 (Figure 22).
- The percentage of metropolitan long-stay nursing home patients experiencing one or more falls with major injury showed no statistically significant changes, remaining at 0.55% in 2013 and 2019. The percentage was 0.51% in 2020 and 0.52% in 2021.
- The percentage of nonmetropolitan long-stay nursing home patients experiencing one or more falls with major injury increased 3% from 0.75% in 2013 to 0.77% in 2019. The percentage was 0.71% in 2020 and 0.77% in 2021.

Figure 23 Long-stay nursing home patients experiencing one or more falls with major injury, by race/ethnicity, 2013-2019, 2020, and 2021 (lower rates are better)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native.

Note: Data reflect care for the latest episode of a beneficiary in the calendar year. Due to COVID-19, CMS temporarily exempted providers from submitting MDS Assessment Data for quarter 1 and quarter 2, 2020. Submission was optional. Discharges on or after July 1, 2020, may have missing MDS admission data. Data for 2020 cannot be compared with previous data due to the COVID-19 exemption in the numerator and a change in the denominator. The data did not include the Native Hawaiian/Pacific Islander population and estimates did not meet the criteria for statistical reliability, data quality, or confidentiality for non-Hispanic-multiracial groups for 2017 and 2021.

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Resident Assessment Files, Minimum Data Set (MDS) 3.0, 2013-2019, 2020, and 2021.

- The percentage of NH-AI/AN long-stay nursing home patients experiencing one or more falls with major injury showed no statistically significant changes, at 0.75% in 2013 and 0.76% in 2019. The percentage was 0.79% in 2020 and 0.74% in 2021 (Figure 23).
- The percentage of NH-Black long-stay nursing home patients experiencing one or more falls with major injury increased from 0.23% in 2013 to 0.26% in 2019. The percentage was 0.21% in 2020 and 0.24% in 2021.

## Discussion and Conclusions

The COVID-19 PHE revealed vulnerabilities in nursing homes and residential care communities. NHQDR data show that case and death rates among nursing home residents exceeded rates reported by other sectors in the healthcare delivery system. Case rates and deaths among nursing home workers were also higher than rates experienced by healthcare workers in other sectors and by the overall population.

A range of issues may have contributed to nursing homes’ vulnerability, including:

- Staffing shortages,
- Insufficient training of nursing home staff,
- Lack of personal protective equipment (PPE),
- Limited testing capacity to guide response to outbreaks, and
- Inconsistent adherence to policies intended to limit disease transmission, such as hand washing and masking.^20^

In addition, older facility designs may have limited nursing homes’ ability to adequately quarantine newly admitted residents and isolate infected current residents.^20^

Staff shortages had been a particular concern before the COVID-19 PHE, but the issue gained prominence during the pandemic. Although the nursing home workforce was shrinking due to economic forces before the pandemic, limited access to PPE exacerbated the problem by increasing workers’ risk of infection, resulting in missed workdays. Concurrently, lockdowns intended to limit virus transmission reduced residents’ access to friends and family, who may have partly compensated for staffing limitations before the pandemic.

Disruptions in CMS’s data monitoring systems prevent us from directly trending data between 2019 and 2020. But these factors appeared to negatively affect measures such as long-stay nursing home residents with an increased need for help with daily activities and long-stay nursing home residents whose ability to move independently worsened. Residents may have received lesser care for issues such as these that require sustained attention from nursing home staff. If so, nursing home residents may continue to experience suboptimal care because staffing shortages persist, even though the PHE has ended.

Several initiatives sought to improve nursing home care through training and mentorships during the COVID-19 pandemic. For example, AHRQ invested $237 million of the Provider Relief Fund to launch the AHRQ ECHO National Nursing Home COVID-19 Action Network (the Network). This partnership between AHRQ, the University of New Mexico’s ECHO Institute, and the Institute for Healthcare Improvement fielded 99 training centers under the Network. The centers provided training and mentorship to more than 9,000 nursing homes (58% of 15,400 eligible nursing homes) and nearly 32,000 nursing home staff in all 50 states, the District of Columbia, and Puerto Rico.^1^ The Network’s 16-week Training and Mentorship Program ultimately benefited 1.7 million nursing home residents.

Most of all, adequate staffing levels should be restored to provide proper healthcare to nursing home residents. The impact of staff shortages, including nursing home staff shortages, will be addressed in an upcoming Data Spotlight on the Healthcare Workforce.

## Resources

COVID-19 Nursing Home Data (https://data.cms.gov/covid-19/covid-19-nursing-home-data) has information on COVID-19 reported by nursing homes to CDC’s National Healthcare Safety Network COVID-19 Long-Term Care Facility Module.

AHRQ’s Role in Nursing Home COVID-19 Response (https://www.ahrq.gov/sites/default/files/wysiwyg/nursing-home/materials/ahrq-network-factsheet.pdf) describes the COVID-19 Action Network and its attempt to remediate the lack of adequate training among nursing home workers to care for residents with and without COVID-19. The Network’s goals are to:

- Keep SARS-COV 2 out of nursing homes.
- Promote early identification of COVID-19 infection among residents and staff.
- Prevent spread between staff, residents, and visitors.
- Provide safe and appropriate care to residents with COVID-19.
- Help nursing home staff implement best practice safety measures.
- Reduce social isolation for residents, families, caregivers, and staff.

CMS Nursing Home Quality Initiative (https://www.cms.gov/medicare/quality/nursing-homeimprovement) focuses on the Minimum Data Set, Care Compare, payment, quality measures, and survey and certification information for providers. The website for the initiative provides information about quality measures shown on the Care Compare website, which allows consumers, providers, states, and researchers to compare information on nursing homes. Many nursing homes have already made significant improvements in the care provided to residents by taking advantage of these materials and the support of Quality Improvement Organization staff.

CMS Skilled Nursing Facility (SNF) Quality Reporting Program (QRP) Measures and Technical Information (https://www.cms.gov/medicare/quality/snf-quality-reporting-program/measures-and-technical-information) provides information on the measures reported by SNFs in accordance with the SNF QRP. This web page includes descriptions of each measure, links to measure specifications, measure updates, and other measure-related information. The page is updated as measure updates become available.

i Unless noted otherwise, for trend analyses, data points under each figure only report differences that are statistically significant (i.e., p value less than 0.1) and show an average annual percentage change greater than 1% per year. For comparison between two populations, data points under each figure only report differences that are statistically significant (i.e., p value less than 0.05) and have a relative difference between the populations of at least 10%, unless noted otherwise. Readers may learn more about NHQDR’s reporting methodology in Appendix A at https://www.ahrq.gov/research/findings/nhqrdr/nhqdr23/index.html.

## References

1 AHRQ’s Role in Nursing Home COVID-19 Response. https://www.ahrq.gov/sites/default/files/wysiwyg/nursing-home/materials/ahrq-network-factsheet.pdf. Accessed October 27, 2023.
2 Chidambaram P. Over 200,000 residents and staff in long-term care facilities have died from COVID-19. KFF Policy Watch; February 3, 2022. https://www.kff.org/policy-watch/over-200000-residents-and-staff-in-long-term-care-facilities-have-died-from-covid-19/. Accessed October 27, 2023.
3 U.S. Department of Health and Human Services, Office of Inspector General. More Than a Thousand Nursing Homes Reached Infection Rates of 75 Percent or More in the First Year of the COVID-19 Pandemic; Better Protections Are Needed for Future Emergencies. January 19, 2023. OEI-02-20-00491. https://oig.hhs.gov/oei/reports/OEI-02-20-00491.asp#:~:text=AddThis%20Sharing%20Buttons-,More%20Than%20a%20Thousand%20Nursing%20Homes%20Reached%20Infection%20Rates%20of,Are%2 0Needed%20for%20Future%20Emergencies. Accessed October 27, 2023.
4 Bureau of Labor Statistics. Labor Force Statistics From the Current Population Survey. Last modified January 2023. https://www.bls.gov/cps/cpsaat18b.htm. Accessed October 27, 2023.
5 Sengupta M, Lendon JP, Caffrey C, Melekin A, Singh P. Post-Acute and Long-Term Care Providers and Services Users in the United States, 2017-2018. Vital Health Stat 3. 2022 May;47:1–93. https://www.cdc.gov/nchs/data/series/sr_03/sr03-047.pdf. Accessed October 27, 2023.
6 Yuan Y, Thierry JM, Bull-Otterson L, Yeargin-Allsopp M, Clark KE N, Rice C, Ritchey M, Ryerson AB. COVID-19 cases and hospitalizations among Medicare beneficiaries with and without disabilities — United States, January 1, 2020–November 20, 2021. MMWR Morb Mortal Wkly Rep. 2022;71:791–796. https://www.cdc.gov/mmwr/volumes/71/wr/mm7124a3.htm. Accessed November 7, 2023.35709015
7 Gorges RJ, Konetzka RT. Factors associated with racial differences in deaths among nursing home residents with COVID-19 infection in the U.S. JAMA Netw Open. 2021 Feb 1;4(2):e2037431. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7876590/. Accessed October 27, 2023.33566110
8 CMS Newsroom. CMS Will Require Nursing Homes To Vaccinate Residents Against the Flu. October 7, 2005. https://www.cms.gov/newsroom/press-releases/cms-will-require-nursing-homes-vaccinate-residents-against-flu#:~:text=Nursing%20homes%20serving%20Medicare%20and,CMS%20in%20today's%20Federal%20Register. Accessed October 27, 2023.
9 U.S. Department of Health and Human Services. COVID-19 Vaccines. Last reviewed September 2023. https://www.hhs.gov/coronavirus/covid-19-vaccines/index.html. Accessed October 27, 2023.
10 Centers for Disease Control and Prevention. COVID-19 Vaccines for Long-Term Care Residents. Last updated September 2023. https://www.cdc.gov/coronavirus/2019-ncov/vaccines/recommendations/LTCF-residents.html.Accessed October 27, 2023.
11 Laise E. Vaccine Push at Nursing Homes Meets Resistance. Barron’s. 2020 Dec 17. https://www.barrons.com/articles/crisis-hit-care-homes-face-covid-vaccine-challenge-51608192341.
12 Infection Control. 42 CFR §483.80. https://www.ecfr.gov/current/title-42/chapter-IV/subchapter-G/part-483/subpart-B/section-483.80. Accessed October 27, 2023.
13 U.S. Department of Health and Human Services, Office of Inspector General. COVID-19 Vaccination Status of Nursing Home Staff. https://oig.hhs.gov/reports-and-publications/workplan/summary/wp-summary-0000664.asp#:~:text=CMS%20amended%20Federal%20regulations%20at,specific%20medical%20and%20religious%20reasons). Accessed October 27, 2023.
14 Chidambaram P, Musumeci MB. Nursing Facility Staff Vaccinations, Boosters, and Shortages After Vaccination Deadlines Passed. KFF; May 16, 2022. https://www.kff.org/coronavirus-covid-19/issue-brief/nursing-facility-staff-vaccinations-boosters-and-shortages-after-vaccination-deadlines-passed/#:~:text=As%20of%20the%20end%20of,25%25%20(Figure%205). Accessed October 27, 2023.
15 Yurkofsky M, Ouslander JG. COVID-19: Management in Nursing Homes. UpToDate. 2023 Oct 2. https://www.uptodate.com/contents/covid-19-management-in-nursing-homes.
16 U.S. Nursing Assistants Employed in Nursing Homes: Key Facts. New York: PHI; 2019. https://www.phinational.org/resource/u-s-nursing-assistants-employed-in-nursing-homes-key-facts-2019/.October 27, 2023.
17 Inadequate Training in Nursing Homes: Patients Pay the Price for the Poor Training of Nursing Home Staff. Last modified September 2023. https://nursinghomesabuse.org/nursing-home-neglect/inadequate-training/#:~:text=Staff%20who%20are%20untrained%20in,to%20neglect%20important%20patient%20needs. Accessed October 27, 2023.
18 Fry R. Some Gender Disparities Widened in the U.S. Workforce During the Pandemic. Pew Research Center; January 13, 2022. Richard Fry. https://www.pewresearch.org/short-reads/2022/01/14/some-gender-disparities-widened-in-the-u-s-workforce-during-the-pandemic/. Accessed October 27, 2023.
19 Centers for Medicare & Medicaid Services. Memorandum on Nursing Home Visitation – COVID-19. Ref: QSO-20-39-NH; September 17, 2020, revised May 8, 2023. https://www.cms.gov/files/document/qso-20-39-nh-revised.pdf. Accessed October 27, 2023.
20 Andersen LE, Tripp L, Perz JF, Stone ND, Viall AH, Ling SM, Fleisher LA. Protecting nursing home residents from COVID-19: federal strike team findings and lessons learned. NEJM Catalyst. 2021 June 28. https://catalyst.nejm.org/doi/full/10.1056/CAT.21.0144. Accessed October 27, 2023.