# Impact of COVID-19 on Ambulatory Care

Ambulatory care is provided by healthcare professionals in outpatient settings. These settings include medical offices and clinics, ambulatory surgery centers, hospital outpatient departments, and dialysis centers. The scope of ambulatory care has expanded over the past decade, as the volume and complexity of interventions have expanded. Safe, high-quality ambulatory care requires complex information management and care coordination across multiple settings, especially for patients with chronic illnesses.^1^

In 2019, physician and clinical services expenditures, which cover services provided in establishments operated by doctors of medicine and doctors of osteopathy, in outpatient care centers was $767.9 billion. In 2021, this total increased 5.6% to $864.6 billion, slower growth than the 6.6% in 2020.^2,3^

This special emphasis topic focuses on the impact of COVID-19 on two exemplar services provided in ambulatory care settings: diabetes management and cancer screening. Findings follow:

- During the COVID-19 pandemic, Hispanic people were less likely to delay both medical and dental care compared with non-Hispanic (NH) White people. Similarly, micropolitan area residents were less likely to delay both medical and dental care compared with large fringe metropolitan area residents.
- Despite the challenges to ambulatory care caused by the COVID-19 pandemic, changes to receipt of recommended diabetes care were minimal for patients in most locations during the first year of the pandemic. The one measure of recommended care for people diagnosed with diabetes that decreased was the percentage of people who had their feet checked for sores or irritation in the calendar year. From 2002 to 2019, worsening trends were observed among residents of large central, large fringe, and medium metropolitan areas. From 2002 to 2020, residents of all four metropolitan areas showed worsening trends.
- Among ethnic groups, in 2021, NH-Black women ages 50-74 were more likely to receive a mammogram in the last 2 years compared with NH-White women. On the other hand, NH-Asian women were less likely to receive a mammogram compared with NH-White women. Women residing in micropolitan and noncore areas were less likely to receive a mammogram compared with women in large fringe metropolitan areas.
- In 2021, Hispanic, NH-Asian, and NH-Black women were all less likely to receive a Pap smear or human papillomavirus test compared with NH-White women.

To evaluate ambulatory care delivery during the COVID-19 public health emergency (PHE), this section highlights quality of preventive care delivered to two exemplar populations: chronic disease management for people diagnosed with diabetes and cancer screening for at-risk groups.

## Delayed Care Due to COVID-19

During the early stages of the 2019 coronavirus (COVID-19) outbreak, the Centers for Medicare & Medicaid Services recommended that all elective surgeries and nonessential medical, surgical, and dental procedures be delayed.^4^ In addition, to limit the spread of COVID-19, CMS recommended that healthcare providers encourage patients to delay in-person care for nonemergency services. This recommendation was to protect others while also limiting one’s own exposure to the virus.^4^

Nearly one-third of U.S. adults reported having delayed or avoided routine medical care, which could reflect adherence to community mitigation efforts such as stay-at-home orders, temporary closures of health facilities, or additional factors. However, if routine care avoidance were sustained, adults could miss opportunities for management of chronic conditions, receipt of routine vaccinations, or early detection of new conditions, which might worsen outcomes.^5^

Figure 1 People delayed in getting medical care due to the coronavirus pandemic, by location and age (top) and by ethnicity and disability status (bottom), 2020

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2020.

- In 2020, residents of medium metro (14.2%) and micropolitan (13.1%) areas were less likely to delay medical care due to the COVID-19 pandemic compared with residents of large fringe metro areas (16.7%) (Figure 1).
- In 2020, adults ages 45-64 (18.3%) and age 65 and over (22.0%) were more likely to delay medical care due to the COVID-19 pandemic compared with adults ages 18-44 (12.8%)
- In 2020, Hispanic adults (19.7%) were less likely to delay medical care due to the COVID-19 pandemic compared with NH-White adults (27.4%).
- In 2020, people with any disability (25.2%) were more likely to delay medical care due to the COVID-19 pandemic compared with people with no disabilities (15%).

Figure 2 People delayed in getting dental treatment due to the coronavirus pandemic, by location and age (top) and race/ethnicity and disability status (bottom) (lower rates are better), 2020

Key: NH = non-Hispanic.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2020.

- In 2020, residents of small metro (21.7%), micropolitan (20.1%), and noncore (21.6%) areas were less likely to delay dental care due to the COVID-19 pandemic compared with residents of large fringe metro areas (27.6%) (Figure 2).
- In 2020, adults ages 45-64 (26.1%) and age 65 and over (28.0%) were more likely to delay dental care due to the COVID-19 pandemic compared with adults ages 18-44 (23.5%)
- In 2020, Hispanic (19.7%) and NH-Black adults (21.0%) were less likely to delay dental care due to the COVID-19 pandemic compared with NH-White adults (27.4%).

## Impact of COVID-19 on Diabetes Care

❖ During the COVID-19 pandemic, fewer residents of urban areas with diabetes had their feet checked for sores or irritation. Conversely, more residents of suburban areas with diabetes received influenza vaccination. Other diabetes care remained stable.

### Importance

Diabetes affects a large percentage of the population and is the leading cause of a wide range of costly complications. During the COVID-19 PHE, the incidence of both type 1 and type 2 diabetes increased among youth, with the largest increases observed among Black and Hispanic individuals.^6^

The COVID-19 pandemic has disproportionately affected certain groups, such as older people, minority populations, and people with specific chronic conditions, including diabetes, cardiovascular disease, kidney disease, and some respiratory diseases. Recurrent lockdowns and public health measures throughout the pandemic have restricted access to routine diabetes care, limiting new diagnoses and affecting self-management, routine followup, and access to medications, as well as affecting lifestyle behaviors. Short-term delays in delivery of routine care, even by 12 months, are associated with adverse effects and worse microvascular, macrovascular, and mortality outcomes in people with diabetes.^7^

Frequency of hemoglobin A1c testing and retinal screening exams in the first 2 months of the pandemic each dropped to less than 50% of prior years’ total frequency but both rebounded to prior years’ assessment frequency during June 2020.^8^

The COVID-19 pandemic challenged the healthcare delivery system, including services responsible for providing diabetes care. Multiple factors created barriers to delivering routine diabetes care, including:

- Lockdowns of nonessential outpatient clinics,
- Decreased inpatient capacity,
- Staff and medicine shortages,
- Unaffordable medicine,
- Delayed care seeking,
- Limited self-care practice,
- Transportation difficulties, and
- Undiagnosed cases/events.^9^

Diabetes was also associated with increased risks of COVID-19 infection and worse COVID-19 outcomes.^10^ Thus, many people with diabetes understandably delayed or avoided interacting with the healthcare delivery system. These delays raised concern that people with diabetes would experience diabetes complications because they did not receive appropriate chronic diabetes management during the pandemic. However, NHQDR data show no evidence that these concerns were realized.

### Findings

Figure 3 Adults age 40 and over with diagnosed diabetes who received at least two hemoglobin A1c measurements in the calendar year, by location, 2002-2020

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2020.

- From 2002 to 2020, the percentage of adults age 40 and over with diagnosed diabetes who received at least two hemoglobin A1c measurements in the calendar year worsened for residents of medium metro areas, decreasing from 79.0% to 74.5%^i^ (Figure 3).

Figure 4 Adults age 40 and over with diagnosed diabetes who received at least two hemoglobin A1c measurements in the calendar year, by ethnicity, 2019 and 2020

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2019 and 2020.

- In 2019, among all ethnic groups, there was little difference in the percentage of adults age 40 and over with diagnosed diabetes who received at least two hemoglobin A1c measurements (Figure 4).
- In 2020, Hispanic adults age 40 and over with diagnosed diabetes were less likely to receive at least two hemoglobin A1c measurements compared with NH-White adults age 40 and over with diagnosed diabetes.

Figure 5 Adults age 40 and over with diagnosed diabetes who received a dilated eye examination in the calendar year, by location, 2002-2020

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2020.

- From 2002 to 2020, the percentage of adults age 40 and over with diagnosed diabetes who received a dilated eye examination in the calendar year showed no statistically significant changes by residence location (Figure 5).

Figure 6 Adults age 40 and over with diagnosed diabetes who received a dilated eye examination in the calendar year, by ethnicity, 2019 and 2020

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2019 and 2020.

- In 2019 and 2020, there were no statistically significant differences by ethnicity in the percentage of adults age 40 and over with diagnosed diabetes who received a dilated eye examination (Figure 6).

Figure 7 Adults age 40 and over with diagnosed diabetes who had their feet checked for sores or irritation in the calendar year, by location, 2002-2020

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2020.

- From 2002 to 2020, the percentage of adults age 40 and over with diagnosed diabetes who had their feet checked for sores or irritation in the calendar year decreased for residents of most locations (Figure 7):
  ■ Residents of large central metro areas experienced a decrease from 73.3% to 57.8%.
  ■ Residents of large fringe metro areas experienced a decrease from 77.8% to 60.3%.
  ■ Residents of medium metro areas experienced a decrease from 74.4% to 54.0%.
  ■ Residents of small metro areas experienced a decrease from 64.4% to 61.9%.

Figure 8 Adults age 40 and over with diagnosed diabetes who had their feet checked for sores or irritation in the calendar year, by ethnicity, 2019 and 2020

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2019 and 2020.

- In 2020, Hispanic adults age 40 and over with diagnosed diabetes were less likely to have their feet checked for sores or irritation compared with NH-White adults (Figure 8).

Figure 9 Adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year, by location, 2008-2020

Note: Data for noncore areas for 2008 did not meet the criteria for statistical reliability.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2008-2020.

- From 2008 to 2020, the percentage of adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year increased among residents of large central metro areas (from 58.9% to 65.6%) (Figure 9).
- From 2019 to 2020, the percentage of adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year increased among residents of large fringe metro areas (from 57.3% to 69.4%).

Figure 10 Adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year, by ethnicity, 2019 and 2020

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2019 and 2020.

- In 2019, NH-Black adults (55.3%) were less likely than NH-White (65.2%) adults age 40 and over with diagnosed diabetes to receive a flu vaccination (Figure 10).
- In 2020, Hispanic (57.3%) and NH-Black (56.2%) adults were less likely than NH-White (69.3%) adults age 40 and over with diagnosed diabetes to receive a flu vaccination.

## Impact of COVID-19 on Cancer Screening

❖ During the COVID-19 pandemic, screening for breast and cervical cancer remained stable overall and there was little change in the differences in screening rates across areas of residence and race.

### Importance

Cancer is the second leading cause of death and is exceeded only by heart disease. One of every five deaths in the United States is due to cancer. In 2019, 264,121 new cases of breast cancer were reported among women, 12,795 new cases of cervical cancer were reported, and 142,462 new cases of colorectal cancer were reported.^11^

The Centers for Disease Control and Prevention (CDC) estimates that screening can prevent thousands of cancer deaths. Mammography can significantly reduce breast cancer mortality, and the notable reductions in cervical cancer incidence and mortality over the past 30 years are largely due to screening with the Pap test.^12^

If the current level of cancer screenings were maintained, 10,179 deaths from breast cancer would be prevented among the cohort of 50-year-old women over their lifetime; 27,166 deaths from cervical cancer would be prevented among the cohort of 21-year-old women; and 74,470 deaths from colorectal cancer would be prevented among the cohort of 50-year-old men and women.^13^

Early in 2020, many cancer screening facilities closed temporarily, while others faced severe staffing shortages. In addition, people feared going to hospitals and other medical facilities for nonemergency procedures for fear of contracting COVID-19.^14^

Consistent with these observations, a 2020 National Cancer Institute report noted that the number of people getting screened for cancer in the United States had dropped dramatically.^15^ This development raised concern that cancer morbidity and mortality would subsequently rise because of missed screening opportunities.^16^

NHQDR data show that, despite these early concerns, overall screening rates for the most common cancers have remained stable; however, disparities among racial and ethnic groups and between urban and rural populations persist. The data also show a sharp rise in deaths from breast and colorectal cancers in 2020 and 2021 among NH-Native Hawaiian/Pacific Islander (NH-NHPI) people, which mirrors the excess COVID-19 deaths experienced by this group.

### Findings

Figure 11 Women ages 50-74 who received a mammogram in the last 2 years, by race/ethnicity (top) and location (bottom), 2019 and 2021

Key: NH = non-Hispanic.

Note: Data for American Indians and Alaska Native groups do not meet the criteria for statistical reliability, data quality, or confidentiality. Data were not available for Native Hawaiian/Pacific Islander groups.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2019 and 2021.

- Overall, and among women ages 50-74 of different racial/ethnic groups and residing in different geographic locations, there were no statistically significant changes in the receipt of a mammogram in 2019 compared with 2021 (Figure 11).

Figure 12 Women ages 21-65 who received a Pap smear in the last 3 years or human papillomavirus test in the last 5 years, by race/ethnicity (top) and location (bottom), 2019 and 2021

Key: NH = non-Hispanic.

Note: Data for American Indian and Alaska Native groups and Native Hawaiian/Pacific Islander groups did not meet the criteria for statistical reliability, data quality, or confidentiality.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2019 and 2021.

- Overall, and among women ages 21-65 of different racial/ethnic groups and residing in different geographic locations, there were no statistically significant differences in the receipt of cervical cancer screening in 2019 compared with 2021 (Figure 12).

Figure 13 Adults ages 50-75 who received any type of colorectal cancer screening, by race/ethnicity (top) and location (bottom), 2021

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native.

Note: Data for Native Hawaiian/Pacific Islander groups did not meet the criteria for statistical reliability, data quality, or confidentiality. Colorectal cancer screening includes blood stool test in the past year, sigmoidoscopy in the past 5 years and blood stool test in the past 3 years, a colonoscopy in the past 10 years, a Cologuard test (FIT-DNA) in the past 3 years, or a CT colonography (“virtual colonoscopy”) in the past 5 years.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- Overall, in 2021, 71.6% of adults ages 50-75 received colorectal cancer screening (Figure 13).
- In 2021, Hispanic adults ages 50-75 were less likely to have received colorectal cancer screening compared with NH-White adults (62.9% compared with 74.2%).
- In 2021, NH-AI/AN adults ages 50-75 were less likely to have received colorectal cancer screening compared with NH-White adults (61.7% compared with 74.2%).
- In 2021, NH-Asian adults ages 50-75 were less likely to have received colorectal cancer screening compared with NH-White adults (60.7% compared with 74.2%).
- In 2021, adults ages 50-75 residing in noncore areas were less likely to have received colorectal cancer screening compared with residents of large fringe metro areas (65.4% compared with 73.5%).

## Discussion and Conclusions

The COVID-19 pandemic changed ambulatory healthcare delivery in many ways. Healthcare systems worked to mitigate barriers, including difficulty coordinating care and delays related to the pandemic, by pivoting to additional delivery mechanisms, such as telehealthcare. Preventive care was delivered during the pandemic at rates similar to prepandemic levels but still below Healthy People 2030 targets and U.S. Preventive Services Task Force recommendations. In addition, disparities persist, with some people more affected than others by the pandemic.

In March 2020, after the World Health Organization classified COVID-19 as a pandemic, national regulatory agencies temporarily recommended curtailing all nonurgent office visits and elective surgeries to preserve personal protective equipment, beds, and ventilators and to limit the spread of COVID-19.^4^ These mitigation strategies and people’s desire to prevent infection resulted in a decrease in in-person visits and an increase in telehealthcare use.^17^ For additional information, refer to special emphasis topic, “Growth of Telehealthcare During the COVID-19 Pandemic” of this report.

The mitigation strategies also led to the temporary closing of many ambulatory care practices. More information is in the “Healthcare Delivery Systems” section of “Portrait of American Healthcare” in this report.

NHQDR data show that the pandemic led to delays in care; in 2020, approximately 15% of people delayed medical care and 25% delayed dental due to COVID-19. The pandemic affected some populations more than others. For example, in 2020, more than 15% of residents of large fringe metropolitan, large central metropolitan, small metropolitan, and noncore areas delayed medical care due to COVID-19.

In addition, adults ages 45-64 (18.3%) and age 65 and over (22.0%) were more likely to delay medical care due to the COVID-19 pandemic compared with adults ages 18-44 (12.8%). Nearly 30% of NH-White people and NH-Asian people delayed dental care.

Despite challenges posed by COVID-19 mitigation strategies and patients’ reluctance to access healthcare facilities due to fear of COVID-19 infection, some people continued to get recommended diabetes and preventive cancer care, which often require in-person visits.

NHQDR data show that for some recommended services, including dilated eye exams, hemoglobin A1c testing, and flu vaccination, trends showed little to no change before and since the onset of the COVID-19 pandemic. The only diabetes care measure that changed reflects a longstanding decline that predates the pandemic in screening patients with diabetes for foot sores. The percentage of adults who had their feet checked for sores or irritation in the calendar year worsened steadily from 2002 to 2020 among people living in metropolitan areas.

Similar to diabetes care, cancer screening rates appeared to rebound to pre-COVID levels after an initial decline, suggesting that health systems were able to recalibrate resources and protocols fairly quickly.^18^ While cancer screening rates have rebounded overall, some groups continue to experience disparities. Findings show that in 2019 and 2021, women ages 50-74 residing in rural areas were less likely to receive a mammogram compared with women in large fringe metropolitan areas.

Among racial/ethnic groups, in 2019, there were no differences in mammogram screening but in 2021, NH-Asian women ages 50-74 were less likely to receive a mammogram compared with NH-White women. NH-Black women were more likely to receive a mammogram compared with NH-White women.

Screening rates did not change in 2019 or in 2021 for cervical cancer screening among women ages 21-65 of different racial/ethnic groups. Among women from different geographic locations, only residents of large central metropolitan areas showed a decrease in screening rates.

Looking forward, telehealthcare could be a path to healthcare for people facing barriers to services such as lack of transportation and regional provider shortages. While the COVID-19 pandemic led to broad cancellations of nonemergency in-person healthcare appointments, telehealthcare appointments appeared to have enabled individuals to still receive medical consultation and advice. It also enabled people to reschedule screening tests. The “Growth of Telehealthcare During the COVID-19 Pandemic” special emphasis topic in this report has more information.

Finally, although the impact of the pandemic on preventive care and management of chronic conditions was not as negative as anticipated, disparities persist, particularly in nonmetropolitan areas. Ambulatory healthcare still has room for improvement in providing timely and equitable care, as measures show that while care remained stable during the pandemic, percentages of people receiving various types of care are suboptimal.

## Resources

The impact of COVID-19 on care provided in ambulatory settings, such as care for diabetes and cancer, points to the importance of awareness and prevention, as well as alternative ways to access care, such as telehealthcare. Below are resources related to these efforts.

The National Cancer Plan was developed by the National Institutes of Health’s National Cancer Institute. The plan provides a framework for everyone across the federal government and the general public to collaborate in ending cancer as we know it. The plan includes eight essential goals and accompanying strategies that outline what must be accomplished to prevent more cancers, reduce deaths from the disease, and improve the lives of everyone after a diagnosis with cancer:

- Prevent Cancer.
- Detect Cancers Early.
- Develop Effective Treatments.
- Eliminate Inequities.
- Deliver Optimal Care.
- Engage Every Person.
- Maximize Data Utility.
- Optimize the Workforce.

The National Breast and Cervical Cancer Early Detection Program (NBCCEDP) helps those with low incomes who do not have adequate insurance gain access to timely breast and cervical cancer screening, diagnostic, and treatment services. NBCCEDP also provides patient navigation services to help them overcome barriers and get timely access to quality care.

In addition to funding screening and diagnostic services for those eligible, the NBCCEDP focuses on factors at the interpersonal, organizational, community, and policy levels that influence screening. The program supports use of population-based approaches to improve systems that increase high-quality breast and cervical cancer screening, including:

- Implementing evidence-based interventions in health systems.
- Connecting those eligible in the community to screening services.
- Informing policies that increase access to cancer screening.

The National Comprehensive Cancer Control Program (NCCCP) provides funds, guidance, and technical assistance to help cancer control coalitions implement effective and sustainable plans to prevent and control cancer. NCCCP brings together organizations interested in keeping community members healthy in places throughout the country to create plans that help lower the number of people affected by cancer. A cancer control plan focuses on the types of cancer unique to each community that have the highest burden and includes strategies that have worked in other places to help prevent and control those cancers.

The purpose of CDC’s Colorectal Cancer Control Program (CRCCP) is to increase colorectal cancer screening rates among people ages 45-75 years. The program works with clinics, hospitals, and other healthcare organizations to implement and strengthen strategies that have been shown to increase colorectal cancer screening. Currently, the CRCCP funds 35 award recipients: 20 states, 8 universities, 2 tribal organizations, and 5 other organizations.

The Special Diabetes Program for Indians (https://www.ihs.gov/sdpi/sdpi-communitydirected/sdpi-basics/) provides funds for diabetes prevention and treatment services to Indian Health Service, tribal, and urban Indian communities across the United States. As a result, AI/AN communities now have much needed diabetes programs and increased access to quality diabetes care.

The National Diabetes Prevention Program (https://www.cdc.gov/diabetes/prevention/about.htm) was created in 2010 to address the increasing burden of prediabetes and type 2 diabetes in the United States. This national effort created partnerships between public and private organizations to offer evidence-based, cost-effective interventions that help prevent type 2 diabetes in communities across the United States.

The Diabetes Self-Management Education and Support (DSMES) Toolkit (https://www.cdc.gov/diabetes/dsmes-toolkit/index.html) provides an evidence-based foundation to empower people with diabetes to navigate self-management decisions and activities. DSMES is a cost-effective tool proven to help improve health behaviors and health outcomes for people with diabetes.

i Unless noted otherwise, data points under each figure only report differences that are statistically significant (i.e., p value less than 0.1) and show an average annual percentage change greater than 1% per year. For comparisons between two populations, data points under each figure only report differences that are statistically significant (i.e., p value less than 0.05) and have a relative difference between the populations of at least 10%, unless noted otherwise. Readers may learn more about NHQDR’s reporting methodology in Appendix A at https://www.ahrq.gov/research/findings/nhqrdr/nhqdr23/index.html.

## References

1 Agency for Healthcare Research and Quality. Ambulatory Care. Last reviewed February 2018. https://www.ahrq.gov/patient-safety/settings/ambulatory/tools.html. Accessed October 27, 2023.
2 Centers for Medicare & Medicaid Services. Quick Definitions for National Health Expenditure Accounts (NHEA) Categories. https://www.cms.gov/files/document/quick-definitions-national-health-expenditures-accounts-nhea-categories.pdf. Accessed October 27, 2023.
3 Centers for Medicare & Medicaid Services. NHE Fact Sheet, including NHE tables. Last modified September 2023. https://www.cms.gov/research-statistics-data-and-systems/statistics-trends-and-reports/nationalhealthexpenddata/nhe-fact-sheet. Accessed October 27, 2023.
4 Centers for Medicare & Medicaid Services. CMS Releases Recommendations on Adult Elective Surgeries, Non-Essential Medical, Surgical, and Dental Procedures During COVID-19 Response. March 18, 2020. https://www.cms.gov/newsroom/press-releases/cms-releases-recommendations-adult-elective-surgeries-nonessential-medical-surgical-and-dental. Accessed October 27, 2023.
5 Czeisler MÉ, Marynak K, Clarke KE N, Salah Z, Shakya I, Thierry JM, Ali N, McMillan H, Wiley JF, Weaver MD, Czeisler CA, Rajaratnam SM W, Howard ME. Delay or avoidance of medical care because of COVID-19– related concerns — United States, June 2020. MMWR Morb Mortal Wkly Rep 2020;69:1250–1257. https://www.cdc.gov/mmwr/volumes/69/wr/mm6936a4.htm?s_cid=mm6936a4_w. Accessed October 27, 2023.32915166
6 Mefford MT, Wei R, Lustigova E, Martin JP, Reynolds K. Incidence of diabetes among youth before and during the COVID-19 pandemic. JAMA Netw Open. 2023 Sep 5;6(9):e2334953. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC10514735/. Accessed November 20, 2023.37733344
7 Khunti K, Aroda VR, Aschner P, Chan JC N, Del Prato S, Hambling CE, Harris S, Lamptey R, McKee M, Tandon N, Valabhji J, Seidu S. The impact of the COVID-19 pandemic on diabetes services: planning for a global recovery. Lancet Diabetes Endocrinol. 2022 Dec;10(12):890–900. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9640202/. Accessed October 27, 2023.36356612
8 Bancks MP, Lin M-Y, Bertoni A, Futrell WM, Liu Z, Ostasiewski B, Wells BJ, Hanchate A. Impact of the COVID-19 pandemic on diabetes care among a North Carolina patient population. Clin Diabetes. 2022;40 (4):467–476. https://doi.org/10.2337/cd21-0136. Accessed October 27, 2023.36385975
9 Mohseni M, Ahmadi S, Azami-Aghdash S, Mousavi Isfahani H, Moosavi A, Fardid M, Etemadi M, Ghazanfari F. Challenges of routine diabetes care during COVID-19 era: a systematic search and narrative review. Prim Care Diabetes. 2021 Dec;15(6):918–922. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC8326007/. Accessed October 27, 2023.34393092
10 Floyd JS, Walker RL, Kuntz JL, Shortreed SM, Fortmann SP, Bayliss EA, Harrington LB, Fuller S, Albertson-Junkans LH, Powers JD, Lee MH, Temposky LA, Dublin S. Association between diabetes severity and risks of COVID-19 infection and outcomes. J Gen Intern Med. 2023;38:1484–1492. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9933797/. Accessed October 27, 2023.36795328
11 Centers for Disease Control and Prevention. U.S. Cancer Statistics: Data Visualizations. Cancer Statistics At a Glance. https://gis.cdc.gov/Cancer/USCS/#/AtAGlance/. Accessed October 27, 2023.
12 Ma Z, Richardson LC. Cancer screening prevalence and associated factors among US adults. Prev Chronic Dis. 2022 Apr 21;19:220063. http://dx.doi.org/10.5888/pcd19.220063. Accessed October 27, 2023.
13 Sharma KP, Grosse SD, Maciosek MV, Djenaba J, Roy K, Richardson LC, Jaffe H. Preventing breast, cervical, and colorectal cancer deaths: assessing the impact of increased screening. Preventing Chronic Disease. 2020 Oct 8;17. https://doi.org/10.5888/pcd17.200039. Accessed October 27, 2023.
14 Wang L. Working To Close the Cancer Screening Gap Caused by COVID. Cancer Currents Blog. 2022 May 17. National Cancer Institute. https://www.cancer.gov/news-events/cancer-currents-blog/2022/covid-increasing-cancer-screening
15 Sharpless NE. COVID-19 and cancer. Science 2020 Jun 19;368(6497). https://www.science.org/doi/10.1126/science.abd3377. Accessed October 27, 2023.
16 Cancino RS, Su Z, Mesa R, Tomlinson GE, Wang J. The impact of COVID-19 on cancer screening: challenges and opportunities. JMIR Cancer. 2020;6(2):e21697. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7599065/.Accessed October 27, 2023.33027039
17 Baum A, Kaboli PJ, Schwartz MD. Reduced in-person and increased telehealth outpatient visits during the COVID-19 pandemic. Ann Intern Med. 2021;174(1):129–131. https://www.acpjournals.org/doi/full/10.7326/M20-3026. Accessed October 27, 2023.32776780
18 McBain RK, Cantor JH, Jena AB, Pera MF, Bravata DM, Whaley CM. Decline and rebound in routine cancer screening rates during the COVID-19 pandemic. J Gen Intern Med. 2021 Jun;36(6):1829–1831. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7978463/. Accessed October 27, 2023.33742300