# Impact of COVID-19 on Hospital Care

On March 13, 2020, the United States declared a public health emergency (PHE) to combat coronavirus disease 2019 (COVID-19). Community mitigation strategies were implemented to slow the spread of the disease and to protect all individuals, especially those at increased risk for severe illness that can result in hospitalization, intensive care, and ventilator use. These strategies were used to minimize morbidity and mortality of COVID-19 in societal sectors such as schools, workplaces, and healthcare organizations.^1^

COVID-19 spreads when an infected person breathes out droplets and very small particles that contain the virus. These droplets and particles can be breathed in by other people or land on their eyes, nose, or mouth. In some cases, people may contaminate surfaces they touch.^2^ Limiting the number of contacts between potentially infected individuals and those who might be susceptible to the pathogen is one of the most valuable nonpharmaceutical interventions.

As part of the nonpharmacologic strategy to stop the spread of COVID-19, the federal government implemented a stay-at-home order to reduce travel. However, when residents perceive an infectious disease to be a threat in their communities, they may voluntarily reduce their movement.^3^

This section highlights the impact of COVID-19 on hospitalizations, emergency department (ED) use, and patient safety. Findings on changes over time and disparities experienced by some populations show that:

- From 2020 to 2022, ED visits and hospital admissions increased during COVID-19 infection surges associated with the Alpha, Delta, and Omicron variants. Hospital admissions and ED visits decreased for non-COVID-19 conditions during surge periods, suggesting that non-COVID-19 conditions were crowded out by COVID-19 cases.
- From 2020 to 2022, hospitalizations were worse for large urban areas at the start of the pandemic but by the time the Alpha variant became dominant, rural areas experienced more hospitalizations than large urban areas.
- In 2020, ED wait times worsened for Black and Hispanic patients, particularly for psychiatric or mental health and cardiovascular conditions, potentially leading to worse outcomes and increased disparities.
- In 2020, several patient safety measures continued to improve through 2020 for non-COVID-19 patients. These included postoperative sepsis, central venous catheter-related bloodstream infections (also known as central line-associated bloodstream infections, or CLABSIs), and postoperative pulmonary embolism or deep vein thrombosis. But data show disparities in patient safety. Residents of rural areas and non-Hispanic (NH) Black patients experienced the worst outcomes.

## Inpatient and Emergency Department Visits With Confirmed COVID-19

❖ As the volume of confirmed COVID-19 patients increased, the number of non-COVID patients seeking both inpatient and ED care decreased. Over time, the locations most affected by COVID-19 changed and adverse outcomes of COVID-19 infections declined in older adults.

By June 30, 2020, an estimated 41% of U.S. adults reported having delayed or avoided medical care during the pandemic because of concerns about COVID-19, including 12% who reported having avoided urgent or emergency care. Avoidance of urgent or emergency care was more prevalent among unpaid caregivers for adults, people with underlying medical conditions, Black adults, Hispanic adults, young adults, and people with disabilities.^4^

People with disabilities hospitalized with COVID-19 had higher risk for severe outcomes, longer stays, and increased readmission, particularly those with mobility or intellectual/developmental disabilities (IDD). Community-dwelling people with disabilities had higher risk of discharge to skilled nursing or long-term care facilities.

Increased risk of severe outcomes due to COVID-19 in hospitalized people with disabilities varied by disability type, with the highest risk for all outcomes among people with IDD. However, people with mobility disabilities also had an increased risk of adverse outcomes. People with any disability and people with each disability type who were admitted from the community were less likely to be discharged home than people without disabilities.^5^

Studies have shown that dementia was associated with an increased COVID-19 risk and lower adherence to hand washing among U.S. older adults.^6^ In addition, people with dementia sought hospital care far less than usual, were not admitted to nursing homes, and experienced excess mortality during the first wave of the pandemic. Most services returned to historic levels, but telehealthcare visits remained a feature of care.^7^

During the COVID-19 pandemic, the number of ED visits was substantially lower than in previous years. Diagnoses associated with lower respiratory disease, pneumonia, difficulty breathing, cardiac arrest, and ventricular fibrillation increased. The number of visits for conditions such as nonspecific chest pain and acute myocardial infarction decreased, suggesting that some people might have delayed care for conditions that could lead to death if left untreated.

The striking decline in ED visits nationwide, with the highest declines in regions where the pandemic was most severe, suggests that the pandemic altered the public’s use of EDs. People who use the ED as a safety net because they lack access to primary care and telehealthcare could be disproportionately affected if they avoid seeking care because of concerns about the infection risk in the ED.^8^

Figure 1 Inpatients with confirmed COVID-19 and non-COVID diagnoses from selected hospitals, March 2020-December 2022

Note: A confirmed COVID-19 hospital encounter is defined as an any listed International Classification of Diseases, 10th Revision, diagnosis code of B97.29 or U07.1. Before April 1, 2020, the Centers for Disease Control and Prevention guidance said to code a confirmed COVID-19 hospital encounter as B97.29. On April 1, 2020, the guidance changed to code confirmed COVID-19 hospital encounters as U07.1. The figure shows the percentage of hospital encounters coded with a B97.29 or U07.1 code. The data are from selected hospitals and considered preliminary. The data are not nationally representative.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Care Survey, March 2020-December 2022.

- From March 2020 to December 2022, the highest percentage of inpatients with confirmed COVID-19 was observed from December 2021 to January 2022 (Figure 1).
- From March 2020 to December 2022, the lowest percentage of non-COVID-19 inpatient visits was observed from December 2021 to January 2022.

Figure 2 Inpatients with confirmed COVID-19 (top) and non-COVID diagnoses from selected hospitals (bottom), by age, March 2020-December 2022

Note: The data are from selected hospitals and considered preliminary. The data are not nationally representative.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Care Survey, March 2020-December 2022.

- From March 2020 to December 2022, the highest percentage of inpatients with confirmed COVID-19 among all age groups was observed from December 2021 to January 2022 (Figure 2).
- From March 2020 to December 2022, the lowest percentage of non-COVID-19 inpatient visits among all age groups was observed from December 2021 to January 2022.

Figure 3 Emergency department visits with confirmed COVID-19 and non-COVID-19 from selected hospitals, March 2020-December 2022

Note: The data are from selected hospitals and considered preliminary. The data are not nationally representative.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Care Survey, March 2020-December 2022.

- From March 2020 to December 2022, the highest percentage of ED visits with confirmed COVID-19 was observed from December 2021 to January 2022 (Figure 3).
- From March 2020 to December 2022, the lowest percentage of non-COVID-19 ED visits was observed from December 2021 to January 2022.

Figure 4 Confirmed COVID-19 (top) and non-COVID-19 (bottom) ED visits from selected hospitals, by age, March 2020-December 2022

Note: The data are from selected hospitals and considered preliminary. The data are not nationally representative.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Care Survey, March 2020-December 2022.

- From March 2020 to December 2022, the highest percentage of confirmed COVID-19 ED visits among all age groups was observed from December 2021 to January 2022 (Figure 4).
- From March 2020 to December 2022, the lowest percentage of non-COVID-19 ED visits among all age groups was observed from December 2021 to January 2022.

Figure 5 Confirmed COVID-19 Inpatient visits from selected hospitals, by hospital location, March 2020-December 2022

Note: The data are from selected hospitals and considered preliminary. The data are not nationally representative.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Care Survey, March 2020-December 2022.

- From March 2020 to December 2022, the highest percentage of confirmed COVID-19 inpatient visits was observed in rural areas during November 2021 (Figure 5).

Figure 6 Confirmed COVID-19 ED visits from selected hospitals, by hospital location, March 2020-December 2022

Note: The data are from selected hospitals and considered preliminary. The data are not nationally representative.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Care Survey, March 2020-December 2022.

- From March 2020 to December 2022, the highest percentage of confirmed COVID-19 ED visits was observed in large central and fringe metropolitan areas during December 2021 (Figure 6).

Figure 7 Confirmed COVID-19 inpatient discharges with intubation use from selected hospitals, by age, March 2020-December 2022

Note: The data are from selected hospitals and considered preliminary. The data are not nationally representative.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Care Survey, March 2020-December 2022.

- From March 2020 to December 2022, the highest percentage of confirmed COVID-19 inpatient discharges with intubation use was observed in the early stage of the PHE (March 2020) among patients age 60 and over (28.2%) and later in 2021 and in 2022 by patients ages 30-59 (21.6% in June 2021) (Figure 7). For context, a 2015 CDC study found that approximately 5.3% of people hospitalized for severe community-acquired pneumonia required intubation and mechanical ventilation.^9^

Figure 8 Confirmed COVID-19 patients who died in the hospital from selected hospitals, by age, April 2020-December 2022

Note: The data are from selected hospitals and considered preliminary. The data are not nationally representative.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Care Survey, April 2020-December 2022.

- From April 2020 to December 2022, the highest percentage of confirmed COVID-19 patients who died in the hospital was observed in the early stage of the PHE (April 2020) (data not shown).
- From April 2020 to December 2022, the highest percentage of confirmed COVID-19 patients who died in the hospital was observed in the early stage of the PHE (April 2020) among patients age 60 and over (Figure 8).

Figure 9 Average length of stay of confirmed COVID-19 inpatients discharged from selected hospitals, by age, March 2020-November 2022

Note: The data are from selected hospitals and considered preliminary. The data are not nationally representative.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Care Survey, March 2020-November 2022.

- In 2020, the average hospital length of stay (LOS) was 4.9 days, compared with 4.7 days in 2019 (data not shown).
- From March 2020 to November 2022, the longest average LOS of confirmed COVID-19 patients was 35 days, observed during March 2022 among patients ages 30-59 years Figure 9).

## Patient Experience With Hospital Care

According to the Consumer Assessment of Healthcare Providers and Systems (CAHPS), patient experience encompasses the range of interactions patients have with the healthcare system. These interactions include their care from health plans and from physicians, nurses, and staff in hospitals, physician practices, and other healthcare facilities.

As an integral component of healthcare quality, patient experience includes several aspects of healthcare delivery that patients value highly when they seek and receive care. These include timely appointments, easy access to information, and good communication with healthcare providers.

Understanding patient experience is a key step in moving toward patient-centered care. By looking at various aspects of patient experience, we can assess the extent to which patients are receiving care that is respectful of and responsive to their preferences, needs, and values. Evaluating patient experience along with other components such as effectiveness and safety of care is essential to providing a complete picture of healthcare quality.

Figure 10 Adult hospital patients who sometimes or never had good communication about medications they received in the hospital, by race, 2009-2021 (lower rates are better)

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Source: Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems, 2009-2021.

- From 2019 to 2021, the percentage of adult hospital patients who sometimes or never had good communication about medications they received in the hospital increased for all racial groups (Figure 10).

Figure 11 Adult hospital patients who did not receive good communication about discharge information, by race, 2009-2021 (lower rates are better)

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Source: Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems, 2009-2021.

- From 2009 to 2021, the percentage of adult hospital patients who did not receive good communication about discharge information decreased for all racial groups (Figure 11).
- From 2019 to 2021, the percentage of adult hospital patients who did not receive good communication about discharge information increased for NHPI and White people.

## Emergency Department Wait Times

❖ Emergency department wait times have worsened overall and for patients with psychiatric or mental health conditions. Wait times for patients with cardiac symptoms also worsened.

The lack of ED capacity during the COVID-19 PHE was in part due to patients waiting in the ED until an inpatient bed became available, a practice referred to as boarding. It occurs when people present to the ED, either for an initial evaluation or after being transferred from another hospital, and then wait an extended time to move from the ED to a hospital ward. In a Centers for Medicare & Medicaid Services review of data from calendar year 2019, of the hospitals that reported using the ED-2 boarding metric, the average median boarding time was 101 minutes.^10^

Boarding is associated with several adverse outcomes, including increased medical errors and death. These outcomes likely occur because the ED is ill equipped to provide longitudinal and focused inpatient care and attention is frequently diverted to new patients who present with undifferentiated conditions.^10^

Negative effects such as death increase exponentially as the system becomes more stressed. The Department of Health and Human Services time series dataset showed that as of October 25, 2021, capacity in adult intensive care units nationwide had exceeded 75% for at least 12 weeks. This level meant that the United States experienced the high and sustained levels of hospital strain associated with significant subsequent increases in excess deaths.^11^

Figure 12 Median time in minutes outpatients spent in the emergency department from arrival to departure, by race/ethnicity, 2016-2021 (lower rates are better)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse, 2016-2021.

- From 2019 to 2021, the median time outpatients spent in the ED from arrival to departure increased overall and for most racial/ethnic groups (Figure 12):
  ■ The median time for Hispanic patients increased from 147 to 160 minutes.
  ■ The median time for NH-AI/AN patients increased from 119 to 128 minutes.
  ■ The median time for NH-Asian patients increased from 164 to 168 minutes.
  ■ The median time for NH-Black patients increased from 145 to 162 minutes.
  ■ The median time for NH-White patients increased from 141 to 154 minutes.
  ■ The median time for NH-NHPI patients decreased by 2 minutes, from 132 to 130 minutes.

Figure 13 Median time in minutes outpatients with psychiatric or mental health conditions spent in the emergency department from arrival to departure, by race/ethnicity, 2016-2021 (lower rates are better)

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse, 2016-2021.

- From 2019 to 2021, the median time outpatients with psychiatric or mental health conditions spent in the ED from arrival to departure increased overall from 242 to 250 minutes (Figure 13):
  ■ The median time for Hispanic patients increased from 244 to 257 minutes.
  ■ The median time for NH-White patients increased from 233 to 249 minutes.

Figure 14 Outpatients with chest pain or possible heart attack who received fibrinolytic therapy within 30 minutes of arrival, by race/ethnicity, 2016-2021

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native.

Note: Data for NH-Native Hawaiian/Pacific Islander patients and 2017 and 2019 data for non-Hispanic Asian patients did not meet the criteria for statistical reliability.

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse, 2016-2021.

- From 2019 to 2021, the percentage of outpatients with chest pain or possible heart attack who received fibrinolytic therapy within 30 minutes of arrival fell, overall, from 57.4% to 52.4% (Figure 14).
- From 2019 to 2021, the percentage of outpatients with chest pain or possible heart attack who received fibrinolytic therapy within 30 minutes of arrival fell sharply for NH-Black (49.2% to 40.2%) and Hispanic patients (54.6% to 47.1%).

Figure 15 Median time to transfer to another facility for acute coronary intervention, by race, 2020 (lower rates are better)

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse, 2020.

- In 2020, the median time to transfer to another facility for acute coronary intervention was longest for Black patients (74 minutes) and shortest for Asian patients (58 minutes) (Figure 15).

Figure 16 Ischemic or hemorrhagic stroke patients who came to the emergency department with stroke symptoms and received head CT or MRI who received the interpretation of the results within 45 minutes of ED arrival, by race/ethnicity, 2016-2021

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse, 2016-2021.

- From 2016 to 2019, the percentage of ischemic or hemorrhagic stroke patients who came to the ED with stroke symptoms and received head CT or MRI who received the interpretation of the results within 45 minutes of ED arrival increased among AI/AN patients but fell between 2019 and 2021 from 66.9% to 61.8% (Figure 16).
- From 2016 to 2019, the percentage of ischemic or hemorrhagic stroke patients who came to the ED with stroke symptoms and received head CT or MRI who received the interpretation of the results within 45 minutes of ED arrival decreased among Hispanic patients. The percentage increased from 64.6% in 2019 to 67.3% in 2021.
- From 2019 to 2021, the percentage of ischemic or hemorrhagic stroke patients who came to the ED with stroke symptoms and received head CT or MRI who received the interpretation of the results within 45 minutes of ED arrival increased from 64.0% to 68.4% among NHPI patients.

Figure 17 Emergency department visits triaged as immediate or emergent at which patients waited to see a physician for 1 hour or more, by ethnicity, 2006-2020 (lower rates are better)

Note: The National Hospital Ambulatory Medical Care Survey classifies emergency department visits based on one of five levels of severity during nursing triage. “Immediate” visits involve the most life-threatening conditions, which require immediate attention. “Emergent refers to conditions that warrant evaluation within 15 minutes.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2006-2020.

- From the 2-year period 2006-2007 to the 2-year period 2019-2020, the percentage of ED visits triaged as immediate or emergent at which patients waited to see a physician for 1 hour or more improved for NH-Black and NH-White patients but showed no statistically significant^i^ change for Hispanic patients (Figure 17).

- From the 2-year period 2018-2019 to the 2-year period 2019-2020, the percentage of ED visits triaged as immediate or emergent at which patients waited to see a physician for 1 hour or more increased from 11.4% to 15.7% for Hispanic patients.

Figure 18 Emergency department visits triaged as urgent at which patients waited to see a physician for 1 hour or more, by ethnicity, 2006-2020 (lower rates are better)

Note: The National Hospital Ambulatory Medical Care Survey classifies emergency department visits based on one of five levels of severity during nursing triage. “Urgent” visits warrant assessment within 15-60 minutes.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2006-2020.

- From the 2-year period 2006-2007 to the 2-year period 2019-2020, the percentage of ED visits triaged as urgent at which patients waited to see a physician for 1 hour or more improved overall and for Hispanic, NH-Black, and NH-White patients (Figure 18).
- In the 2-year period 2019-2020, overall, 12.7% of ED visits triaged as urgent had patients who waited to see a physician for 1 hour or more. Among Hispanic patients, 14.8% of visits, among NH-Black patients, 14.3% of visits, and among NH-White patients, 11.4% of visits triaged as urgent had patients who waited to see a physician for 1 hour or more.

## COVID-19 and Patient Safety

❖ The COVID-19 public health emergency put enormous stress on the healthcare system and disrupted many normal activities in hospitals and other facilities. However, postoperative sepsis, central venous catheter-related bloodstream infections, and postoperative pulmonary embolism or deep vein thrombosis all continued to improve through 2020 for non-COVID-19 patients.

An AHRQ study published in JAMA showed that rates of in-hospital adverse events for healthcare-related patient harm fell significantly in the United States in the decade before the onset of the COVID-19 pandemic.^12^ Unfortunately, multiple sources have reported a reversal in this trend since 2020. It was both difficult and essential to manage the competing priorities of providing care for large numbers of patients with COVID-19, as well as for the patients without COVID-19 who needed routine care. At the same time, it was crucial to maintain safety efforts such as robust infection control practices.^13^

Since the COVID-19 pandemic began, many indicators make it clear that patient safety has declined. The average risk of healthcare-associated infections,^14^ CLABSIs, and falls increased during the pandemic.^13^ Potential reasons for the increase in patient safety events include newly implemented contact isolation procedures and use of personal protective equipment (PPE). PPE, particularly respiratory protection (e.g., face masks, respirators), muffles sounds, prevents lip reading, and makes reading facial expressions challenging, creating potential patient safety challenges.^15^

The risk of pressure injuries of the skin and soft tissue has increased during the pandemic. Prone positioning for ventilated patients has been widely adopted for patients with COVID-19. While the prone position has led to better outcomes, it has also created a unique challenge for nursing staff when it comes to preventing pressure injuries. Not only is patient repositioning more challenging, but also the continuous pressure points are very different from those nurses typically encounter and manage.^16^

Among COVID-19 patients in particular, hospital data have indicated an increased risk of hospital-acquired infections during the pandemic. This increased risk of infection may, in part, be due to increased device utilization and prolonged hospitalization of COVID-19 patients, but also to challenges in maintaining those devices (catheters, central lines, etc.) while trying to limit provider exposure and conserve PPE.^16^

Patient safety analyses in this report use AHRQ Patient Safety Indicators (PSIs), Healthcare Cost and Utilization Project data on postoperative sepsis, CLABSI, and postoperative pulmonary embolism or deep vein thrombosis that exclude COVID-19 patients. When the PSIs were calculated for the NHQDR, PSI software excluded all COVID-19 hospitalizations. We report patient safety events only for people hospitalized without COVID-19.^17^ This approach may have resulted in lower rates of patient safety events compared with other studies.

Figure 19 Postoperative sepsis per 1,000 elective-surgery admissions, age 18 and over, by residence location, 2016-2020 (lower rates are better)

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), State Inpatient Databases, weighted to provide national estimates; and the AHRQ Quality Indicators, v2022.1, 2016-2020. For more information, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

- From 2016 to 2020, the rate of postoperative sepsis declined among patients in all residence locations (Figure 19).

Figure 20 Hospital admissions with central venous catheter-related bloodstream infection per 1,000 medical and surgical discharges of length 2 or more days, age 18 and over or obstetric admissions, by residence location (top) and race/ethnicity (bottom), 2016-2020 (lower rates are better)

Key: API = Asian or Pacific Islander.

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), State Inpatient Databases, weighted to provide national estimates; and the AHRQ Quality Indicators, v2022.1, 2016-2020. For more information, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

- From 2016 to 2020, the rate of hospital admissions with CLABSI decreased among residents of large central and medium metro areas from 0.13 to 0.09 per 1,000 medical and surgical discharges and from 0.13 to 0.08 per 1,000 medical and surgical discharges, respectively (Figure 20).
- The rate of hospital admissions with CLABSI decreased among patients from noncore areas from 0.09 to 0.08 per 1,000 medical and surgical discharges.
- From 2016 to 2020, the rate of hospital admissions with CLABSI decreased among patients from all ethnic groups.

Figure 21 Postoperative pulmonary embolism or deep vein thrombosis per 1,000 surgical admissions, age 18 and over, race/ethnicity, 2016-2020 (lower rates are better)

Key: API = Asian or Pacific Islander.

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), State Inpatient Databases, weighted to provide national estimates; and the AHRQ Quality Indicators, v2022.1, 2016-2020. For more information, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

- From 2016 to 2020, the rate of postoperative pulmonary embolism or deep vein thrombosis improved overall and for Hispanic, non-Hispanic Black, and non-Hispanic White patients (Figure 21):
  ■ Overall, patients experienced a decrease from 3.8 to 3.0 per 1,000 surgical admissions.
  ■ Non-Hispanic Black patients experienced a decrease from 4.9 to 4.1 per 1,000 surgical admissions.
  ■ Hispanic patients experienced a decrease from 3.7 to 3.1 per 1,000 surgical admissions.
  ■ Non-Hispanic White patients experienced a decrease from 3.7 to 2.9 per 1,000 surgical admissions.

Figure 22 Postoperative hip fracture per 1,000 surgical admissions who were not susceptible to falling, age 18 and over, by race/ethnicity (top) and residence location (bottom), 2016-2020 (lower rates are better)

Key: API = Asian or Pacific Islander.

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), State Inpatient Databases, weighted to provide national estimates; and the AHRQ Quality Indicators, v2022.1, 2016-2020. For more information, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

- From 2016 to 2020, rates of postoperative hip fracture decreased for Hispanic patients and residents of medium metro areas but increased for residents of noncore areas (Figure 22):
  ■ Hispanic patients experienced a decrease from 0.06 to 0.05 per 1,000 surgical admissions.
  ■ From 2016 to 2020, rates decreased for residents of medium metro areas from 0.09 to 0.08 per 1,000 surgical admissions.
  ■ From 2016 to 2020, rates increased for residents of noncore areas from 0.11 to 0.12 per 1,000 surgical admissions.

## Discussion and Conclusions

The COVID-19 pandemic caused massive disruption in the usual care delivery patterns in hospitals across the United States and highlighted longstanding inequities in healthcare delivery and outcomes.^18^

Hospital and ED visits closely aligned with the volume of COVID-19 cases. Data show increased hospitalization and ED visits with confirmed COVID-19 during surges associated with the Alpha and Omicron variants. At the same time, data show a decrease in hospitalization and ED visits for non-COVID-19 conditions during surge periods, suggesting that patients with non-COVID-19 chose to avoid hospitals or capacity was reduced due to the number of COVID-19 cases.

During the first 3 months of the pandemic before effective treatments and vaccines became available, worse health outcomes, including ventilator use and deaths, were observed in large central and fringe metropolitan areas. As the alpha variant emerged, rural areas began experiencing more hospitalizations.

Delays in emergency care can lead to serious health consequences. Routinely crowded EDs are associated with increased stress on staff, poor adherence to protocols, and clinical errors.^19^ Data show that during the COVID-19 pandemic, ED wait times worsened for Black and Hispanic patients, particularly for psychiatric or mental health and cardiovascular conditions, potentially leading to worse outcomes and increased disparities.

The COVID-19 pandemic necessitated drastic changes to the way healthcare services were delivered across care settings, in particular in hospital EDs and inpatient units. Hospitals experienced an increase in device use (e.g., ventilators, catheters) and strains on availability of PPE. Particularly in the earlier phases of the pandemic, there were patient safety concerns associated with factors such as disease exposure, timely diagnosis, and treatment access related to pressures on the system.^16^

During the COVID-19 PHE, wait times for “treat and release” ED patients appeared to increase, but triage for immediate and emergent need patients continued to improve. While earlier accounts had reported increased patient safety events during the COVID-19 PHE, data collected for the NHQDR do not show higher event rates when analyses are restricted to hospitalized non-COVID-19 patients. NHQDR data, however, do show disparities in some patient safety outcomes. Hispanic, non-Hispanic Black, and non-Hispanic API patients experienced the worst outcomes for postoperative sepsis.

## Resources

AHRQ Tools To Reduce Hospital-Acquired Conditions (https://www.ahrq.gov/hai/hac/tools.html). Hospital-acquired conditions (HACs) are those a patient develops while in the hospital being treated for something else. These conditions harm patients. Hospitals and healthcare providers are focused on reducing specific HACs that occur frequently, can cause significant harm, and are often preventable based on existing evidence. To reduce these HACs and other adverse events in hospitals, AHRQ has created numerous tools and resources.

Toolkit for Decolonization of Non-ICU Patients With Devices (https://www.ahrq.gov/hai/tools/abate/index.html) can help hospital infection prevention programs implement a decolonization protocol that was found to reduce bloodstream infections by more than 30% in adult inpatients who were not in intensive care units and who had specific medical devices. It includes implementation instructions, demonstration videos, and customizable tools.

i Unless noted otherwise, for trend analyses, data points under each figure only report differences that are statistically significant (i.e., p value less than 0.1) and show an average annual percentage change greater than 1% per year. For comparisons between two populations, data points under each figure only report differences that are statistically significant (i.e., p value less than 0.05) and have a relative difference between the populations of at least 10%. Readers may learn more about NHQDR’s reporting methodology in Appendix A at https://www.ahrq.gov/research/findings/nhqrdr/nhqdr23/index.html.

## References

1 Centers for Disease Control and Prevention. Implementation of Mitigation Strategies for Communities With Local COVID-19 Transmission. Updated May 23, 2021.
2 Centers for Disease Control and Prevention. How COVID-19 Spreads. Last updated August 11, 2022. https://www.cdc.gov/coronavirus/2019-ncov/prevent-getting-sick/how-covid-spreads.html. Accessed October 27, 2023.
3 Jacobsen GD, Jacobsen KH. Statewide COVID-19 stay-at-home orders and population mobility in the United States. World Med Health Policy. 2020 Dec;12(4):347–356. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7405141/. Accessed October 27, 2023.32837774
4 Czeisler MÉ, Marynak K, Clarke KE, Salah Z, Shakya I, Thierry JM, Ali N, McMillan H, Wiley JF, Weaver MD, Czeisler CA, Rajaratnam SM W, Howard ME. Delay or avoidance of medical care because of COVID-19– related concerns — United States, June 2020. MMWR Morb Mortal Wkly Rep. 2020;69:1250–1257. 10.15585/mmwr.mm6936a4. Accessed October 27, 2023.32915166
5 Clarke KE N, Hong K, Schoonveld M, Greenspan AI, Montgomery M, Thierry JM. Severity of coronavirus disease 2019 hospitalization outcomes and patient disposition differ by disability status and disability type. Clin Infect Dis. 2023 Mar 4;76(5):871–880. 10.1093/cid/ciac826. Accessed October 27, 2023.36259559
6 Wong R, Lovier MA. Relationship between dementia, COVID-19 risk, and adherence to COVID-19 mitigation behaviors among older adults in the United States. Int J Geriatr Psychiatry. 2022 Jun;37(6):10.1002/gps.5735. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9348266/. Accessed November 20, 2023.
7 Bronskill SE, Maclagan LC, Maxwell CJ, Iaboni A, Jaakkimainen RL, Marras C, Wang X, Guan J, Harris DA, Emdin A, Jones A, Sourial N, Godard-Sebillotte C, Vedel I, Austin PC, Swartz RH. Trends in health service use for Canadian adults with dementia and Parkinson disease during the first wave of the COVID-19 pandemic. JAMA Health Forum. 2022;3(1):e214599. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC8903126/. Accessed November 20, 2023.35977228
8 Hartnett KP, Kite-Powell A, DeVies J, Coletta MA, Boehmer TK, Adjemian J, Gundlapalli AV; National Syndromic Surveillance Program Community of Practice. Impact of the COVID-19 pandemic on emergency department visits — United States, January1, 2019–May 30, 2020. MMWR Morb Mortal Wkly Rep. 2020;69:699–704. 10.15585/mmwr.mm6923e1.32525856
9 Jain S, Self WH, Wunderink RG, ; CDC EPIC Study Team. Community-acquired pneumonia requiring hospitalization among U.S. adults. N Engl J Med. 2015 Jul 30;373(5):415–427. https://www.nejm.org/doi/10.1056/NEJMoa1500245. Accessed October 27, 2023.26172429
10 Weiner SG, Venkatesh AK. Despite CMS reporting policies, emergency department boarding is still a big problem—the right quality measures can help fix it. Health Affairs Forefront. 2022 Mar 29. https://www.healthaffairs.org/content/forefront/despite-cms-reporting-policies-emergency-department-boarding-still-big-problem-right. Accessed November 20, 2023.
11 French G, Hulse M, Nguyen D, Sobotka K, Webster K, Corman J, Aboagye-Nyame B, Dion M, Johnson M, Zalinger B, Ewing M. Impact of hospital strain on excess deaths during the COVID-19 pandemic — United States, July 2020–July 2021. MMWR Morb Mortal Wkly Rep. 2021;70:1613–1616. 10.15585/mmwr.mm7046a5. Accessed October 27, 2023.34793414
12 Eldridge N, Wang Y, Metersky M, Eckenrode S, Mathew J, Sonnenfeld N, Perdue-Puli J, Hunt D, Brady PJ, McGann P, Grace E, Rodrick D, Drye E, Krumholz HM.. Trends in adverse event rates in hospitalized patients, 2010-2019. JAMA. 2022;328(2):173–183. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9277501/. Accessed November 20, 2023.35819424
13 Fleisher L, Schreiber M, Cardo D, Srinivasan A. Health care safety during the pandemic and beyond - building a system that ensures resilience. N Engl J Med. 2022;386(7):609–611. https://www.nejm.org/doi/10.1056/NEJMp2118285. Accessed November 27, 2023.35148040
14 Weiner-Lastinger LM, Pattabiraman V, Konnor RY, Patel PR, Wong E, Xu SY, Smith B, Edwards JR, Dudeck MA. The impact of coronavirus disease 2019 (COVID-19) on healthcare-associated infections in 2020: a summary of data reported to the National Healthcare Safety Network. Infect Control Hosp Epidemiol. 2022 Jan;43(1):12–25. https://www.cambridge.org/core/journals/infection-control-and-hospital-epidemiology/article/impact-of-coronavirus-disease-2019-covid19-on-healthcareassociated-infections-in-2020-a-summary-of-data-reported-to-the-national-healthcare-safety-network/8197F323F4840D233A0C62F4726287E1. Accessed November 20, 2023.34473013
15 Isaacs K. How PPE for COVID-19 impacts patient communication. RDH. 2021 Mar 1. https://www.rdhmag.com/infection-control/article/14189079/how-personal-protective-equipment-ppe-for-covid19-impacts-patient-communication (https://www.rdhmag.com/infection-control/article/14189079/how-personal-protective-equipment-ppe-for). Accessed November 27, 2023.
16 Agency for Healthcare Research and Quality. PSNet. Patient Safety Events and the Role of Patient Safety Organizations During the COVID-19 Pandemic. https://psnet.ahrq.gov/perspective/patient-safety-events-and-role-patient-safety-organizations-during-covid-19-pandemic (https://psnet.ahrq.gov/perspective/patient-safety-events-and). Accessed November 27, 2023.
17 Agency for Healthcare Research and Quality. User Notification on COVID-19 Impact on AHRQ QI Software. July 2020. https://qualityindicators.ahrq.gov/Downloads/Resources/User_note_COVID.pdf. Accessed November 27, 2023.
18 Huggins A, Husaini M, Wang F, Waken RJ, Epstein AM, Orav EJ, Joynt Maddox KE. Care disruption during COVID-19: a national survey of hospital leaders. J Gen Intern Med. 2023 Apr;38(5):1232–1238. https://doi.org/10.1007/s11606-022-08002-5. Accessed October 27, 2023.36650332
19 Woodruff A, Frakt AB. COVID-19 pandemic leads to decrease in emergency department wait times. JAMA Health Forum. 2020;1(9):e201172. https://doi.org/10.1001/jamahealthforum.2020.1172. Accessed October 27, 2023.36218735