# Impact of COVID-19 on Population Health, 2020-2022

Americans experienced COVID-19 in starkly different ways across regions and communities. The virus initially appeared in densely populated coastal cities, such as New York, Seattle, and Los Angeles, where high population density and close living arrangements facilitated its rapid spread through communities. The sudden surge in cases strained healthcare systems, states, and communities and generated visibly alarming images.

As the pandemic progressed, its spread to suburban, rural, and remote communities became less visible and manifested in different ways, even as COVID-19 deaths grew. In less densely populated communities, the virus often spread more slowly but had higher case-fatality rates, due in part to limited healthcare infrastructure. Thus, paradoxically, people living in these areas were often physically separated from the immediate effects of the pandemic and did not always perceive its impact.

Americans’ varying experiences during the COVID-19 public health emergency (PHE) may partially explain how different communities held diverging perceptions of the pandemic’s toll in the face of varying levels of risk and access to healthcare services. Nationally, however, COVID-19’s effect on the population may be viewed as occurring in three overlapping periods between January 2020 and May 2023. During this time, the nation’s response appeared to worsen, as deaths increased despite having more knowledge about the virus and greater access to tests, treatments, and, most notably, vaccines.

❖ COVID-19 deaths increased during the second year of the public health emergency.

January 2020 through February 2021. The first period was characterized by the emergence of a contagious, previously unknown pathogenic virus. It began with the Secretary of Health and Human Services announcing the COVID-19 PHE on January 31, 2020, and ended shortly after the Food and Drug Administration issued an emergency use authorization (EUA) for a third effective COVID-19 vaccine on February 27, 2021.

During this time, healthcare delivery systems had less knowledge about the disease, limited capacity to detect the virus that caused it, and few treatment options for people who got it. Global supply chain disruptions across multiple sectors added to the challenges, forcing healthcare delivery systems to contend with shortages of critical resources such as ventilators, disinfectants, and personal protective equipment.

The nation’s initial response focused on limiting disease transmission, increasing capacity to treat it, and redirecting many healthcare delivery systems’ resources to supporting public health activities. Although the disease continued to spread to previously unaffected regions of the country, the initial response appeared to blunt COVID-19’s impact, as national mortality rates decreased in the latter half of 2020.

December 2020 through March 2022. The second period was characterized by the emergence of successive “variants of concern.” It began with detection of the Alpha variant in Colorado on December 29, 2020, and continued through the tapering of a surge in COVID-19 associated with the Omicron variant in March 2022. The variants of concern were more transmissible than the original SARS-CoV-2 strain. But by the beginning of this period, knowledge about the disease and testing capacity had increased, treatments had improved, and effective vaccines had become available. Thus, the rise in COVID-19 mortality rates that occurred in 37 states in 2021 (Figure 1) may have been avoidable.

March 2022-May 2023. The third period began with the waning of the Omicron surge and ended with the lapse of the COVID-19 PHE declaration on May 11, 2023, when the nation left the emergency phase of the pandemic. This special emphasis topic does not cover this phase because data from this period are emerging or not yet available.

Figure 1 COVID-19 deaths per 100,000 population, 2020 (top) and 2021 (bottom)

Source: Centers for Disease Control and Prevention, National Center for Health Statistics. National Vital Statistics System, Mortality, 2020 and 2021. Accessed on CDC WONDER Online Database, released in 2023.

- In 2020, the median state-level mortality rate due to COVID-19 was 842 deaths per 100,000 population, ranging between 588 deaths per 100,000 population (Hawaii) and 1,139 deaths per 100,000 population (Mississippi) (Figure 1).
- In 2021, the median state-level mortality rate due to COVID-19 was 881 deaths per 100,000 population, ranging between 630 deaths per 100,000 population (Hawaii) and 1,229 deaths per 100,000 population (West Virginia).
- Ten States had lower COVID-19 mortality rates in 2021 than in 2020. Six began with 2020 COVID-19 death rates that were lower than the median:
  ■ Connecticut (decrease from 769.1 to 725.1 deaths per 100,000 population),
  ■ Maryland (decrease from 820.5 to 805.5 deaths per 100,000 population).
  ■ Massachusetts (decrease from 756.7 to 721.4 deaths per 100,000 population),
  ■ New Jersey (decrease from 834.4 to 731.1 deaths per 100,000 population),
  ■ New York (decrease from 797.1 to 713.1 deaths per 100,000 population), and
  ■ Rhode Island (decrease from 806.6 to 781.3 deaths per 100,000 population).
  - The other four states were:
  ■ Illinois (decrease from 850.7 to 825.3 deaths per 100,000 population),
  ■ Iowa (decrease from 848.6 to 841.8 deaths per 100,000 population),
  ■ North Dakota (decrease from 848.8 to 794.2 deaths per 100,000 population), and
  ■ South Dakota (decrease from 868.1 to 858.9 deaths per 100,000 population).

## Factors Contributing to COVID-19 Mortality

The two primary risks that determined overall COVID-19 mortality rates were:

1. The risk of becoming infected.
2. The risk of dying when infected.

Factors that influenced whether a person became infected included:

- The transmissibility of the virus and its variants.
- A weakened immune system, such as from cancer, previous organ transplantation, and chronic diseases, such as obesity and diabetes.
- Living conditions that increased risk for exposure to infected people, such as crowded multifamily housing and residential long-term care facilities.
- Activities that increased exposure to many people or to people likely to have an active infection, including:
  ■ Employment in “essential worker” occupations, such as serving food in restaurants; processing food in meat-packing facilities; teaching in schools; and providing healthcare services. Essential occupations were deemed necessary to maintain societal and economic activity, although states varied in terms of which occupations were included in this definition. Essential occupations often involved working in crowded conditions or in direct contact with customers, clients, and patients.
  ■ Participating in social activities, such as concerts or other large social gatherings.
- Lack of appropriate barrier protections, such as masks in public settings and personal protective equipment in healthcare delivery settings.
- Lack of receipt of the COVID-19 vaccine or its boosters.

Factors that influenced whether a person died from COVID-19 when infected included:

- The lethality of the virus and its variants.
- A weakened immune system, such as from cancer, previous organ transplantation, and chronic diseases, such as obesity and diabetes.
- Lack of COVID-19 vaccination.
- Lack of access to appropriate healthcare resources to support vital functions, such as oxygen, ventilators, and other intensive care services.
- Lack of access to treatments specific to COVID-19, such as monoclonal antibodies and antiviral medications.

Healthcare delivery systems played important roles responding to both risks.

❖ Responding to COVID-19 depended on both the public health system and healthcare delivery systems.

Although the COVID-19 pandemic was a PHE, decades of chronic underfunding left the public health system poorly prepared to respond to the scale and urgency of the threat posed by COVID-19. Thus, the nation also relied on healthcare delivery systems, such as hospitals, nursing homes, pharmacies, and medical offices, to perform essential functions, such as surveillance testing, contact tracing, and vaccine distribution. The data that follow reflect the effectiveness of both public health and healthcare delivery systems combined.

## COVID-19 Vaccine Use

The nation initially anticipated that several years would be needed to develop a COVID-19 vaccine. Thus, the availability of effective vaccines by December 2020 was a welcome result of Operation Warp Speed (OWS), a public-private partnership to accelerate development, manufacturing, and distribution of vaccines, diagnostic tests, and treatments. This initiative involved the Departments of Health and Human Services and Defense, among others.

OWS ultimately produced four vaccines that received EUA from the Food and Drug Administration.^i^ Two were developed with previously untested mRNA technology. This process significantly accelerated vaccine development over previously established methods such as using adenovirus vectors or using adjuvanted recombinant proteins to stimulate antibody production.

Efficacy-focused clinical trials reported that the two-dose “primary series” Pfizer-BioNTech (BNT162b2) vaccine was 95% effective in preventing SARS-CoV-2 infection.^1^ Other studies reported two-dose Moderna (mRNA-1273) COVID-19 vaccines as 94.1% effective in preventing infection.^2^

In addition to reducing disease transmission, COVID-19 vaccines decreased emergency department visits, hospitalizations, need for intensive care, and deaths associated with the virus.3,4 A recent analysis by the Commonwealth Fund estimates that the vaccines averted more than 18.5 million hospitalizations and 3.2 million deaths between their EUA in December 2020 and the end of November 2022.^5^

Guidelines initially prioritized healthcare workers, residents of long-term care facilities, people age 65 and over, and people with certain medical conditions to receive the vaccine due to limited supplies in December 2020. But by May 2021, the nation had produced sufficient supplies to vaccinate all eligible adults, encouraging confidence that the United States would achieve the goal of administering at least one COVID-19 vaccine to 70% of the eligible population.^6,7^

Figure 2 Adults who received at least one dose or two doses of the COVID-19 vaccine, total and by age, 2021

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- In 2021, 71.6% of all adults had received one dose of a COVID-19 vaccine, and 56.6% had received two doses (Figure 2).^ii^
- Adults age 65 years and over were more likely to receive two doses of the COVID-19 vaccine than adults ages 45-64 years (68.3% vs. 60.3%) and adults ages 18-44 years (68.3% vs. 48.3%).

Federal efforts to ensure wide distribution and use of the COVID-19 vaccine included funding information campaigns, establishing mass vaccination sites, and requiring health insurance coverage for the vaccine without cost sharing, prior authorization, or other cost management requirements.^iii^ Despite these efforts, data show disparities in the percentage of people who received the primary series (i.e., two doses) of COVID-19 vaccines (Figures 3–6).

The data show state-level variation in vaccine use with a median state-level vaccination rate of 61.1%, ranging from 49.1% to 79.6%. Notably, the data show socioeconomic differences in vaccination rates, indicating that universal coverage for the vaccine was, by itself, insufficient to ensure equitable vaccine use.

Figure 3 Adults who received two doses of the COVID-19 vaccine, by state, 2021

Source: Centers for Disease Control and Prevention, COVID-19 Data Tracker, COVID-19 Case Surveillance Public Use Data, 2021.

Figure 4 Adults who received two doses of the COVID-19 vaccine, by age, 2021

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- In 2021, a higher percentage of adults age 65 years and over (68.3%) completed the primary series COVID-19 vaccine than adults ages 45-64 years (60.3%) or adults ages 18-44 years (48.3%) (Figure 4).

❖ People in nonmetropolitan locations were less likely to get the COVID-19 vaccine.

Figure 5 Adults who received two doses of the COVID-19 vaccine, by race/ethnicity and location of residence, 2021

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native.

Note: Data for Native Hawaiian/Pacific Islander individuals did not meet the criteria for statistical reliability.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- The percentages of adults who completed the primary COVID-19 vaccine series were similar among non-Hispanic American Indian or Alaska Native (NH-AI/AN) (47.6%), NH-multiracial (50.2%), Hispanic (52.1%), and NH-Black (52.3%) adults (Figure 5).
- For comparison, 57.4% of NH-White and 72.6% of NH-Asian adults completed the primary COVID-19 vaccine series.
- The percentages were similar for people living in large central and large fringe metro areas (60.5% and 60.0%) and for people in micropolitan and noncore areas (46.9% and 45.1%).
- The percentages were higher for people in large central (60.5%) and large fringe metro areas (60.0%) than for people in medium metro areas (55.5%), followed by people in small metro areas (51.9%) and people in noncore areas (45.1%).

❖ Private health insurance and higher socioeconomic status increased vaccine use.

Figure 6 Adults who received two doses of the COVID-19 vaccine, by health insurance, household income, and Social Vulnerability Index group, 2021

Key: PG = federal poverty guideline; SVI = Social Vulnerability Index.

Note: Vaccination rates by health insurance status include data only for adults under age 65 years.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- In 2021, the percentage of adults who completed the primary COVID-19 vaccine series was higher among people with private insurance (59.0%) than among those with publicly sponsored insurance (42.6%) or no insurance (37.4%) (Figure 6).
- The percentage of adults who completed the primary COVID-19 vaccine series was higher among people with household incomes 400% or more of the poverty guideline (PG) (63.8%) than among people with incomes 200%-399% of the PG (55.9%), 100%-199% of the PG (47.3%), or below the PG (43.1%).
- The percentage of adults who completed the primary COVID-19 vaccine series was higher among people who lived in the lowest Social Vulnerability Index (SVI)^iv^ areas (60.3%) than among those who lived in low SVI areas (57.6%), medium SVI areas (56.0%), or high SVI areas (53.0%).

## Healthcare Delivery of COVID-19 Vaccines

Factors that may explain variation in COVID-19 vaccine use include:

- Structural health system barriers (e.g., not knowing where to get the vaccine, having trouble using online scheduling systems, having trouble getting to vaccination sites, living in areas without appropriate vaccine storage facilities);
- Socioeconomic barriers (e.g., inability to take time off from work to get the vaccine or to recover from vaccination side effects); and
- Vaccine hesitancy (e.g., concern about risks associated with getting the vaccine).

Surveys and polls show that people, notably those living in rural areas, trusted their healthcare providers over other sources for information about the COVID-19 vaccine. Thus, local healthcare providers recommending the vaccine may have been an important determinant of vaccine use.^8,9,10^

National Immunization Survey data show that the percentage of people who received a recommendation for the vaccine from their healthcare provider varied among states (Figure 7) and by age (Figure 8). They also show that a lower percentage of people in nonmetropolitan areas (not in a metropolitan statistical area, or MSA) received a recommendation than people in MSAs, both in principal cities and non-principal cities (Figure 9).

The percentage was also lower for people without health insurance compared with people with insurance. However, the percentage of people recommended to get the vaccine was similar among people with different incomes and among people living in counties with different SVI scores (Figure 10).

The overall pattern shown below suggests that people in non-MSAs were less likely to be recommended for the vaccine because they were also less likely to have access to a provider, not because providers in metropolitan and nonmetropolitan locations recommended the vaccine at different rates.

Figure 7 Adults who received a recommendation from a doctor, nurse, or other health professional to get the COVID-19 vaccine, by state, 2021

U.S. map showing percentage by state; Massachusetts was highest and wyoming was lowest; key points are in the text below

Source: Centers for Disease Control and Prevention, National Center for Immunization and Respiratory Diseases, National Immunization Survey - Adult COVID Module, 2021.

- The median state-level percentage of people who received a recommendation from a health professional to get the COVID-19 vaccine was 38.6% in 2021. It ranged from 32.3% to 47.2% (Figure 7).

Figure 8 Adults who received a recommendation from a doctor, nurse, or other health professional to get the COVID-19 vaccine, by age, 2021

Source: Centers for Disease Control and Prevention, National Center for Immunization and Respiratory Diseases, National Immunization Survey - Adult COVID Module, 2021.

- In 2021, the percentage of people who received a recommendation to get the COVID-19 vaccine was higher among people ages 65-74 years (46.7%) than among people ages 50-64 years (43.1%), 40-49 years (40.4%), 30-39 years (38.1%), 25-29 years (32.1%), and 18-24 years (30.5%) (Figure 8).
- In 2021, the percentage of people who received a recommendation to get the COVID-19 vaccine also was higher for people ages 65-74 years (46.7%) than for people age 75 years and over (43.5%).

Figure 9 Adults who received a recommendation from a doctor, nurse, or other health professional to get the COVID-19 vaccine, by race/ethnicity and location of residence, 2021

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander; MSA = metropolitan statistical area.

Source: Centers for Disease Control and Prevention, National Center for Immunization and Respiratory Diseases, National Immunization Survey - Adult COVID Module, 2021.

- Similar percentages of people in different racial/ethnic groups received a recommendation to get the COVID-19 vaccine (Figure 9).
- Similar percentages of people in the principal and non-principal cities of metropolitan statistical areas (MSAs) (40.8% and 39.8%, respectively) received a recommendation to get the COVID-19 vaccine. But a lower percentage of people in non-MSAs (37.0%) received the same recommendation. The difference between MSAs and non-MSAs falls just short of statistical significance.

❖ Socioeconomic factors did not influence being counseled to get the vaccine, but lack of health insurance did.

Figure 10 Adults who received a recommendation from a doctor, nurse, or other health professional to get the COVID-19 vaccine, by health insurance status, income, and Social Vulnerability Index group, 2021

Key: PG = federal poverty guideline; SVI = Social Vulnerability Index.

Source: Centers for Disease Control and Prevention, National Center for Immunization and Respiratory Diseases, National Immunization Survey - Adult COVID Module, 2021.

- The percentages of people who received a recommendation to get the COVID-19 vaccine was higher for adults with health insurance (41.4%) than for adults without health insurance (26.6%) (Figure 10).
- People with annual incomes higher than $75,000 per year were more likely to receive a recommendation for the COVID-19 vaccine than people with annual incomes between the PG and $75,000 and people below the PG (42.4% vs. 38.3% and 39.1%, respectively).
- The percentages of people who received a recommendation to get the COVID-19 vaccine were similar for people in counties in all SVI groups (low SVI, 40.7%; moderate SVI, 39.8%; high SVI, 39.7%,).

## Healthcare Worker Use of COVID-19 Vaccines

Healthcare workers were a vulnerable population during the COVID-19 PHE.^11^ More than 1.1 million were reported infected at work.^12^ Counts compiled from published obituaries, news reports, and government private data sources estimate that more than 3,600 died during the first 12 months of the pandemic.^13^

Healthcare workers’ vulnerability to COVID-19 also increased risks to patients due to the potential for disease transmission during the asymptomatic incubation phase of an infection. Data for healthcare worker vaccination rates provide an opportunity to further examine disparities in COVID-19 vaccine receipt.

We examined National Health Interview Survey (NHIS) public use data to characterize two groups of healthcare workers.^v^ “Direct care workers” were people who provided in-person medical services to patients, including physicians, nurses, home care workers, dental assistants, emergency responders, and other clinical professions. “Non-direct care workers” were people who worked in clinical facilities but did not have in-person contact with patients, such as hospital administrators, laboratory technicians, volunteers, and other roles. We then report vaccination rates among these groups of workers using measures provided by NHIS.

We might expect people who work in healthcare settings to have higher vaccination rates than the overall population, because they are at higher risk and direct healthcare workers were among the earliest group prioritized to receive the vaccine. In addition, we might anticipate that structural barriers, such as difficulty scheduling a vaccine appointment and getting to vaccination sites, were less likely to prevent healthcare workers from receiving the COVID-19 vaccine. Healthcare organizations actively facilitated employee vaccination and, in many cases, provided vaccines at work.

Outside their profession, healthcare workers shared many characteristics with the overall adult population. In the 2021 NHIS, the median age of direct healthcare workers was 43 years, 73.0% were female, and 85.3% lived in metropolitan counties. Most (78.3%) had private health insurance, 14.0% had publicly sponsored insurance or other coverage, and 7.6% had no insurance coverage (0.2% did not know their insurance coverage). More than half (52.4%) had household incomes 400% or more of the PG, 28.4% had incomes 200%-399% of the PG, 13.0% had incomes 100%-199% of the PG, and 6.2% lived below the PG.

The median age of non-direct healthcare workers was 50 years, 68.1% were female, and 87.3% lived in metropolitan counties. Most (81.3%) had private insurance, 11.6% had publicly sponsored or other coverage, 6.4% were uninsured, and 0.6% did not know their insurance coverage. Among non-direct healthcare workers, 48.3% had household incomes at least 400% of the PG, 32.7% had incomes 200%-399% of the PG, 12.7% had incomes 100%-199% of the PG, and 6.3% had household incomes below the PG.

Many findings related to healthcare worker vaccinations fall short of statistical significance due to the small sample of healthcare workers surveyed. But the data show that the percentage of healthcare workers who received the COVID-19 vaccine was higher than in the general population, as anticipated. They also show differences in health insurance status, household income, and location of residence associated with getting the COVID-19 vaccine. When considered in context with the overall adult population, the data suggest financial coverage for the vaccine was insufficient to ensure equitable vaccine distribution and implicate other structural, financial, and access barriers (Figures 11–16).

Figure 11 Healthcare workers and all adults who received two doses of the COVID-19 vaccine, by age, 2021

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- In 2021, among adults age 65 years and over, direct healthcare workers (73.1%) were more likely to complete the COVID-19 vaccine primary series than all adults (68.3%) and non-direct healthcare workers (63.2%). But the differences fell short of statistical significance (Figure 11).
- Among adults ages 45-64 years, direct and non-direct healthcare workers (68.6% and 69.8%) were more likely to complete the COVID-19 vaccine primary series than all adults (60.3%).
- Among adults ages 18-44 years, non-direct healthcare workers (62.6%) were more likely to complete the COVID-19 vaccine primary series than either direct healthcare workers (58.0%) or all adults (48.3%).

Figure 12 Healthcare workers and all adults who received two doses of the COVID-19 vaccine, by ethnicity, 2021

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- In 2021, within each ethnic group, direct and non-direct healthcare workers were more likely than all adults to complete the primary COVID-19 vaccine series, but the differences fell short of statistical significance due to small sample sizes of healthcare workers (Figure 12).
- Among direct and non-direct healthcare workers, ethnic differences in getting the vaccine were not statistically significant: 57.9% of NH-Black, 60.2% of Hispanic, and 63.5% of NH-White direct healthcare workers completed the COVID-19 vaccine primary series. Among non-direct healthcare workers, 57.7% of NH-Black, 65.5% of NH-White, and 69.8% of Hispanic workers did.

Figure 13 Healthcare workers and all adults who received two doses of the COVID-19 vaccine, by location of residence, 2021

Note: Data for non-direct healthcare workers in micropolitan and noncore areas are not included because the sample sizes are too small to produce statistically reliable estimates.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- Healthcare worker vaccination correlated with metropolitan location of residence (Figure 13).
- The percentage of direct healthcare workers who completed the primary COVID-19 vaccine series in 2021 was higher in large central metro (64.5%), large fringe metro (65.3%), and medium metro (66.4%) counties than in small metro counties (52.2%) and noncore areas (52.2%).
- The percentage of non-direct healthcare workers who completed the primary COVID-19 vaccine series was higher in large central metro (71.1%) and large fringe metro (69.3%) counties than in medium metro (61.2%) and small metro (58.3%) counties, but the differences fell short of statistical significance.

❖ Lack of health insurance and low socioeconomic status hindered COVID-19 vaccine receipt, even for healthcare workers.

Figure 14 Healthcare workers and all adults under age 65 years who received two doses of the COVID-19 vaccine, by health insurance status, 2021

Note: Data for non-direct healthcare workers with publicly sponsored or no insurance are not included because the sample sizes are too small to produce statistically reliable estimates.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- Direct healthcare worker vaccination correlated with private insurance status (Figure 14).
- In 2021, direct healthcare workers with private health insurance (66.8%) were approximately 1.5 times as likely to complete the primary series COVID-19 vaccine as direct healthcare workers with publicly sponsored insurance (44.7%) or no health insurance (44.3%).

Figure 15 Healthcare workers and all adults who received two doses of the COVID-19 vaccine, by household income, 2021

Key: PG = federal poverty guideline.

Note: Data for non-direct healthcare workers with household incomes less than 100% of the PG are not included because the sample sizes are too small to produce statistically reliable estimates.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- Healthcare worker vaccination correlated with higher household income (Figure 15).
- In 2021, the percentage of direct healthcare workers completing the primary COVID-19 vaccine series was higher among workers earning 400% or more of the PG (68.0%) than for workers earning less than the PG (57.1%) and those earning 100%-199% of the PG (45.1%).
- The percentage of non-direct healthcare workers completing the primary COVID-19 vaccine series was similarly higher among workers with incomes 400% of the PG or more (69.6%) or incomes 200%-399% of the PG (68.1%) than among workers earning 100%-199% of the PG (51.6%).

Figure 16 Healthcare workers and all adults who received two doses of the COVID-19 vaccine, by Social Vulnerability Index group, 2021

Key: SVI = Social Vulnerability Index.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- In 2021, direct healthcare workers in areas with little or no social vulnerability (67.6%) were more likely to complete the primary COVID-19 vaccine series than people in areas with high SVI scores (59.9%) (Figure 16).
- Among non-direct healthcare workers, the percentages completing the primary COVID-19 vaccine series were similar in areas with little or no (64.2%), low (66.8%), moderate (64.9%), and high (65.3%) social vulnerability.

## Disparities in COVID-19 Outcomes

The COVID-19 PHE exposed wide health disparities among people of different ages, racial and ethnic groups, and residence locations.^14,15^ The data show different risk patterns behind the disparities experienced by different groups. Some groups had disproportionately high rates of infections (i.e., case rates), leading to more deaths (i.e., mortality rates). Other groups had relatively low case rates but still exhibited high mortality rates because their risk of dying when infected (i.e., case-mortality rates) was disproportionately high.

In some cases, high case-mortality rates may be explained by frailty and other age-related vulnerabilities. But in other cases, disproportionate case-mortality rates suggest that suboptimal vaccine use, access to hospital care, and quality of care or a combination of these factors contributed to the health disparity.

### Age Disparities

COVID-19 disproportionately affected older populations. Although adults age 65 years and over were less likely to become infected with COVID-19 during surges associated with the Alpha, Delta, and Omicron variants and were more likely to get the COVID-19 vaccine when they became available, they were more likely to die from the disease. A plausible explanation for these findings is that older people sought to avoid exposure to COVID, but they were at greater risk of dying when infected due to age-related factors such as physical frailty, chronic illness, and a weakened immune system.

Data also show that older adults’ risk of dying when infected decreased over time, possibly related to factors such as higher vaccination rates, rising prevalence of population-level immunity, and attenuation of the virus’s virulence. It is also possible that the most vulnerable people died in earlier waves of the pandemic. Still, adults age 65 years and over remained at higher risk of dying from COVID-19 than the overall population as recently as 2022.

Figure 17 COVID-19 cases per 100,000 population, by age, January 2020-December 2022

Note: Case rate estimates in the first half of 2020 reflect limited testing capacity in the first months of the COVID-19 public health emergency and thus are artificially low.

Source: Centers for Disease Control and Prevention, COVID Data Tracker, Surveillance Public Use Data, January 2020-December 2022.

- In 2021, older adults were less likely than other age groups to get infected (Figure 17).
- In December 2020, during a surge in cases associated with the Alpha variant, the highest case rates were reported in adults ages 18-49 years (2,128 cases per 100,000 population), followed by adults ages 50-64 years (1,824 cases per 100,000 population). The rate among adults age 65 years and over was 1,399 cases per 100,000 population, and the rate among children and adolescents ages 0-17 years was 930 cases per 100,000 population.
- In August 2021, during a surge in cases associated with the Delta variant, the highest case rates were reported in adults ages 18-49 years (1,367 cases per 100,000 population), followed by children and adolescents ages 0-17 years (1,158 cases per 100,000 population). The rate for adults ages 50-64 years was 896 cases per 100,000 population, and the rate for adults age 65 years and over was 628 cases per 100,000 population.
- In January 2022, during a surge in cases associated with the Omicron variant, the highest case rates were reported in adults ages 18-49 years (5,642 cases per 100,000 population), followed by children and adolescents ages 0-17 years (4,770 cases per 100,000 population). The rate for adults ages 50-64 years was 3,910 cases per 100,000 population, and the rate for adults age 65 years and over was 2,525 cases per 100,000 population.

Figure 18 Adults who received two doses of the COVID-19 vaccine, by age, 2021

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- Older adults were more likely to get the COVID-19 vaccine than younger adults (Figure 18), but older adults were more likely to die from COVID-19 (Figure 19).

Figure 19 COVID-19 deaths, by age, January 2020-December 2022

Source: Centers for Disease Control and Prevention, COVID Data Tracker, Surveillance Public Use Data, January 2020-December 2022.

- In April 2020, during a surge associated with the original SARS-CoV-2 virus, the highest number of deaths occurred in adults age 65 years and over (49,705 deaths), followed by adults ages 50-64 years (9,409 deaths) and adults ages 18-49 years (2,689 deaths) (Figure 19).
- In January 2021, during a surge associated with the Alpha variant, the highest number of deaths occurred in adults age 65 years and over (77,583 deaths), followed by adults ages 50-64 years (14,764 deaths). The number of deaths among adults ages 18-49 years was 3,845, and 11 children and adolescents ages 0-17 years died.
- In September 2021, during a surge associated with the Delta variant, the highest number of deaths occurred in adults age 65 years and over (33,762 deaths), followed by adults ages 50-64 years (16,961 deaths). The number of deaths among adults ages 18-49 years was 8,268, and 78 children and adolescents ages 0-17 years died.
- In January 2022, during a surge associated with the Omicron variant, the highest number of deaths occurred in adults age 65 years and over (53,218 deaths), followed by adults ages 50-64 years (11,274 deaths). The number of deaths among adults ages 18-49 years was 4,879, and 115 children and adolescents ages 0-17 years died.

Figure 20 COVID-19 deaths per 1,000 cases, by age, January 2020-December 2022

Source: Centers for Disease Control and Prevention, COVID Data Tracker, Surveillance Public Use Data, January 2020-December 2022.

- A major reason for higher mortality rates is that older adults were more likely to die from COVID-19 if infected (Figure 20). Notably, the risk has decreased over time.
- In April 2020, during a surge associated with the original SARS-CoV-2 virus, the case-mortality rate was highest in adults age 65 years and over (270.1 deaths per 1,000 cases), followed by adults ages 50-64 years (49.3 deaths per 1,000 cases), and adults ages 18-49 years (7.6 deaths per 1,000 cases).
- In February 2021, during a surge associated with the Alpha variant, the case-mortality rate was highest in adults age 65 years and over (138.9 deaths per 1,000 cases), followed by adults ages 50-64 years (19.9 deaths per 1,000 cases), and adults ages 18-49 years (1.8 deaths per 1,000 cases).
- In September 2021, during a surge associated with the Delta variant, the case-mortality rate was highest in adults age 65 years and over (99.6 deaths per 1,000 cases), followed by adults ages 50-64 years (33.1 deaths per 1,000 cases), adults ages 18-49 years (5.2 deaths per 1,000 cases), and children and adolescents ages 0-17 years (0.1 deaths per 1,000 cases).
- In February 2022, during a surge associated with the Omicron variant, the case-mortality rate was highest in adults age 65 years and over (86.2 deaths per 1,000 cases), followed by adults ages 50-64 years (12.7 deaths per 1,000 cases), adults ages 18-49 years (1.5 deaths per 1,000 cases), and children and adolescents ages 0-17 years (0.1 deaths per 1,000 cases).

### Racial and Ethnic Disparities

Although the Centers for Disease Control and Prevention (CDC) case surveillance data must be interpreted with caution, as only an estimated 67% of cases had data for race and ethnicity, they show that COVID-19 affected some racial and ethnic groups more than others. Of seven racial and ethnic groups monitored by the NHQDR team, four (Hispanic, NH-AI/AN, NH-Black, and NH-Native Hawaiian/Pacific Islander [NHPI]) experienced disproportionately high COVID-19 mortality rates in 2021 compared with the overall population. Among these groups, however, the patterns of case and case-mortality data suggest different underlying causes of the disparities.

Case data show that NH-NHPI people were one of the least likely racial and ethnic groups to get infected with COVID-19 during the variant-associated surges. But case-mortality data indicate that NH-NHPI populations had the highest deaths per 1,000 cases when infected. This pattern suggests that lack of access to treatment or lack of treatment effectiveness was a more likely explanation for high COVID-19 deaths in this group than conditions exposing them to the disease.

Limited use of COVID-19 vaccines, which enhance treatment effectiveness, may have contributed to preventable deaths in this population, as case-mortality rates correlated with low vaccination rates among these groups. Barriers preventing access to treatment when local hospitals were overwhelmed during variant-associated surges may also have contributed.

In contrast, Hispanic and NH-Black populations had high case rates and case-mortality rates similar to or lower than NH-White populations. This finding suggests that elevated risk of acquiring the infection (e.g., work-related exposures or crowded housing conditions) was a more important contributor to high COVID-19 mortality than access to care or treatment effectiveness.

NH-AI/AN people experienced the highest overall COVID-19 mortality rates from 2020 to 2022. The pattern of disproportionately high case and case-mortality rates in this population suggests both increased risk of getting infected and decreased access to vaccines and healthcare services as contributing to high COVID-19 mortality rates in this population.

Figure 21 Monthly COVID-19 cases per 100,000 population, by race/ethnicity, January 2020-December 2022

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: CDC estimates that racial/ethnic data in public case surveillance files were available for approximately 67% of cases. Case rate estimates in the first half of 2020 reflect limited testing capacity in the first months of the COVID-19 public health emergency and thus are artificially low. Lower panels use different vertical axis scales to show differences among racial/ethnic groups.

Source: Centers for Disease Control and Prevention, COVID Data Tracker, Surveillance Public Use Data, January 2020-December 2022.

- Case rates between the highest and lowest groups varied among people of different racial/ethnic groups, with rankings shifting among groups between January 2020 and December 2022 (Figure 21).
- In December 2020, during a surge in cases associated with the Alpha variant, the highest case rates were reported in NH-AI/AN groups (1,055 cases per 100,000 population), followed by Hispanic (988 per 100,000 population), NH-White (914 per 100,000 population), NH-Black (765 per 100,000 population), NH-Asian (659 per 100,000 population), NH-multiracial (630 per 100,000 population), and NH-NHPI (566 per 100,000 population) groups.
- In August 2021, during a surge in cases associated with the Delta variant, the highest case rates were reported in NH-Black groups (930 cases per 100,000 population), followed by NH-AI/AN (808 per 100,000 population), NH White (742 per 100,000 population), Hispanic (591 per 100,000 population), NH-NHPI (520 per 100,000 population), NH-multiracial (449 per 100,000 population), and NH-Asian (250 per 100,000 population) groups.
- In January 2022, during a surge in cases associated with the Omicron variant, the highest case rates were reported in NH-multiracial groups (3,074 cases per 100,000 population), followed by NH-AI/AN (2,979 per 100,000 population), NH-Black (2,877 per 100,000 population), Hispanic (2,837 per 100,000 population), NH-Asian (2,682 per 100,000 population), NH-White (2,485 per 100,000 population), and NH-NHPI (2,369 per 100,000 population) groups.

Figure 22 Adults who ever had COVID-19, by race/ethnicity, 2021

Key: NH = non-Hispanic.

Note: Percentage of COVID-19 cases not shown for NH-AI/AN and NH-NHPI groups because sample sizes were too small to produce statistically reliable estimates.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- In 2021, the percentage of adults who ever had COVID-19 was highest for Hispanic people (19.6%) and lowest for NH-Asian people (7.0%) (Figure 22).

Figure 23 Adults who received two doses of the COVID-19 vaccine, by race/ethnicity (top) and by race alone (bottom), 2021

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Data for race-only groups are included because sample sizes for NHPI individuals were too small to produce results that meet the criteria for statistical reliability when stratified by race and ethnicity.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- In 2021, for racial/ethnic groups, the percentage of adults completing the primary COVID-19 vaccine series (from lowest to highest) was:
  ■ NH-AI/AN, 47.6%,
  ■ NH-multiracial, 50.2%,
  ■ Hispanic, 52.1%,
  ■ NH-Black, 52.3%,
  ■ NH-White, 57.4%, and
  ■ NH-Asian, 72.6% (Figure 23).
- In 2021, for race-only groups, the percentage of adults completing the primary COVID-19 vaccine series (from lowest to highest) was:
  ■ NHPI, 45.8%,
  ■ AI/AN, 47.8%,
  ■ Multiracial, 50.4%,
  ■ Black, 52.0%,
  ■ White, 56.7%, and
  ■ Asian adults, 72.5%.

Figure 24 Monthly COVID-19 deaths per 1,000 cases, by race/ethnicity, January 2020-December 2022

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Data for Hispanic, NH-AI/AN, NH-Asian, NH-NHPI, and NH-multiracial groups were not available before March 2020. Lower panels use different vertical axis scales to show differences among racial/ethnic groups.

Source: Centers for Disease Control and Prevention, COVID Data Tracker, Surveillance Public Use Data, January 2020-December 2022.

- The case-mortality rate varied throughout January 2020 to December 2022, but NH-NHPI and NH-AI/AN exhibited disproportionately high deaths per 1,000 cases during surges associated with the Alpha, Delta, and Omicron variants (Figure 24).
- In April 2020, during the first COVID-19 surge, case-mortality was highest among NH-NHPI people (282 deaths per 1,000 cases), followed by NH-White people (215 deaths per 1,000 cases), NH-Asian people (196 deaths per 1,000 cases), NH-Black people (178 deaths per 1,000 cases), Hispanic people (114 deaths per 1,000 cases), NH-AI/AN people (103 deaths per 1,000 cases), and NH-multiracial people (53 deaths per 1,000 cases).
- In February 2021, during a surge associated with the Alpha variant, the case-mortality rate was highest among NH-NHPI people (181 deaths per 1,000 cases), followed by NH-AI/AN people (103 deaths per 1,000 cases), NH-Asian people (44 deaths per 1,000 cases), Hispanic people (41 deaths per 1,000 cases), NH-Black people (38 deaths per 1,000 cases), NH-White people (35 deaths per 1,000 people), and NH-multiracial people (11 deaths per 1,000 cases).
- In May and June 2021, during a surge associated with the Delta variant, a disproportionately high case-mortality rate was experienced by NH-AI/AN people (131 deaths per 1,000 cases in May 2021) and NH-NHPI people (102 deaths per 1,000 cases in June 2021). For comparison, the next highest case-mortality rates, experienced by NH-Asian people, were less than half as high (45 and 43 deaths per 1,000 cases in May and June 2021).
- In November 2021, at the beginning of a surge associated with the Omicron variant, case mortality was highest among NH-NHPI people (67 deaths per 1,000 cases), followed by NH-AI/AN people (33 deaths per 1,000 cases), Hispanic people (24 deaths per 1,000 cases), NH-Black people (21 deaths per 1,000 cases), NH-White people (20 deaths per 1,000 cases), NH-Asian people (14 deaths per 1,000 cases), and NH-multiracial people (6 deaths per 1,000 cases).
- In February 2022, during a surge associated with the Omicron variant, case-mortality rates had decreased in all racial and ethnic groups, and disparities among groups were also smaller. Case-mortality rates were highest among NH-AI/AN people (30 deaths per 1,000 cases) and NH-Black and NH-White people (both at 29 deaths per 1,000 cases), followed by Hispanic people (20 deaths per 1,000 cases), NH-Asian people (15 deaths per 1,000 cases), NH-NHPI people (13 deaths per 1,000 cases), and NH-multiracial people (6 deaths per 1,000 cases).

Figure 25 Annual COVID-19 deaths per 100,000 population, by race/ethnicity, 2020-2022

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Mortality, 2020-2022, Accessed on CDC WONDER Online Database, released in 2023.

- The groups with the highest COVID-19 death rates from 2020 to 2022 were NH-AI/AN, Hispanic, NH-NHPI, and NH-Black people. Death rates among NH-NHPI people are notable for the sharp rise in 2021 (Figure 25).

### Urban-Rural Disparities

Although people in densely populated cities accounted for a large portion of COVID-19 deaths in early 2020, people in nonmetropolitan communities were more likely to die from the disease during the surges associated with the Alpha, Delta, and Omicron variants in the latter half of 2020 and 2021.

Monthly case surveillance data from 2021 show an inconsistent pattern of infection risk among rural and urban communities, whereby rural case rates were higher than urban case rates during some variant-associated surges and lower in other surges. However, mortality rates (i.e., risk of dying from COVID-19) were consistently higher in rural communities during every variant-associated surge in 2021.

One explanation for this pattern is rural populations are older than those in urban communities and thus more likely to die from age-related vulnerability to COVID-19. However, younger adults in rural communities also experienced higher mortality rates than people in urban areas. Another, more plausible explanation is that people in nonmetropolitan communities were less likely to be vaccinated.

Other potential reasons include less access to critical care services, worse care due to overwhelmed hospital capacity, or a combination of these factors. Although NHQDR data cannot disentangle the possibilities, they point to opportunities for improving vaccine distribution and increasing access to care in rural communities.

Figure 26 Monthly COVID-19 cases, by location of residence, March 2020-December 2022

Note: Case-rate estimates in the first half of 2020 reflect limited testing capacity in the first months of the COVID-19 public health emergency and thus are artificially low.

Source: Centers for Disease Control and Prevention, COVID Data Tracker, Surveillance Public Use Data, March 2020-December 2022.

- Case rates did not follow a consistent pattern with regard to urban-rural status (Figure 26).
- In December 2020, during a surge associated with the Alpha variant, the highest to lowest cases per 100,000 population were 2,245 in micropolitan counties, 2,177 in large central metro counties, 2,171 in noncore areas, 2,127 in small metro counties, 2,070 in medium metro counties, and 2,005 in large fringe metro counties.
- In September 2021, during a surge associated with the Delta variant, case rates correlated with rurality. The highest to lowest cases per 100,000 population were 2,245 in noncore areas, 2,154 in micropolitan areas, 1,967 in small metro counties, 1,731 in medium metro counties, 1,325 in large fringe metro counties, and 1,131 in large central metro counties.
- In January 2022, during a surge associated with the Omicron variant, case rates correlated with urbanicity. The highest to lowest cases per 100,000 population were 6,745 in large central metro counties, 5,706 in large fringe metro counties, 5,667 in medium metro counties, 5,464 in small metro counties, 5,025 in micropolitan counties, and 4,517 in noncore areas.

Figure 27 Adults who ever had COVID-19, by location of residence, 2021

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- The percentage of adults who ever had COVID-19 was highest in nonmetropolitan counties (Figure 27).
- In 2021, 16.2% of adults living in noncore counties and 15.6% of adults living in micropolitan counties reported ever having COVID-19, compared with 13.3%, 13.4%, 13.2%, and 12.7% of people living in large central metro, large fringe metro, medium metro, and small metro counties, respectively.

Figure 28 Adults who received two doses of the COVID-19 vaccine, by location of residence, 2021

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- Vaccination rates in 2021 were highest in metropolitan areas and progressively decreased with rurality (Figure 28).
- In 2021, 45.1% of adults living in noncore areas and 46.9% of adults in micropolitan counties completed the primary COVID-19 vaccine series, compared with 60.5%, 60.0%, 55.5%, and 51.9% in large central metro counties, large fringe metro counties, medium metro counties, and small metro counties, respectively.

Figure 29 Monthly COVID-19 deaths per 100,000 population, by location of residence, March 2020-December 2022

Source: Centers for Disease Control and Prevention, COVID Data Tracker, Surveillance Public Use Data, March 2020-December 2022.

- Although urban communities bore the burden of deaths associated with the original SARS-CoV-2 strain, smaller metropolitan communities and rural areas experienced the highest rates of COVID-19 deaths in every subsequent variant-associated surge (Figure 29).
- In April 2020, during a surge associated with the original SARS-CoV-2 strain, COVID-19 death rates correlated with urbanicity. Deaths per 100,000 population from highest to lowest were 27.9 in large central metro counties, 22.3 in large fringe metro counties, 9.1 in medium metro counties, 5.7 in small metro counties, 5.2 in micropolitan counties, and 4.6 in noncore areas.
- In December 2020, during a surge associated with the Alpha variant, COVID-19 death rates correlated with rurality. Deaths per 100,000 population from highest to lowest were 42.7 in noncore areas, 37.8 in micropolitan counties, 33.1 in small metro counties, 26.4 in medium metro counties, 20.7 in large fringe metro counties, and 19.1 in large central metro counties.
- In September 2021, during a surge associated with the Delta variant, death rates correlated with rurality. Deaths per 100,000 population from highest to lowest were 31.0 in noncore areas, 27.6 in micropolitan counties, 24.7 in small metro counties, 21.9 in medium metro counties, 15.2 in large fringe metro counties, and 14.3 in large central metro counties.
- In December 2021, during a surge associated with the Omicron variant, death rates correlated with rurality. Deaths per 100,000 population from highest to lowest were 30.5 in noncore areas, 26.4 in micropolitan counties, 20.5 in small metro counties, 15.5 in medium metro counties, 12.3 in large fringe metro counties, and 9.4 in large central metro counties.

- In February 2022, during the continued Omicron variant surge, death rates correlated with rurality. Deaths per 100,000 population from highest to lowest were 26.6 in noncore areas, 23.4 in micropolitan counties, 21.5 in small metro counties, 18.7 in medium metro counties, 16.4 in large fringe metro counties, and 16.2 in large central metro counties.

Figure 30 Crude COVID-19 deaths per 100,000 population, by location of residence, 2020 and 2021

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System, Mortality, 2020 and 2021, Accessed on CDC WONDER Online Database, released in 2023.

- Nonmetropolitan communities experienced the highest COVID-19 death rates in both 2020 and 2021 (Figure 30).
- COVID-19 death rates were higher in nonmetropolitan counties than in metropolitan counties in 2020. Crude COVID-19 death rates in 2020 were:
  ■ 109.9 deaths per 100,000 population in large central metro,
  ■ 98.7 deaths per 100,000 population in large fringe metro,
  ■ 96.3 deaths per 100,000 population in medium metro,
  ■ 105.1 deaths per 100,000 population in small metro,
  ■ 120.9 deaths per 100,000 population in micropolitan, and
  ■ 141.6 deaths per 100,000 population in noncore counties.
- COVID-19 death rates in the largest metropolitan areas remained statistically unchanged in 2021 but increased in less densely populated counties. Crude COVID-19 death rates in 2021 were:
  ■ 109.2 deaths per 100,000 population in large central metro,
  ■ 103.7 deaths per 100,000 population in large fringe metro,
  ■ 128.9 deaths per 100,000 population in medium metro,
  ■ 147.1 deaths per 100,000 population in small metro,
  ■ 171.6 deaths per 100,000 population in micropolitan, and
  ■ 199.3 deaths per 100,000 population in noncore counties.

## Discussion and Conclusions

COVID-19 imposed a heavy burden on the United States, accounting for more than 767,000 deaths in the first 2 years of the pandemic. It also exacerbated existing health disparities, leading to disproportionately high mortality among older adults, people in nonmetropolitan communities, and NH-AI/AN, NH-NHPI, Hispanic, and NH-Black populations.

Importantly, COVID-19 deaths grew by nearly 20% in the second year of the PHE, even though the nation had more knowledge about this previously unknown virus and greater access to tests, treatments, and vaccines. This observation prompts us to ask: what factors accounted for these deaths, and how might healthcare delivery systems have prevented them?

The emergence of more transmissible variants in 2021 provides a partial answer. Genetic mutations in the variants of concern enabled them to evade existing immunity and spread more easily through the population. Their emergence also coincided with a time when national consensus on pandemic mitigation strategies such as masking and social distancing had begun to fracture, potentially enabling the virus to spread further. But Americans also had access to COVID-19 vaccines, which had not yet been developed in the first year of the pandemic.

The public health and healthcare delivery systems achieved remarkable success engaging with communities (https://covid19community.nih.gov/) and administering at least one dose of the COVID-19 vaccine to more than 70% of adults within the first year of vaccine availability. Although this accomplishment has been credited with averting millions of hospitalizations and death,^5^ evidence suggests that more vaccination was both desirable and achievable.

A CDC analysis from early 2021 found that a single dose of mRNA COVID-19 vaccines was approximately 82% effective in reducing virus transmission compared with 94% effectiveness for two doses.^16^ Earlier efficacy studies had reported lower levels of protection from a one-dose vaccination.^1,17^ In addition, vaccine-induced immunity waned over time, and variants appeared that were capable of escaping vaccine-induced immunity and natural immunity generated by previous variants.

While 70% vaccine coverage was expected to confer herd immunity when COVID-19 vaccines first became available, subsequent studies found that vaccination levels approaching 90% would have been needed for highly transmissible viruses such as the Omicron variant.^18^

Data also show uneven distribution and use of COVID-19 vaccines in 2021, especially among uninsured, underinsured, and low-income people and people in nonmetropolitan communities. Federal law mandated health insurance coverage for COVID-19 vaccines without barriers (such as prior authorization or cost sharing) to increase use. However, lower rates of vaccine receipt by socioeconomically disadvantaged people (including healthcare workers) signal that other structural barriers may have reduced vaccine use.

For example, lack of paid sick leave and limited job flexibility appeared to prevent many low-income people from getting vaccinated.^19^ Similarly, requiring online vaccine appointments may have limited access to people lacking computers and internet access, while locating mass vaccination sites in geographically isolated areas may have limited access for people with limited transportation options.^20^

The disparities may reflect, in part, the nation’s reliance on personal healthcare delivery systems to equitably distribute vaccines instead of having a robust public health system to do it.^19^ Providers of healthcare services, such as hospitals, nursing homes, and pharmacies, traditionally focus on providing care to individuals. Thus, many appeared to lack the capacity to serve populations beyond their traditional markets, including people who already had difficulty accessing their services due to socioeconomic and geographic barriers, such as people with disabilities. Yet, paradoxically, insufficient vaccination among these disadvantaged populations may have contributed to the surges that strained hospitals and nursing homes and potentially led to excess deaths.^21,22^

These findings underscore an urgent need to strengthen the public health system as a first line of defense against future transnational health crises, while reimagining how healthcare delivery systems might also address broader public health needs.

## Resources

The CDC Bridge Access Program (https://www.cdc.gov/vaccines/programs/bridge/index.html) has been established to provide free COVID-19 vaccines to uninsured and underinsured people through local providers, publicly sponsored community health centers, and commercial pharmacies after the vaccines transition to the commercial market in fall 2023. The program is temporary and will phase out after December 2024.

i The Pfizer-BioNTech mRNA vaccine was developed outside of Operation Warp Speed but received support from the program in the form of a $2 billion advance purchase order. It received EUA on December 11, 2020; it is currently available in the United States as a bivalent vaccine (original strain + Omicron BA.4). The Moderna mRNA vaccine(mRNA-1273) received EUA on December 18, 2020, and is currently available in the United States as a bivalent vaccine. The Janssen/Johnson & Johnson adenoviral vector vaccine (Ad25.COV2.S) received EUA on February 27 2021; the vaccine’s EUA has expired, and it is no longer available in the United States. The Novavax adjuvanted recombinant protein vaccine (NVX-CoV2373) received EUA for people age 12 years and over on July 13, 2022.

ii Unless noted otherwise, data points for trend analyses under each figure only report differences if they are statistically significant (i.e., p value less than 0.1) and show an average annual percentage change greater than 1% per year. For comparison between two populations, data points under each figure only report differences that are statistically significant (i.e., p value less than 0.05) and have a relative difference between the populations of at least 10%, unless noted otherwise. Readers may learn more about NHQDR’s reporting methodology in Appendix A at https://www.ahrq.gov/research/findings/nhqrdr/nhqdr23/index.html.

iii The Office of the Assistant Secretary of Planning and Evaluation has compiled a list of federal and state-level vaccine outreach efforts: https://aspe.hhs.gov/reports/covid-19-vaccine-outreach.

iv The Social Vulnerability Index is described in more detail in the Portrait of American Healthcare section of this report. Details may also be found at https://www.atsdr.cdc.gov/placeandhealth/svi/index.html.

v National Center for Health Statistics. 2021 National Health Interview Survey, public use data. https://www.cdc.gov/nchs/nhis/2021nhis.htm.

## References

1 Polack FP, Thomas SJ, Kitchin N, ; C4591001 Clinical Trial Group. Safety and efficacy of the BNT162b2 mRNA Covid-19 vaccine through 6 months. N Engl J Med. 2021 Nov 4;385(19):1761–1773. https://www.nejm.org/doi/10.1056/NEJMoa2110345. Accessed October 24, 2023.34525277
2 Baden LR, El Sahly HM, Essink B, ; COVE Study Group. Efficacy and safety of the mRNA-1273 SARS-CoV-2 vaccine. N Engl J Med. 2021 Feb 4;384(5):403–416. https://www.nejm.org/doi/10.1056/NEJMoa2035389. Accessed October 24, 2023.33378609
3 Holtkamp N, Kolbe A, Beleche T. COVID-19 Vaccination Associated With Reductions in COVID-19 Mortality and Morbidity in the United States, and an Approach to Valuing These Benefits. Washington, DC: U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation; December 2021. https://aspe.hhs.gov/reports/economic-health-benefits-covid-19-vaccination. Accessed October 24, 2023.
4 Lin DY, Gu Y, Xu Y, Wheeler B, Young H, Sunny SK, Moore Z, Zeng D. Association of primary and booster vaccination and prior infection with SARS-CoV-2 infection and severe COVID-19 outcomes. JAMA. 2022 Oct 11;328(14):1415–1426. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9513711/. Accessed October 24, 2023.36155617
5 Fitzpatrick MC, Moghadas SM, Pandey A, Galvani AP. Two Years of U.S. COVID-19 Vaccines Have Prevented Millions of Hospitalizations and Deaths. Commonwealth Fund Blog, December 13, 2022. https://www.commonwealthfund.org/blog/2022/two-years-covid-vaccines-prevented-millions-deaths-hospitalizations. Accessed October 24, 2023.
6 Anderson RM, Vegvari C, Truscott J, Collyer BS. Challenges in creating herd immunity to SARS-CoV-2 infection by mass vaccination. Lancet. 2020 Nov 21;396(10263):1614–1616. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7836302/. Accessed October 24, 2023.33159850
7 The White House. President Biden to announce goal to administer at least one vaccine shot to 70% of the U.S. adult population by July 4th. May 4, 2021. https://www.whitehouse.gov/briefing-room/statements-releases/2021/05/04/fact-sheet-president-biden-to-announce-goal-to-administer-at-least-one-vaccine-shot-to-70-of-the-u-s-adult-population-by-july-4th/. Accessed October 24, 2023.
8 Silver D, Kim Y, McNeill E, Piltch-Loeb R, Wang V, Abramson D. Association between COVID-19 vaccine hesitancy and trust in the medical profession and public health officials. Prev Med. 2022 Nov;164:107311. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9580241/. Accessed October 24, 2023.36272515
9 Viskupič F, Wiltse DL, Meyer BA. Trust in physicians and trust in government predict COVID-19 vaccine uptake. Soc Sci Q. 2022 May;103(3):509–520. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9115527/.Accessed October 24, 2023.35600052
10 Kirzinger A, Munana C, Brodie M. Vaccine hesitancy in rural America. Kaiser Family Foundation; 2021. https://www.kff.org/coronavirus-covid-19/poll-finding/vaccine-hesitancy-in-rural-america/. Accessed October 24, 2023.
11 Kiang MV, Carlasare LE, Thadaney Israni S, Norcini JJ, Zaman JA B, Bibbins-Domingo K. Excess mortality among U.S. physicians during the COVID-19 pandemic. JAMA Intern Med. 2023 Apr 1;183(4):374–376. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC10071333/. Accessed October 24, 2023.36745424
12 Centers for Disease Control and Prevention. COVID Data Tracker. Cases & Deaths Among Healthcare Personnel. February 1, 2023.
13 Lost on the Frontline. The Guardian, Kaiser Health News, 2021. https://www.theguardian.com/us-news/ng-interactive/2020/aug/11/lost-on-the-frontline-covid-19-coronavirus-us-healthcare-workers-deaths-database. Accessed October 24, 2023.
14 Shiels MS, Haque AT, Haozous EA, Albert PS, Almeida JS, García-Closas M, Nápoles AM, Pérez-Stable EJ, Freedman ND, Berrington de González A. Racial and ethnic disparities in excess deaths during the COVID-19 pandemic, March to December 2020. Ann Intern Med. 2021 Dec;174(12):1693–1699. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC8489677/. Accessed October 24, 2023.34606321
15 Mackey K, Ayers CK, Kondo KK, Saha S, Advani SM, Young S, Spencer H, Rusek M, Anderson J, Veazie S, Smith M, Kansagara D. Racial and ethnic disparities in COVID-19-related infections, hospitalizations, and deaths: a systematic review. Ann Intern Med. 2021 Mar;174(3):362–373. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7772883/. Accessed October 24, 2023.33253040
16 Pilishvili T, Fleming-Dutra KE, Farrar JL, Interim estimates of vaccine effectiveness of Pfizer-BioNTech and Moderna COVID-19 vaccines among health care personnel — 33 U.S. sites, January–March 2021. MMWR Morb Mortal Wkly Rep. 2021;70:753–758. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC8136422/.Accessed October 24, 2023.34014909
17 Dagan N, Barda N, Kepten E, Miron O, Perchik S, Katz MA, Hernán MA, Lipsitch M, Reis B, Balicer RD. BNT162b2 mRNA Covid-19 vaccine in a nationwide mass vaccination setting. N Engl J Med. 2021 Apr 15;384(15):1412–1423. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7944975/. Accessed October 24, 2023.33626250
18 Plans-Rubió P. Percentages of vaccination coverage required to establish herd immunity against SARS-CoV-2. Vaccines (Basel). 2022 May 8;10(5):736. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9144560/. Accessed October 24, 2023.35632492
19 Gonzales A, Lee EC, Grigrescu V, Smit SR, De Lew N, Sommers BD. Overview of Barriers and Facilitators in COVID-19 Vaccine Outreach. (Research Report No. HP-2021-19). Washington, DC: U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation; September 2021. https://aspe.hhs.gov/reports/covid-19-vaccine-outreach. Accessed October 24, 2023.
20 Ndugga N, Artiga S, Pham O. How Are States Addressing Racial Equity in COVID-19 Vaccine Efforts? Kaiser Family Foundation; March 10, 2021. https://www.kff.org/racial-equity-and-health-policy/issue-brief/how-are-states-addressing-racial-equity-in-covid-19-vaccine-efforts/. Accessed October 24, 2023.
21 French G, Hulse M, Nguyen D, Sobotka K, Webster K, Corman J, Aboagye-Nyame B, Dion M, Johnson M, Zalinger B, Ewing M. Impact of hospital strain on excess deaths during the COVID-19 pandemic — United States, July 2020–July 2021. MMWR Morb Mortal Wkly Rep. 2021;70:1613–1616. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC8601411/. Accessed October 24, 2023.34793414
22 Agency for Healthcare Research and Quality. Impact of the COVID-19 pandemic on patient safety. AHRQ Patient Safety Network Annual Perspective; March 30, 2021. https://psnet.ahrq.gov/perspective/ahrq-psnet-annual-perspective-impact-covid-19-pandemic-patient-safety. Accessed October 24, 2023.