# Overview of NHQDR Special Emphasis Topics

Each year, the World Health Organization (WHO), U.S. Centers for Disease Control and Prevention (CDC), and other public health authorities receive multiple reports of disease clusters to investigate. On December 31, 2019, the Wuhan Municipal Health Commission informed the WHO China Office of a cluster of cases of severe, often-fatal pneumonia spreading through Wuhan City in the Hubei Province of the People’s Republic of China.^1^ Little was known about the cases initially, other than that the disease appeared to be severe and that the earliest documented symptoms from this cluster of cases dated to December 1, 2019.^2^

Epidemiologic investigation traced most cases to the Huanan Seafood Wholesale Market, where sellers trade live animals as well as seafood. Health authorities would subsequently confirm that the causative agent was a novel coronavirus, which would later be named the severe acute respiratory syndrome coronavirus-2 (SARS-CoV-2).^3^ The disease resulting from infection with this virus would be termed coronavirus disease-2019 (COVID-19).^4^

SARS-CoV-2 was one of several novel viruses identified around the world each year.^5^ Most do not affect humans, and health authorities initially thought that SARS-CoV-2 was only transmitted from animals to humans. However, evidence for human-to-human transmission among people with symptomatic disease emerged by late January 2020.^6,7,8,9^ Soon after, the first human-to-human transmission case from an asymptomatic carrier was documented in Germany.^10^

After more than 118,000 cases in 114 countries and 4,291 deaths, the WHO declared COVID-19 a pandemic on March 11, 2020.^11^ COVID-19 would become the seventh and most widespread viral pandemic since the influenza pandemic of 1918.^12^

In response to the spread of COVID-19, the Secretary of Health and Human Services issued a public health emergency (PHE) notice on January 31, 2020.^13^ The COVID-19 PHE had an outsized influence on the healthcare delivery system through direct and indirect effects on the organization of healthcare services, as well as on the health and well-being of the public and healthcare workers. The Special Emphasis Topics in this year’s NHQDR describe how the healthcare delivery system responded to the COVID-19 PHE and anticipate its ability to respond to other emergencies in the years ahead.

## Biologic and Clinical Features of COVID-19

SARS-CoV-2 is an RNA virus with genetic makeup and appearance under electron microscope that places it within the family of coronaviruses. This group includes hundreds of viruses that do not affect humans, as well as the highly pathogenic viruses SARS-CoV and Middle East respiratory syndrome virus (MERS-CoV).^14,15^

SARS-CoV-2 spreads through respiratory droplets transmitted by an infected person when they sneeze, cough, speak, sing, laugh, or breathe and enters the human body by invading epithelial cells in exposed mucous membranes, such as in the respiratory tract. Once infected, people may respond in different ways, ranging from having no symptoms to dying from severe cardiopulmonary complications.

A review of data collected from people with test-confirmed COVID-19 early in the COVID-19 pandemic (before vaccines became available) estimated that approximately 33% of people infected with SARS-CoV-2 never developed symptoms. Those who had symptoms typically exhibited them after an incubation period, which lasted 1-14 days (typically 5 days). During the incubation period, people were often contagious despite not exhibiting symptoms.^16^

After the incubation period, many people only developed mild symptoms, which included fever, fatigue, dry cough, and loss of smell that typically lasted 7-14 days before full recovery. However, a small percentage of infected people would go on to develop severe disease, which manifested as severe shortness of breath, need for supplemental oxygen, or pneumonia requiring hospitalization. An even smaller percentage would develop critical symptoms that required mechanical ventilator support in an intensive care unit. Of 1.3 million U.S. cases reported to CDC through May 2020, 14% were hospitalized, 2% were admitted to an intensive care unit, and 5% died.^17^

In addition to its direct effects on people, COVID-19’s transmissibility produced surges in severe cases of COVID-19 that strained hospital capacity and hindered their ability to treat people with other illnesses.

## COVID-19 vs. Influenza

COVID-19 has been described as a respiratory disease comparable to influenza. Influenza is a “top 10” cause of overall mortality in the United States, accounting for an estimated 9 million to 41 million illnesses, 140,000 to 710,000 hospitalizations, and 12,000 to 52,000 deaths annually between 2010 and 2020.^18^ But it is sometimes perceived as a relatively benign illness, giving a false impression that COVID-19 may also be benign.

In contrast to typical strains of the influenza virus, SARS-CoV-2 exhibited greater potential for inducing a severe inflammatory response that manifested in various ways, including:

- Acute respiratory distress syndrome, leading to respiratory failure and need for mechanical ventilation to support lung function.
- Heart-related complications, including heart attacks, heart failure, and arrhythmia.
- Blood clotting disorders, which may present as stroke, heart attacks, or need for amputation due to loss of blood supply to the limbs.
- Inflammation of brain and spinal cord tissue, leading to events such as stroke, mental confusion, abnormal sensation, and movement disorders.^19^

In addition, people with severe manifestations of COVID-19 were more likely to need prolonged hospital care, increasing their risk of developing hospital-associated complications, such as:

- Pressure ulcers,
- Ventilator-associated pneumonia,
- Central line-associated bloodstream infections,
- Nutritional deficiencies,
- Cognitive impairment, and
- Physical deconditioning.^20^

The severity of COVID-19 led to more deaths and produced wider racial and ethnic disparities than recent strains of influenza.

Figure 1 Deaths per 100,000 population due to COVID-19 and Influenza (left) for the U.S. population, and due to COVID-19, 2020-2022 (upper right) and influenza, 2018-2022 (lower right), by race/ethnicity

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Data for 2022 (shown with dotted lines) are provisional estimates. Vertical scales for upper and lower right panels differ to show disparities among racial and ethnic groups.

U.S. map showing deaths per 100,000 population in 2020 by state; key points are in the text below. U.S. map showing deaths per 100,000 population in 2021 by state; key points are in the text below.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Mortality, 2018-2022. Accessed on CDC WONDER Online Database, released in 2023.

- COVID-19 death rates for the overall population were 85.0, 104.1, and 46.5 deaths per 100,000 population in 2020, 2021, and 2022, respectively (Figure 1).
- COVID-19 death rates varied approximately 3.5- to 6-fold among racial/ethnic groups. They were highest among non-Hispanic American Indian or Alaska Native (NH-AI/AN) groups (175.9, 184.0, and 68.8 deaths per 100,000 population in 2020, 2021, and 2022, respectively). Rates were lowest among NH-multiracial groups (29.6, 45.7, and 19.9 deaths per 100,000 population in 2020, 2021, and 2022, respectively).
- Influenza death rates for the overall population were 14.9, 12.3, 13.0, and 10.5 per 100,000 population in 2018, 2019, 2020, and 2021, respectively. The death rate for 2022 was 11.8 per 100,000 population.
- Influenza death rates varied approximately 2.5- to 3.5-fold among racial/ethnic groups. They were highest among NH-AI/AN groups (19.3, 16.3, 18.5, 14.1, and 16.4 deaths per 100,000 population in 2018, 2019, 2020, 2021, and 2022, respectively). Rates were lowest among NH-multiracial groups (7.1, 5.5, 5.5, 4.3, and 5.4 deaths per 100,000 population in 2018, 2019, 2020, 2021, and 2022, respectively).

## Post-COVID-19 Conditions

Reports have also linked COVID-19 with symptoms that persist for months beyond the initial SARS-CoV-2 infection, particularly among people infected early in the pandemic. This condition has been termed “Long COVID” by advocacy groups and “Post-COVID-19 condition” (PCC) by CDC and WHO.^21^ It encompasses a range of symptoms associated with reduced function, impairment in people’s ability to work, and worsened quality of life.^i^

Estimates of the incidence and prevalence of PCC vary, in part due to varying definitions and timing of surveys. However, the U.S. Household Pulse Survey reported that as many as 35.1% of adults with a history of SARS-CoV-2 infection have experienced symptoms consistent with PCC.^22^

In response to the potential burden of PCC on the population, economic activity, and healthcare delivery systems, Congress allocated funds to the National Institutes of Health to launch a variety of programs related to COVID-19. These programs include:

- RECOVER (Researching COVID to Enhance Recovery) (https://recovercovid.org/), a 4-year initiative to conduct basic and clinical research about this condition; and
- CEAL (Community Engagement Alliance) (https://ceal.nih.gov/), which continues to convene representatives of communities most affected by COVID-19.

Congress has also allocated funds to the Agency for Healthcare Research and Quality to support nine multidisciplinary Long COVID clinics (https://www.ahrq.gov/coronavirus/long-covid.html). These clinics, which often serve rural, minority, and other disadvantaged populations, had developed during the pandemic in response to this novel disease and, in doing so, had become exemplars for treating people affected by PCC.

With AHRQ support, the clinics will expand access to treatment for PCC and will provide the nation with applied research, education, and consultative support needed to help other health systems learn how to deliver comprehensive, coordinated, and person-centered PCC services. A more extensive examination of PCC’s impact on healthcare delivery is currently beyond the scope of this report.

## COVID-19 Variants of Concern

Like influenza and other RNA viruses, SARS-CoV-2 is prone to genetic mutations due to inherent instability in how the virus copies its genetic material. These mutations result in variants with different characteristics than earlier strains and create potential for the virus to resist previously effective treatments or to exhibit increased virulence. Although dozens of variants of SARS-CoV-2 were detected between 2020 and 2023, only a few resulted in meaningful changes that enhanced the virus’s virulence or decreased its susceptibility to vaccines or treatments.

The WHO has described five variants of concern based on epidemiologic evidence of their impact on public health^23^:

- Alpha (B.1.1.7) was the first variant of concern. It was first reported in the United Kingdom in late December 2020 and later determined to have been circulating as early as September 2020. Its arrival in the United States resulted in a second major wave of COVID-19 deaths. The Alpha variant was approximately 50% to 75% more transmissible than earlier strains. Studies also associated this variant with more severe disease. For example, a matched cohort study linked infection with the Alpha strain with approximately 60% higher mortality.
- Beta (B.1.351) was first reported in South Africa in December 2020 and in the United States at the end of January 2021. Mutations associated with this variant raised concern for increased transmissibility due to immune evasion. (Studies had found that the variant was less susceptible to neutralization antibodies collected from vaccinated or previously infected people). It did not become a globally dominant variant.
- Gamma (P.1) was first reported in Brazil in early January 2021 and first detected in the United States in January 2021. As with the Beta variant, studies raised concern for increased transmissibility and antibody evasion with this variant. It also did not become a globally dominant variant.
- Delta (B.1.617.2) was first reported in India in December 2020 and first detected in the United States in March 2021. The Delta variant was more transmissible than the Alpha variant and was associated with more severe disease among those infected. However, studies found that COVID-19 vaccines were highly effective in reducing risk for severe disease, hospitalization, and death among those who received the vaccine. The Delta variant was responsible for the third major wave of COVID-19 deaths in the United States.
- Omicron (B.1.1.529) was first reported in Botswana in November 2021 and first detected in the United States in December 2021. Studies indicated that this variant was associated with a higher rate of infectivity and transmission than the Delta variant, due in part to mutations that enabled it to evade the immune systems of vaccinated people and previously infected people.

Although the Omicron variant had lower potential to induce severe disease than earlier variants of concern, its high rate of infection cumulatively resulted in excess hospitalizations and deaths. Omicron led to the fourth major wave of COVID-19 in the United States.

Figure 2 shows the number of deaths associated with the original strain of SARS-CoV-2 and the variants associated with additional major waves of COVID-19.

Figure 2 SARS-CoV-2 variants relative to monthly COVID-19 deaths, January 2020-December 2022

Source: Centers for Disease Control and Prevention, COVID Data Tracker, Surveillance Public Use Data, January 2020-December 2022.

## National Response to the COVID-19 Public Health Emergency

The healthcare delivery system’s response to COVID-19 occurred within the context of federal and state responses to the pandemic starting in 2020, which sought to reduce disease transmission while concurrently expanding the healthcare delivery system’s capacity to provide services. In issuing PHE and national emergency declarations in the first quarter of 2020, the federal government gained flexibilities under several statutes to respond to the pandemic, including:

- Public Health Service Act;
- Social Security Act;
- Food, Drug, and Cosmetic Act;
- Public Readiness and Emergency Preparedness (PREP) Act; and
- National Emergencies Act.

The pandemic response coordinated the efforts of multiple departments and agencies intended to address key concerns related to COVID-19, including the strategies noted below. Most of these strategies were implemented in the first months of the PHE and illustrate the uncertainty under which the policies were developed. Although many were sustained until the end of the PHE in May 2023, some were abandoned because they were ineffective, no longer relevant, or lacked funding.

### Mitigating SARS-CoV-2 Transmission

- Implementing international entry screening requirements at selected airports.
- Restricting travel from selected countries.
- Requiring nursing homes and hospitals to restrict access to visitors and nonessential personnel (with limited exceptions).
- Issuing national social distancing recommendations, including to temporarily close schools and avoid gatherings of more than 10 people.
- Requiring the wearing of masks by federal employees and contractors and on federal property and public transportation.

### Accelerating Development of COVID-19 Tests, Treatments, and Vaccines

- Exercising emergency authority under the Defense Production Act to accelerate production of mechanical ventilators, syringes, glass vials, and other items.
- Exercising authority under the Public Health and Emergency Preparedness Act to issue emergency use authorization for “medical countermeasures” determined to be safe and effective but not yet formally approved.
- Funding the Biomedical Advanced Research and Development Authority (BARDA) and National Institutes of Health to research and develop diagnostics, therapeutics, and vaccines for COVID-19.
- Prepurchasing vaccines.

### Expanding Health Insurance Coverage To Respond to COVID-19

- Requiring coverage for tests, test-related services, vaccines, and antiviral treatment without cost sharing, prior authorization, or other cost management requirements.
- Increasing federal match rates for Medicaid if states continuously enrolled beneficiaries, did not restrict eligibility requirements, did not increase premiums, and covered COVID-19-related services.

### Expanding Healthcare System Capacity To Respond to COVID-19

- Modifying Medicare payment requirements to enable nonphysicians, such as nurse practitioners, physician assistants, physical therapists, and pharmacists, to provide and bill for a wider range of services than previously allowed.
- Modifying Medicare supervision requirements, enabling certain trainees and auxiliary personnel to deliver a wider range of services without physician supervision.
- Modifying Medicare payment requirements to cover acute care services delivered in a wider range of settings, such as delivering outpatient infusion services in a beneficiary’s home.
- Expanding the range of telehealth services covered by Medicare.
- Expanding the range of healthcare practitioners who could provide telehealth services, such as physical therapists, occupational therapists, dietitians, and behavioral health counselors.
- Expanding the range of healthcare settings that could provide telehealth services.
- Allowing clinicians to provide telehealth services across state lines.
- Allowing clinicians to prescribe Schedule III-V nonnarcotic controlled substances via telemedicine.
- Allowing qualified practitioners to prescribe buprenorphine to people with opioid use disorder via telemedicine.
- Waiving penalties related to certain Health Insurance Portability and Accountability Act privacy and security rules, thereby allowing providers to use a wider range of technologies to provide telehealthcare services..
- Providing liability immunity to providers who administer critical services; for example, to enable pharmacists to administer vaccines to children.
- Suspending nonemergency survey inspections and certain administrative documentation and quality reporting requirements.
- Allowing state governments to obtain waivers from certain Medicare, Medicaid, and Children’s Health Insurance Program requirements to respond more effectively to the pandemic, such as allowing critical access hospitals to admit more than the statutorily mandated limit of 25 patients to respond to surges in demand for hospital care.

### Mitigating Socioeconomic Impact of COVID-19

- Distributing loans to support financially distressed businesses using disaster relief funds.
- Providing federal financial relief to states to support state unemployment insurance programs.
- Deferring payroll tax withholding, deposit, and payments without penalty.
- Temporarily waiving interest on federally held student loans and allowing borrowers to suspend student loan repayments without penalty.
- Issuing a moratorium on residential evictions and foreclosures.
- Allowing borrowers with federally guaranteed home loans to suspend mortgage payments if they lost income during the COVID-19 PHE.

In addition to the executive branch actions, Congress enacted six major bills relevant to the COVID-19 PHE, providing additional flexibilities and approximately $5.3 trillion to support the nation’s COVID-19 response. The first four were enacted in March and April of 2020:

1. Coronavirus Preparedness and Response Supplemental Appropriations Act, enacted March 6, 2020;
2. Families First Coronavirus Response Act, enacted March 18, 2020;
3. Coronavirus Aid Relief and Economic Security (CARES) Act, enacted March 27, 2020; and
4. Paycheck Protection Program and Health Care Enhancement Act, enacted April 24, 2020.

Subsequently, Congress enacted the Consolidated Appropriations Act of 2021 on December 27, 2020; and the American Rescue Plan Act on March 11, 2021.

Details about these legislative actions are beyond the scope of this report. Collectively, they directed the healthcare delivery system’s response to COVID-19 in important ways, including:

- Funding the development of COVID-19 tests, vaccines, and treatments.
- Funding public health services to disseminate and administer COVID-19 tests and vaccines and funding direct investments in public health infrastructure, such as community health centers and community health workers.
- Funding global health programs related to COVID-19.
- Modifying Medicare requirements to remove certain face-to-face encounter requirements and allow provision of telehealth services regardless of beneficiary location.
- Providing financial support to hospitals and healthcare provider practices.
- Providing financial relief to companies in economically distressed sectors.
- Providing people with a temporary basic income in the form of direct payments to taxpayers.
- Extending unemployment benefits.
- Funding and facilitating increased access to food assistance programs, including school breakfast and lunch programs and the Supplemental Nutrition Assistance Program.
- Expanding access to sick leave and family medical leave for certain employees and providing tax credits to fund program changes.

Taken together, these policy and legislative events produced a time-limited environment in which more people had access to national health insurance and social safety net services. In addition, national standards for certain services, such as those related to telehealthcare, superseded state requirements.

## Tracking COVID-19: National Measures of COVID-19 Activity

One advance that resulted from the COVID-19 PHE was the popularization of data visualizations that informed people about national and local disease activity. COVID-19 dashboards published on federal websites and in lay media often reported four surveillance indicators: case rate, hospitalization rate, death count, and case-mortality rate.

The case rate reports the number of people per 100,000 population with epidemiologic links to people with laboratory-confirmed COVID-19 and documented signs and symptoms of COVID-19 infection or with laboratory-confirmed COVID-19 infection. As a measure of COVID-19 activity, the monthly case rate describes how extensively and how quickly SARS-CoV-2 spread in the United States at different points in time.

A lag may occur between the time a person becomes ill with COVID-19 and the time their case is reported. In addition, the case rate depends on people feeling symptomatic enough to seek testing and having access to testing facilities that also report results to data sources. Therefore, case rates may not show the precise time when the number of people infected changed and are likely to underestimate the actual number of cases at a particular time. For example, Figure 3 shows low case rates in March through May 2020, even though the initial surge of cases peaked in these months, because the United States lacked capacity to conduct national surveillance testing then.

Figure 3 Monthly COVID-19 case rate per 100,000 population, January 2020-December 2022

U.S. map showing percentage of adults who received two doses by state, ranging from 49.1% to 79.6%; median was 61.1% percentages were highest in Hawaii, Maina, and Vermont and lowest in Alabama, Mississippi, and Wyoming

Source: Centers for Disease Control and Prevention, COVID-19 Response, COVID-19 Case Surveillance Public Use Data With Geography (version date: June 2, 2023).

- Monthly COVID-19 case rates increased at six points between January 2020 and December 2022. Cases peaked in:
  ■ July 2020 (508 per 100,000 population),
  ■ December 2020 (1,702 per 100,000 population),
  ■ August 2021 (1,133 per 100,000 population),
  ■ January 2022 (4,662 per 100,000 population),
  ■ May 2022 (907 per 100,000 population), and
  ■ July 2022 (929 per 100,000 population) (Figure 3).
- Low case rates reported in early 2020 likely represent artifacts resulting from limited testing capacity during the early months of the COVID-19 pandemic.

The hospitalization rate reports the number of people hospitalized with the principal diagnosis of COVID-19 per 100,000 population. This measure assesses the impact of COVID-19 on healthcare utilization at different times during the PHE. When the COVID-19 hospitalization rate was high, demand for services may have exceeded emergency departments’ and hospitals’ capacity and crowded out their ability to provide care for people with non-COVID-19 conditions.

Figure 4 Monthly COVID-19 hospitalizations, January 2020-December 2022

Source: Centers for Disease Control and Prevention, COVID-19 Response, COVID-19 Case Surveillance Public Use Data With Geography (version date: June 2, 2023).

- Monthly COVID-19 hospitalization counts increased at seven points between January 2020 and December 2022. Peaks in COVID-19 hospitalizations were reported for the months of:
  ■ April 2020 (141,165 admissions),
  ■ July 2020 (103,192 admissions),
  ■ December 2020 (220,360 admissions),
  ■ August 2021 (146,146 admissions),
  ■ January 2022 (229,865 admission),
  ■ July 2022 (64,725 admissions), and
  ■ December 2022 (65,211 admissions) (Figure 4).

The death count reports the number of people who died with COVID-19 within a given time. This measure assesses COVID-19’s impact on the population at different times during the PHE. Population death rates may change in response to many conditions other than severity of the disease. For example, COVID-19 death rates may have increased during surge periods because critical supplies were unavailable or because the need for healthcare services overwhelmed the capacity of healthcare delivery organizations to provide them.

Figure 5 Monthly COVID-19 deaths, January 2020-December 2022

Source: Centers for Disease Control and Prevention, COVID-19 Response, COVID-19 Case Surveillance Public Use Data With Geography (version date: June 2, 2023).

- Monthly COVID-19 death counts increased six times between January 2020 and December 2022. Deaths peaked in:
  ■ April 2020 (61,824 deaths),
  ■ July 2020 (28,174 deaths),
  ■ January 2021 (96,235 deaths),
  ■ September 2021 (59,084 deaths),
  ■ January 2022 (72,483 deaths), and
  ■ August 2022 (9,310 deaths) (Figure 5).

The case-mortality rate (also called case-fatality rate and death per case) reports the number of people who died out of only those people with confirmed COVID-19 infections. As a measure of COVID-19 activity, it provides a useful complement to simple COVID-19 death rates. The case-mortality rate can be used to distinguish between changes in death rates resulting from changes in the number of people infected and changes in the severity of COVID-19 infections or the quality of treatment infected people received.

Figure 6 Monthly COVID-19 deaths per 1,000 cases, January 2020-December 2022

Source: Centers for Disease Control and Prevention, COVID-19 Response, COVID-19 Case Surveillance Public Use Data With Geography (version date: June 2, 2023).

- Deaths per 1,000 cases decreased gradually after SARS-COV-2’s initial appearance in the United States. The case-mortality rate peaked at 80 deaths per 1,000 cases in April 2020, followed by lower peaks in the case-mortality rate of:
  ■ 21 deaths per 1,000 cases in August 2020,
  ■ 22 deaths per 1,000 cases in February 2021,
  ■ 15 deaths per 1,000 cases in May and June 2021,
  ■ 18 deaths per 1,000 cases in September and October 2021, and
  ■ 15 deaths per 1,000 cases in February 2022 (Figure 6).
- As of December 2022, the COVID-19 case-mortality rate was 3 per 1,000 cases.

## NHQDR Special Emphasis Topics

In the next five sections, the NHQDR will examine healthcare delivery during the COVID-19 PHE from five perspectives:

1. Impact of COVID-19 on U.S. population.
2. Impact of COVID-19 on hospitals.
3. Impact of COVID-19 on ambulatory care.
4. Impact of COVID-19 on nursing homes.
5. Impact of COVID-19 on telehealthcare.

i Examples include tiredness, malaise after exertion, mental confusion, abnormal sensation, elevated heart rate, difficulty breathing, persistent abdominal discomfort, chronic diarrhea, and chronic muscle and joint pain.

## References

1 Centers for Disease Control and Prevention. CDC Museum COVID-19 Timeline. March 15, 2023. https://www.cdc.gov/museum/timeline/covid19.html. Accessed October 23, 2023.
2 Huang C, Wang Y, Li X, Clinical features of patients infected with 2019 novel coronavirus in Wuhan, China. Lancet. 2020 Feb 15;395(10223):497–506. Erratum in: Lancet. 2020 Jan 30. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7159299/. Accessed October 23, 2023.31986264
3 Coronaviridae Study Group of the International Committee on Taxonomy of Viruses. The species Severe acute respiratory syndrome-related coronavirus: classifying 2019-nCoV and naming it SARS-CoV-2. Nat Microbiol. 2020 Apr;5(4):536–544. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7095448/. Accessed October 23, 2023.32123347
4 World Health Organization. Naming the Coronavirus Disease (COVID-19) and the Virus That Causes It. Technical Guidance. February 2020. Accessed at https://www.who.int/emergencies/diseases/novel-coronavirus-2019/technical-guidance/naming-the-coronavirus-disease-(covid-2019)-and-the-virus-that-causes-it. Accessed October 23, 2023.
5 Hu B, Guo H, Zhou P, Shi ZL. Characteristics of SARS-CoV-2 and COVID-19. Nat Rev Microbiol. 2021 Mar;19(3):141–154. Erratum in: Nat Rev Microbiol. 2022 May;20(5):315. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7537588/. Accessed October 23, 2023.33024307
6 Wang C, Horby PW, Hayden FG, Gao GF. A novel coronavirus outbreak of global health concern. Lancet. 2020 Feb 15;395(10223):470–473. Erratum in: Lancet. 2020 Jan 29. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7135038/. Accessed October 23, 2023.31986257
7 Chan JF, Yuan S, Kok KH, A familial cluster of pneumonia associated with the 2019 novel coronavirus indicating person-to-person transmission: a study of a family cluster. Lancet. 2020 Feb 15;395(10223):514–523. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7159286/. Accessed October 23, 2023.31986261
8 Phan LT, Nguyen TV, Luong QC, Nguyen TV, Nguyen HT, Le HQ, Nguyen TT, Cao TM, Pham QD. Importation and human-to-human transmission of a novel coronavirus in Vietnam. N Engl J Med. 2020 Feb 27;382(9):872–874. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7121428/. Accessed October 23, 2023.31991079
9 Holshue ML, DeBolt C, Lindquist S, ; Washington State 2019-nCoV Case Investigation Team. First case of 2019 novel coronavirus in the United States. N Engl J Med. 2020 Mar 5;382(10):929–936. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7092802/. Accessed October 23, 2023.32004427
10 Rothe C, Schunk M, Sothmann P, Bretzel G, Froeschl G, Wallrauch C, Zimmer T, Thiel V, Janke C, Guggemos W, Seilmaier M, Drosten C, Vollmar P, Zwirglmaier K, Zange S, Wölfel R, Hoelscher M. Transmission of 2019-nCoV infection from an asymptomatic contact in Germany. N Engl J Med. 2020 Mar 5;382(10):970–971. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7120970/. Accessed October 23, 2023.32003551
11 Cucinotta D, Vanelli M. WHO declares COVID-19 a pandemic. Acta Biomed. 2020 Mar 19;91(1):157–160. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7569573/. Accessed October 23, 2023.32191675
12 Morens DM, Taubenberger JK, Fauci AS. A centenary tale of two pandemics: the 1918 influenza pandemic and COVID-19, Part I. Am J Public Health. 2021 Jun;111(6):1086–1094. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC8101587/. Accessed October 23, 2023.33950739
13 Azar AM. PHE Declarations. Determination That a Public Health Emergency Exists. January 31, 2023. https://aspr.hhs.gov/legal/PHE/Pages/2019-nCoV.aspx. Accessed October 23, 2023.
14 Zhu N, Zhang D, Wang W, Li X, Yang B, Song J, Zhao X, Huang B, Shi W, Lu R, Niu P, Zhan F, Ma X, Wang D, Xu W, Wu G, Gao GF, Tan W; China Novel Coronavirus Investigating and Research Team. A novel coronavirus from patients with pneumonia in China, 2019. N Engl J Med. 2020 Feb 20;382(8):727–733. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7092803/. Accessed October 23, 2023.31978945
15 Perlman S. Another decade, another coronavirus. N Engl J Med. 2020 Feb 20;382(8):760–762. https://www.nejm.org/doi/10.1056/NEJMe2001126. Accessed October 24, 2023.31978944
16 Oran DP, Topol EJ. The proportion of SARS-CoV-2 infections that are asymptomatic: a systematic review. Ann Intern Med. 2021 May;174(5):655–662. https://www.acpjournals.org/doi/full/10.7326/M20-6976. Accessed October 24, 2023.33481642
17 Stokes EK, Zambrano LD, Anderson KN, Marder EP, Raz KM, El Burai Felix S, Tie Y, Fullerton KE. Coronavirus disease 2019 case surveillance - United States, January 22-May 30, 2020. MMWR Morb Mortal Wkly Rep. 2020 Jun 19;69(24):759-765. https://www.cdc.gov/mmwr/volumes/69/wr/mm6924e2.htm. Accessed October 24, 2023.
18 Centers for Disease Control and Prevention. Disease Burden of Flu. Last reviewed October 2022. https://www.cdc.gov/flu/about/burden/index.html. Accessed October 24, 2023.
19 Wiersinga WJ, Rhodes A, Cheng AC, Peacock SJ, Prescott HC. Pathophysiology, transmission, diagnosis, and treatment of coronavirus disease 2019 (COVID-19): a review. JAMA. 2020 Aug 25;324(8):782–793. 10.1001/jama.2020.12839. Accessed October 24, 2023.32648899
20 Krumholz HM. Post-hospital syndrome – a condition of generalized risk. N Engl J Med. 2013 Jan 10;368(2):100–102. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3688067/. Accessed October 24, 2023.23301730
21 Katz GM, Bach K, Bobos P, Cheung A, Décary S, Goulding S, Herridge MS, McNaughton CD, Palmer KS, Razak FA, Zhang B, Quinn KL. Understanding how post-COVID-19 condition affects adults and health care systems. JAMA Health Forum. 2023 Jul 7;4(7):e231933. 10.1001/jamahealthforum.2023.1933.Accessed October 24, 2023.37418268
22 U.S. Census Bureau; Centers for Disease Control and Prevention, National Center for Health Statistics. Long COVID: Household Pulse Survey. July 19, 2023. Accessed at https://www.cdc.gov/nchs/covid19/pulse/long-covid.htm on 8/15/2023.
23 Cascella M, Rajnik M, Aleem A, Dulebohn SC, Di Napoli R. Features, Evaluation, and Treatment of Coronavirus (COVID-19) [Updated 2023 Jan 9]. In: StatPearls [Internet]. Treasure Island, FL: StatPearls Publishing; 2023. https://www.ncbi.nlm.nih.gov/books/NBK554776/. Accessed October 24, 2023.