# Portrait of American Healthcare

Healthcare quality assessments evaluate health systems’ effectiveness to provide patient care that is timely, affordable, and based on reliable evidence. This section of the report provides a broad portrait of U.S. healthcare to support contextual understanding of the structural factors, including societal inequities, that affect how today’s healthcare is organized, financed, and delivered.

This section includes:

- Demographics: trends in age, race and ethnicity, population density.
- Leading Health Concerns: trends in life expectancy, mortality.
- Social Determinants of Health: prevalence of social, economic, environmental, and community conditions affecting health outcomes.
- Healthcare Delivery Systems: capacities of the healthcare workforce and organizations.
- National Healthcare Expenditures: estimates on spending for medical goods and services.
- Geographic Variations in Care: state-level data on quality and disparities.

## Demographics

Healthcare systems and providers in the United States serve a large and growing population. Over the 10 years between the 2010 Census and the 2020 Census,^i^ the U.S. population increased 7.4% to 331,449,281 people.^1^

The following demographic data describe emerging trends related to the aging population, increasing racial and ethnic diversity, and more Americans living in metropolitan areas.

❖ The U.S. population is aging.

The U.S. Census Bureau estimates that the percentage of the population age 65 years and over increased from 12.7% to 16.1% between 2010 and 2020. Compared with 2010, when nearly 1 in 8 people in the United States was age 65 years or over, now approximately 1 in 6 people is age 65 years or over.

Figure 1 Distribution of people in the United States, by age group, 2010 and 2021

Source: U.S. Census Bureau, American Communities Survey, 1-year estimates, 2010 and 2021 (Table S0101).

- The number of youths under age 20 years decreased from 83,215,066 (26.9% of the population) in 2010 to 82,317,638 (24.8% of the population) in 2021 (Figure 1).
- The number of adults ages 20-44 years increased from 103,941,496 in 2010 to 110,195,342 in 2021 but decreased as a percentage of the total population (from (33.6% to 33.2%).
- The number of adults ages 45-64 years increased from 81,668,318 in 2010 to 83,488,751 in 2021 but decreased as a percentage of the total population (from 26.4% to 25.2%) .
- The number of adults age 65 years and over increased from 40,215,460 (13.0% of the population) in 2010 to 55,892,014 (16.8% of the population) in 2021.

The Census Bureau anticipates that the population will continue to age in the coming decades, with the population of people age 65 years and over projected to exceed the population of children and adolescents around 2040.

Figure 2 Historic, current, and projected U.S. population, by age, 2000-2060

Source: U.S. Census Bureau, Decennial Census 2000, Table DP1 and American Community Survey 1-year estimates, 2010 and 2021, Table S0101 (solid trend lines); and Projected Age Groups and Sex Composition of the Population: Main Projections Series for the United States, 2017-2060, Table 2 (dotted trend lines).

- Between 2000 and 2021, the number of adults age 65 years and over grew from approximately 35 million to nearly 56 million. This population is projected to increase to approximately 95 million people by 2060 (Figure 2).
- Between 2000 and 2021, the number of adults ages 18-64 years grew from approximately 174 million to approximately 202.5 million. This population is projected to increase to nearly 230 million people by 2060.
- Between 2000 and 2021, the number of children and adolescents less than 18 years old remained relatively stable, growing from approximately 72 million to 73 million. This population is projected to grow slowly to approximately 80 million people by 2060.

❖ An aging population has implications for healthcare delivery.

An aging population has significance for healthcare delivery because many older adults have left the workforce and rely on younger adults to provide clinical care and long-term services and supports (LTSS). The “dependency ratio” is often used to measure a population’s potential for economic activity and the burden borne by its workforce. It compares the total number of dependent youths under age 15 plus the number of adults age 65 and over to the number of “working age” people ages 15-64 years.

A higher dependency ratio indicates that more people need socioeconomic support relative to the number of people who can provide support. For example, a population with a 0.25 dependency ratio is one in which only 1 in 4 people is either younger than 15 or age 65 and over; thus, three working age people are available to support every dependent person. In contrast, a population with a 0.6 dependency ratio is one in which 3 in 5 people are potentially dependent and signals a relatively higher burden for the 2 in 5 people left to support them.

Projections from the Census Bureau anticipate a meaningful rise in the dependency ratio, driven entirely by the growth in the number of older adults.

Figure 3 Historic, current, and projected dependency ratio, 2010-2060

Note: Dependency ratio is the ratio of people less than 15 years old and people 65 years and over to people ages 15-64 years. The dependency ratio sums together the old-age dependency ratio, which is the ratio of people 65 years and over to people ages 15-64 years, and the youth dependency ratio, which is the ratio of people less than 15 years old to people ages 15-64 years. The Census Main Projection Series data assume historical immigration patterns, based on trends that occurred in 1980-2014. Data for alternate immigration scenarios are available from Johnson S. A Changing Nation: Population Projections Under Alternative Migration Scenarios. Current Population Reports, P25-1146. Washington, DC: U.S. Census Bureau; 2020. https://www.census.gov/content/dam/Census/library/publications/2020/demo/p25-1146.pdf.

Source: Estimates generated with data from U.S. Census Bureau, Decennial Census 2000, Table P1 and American Community Survey 1-year estimates, 2010 and 2021, Table S0101 (solid lines); and Projected Age Groups and Sex Composition of the Population: Main Projections Series for the United States, 2017-2060, Table 2 (dotted trend lines).

- Between 2000 and 2021, the dependency ratio increased from 0.51 to 0.54. This change was led by an increase in the old-age dependency ratio from 0.19 to 0.26. During the same period, the youth dependency ratio decreased from 0.32 to 0.28 (Figure 3).
- By 2060, the dependency ratio is projected to rise to 0.66. The old-age dependency ratio is projected to increase to 0.39, while the youth dependency ratio is projected to decrease to 0.27.

An aging population also implies greater need for healthcare services because the prevalence of chronic disease, multiple chronic diseases, functional decline, and cognitive decline all increase with advancing age. Thus, older people are more likely to need healthcare services and long-term care. For example, one analysis conducted for the Administration on Community Living estimated that 70% of people age 65 and over will require LTSS before they die.^2^

Figure 4 Adults with chronic conditions, by age, 2018

Note: Chronic conditions measured were arthritis, cancer, chronic obstructive pulmonary disease, coronary heart disease, current asthma, diabetes, hepatitis, hypertension, stroke, and weak/failing kidneys.

Source: Boersma P, Black LI, Ward BW. Prevalence of multiple chronic conditions among U.S. adults, 2018. Prev Chronic Dis. 2020 Sep 17:17:E106. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7553211/.

- In 2018, the percentage of people with no chronic diseases was 72.6% among adults ages 18-44 years, 36.6% among adults ages 45-64 years, and 12.4% among adults age 65 years and over (Figure 4).
- The percentage of people with one chronic disease was 20.7% among adults ages 18-44 years, 30.4% among adults ages 45-64 years, and 23.9% among adults age 65 years and over.
- The percentage of people with two or more chronic diseases was 6.7% among adults ages 18-44 years, 33.0% among adults ages 45-64 years, and 63.7% among adults age 65 years and over.

Figure 5 Adults reporting any limitation with performing tasks, by age, 2021

Note: “Any limitation” includes responses in which respondents indicated “some difficulty,” “a lot of difficulty,” or “cannot do at all.” The survey asks about the use of assistive devices, such as eyeglasses and hearing aids, and whether the person has difficulty seeing, hearing, walking, or completing other activities even with the use of devices.

Source: AHRQ analysis of Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey public use data, Adult Sample, 2021.

- In 2021, among adults age 65 years and over, 29.3% reported any difficulty hearing; 21.7% reported any difficulty seeing, even with glasses; 30.9% reported any difficulty with memory or cognition; 39.3% reported any difficulty walking; 8.3% reported any difficulty with self-care activities such as dressing or bathing; 7.8% reported any difficulty communicating; 16.0% reported any difficulty running errands alone; and 13.3% reported any difficulty participating in social activities (Figure 5).
- Among adults ages 18-64 years, 10.1% reported any difficulty hearing; 15.6% reported any difficulty seeing, even with glasses; 17.7% reported any difficulty with memory or cognition; 11.3% reported any difficulty walking; 2.7% reported any difficulty with self-care activities such as dressing or bathing; 4.4% reported any difficulty communicating; 5.8% reported any difficulty running errands alone; and 8.5% reported any difficulty participating in social activities.

Most older people live productive and meaningful lives. While many people age 65 years and over experience some disability, only a small percentage have severe limitations, mostly due to limited mobility (Figure 6). The gap between the prevalence of older people with some disability and those with severe disability signals an important role for healthcare delivery systems as promoters of healthy aging.^3^ It suggests high-quality healthcare services can mitigate the most important consequences of an aging population by:

- Preventing chronic diseases.
- Managing chronic illnesses early and effectively enough to delay the onset of disability.
- Enabling people with disabilities to participate in society more fully.

Figure 6 Adults reporting severe limitation with performing tasks, by age, 2021

Note: “Severe limitation” includes only responses in which respondents indicated “a lot of difficulty” or “cannot do at all.”

Source: AHRQ analysis of Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey public use data, Adult Sample, 2021.

- In 2021, among adults age 65 years and over, 3.6% reported severe limitation hearing; 2.9% reported severe limitation seeing, even with glasses; 3.5% reported severe limitation with memory or cognition; 13.5% reported severe limitation walking; 2.8% reported severe limitation with self-care activities such as dressing or bathing; 1.5% reported severe limitation communicating; 10.0% reported severe limitation running errands alone; and 6.9% reported severe limitation participating in social activities (Figure 6).
- Among adults ages 18-64 years, 0.9% reported severe limitation hearing; 1.1% reported severe limitation seeing, even with glasses; 2.2% reported severe limitation with memory or cognition; 2.7% reported severe limitation walking; 0.5% reported severe limitation with self-care activities such as dressing or bathing; 0.6% reported severe limitation communicating; 2.4% reported severe limitation running errands alone; and 3.0% reported severe limitation participating in social activities.

The impact of aging on healthcare delivery will vary by location, with some areas anticipating greater burden than others. In 2020, more than one-third of all people age 65 and over lived in five states (Figure 7): California (6.0 million), Florida (4.6 million), Texas (3.9 million), New York (3.4 million), and Pennsylvania (2.4 million).

States also vary in the percentage of older people in their populations (Figure 8). People age 65 and over accounted for 20% or more of the population in five states in 2020: Maine (21.8%), Florida (21.3%), West Virginia (20.9%), Vermont (20.6%), and Delaware (20.0%). Within states, rural communities often have older populations than metropolitan ones.^4^

Figure 7 Number of people age 65 and over, by state, 2020

U.S. map showing number of people 65 and over; numbers range from 90,000 to 5,976,000, with a median of 771,000; as noted above, more than one-third of all people age 65 and over lived in five states: California, Florida, Texas, New York, and Pennsylvania; the lowest numbers were in Alaska, North Dakota, South Dakota, Vermont, and Wyoming.

Source: Administration for Community Living, 2021 Profile of Older Americans, November 2022, using Census Bureau population estimates. https://acl.gov/sites/default/files/Profile%20of%20QA/2021%20Profile%20of%20QA/2021ProfileOlderAmericans_508.pdf.

Figure 8 People 65 years and over as a percentage of state population, 2020

U.S. map showing people 65 and over as a percentage of state population; as noted above, older adults make up 20% of the population in five states. The percentages for all states are between 15 and 20%.

Source: Administration for Community Living, 2021 Profile of Older Americans, November 2022, using Census Bureau population estimates. https://acl.gov/sites/default/files/Profile%20of%20QA/2021%20Profile%20of%20QA/2021ProfileOlderAmericans_508.pdf.

❖ The United States has grown more racially and ethnically diverse.

The NHQDR defines racial and ethnic groups according to Standards for the Classification of Federal Data on Race and Ethnicity (https://www.govinfo.gov/app/details/FR-1997-10-30/97-28653), issued by the Office of Management and Budget. Racial and ethnic categories for federal statistics and program administrative reporting are defined as follows:

- American Indian or Alaska Native (AI/AN). A person who has origins in any of the original peoples of North and South America (including Central America) and maintains tribal affiliation or community attachment.
- Asian. A person having origins in any of the original peoples of the Far East, Southeast Asia, or Indian subcontinent, including, for example, Cambodia, China, India, Japan, Korea, Malaysia, Pakistan, the Philippine Islands, Thailand, and Vietnam.
- Black or African American. A person having origins in any of the Black racial groups of Africa. Regional, cultural, geographic, and heritage terms such as “Haitian” are sometimes used in addition to “Black or African American.”
- Hispanic or Latino. A person of Cuban, Mexican, Puerto Rican, Central or South American, or other Spanish culture or origin, regardless of race. The term “Spanish origin” can be used in addition to “Hispanic or Latino.”
- Native Hawaiian/Pacific Islander (NHPI). A person having origins in any of the original peoples of Hawaii, Guam, Samoa, or other Pacific islands.
- White. A person having origins in any of the original peoples of Europe, the Middle East, or North Africa.

In 2020, non-Hispanic (NH) White people made up the largest racial and ethnic group in the United States, accounting for 191,697,647 people. The next largest groups were:

- Hispanic (62,080,044 people),
- NH-Black (39,940,338 people),
- NH-Asian (19,618,719 people),
- NH-multiracial/other race (15,238,816 people),
- NH-AI/AN (2,252,699 people), and
- NH-NHPI (622,018 people).

Although they are the largest racial and ethnic group, non-Hispanic White people’s share of the population has decreased over the past decade. Between 2010 and 2020, the percentage of people who self-identify as NH-White decreased by 9.3%. Much of the increase in racial and ethnic diversity can be attributed to a larger number of people who identify as NH-multiracial, NH-other race, or Hispanic.^ii^

As a percentage of the population, Hispanic groups grew by 14.7%. As a percentage of the population, NH-Asian groups grew by 25.5%, NH-multiracial groups grew by 115.8%, and NH-other race groups grew by 150.0%, but these still account for a smaller number of people than Hispanic groups. NH-Black, NH-AI/AN, and NH-NHPI groups accounted for approximately the same percentage of the population as they did in 2010.

Figure 9 Distribution of people in the United States, by ethnicity and race, 2010 and 2020

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Percentages may not add to 100 due to rounding.

Source: U.S. Census Bureau. American Community Survey, Table P2, 2010 and 2020.

- In 2020, 18.7% of people identified as Hispanic alone, 0.7% of people identified as NH-AI/AN, 5.9% identified as NH-Asian, 12.1% identified as NH-Black, 0.2% identified as NH-NHPI, 57.8% identified as NH-White, 4.1% identified as NH-multiracial, and 0.5% identified as NH-some other race (Figure 9).
- In 2010, the percentages of racial and ethnic groups were 16.3% Hispanic, 0.7% NH-AI/AN, 4.7% NH-Asian, 12.2% NH-Black, 0.2% NH-NHPI, 63.7% NH-White, 1.9% NH-multiracial, and 0.2% NH-some other race.

Minority populations that grew in the past decade are also younger than the NH-White population. This difference contributed to widening age differences between the majority NH-White population and minority groups. For example, in 2021, 22% of NH-White people were adults age 65 years and over, while 19% were children or adolescents less than 18 years old. But among Hispanic people, the next largest racial/ethnic group, only 8% were adults age 65 years and over, while 32% were children and adolescents less than 18 years old.^5^

In 2020, most (75.7%) adults age 65 and over were NH-White, while just over half (50.4%) of all children and adolescents under 18 years old were in minority groups (Figure 10). Increased diversity among children and working age adults has important implications for healthcare delivery, including a growing need for a broader range of culturally and linguistically appropriate pediatric, obstetric, and mental health services. Higher rates of socioeconomic disadvantage among racial and ethnic minority groups also suggests a growing need to address social determinants of health in addition to healthcare needs.

❖ Demographic trends suggest an increased need for more culturally and linguistically appropriate services for younger populations.

Figure 10 U.S. population by race/ethnicity and age, 2020

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Source: Annual Estimates of the Resident Population by Sex, Age, Race, and Hispanic Origin for the United States: April 1, 2020, to July 1, 2022 (NC-EST2022-ASR6H), released June 2023.

- In 2020, among children and adolescents less than 18 years old, 18,771,972 (25.6%) identified as Hispanic; 585,847 (0.8%) identified as NH-AI/AN; 3,992,252 (5.4%) identified as NH-Asian; 10,103,581 (13.8%) identified as NH-Black; 156,622 identified as NH-NHPI (0.2%); 36,424,964 (49.6%) identified as NH-White; and 3,380,954 (4.6%) identified as NH-multiracial (Figure 10).
- In 2020, among adults ages 18-64 years, 38,262,455 (18.8%) identified as Hispanic; 1,509,615 (0.7%) identified as NH-AI/AN; 13,000,114 (6.4%) identified as NH-Asian; 26,525,792 (13.0%) identified as NH-Black; 396,347 (0.2%) identified as NH-NHPI; 119,782,248 (58.9%) identified as NH-White; and 3,792,226 (1.9%) identified as NH-multiracial.
- Among adults age 65 years and over, 4,804,123 (8.8%) identified as Hispanic; 310,327 (0.6%) identified as NH-AI/AN; 2,586,750 (4.7%) identified as NH-Asian; 5,108,118 (9.3%) identified as NH-Black; 63,998 (0.1%) identified as NH-NHPI; 41,496,956 (75.7%) identified as NH-White; and 456,251 (0.8%) identified as NH-multiracial.

❖ A growing percentage of people resides in metropolitan communities.

Between 2010 and 2020, the percentage of people who live in metropolitan areas increased from 85.0% to 86.2% of the population, while the percentage of people in nonmetropolitan counties decreased from 15% to 13.9% of the population.^6^

The NHQDR examines differences in health outcomes by rural-urban location of residence using the 2013 National Center for Health Statistics (NCHS) classification.^iii^ Data on state-based rural-urban metrics are also available through the NHQDR State Snapshots (https://datatools.ahrq.gov/nhqdr).

The 2013 NCHS classification approach includes six urbanization categories. Four are metropolitan county designations derived from census-defined metropolitan statistical areas (MSAs). MSAs are areas containing a large population center and adjacent communities that have a high degree of economic and social integration with that core. MSAs have at least 50,000 residents and include an urban core with population density of at least 1,000 people per square mile and adjacent areas with at least 500 people per square mile. The four metropolitan county descriptions are:

- Large Central Metropolitan: Counties in an MSA of 1 million or more residents:
  1. That contain the entire population of the largest principal city of the MSA, or
  2. Whose entire population is contained within the largest principal city of the MSA, or
  3. That contain at least 250,000 residents of any principal city in the MSA.
    Examples of large central metro areas are Denver County, Colorado; Washington, DC; and Cook County, Illinois.
- Large Fringe Metropolitan: Counties in MSAs of 1 million or more population that do not qualify as large central areas.^iv^ Large fringe metropolitan areas are also described as suburban areas. Examples of large fringe metro areas are San Bernardino County, California; Broward County, Florida; and Bergen County, New Jersey.
- Medium Metropolitan: Counties in MSAs of 250,000 to 999,999 population. Examples of medium metro areas are Scott County, Kentucky; York County, Maine; and Douglas County, Nebraska.
- Small Metropolitan: Counties in MSAs of less than 250,000 population. Examples of small metro areas are Baldwin County, Alabama; Wayne County, North Carolina; and Allen County, Ohio.

The remaining two categories are nonmetropolitan county designations, which are defined as not meeting the criteria for being an MSA (i.e., population less than 50,000 inhabitants and/or population density less than 500 people per square mile). These nonmetropolitan designations are:

- Micropolitan: Nonmetropolitan counties in a “micropolitan statistical area,” which are defined as counties that are less densely populated than MSAs and centered around smaller urban clusters with 2,500-49,999 inhabitants. Examples of micropolitan areas are Woodward County, Oklahoma; Cherokee County, South Carolina; and Harrison County, West Virginia.
- Noncore: Nonmetropolitan counties that are outside of a micropolitan statistical area. Noncore counties are also described as rural. Examples of noncore areas are Wallowa County, Oregon; Bedford County, Pennsylvania; and Crane County, Texas.

When examining trends, it is important to recognize that the key differences between the 2013 NCHS Urban-Rural Classification scheme and the earlier 2006 version are in how it describes small metropolitan, micropolitan, and noncore areas. The 2013 classification broadens the inclusion criteria for each of these residence locations. All other definitions are unchanged (Table 1).^7^

Table 1 NCHS Urban-Rural Classification Scheme, 2006 vs. 2013

Areas | 2006 Classification | 2013 Classification
Small Metropolitan | Counties in MSAs of 50,000–249,999 population | Counties in MSAs of less than 250,000 population
Micropolitan | Urban cluster population of 10,000–49,999 individuals | Counties in a micropolitan statistical area
Noncore | Nonmetropolitan counties that did not qualify as micropolitan | Nonmetropolitan counties that are not in a micropolitan statistical area

Figure 11 shows a map of U.S. county classifications according to the 2013 NCHS Urban-Rural Classification system.

Figure 11 2013 NCHS Urban-Rural County Classifications in the United States

Map of United States showing county groupings, which are described in the text above

Source: Ingram DD, Franco SJ. 2013 NCHS Urban–Rural Classification Scheme for Counties. National Center for Health Statistics. Vital Health Stat 2. 2014 Apr;(166):1-73. https://www.cdc.gov/nchs/data/series/sr_02/sr02_166.pdf.

Between 1990 and 2022, the number of people grew faster in metropolitan counties than nonmetropolitan counties. But between 2020 and 2022, during the COVID-19 public health emergency (PHE), the population of large central metro areas decreased slightly, while large fringe metro areas continued to grow.

Figure 12 U.S. population, by location of residence, 1990-2022

Source: U.S. Department of Agriculture Economic Research Service county-level population data files, using data from U.S. Census Bureau population estimates. Accessed at https://www.ers.usda.gov/data-products/county-leveldata-sets/ and linked with National Center for Health Statistics 2013 Urban-Rural Classification Scheme for Counties data files located at https://www.cdc.gov/nchs/data_access/urban_rural.htm.

- Between 1990 and 2020, the population increased:
  ■ 32.0% in large central metro counties (from 77.5 million to 102.3 million),
  ■ 52.7% in large fringe metro counties (from 56.3 million to 85.9 million),
  ■ 32.1% in medium metro counties (from 50.9 million to 67.3 million),
  ■ 25.9% in small metro counties (from 23.9 million to 30.2 million),
  ■ 14.5% in micropolitan counties (from 23.8 million to 27.2 million), and
  ■ 5.7% in noncore counties (from 17.6 million to 18.6 million) (Figure 12).
- Between 2020 and 2022, the population decreased 0.9% in large central metro counties (from 102.3 million to 101.4 million). It increased:
  ■ 1.5% in large fringe metro counties (from 85.9 million to 87.2 million),
  ■ 1.5% in medium metro counties (from 67.3 million to 68.3 million),
  ■ 1.0% in small metro counties (from 30.2 million to 30.5 million),
  ■ 0.2% in micropolitan counties (from 27.22 million to 27.28 million), and
  ■ 0.2% in noncore counties (from 18.61 million to 18.64 million).

### Summary

The U.S. population is aging rapidly, even as it grows more diverse racially and ethnically and becomes more metropolitan. These demographic trends have important implications for healthcare delivery, including an urgent need for services that address the needs of older adults and that support people with disabilities.

In addition, growing racial and ethnic diversity has largely occurred among younger adults and children, which suggests a growing need for culturally and linguistically appropriate healthcare services for conditions that affect younger populations, including pediatric, obstetric, mental health, and substance use treatment services.

## Leading Health Concerns

Measures of life expectancy and premature death suggest that the United States has fallen short of its potential to promote and protect health. The following data quantify those trends.

❖ Life expectancy has not kept pace with other nations.

U.S. life expectancy at birth lags behind the average life expectancy of similar industrialized nations in the Organisation for Economic Co-operation and Development (OECD).^v^ The gap grew steadily after 1980 and widened markedly during the COVID-19 pandemic, when life expectancy decreased from 78.8 years in 2019 to 76.1 years in 2021.^8^

The 2021 decrease in U.S. life expectancy is largely attributable to deaths from COVID-19, which contributed to half of the decrease. Unintentional injuries (a plurality of which were drug overdose, 15.9% of the decrease), heart disease (4.1% of the decrease), liver disease (3.0% of the decrease), and suicide (2.1% of the decrease) were other important causes. The decrease in life expectancy would have been even greater except that deaths due to homicide, influenza and pneumonia, congenital malformations, and perinatal events decreased in 2021 compared with historical trends.^9^

Figure 13 Life expectancy in United States vs. comparable OECD countries, 1980-2021

Source: Peterson-Kaiser Family Foundation Health System Tracker analysis of Centers for Disease Control and Prevention, Australian Bureau of Statistics, and Organisation for Economic Co-operation and Development data. https://www.healthsystemtracker.org/chart-collection/quality-u-s-healthcare-system-compare-countries/.

- In 2019, before the COVID-19 global pandemic, average life expectancy in the United States was 78.8 years vs. 82.6 years in comparable OECD countries (Figure 13).
- In 2020, average life expectancy in the United States was 77.0 years vs. 82.1 years in comparable OECD countries.
- In 2021, average life expectancy in the United States decreased further to 76.1 years even as life expectancy improved to 82.4 years in comparable OECD countries.

❖ U.S. life expectancy lags behind that of people in similar OECD countries for all racial/ethnic groups except non-Hispanic Asian people. All groups experienced sharp declines in life expectancy during the COVID-19 public health emergency.

National averages can obscure wide disparities in life expectancy among racial/ethnic groups. Gaps among Hispanic, NH-Black, and NH-White groups were persistent in the decade that preceded the COVID-19 pandemic and all groups experienced large drops in life expectancy in 2020 and 2021.

Figure 14 Life expectancy, United States, by race/ethnicity, 2008-2021

Key: OECD = Organisation for Economic Co-operation and Development; NH = non-Hispanic; AI/AN = American Indian or Alaska Native.

Note: Data for NH-AI/AN and NH-Asian groups are not available for years prior to 2019.

Source: Peterson-Kaiser Family Foundation Health System Tracker analysis of Centers for Disease Control and Prevention data, 2008-2021. https://www.healthsystemtracker.org/indicator/health-well-being/life-expectancy/.

- In 2021, life expectancy was highest for NH-Asian individuals (83.5 years). They were the only group in which average life expectancy was higher than the average life expectancy of comparable OECD countries(Figure 14).
- NH-Asian life expectancy was followed by that of Hispanic (77.7 years), NH-White (76.4 years), NH-Black (70.8 years), and NH-AI/AN (65.2 years) people.
- Life expectancy was higher for all groups before the COVID-19 pandemic. In 2019, life expectancy was highest for NH-Asian individuals (85.6 years), followed by Hispanic (81.9 years), NH-White (78.8 years), NH-Black (74.8 years), and NH-AI/AN (71.8 years) people.
- The largest declines in life expectancy between 2019 and 2021 occurred among NH-AI/AN individuals (9.2% decrease in life expectancy), followed by NH-Black (5.3% decrease), Hispanic (5.1% decrease), NH-White (3.0% decrease), and NH-Asian (2.5% decrease) people.

Exploring the clinical conditions that contribute to shortened life expectancy and widened disparities can provide insights for improving healthcare delivery and associated outcomes. The following figures and tables characterize the leading causes of death and years of potential life lost among Americans.

❖ The leading causes of death in the United States include heart disease, cancer, COVID-19, and unintentional injuries/accidents.

Figure 15 Ten leading causes of death, based on age-adjusted mortality, 2018-2022

Note: Mortality data for 2022 are based on provisional estimates.

Source: Centers for Disease Control and Prevention, Web-based Injury Statistics Query and Reporting System (WISQARS), 2018-2022. https://www.cdc.gov/injury/wisqars/index.html.

- Heart disease and cancer remained the leading causes of death in 2021, accounting for 173.8 deaths and 146.6 deaths per 100,000 population, respectively (Figure 15).
- Provisional data indicate that death rates for these causes continued to increase in 2022 to 175.5 heart disease deaths per 100,000 population and to 147.6 cancer deaths per 100,000 population.
- COVID-19 remained the third leading cause of death in 2021, with mortality rates rising from 85.0 deaths per 100,000 population in 2020 to 104.1 deaths per 100,000 population in 2021. However, provisional data indicate that COVID-19 death rates decreased to 46.5 deaths per 100,000 population in 2022.
- Unintentional injuries were the 4th leading cause of death in 2021, accounting for 64.8 deaths per 100,000 population. Approximately 40% of these deaths were attributable to accidental poisonings/overdoses, including those caused by overdose due to opioids and other drugs. Provisional data indicate that deaths from this cause declined in 2022 to 59.7 deaths per 100,000 population.
- Other leading causes of death in 2021 were stroke, chronic lung disease, Alzheimer’s disease, diabetes, kidney disease, and influenza and pneumonia.

❖ The leading causes of death vary among racial/ethnic groups, locations of residence, and age groups.

Age-adjusted mortality and the leading causes of death vary by race/ethnicity, location of residence, and age. But the ways they vary depend on which groups are compared.

Table 2 shows the top five leading causes of death by race and ethnicity, in ranked order. It shows that each group has different patterns of vulnerability to specific diseases. For example, COVID-19 was the third leading cause of death in the overall population in 2021, but it was the number 1 cause of death for Hispanic, NH-AI/AN, and NH-NHPI groups. Age-adjusted mortality rates due to COVID-19 for these groups were similar in magnitude to mortality rates due to the leading cause of death for NH-White people, heart disease.

Table 2 Five leading causes of death, by race/ethnicity, based on age-adjusted deaths per 100,000 population, 2021

Race/Ethnicity | #1 | #2 | #3 | #4 | #5
Hispanic | COVID-19 (151.8) | Heart disease (119.0) | Cancer (105.1) | Unintentional injury (47.3) | Stroke (36.1)
NH-AI/AN | COVID-19 (184.0) | Heart disease (155.2) | Cancer (124.9) | Unintentional injury (122.8) | Liver disease (77.8)
NH-Asian | Cancer (92.9) | Heart disease (85.5) | COVID-19 (61.9) | Stroke (32.6) | Unintentional injury (18.8)
NH-Black | Heart disease (226.2) | Cancer (167.4) | COVID-19 (136.4) | Unintentional injury (79.6) | Stroke (59.6)
NH-NHPI | COVID-19 (185.4) | Heart disease (182.4) | Cancer (144.6) | Unintentional injury (53.1) | Diabetes (54.4)
NH-White | Heart disease (179.8) | Cancer (153.7) | COVID-19 (93.5) | Unintentional injury (70.0) | Chronic lung disease (39.9)
NH-Multiracial | Heart disease (74.9) | Cancer (67.3) | Unintentional injury (37.0) | COVID-19 (45.7) | Stroke (20.3)

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Mortality, 2018–2021, Single Race. Accessed on CDC WONDER Online Database, released in 2023.

Table 3 similarly ranks leading causes of death by geographic location of residence. Among these groups, the relative ranks of heart disease, cancer, COVID-19, and unintentional injury are consistent across urban-rural settings, but the scale of deaths varies. For each disease condition, people in less densely populated communities experienced higher death rates than those who lived in more metropolitan communities.

Table 3 Five leading causes of death, by location of residence, based on age-adjusted deaths per 100,000 population, 2021

Location | #1 | #2 | #3 | #4 | #5
Large Central Metropolitan | Heart disease (178.1) | Cancer (151.4) | COVID-19 (109.2) | Unintentional injury (63.0) | Stroke (43.3)
Large Fringe Metropolitan | Heart disease (188.3) | Cancer (173.1) | COVID-19 (103.7) | Unintentional injury (58.5) | Stroke (46.4)
Medium Metropolitan | Heart disease (213.0) | Cancer (188.5) | COVID-19 (128.9) | Unintentional injury (73.9) | Stroke (51.7)
Small Metropolitan | Heart disease (240.6) | Cancer (205.9) | COVID-19 (147.1) | Unintentional injury (72.2) | Chronic lung disease (56.9)
Micropolitan | Heart disease (274.6) | Cancer (227.2) | COVID-19 (171.6) | Unintentional injury (80.0) | Chronic lung disease (68.0)
Noncore | Heart disease (318.2) | Cancer (265.0) | COVID-19 (199.3) | Unintentional injury (87.9) | Chronic lung disease (80.7)

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Mortality, 2018–2021, Single Race. Accessed on CDC WONDER Online Database, released in 2023.

Table 4 examines the leading causes of death by age group. It shows that suicide, homicide, and unintentional injuries (including drug overdose) are important causes of death among children, adolescents, and younger adults.

Table 4 Five leading causes of death, by age group, based on age-adjusted deaths per 100,000 population, 2021

Age | #1 | #2 | #3 | #4 | #5
<5 years | Perinatal event (53.2) | Congenital abnormality (24.4) | Unintentional injury (14.1) | Homicide (3.1) | Heart disease (2.1)
5–24 years | Unintentional injury (20.1) | Suicide (8.2) | Homicide (8.1) | Cancer (2.5) | COVID-19 (1.8)
25–44 years | Unintentional injury (80.2) | COVID-19 (26.3) | Heart disease (20.2) | Suicide (18.7) | Cancer (17.1)
45–64 years | Cancer (149.2) | Heart disease (133.5) | COVID-19 (122.7) | Unintentional injury (77.6) | Liver disease (31.9)
≥65 years | Heart disease (1,088.6) | Cancer (849.1) | COVID-19 (541.9) | Stroke (277.8) | Chronic lung disease (234.0)

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Mortality, 2018–2021, Single Race. Accessed on CDC WONDER Online Database, released in 2023.

❖ “Unintentional injuries” describe multiple causes of death. For many racial/ethnic groups, opioid overdose contributes to a plurality of these deaths.

“Unintentional injuries” is a category that reflects many different causes of death. Three causes (poisonings/overdoses, falls, and motor vehicle accidents) account for more than 90% of deaths due to unintentional injuries. Overall, poisonings/overdoses accounted for 43.6% of these deaths, but they accounted for a larger share of unintentional injury deaths for NH-AI/AN, NH-Black, and NH-White people and a smaller share among Hispanic and NH-API people (Figure 16).

Figure 16 Underlying causes of death due to unintentional injuries/accidents, by race/ethnicity, 2020

Key: NH = non-Hispanic; AI/AN = American Indian or Alaska Native; API = Asian or Pacific Islander.

Note: “Other Causes” include suffocation, drowning, fire/burn related, natural environment related, other land transportation-related accident, struck by/against physical object, pedestrian accident, firearm related, machinery related, other transportation related, pedal cyclist accident, cut/piercing related, overexertion, and unspecified accidents. The category “Asian or Pacific Islander” combines data for non-Hispanic Asian and non-Hispanic Native Hawaiian/Pacific Islander populations.

Source: Centers for Disease Control and Prevention. Web-based Injury Statistics Query and Reporting System (WISQARS), 2020. https://www.cdc.gov/injury/wisqars/index.html.

- In 2020, the overall rate of death due to unintentional injuries/accidents was 57.6 deaths per 100,000 population. Poisonings/overdoses, falls, motor vehicle-related accidents, and other causes contributed to 43.6%, 21.0%, 20.3%, and 15.3% of these deaths, respectively.
- Among NH-AI/AN people, 99.6 deaths per 100,000 population were due to unintentional injuries/accidents. Poisonings/overdoses, falls, motor vehicle-related accidents, and other causes contributed to 47.4%, 10.5%, 24.9%, and 17.2% of these deaths, respectively.
- Among NH-Black people, 67.1 deaths per 100,000 population were due to unintentional injuries/accidents. Poisonings/overdoses, falls, motor vehicle-related accidents, and other causes contributed to 50.8%, 7.0%, 27.1%, and 15.2% of these deaths, respectively.
- Among NH-White people, 62.8 deaths per 100,000 population were due to unintentional injuries/accidents. Poisonings/overdoses, falls, motor vehicle-related accidents, and other causes contributed to 41.7%, 25.5%, 17.2%, and 15.4% of these deaths, respectively.
- Among Hispanic people, 41.2 deaths per 100,000 population were due to unintentional injuries/accidents. Poisonings/overdoses, falls, motor vehicle-related accidents, and other causes contributed to 46.1%, 29.6%, 10.9%, and 13.3% of these deaths, respectively.
- Among NH-Asian/Pacific Islander people, 18.2 deaths per 100,000 population were due to unintentional injuries/accidents. Poisonings/overdoses, falls, motor vehicle-related accidents, and other causes contributed to 28.6%, 29.1%, 22.0%, and 20.3% of these deaths, respectively.

❖ Chronic diseases contribute to many of the leading causes of death.

Chronic diseases are conditions that last 1 year or more and require ongoing medical attention or limit activities of daily living or both.^vi^ They are the primary factor underlying most leading causes of death. Healthcare delivery systems and clinicians can mitigate their impact on the population’s health by managing and treating these conditions to delay onset of complications and prevent premature mortality.

Six in 10 adults in the United States have a chronic disease, and 4 in 10 have two or more chronic conditions. Chronic conditions contribute to 7 of the 10 leading causes of death and 6 of the 10 leading causes of premature death. Many could be eased or avoided by helping people modify a short list of health behaviors or by managing or treating prevalent health conditions that influence the outcomes of other chronic diseases:

- Healthcare delivery organizations and providers can partner with communities, local social service providers, and public health departments to reduce the burden of chronic diseases by helping people engage in lifestyles and behaviors that reduce risk factors associated with chronic diseases, including:
  ■ Poor nutrition.
  ■ Inadequate physical activity.
  ■ Tobacco use and exposure to secondhand smoke.
  ■ Alcohol use.
  ■ Use of illicit opioids and other substances.
  ■ Unsafe driving.
- Healthcare delivery organizations and providers can also reduce the burden of chronic diseases by treating health conditions that are risk factors for other chronic disease outcomes, including:
  ■ Obesity.
  ■ High blood pressure.
  ■ High cholesterol.
  ■ Uncontrolled diabetes.
  ■ Mental illness.
  ■ Substance use disorders (including use of alcohol, tobacco, opioids, and other drugs).
  ■ Some infections, such as human papillomavirus (HPV), HIV, and hepatitis B and
  - hepatitis C viruses.

### Summary

Between 1980 and 2020, U.S. life expectancy improved by 6.9% before decreasing sharply during the COVID-19 PHE. However, this assessment overlooks the greater gains experienced by similar OECD countries, where life expectancy increased by an average of 10.9% during the same years and COVID-19 had a smaller impact on health.

The National Academies of Sciences, Engineering, and Medicine reported that deaths from drug overdose, alcohol-related causes, suicide, and cardiometabolic disease, such as heart disease and diabetes, were the primary causes for the United States’ lagging performance before 2020.^10^ Deaths due to COVID-19 compounded this trend, resulting in a loss of more than 20 years of life expectancy gains in 2020 and 2021.

Because life expectancy is more strongly influenced by conditions that disproportionately affect the lifespans of working-age people, the nation’s lagging performance on this measure suggests other economic and societal concerns, including a smaller workforce and fewer people to care for children and an aging population.

National vital statistics also show that life expectancy varies across different racial and ethnic groups but the rate of improvement lags the average for similar OECD countries for all groups, indicating that life expectancy for all groups may soon fall below that of people in other industrialized economies. As the ranking and magnitude of causes of death vary among different racial and ethnic groups, the data suggest that each racial and ethnic group may require tailored policies and interventions to achieve optimal health outcomes.

In contrast, data showing that people in nonmetropolitan areas die from the same underlying causes but at higher rates than people in metropolitan areas suggest that nonmetropolitan communities may have less access to effective healthcare services.

Researchers recently studied 12 disease conditions that contribute most to life expectancy. They estimated that public health activities (including reducing tobacco use, screening for cancer, and improving motor vehicle safety) accounted for 44% of the nation’s life expectancy gains between 1990 and 2015. They found that access to improved pharmaceutical treatment (such as antihypertensive medications) and improved medical treatment (such as interventional cardiac procedures) accounted for 35% and 13%, respectively.^11^

The findings of this study suggest that catching up to the life expectancy experienced by people in similar OECD countries will require attention to both public health and medical care services, particularly services that address chronic disease.

## Social Determinants of Health

Considerable evidence indicates that social determinants of health (SDOH)—the social, economic, environmental, and community conditions in which people live—have an even stronger influence on people’s health outcomes than clinical services provided by healthcare delivery systems.^12^ Thus, healthcare delivery systems and healthcare workers should account for SDOH when addressing patients’ health concerns.

This section describes the extent to which SDOH factors are present among people in the United States, which healthcare delivery systems must address to produce optimal health outcomes.

The importance of understanding SDOH is underscored in Healthy People 2030 (https://health.gov/healthypeople), which sets national objectives for improving health and well-being. Healthy People 2030 describes five SDOH domains that can influence health outcomes (Figure 17). Only one of these specifically includes services provided by healthcare delivery systems.

The Health Care Access and Quality domain accounts for a population’s ability to receive healthcare services when needed. It characterizes the extent to which people can access healthcare services and whether they receive high-quality care.^vii^ It also addresses whether people have access to health insurance, which increases access to preventive and chronic disease care, as well as care for major health conditions.

Figure 17 Social Determinants of Health

Circular diagram of five social determinants of health around a drawing of a person: health care access and quality, neighborhood and built environment, social and community context, economic stability, and education access and quality

Source: U.S. Department of Health and Human Services. Healthy People 2030. https://health.gov/healthvpeople/prioritv-areas/social-deteiTninants-health.

❖ Health insurance coverage in the United States has expanded in recent years.

Evidence from observational studies and randomized controlled trials such as the Oregon Health Insurance Experiment (OHIE) links having health insurance coverage with positive outcomes, including:

- Increased financial security,
- Access to primary care,
- Adherence to prescription medications,

- Screening for treatable health conditions (such as diabetes, cholesterol, HIV, and breast, prostate, and colon cancer),
- Improved perceptions of health,
- Reduced depression symptoms, and
- Earlier detection of cancer.^13,14^

The OHIE also reported increased outpatient medical office visits and increased ED and hospital use among people randomized to receive health insurance.^15^ However, longer term studies found decreased ED utilization and increased use of preventive care services after Medicaid expansion under the Affordable Care Act.^16,17^

Viewed together, these studies show that expanding health insurance access increases demand for primary care services and may reduce long-term demand for emergency and acute care services, after a backlog of unmet need has been addressed.

The NHQDR mostly reports on disparities related to insurance status among people ages 0-64 years. It focuses on people less than age 65 years because more than 98% of Americans age 65 years and over have Medicare.^18^ It should be noted, however, that this statistic also means approximately 2% of older adults, or more than 1.1 million people, lack insurance coverage despite meeting Medicare’s age criteria for eligibility.

Insurance status for people ages 0-64 years consists of three categories:

- Private Insurance: Person has insurance from a private insurer.
- Publicly Sponsored Insurance: Person receives insurance from one or more government-sponsored sources, including Medicaid, State Children’s Health Insurance Program (S-CHIP), state-sponsored or other government-sponsored health plans, Medicare, and military and veteran health plans.
- Uninsured: Person does not have any health insurance.

❖ Health insurance coverage in the United States has expanded in recent years.

Data from the National Health Interview Survey indicate that an average of 89.7% of people under age 65 had some form of health insurance in 2021, a 1.3% increase from 2020. But level of health insurance coverage varies among states (Figure 18).

Figure 18 People under age 65 years with any health insurance coverage, 2022

U.S. map showing percentage of people with any health insurance; Massachusetts and Hawaii have the highest percentages and Texas the lowest; key points are in the text below

Source: U.S. Census Bureau, American Community Survey, Table HI05 ACS, 2022.

- The percentage of state population with any health insurance coverage ranges from 77.6% to 96.7%. The median percentage is 90.6%.

Of those with health insurance, approximately 27% had Medicaid, a combination of Medicare and Medicaid, or some other form of publicly sponsored health insurance. Just under three-fourths of people with health insurance had private insurance, often from an employer.

Figure 19 People under age 65 years with private, public, or no health insurance, 2019-2021

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2019-2021.

- In 2019, 88.0% of people under age 65 years had health insurance nationally: 64.3% had any private health insurance; 23.6% had publicly sponsored health insurance^viii^ (Figure 19).
- In 2020, 88.5% of people under age 65 years had health insurance nationally: 64.3% had any private health insurance; 24.0% had publicly sponsored health insurance.
- In 2021, 89.7% of people under age 65 years had health insurance nationally: 65.4% had any private health insurance; 24.2% had publicly sponsored health insurance.

The distribution of people with health insurance varies by demographic factors, including race/ethnicity and location of residence.

Figure 20 People under age 65 years with any health insurance, by race/ethnicity and location of residence, 2021

Key: NH = non-Hispanic.

Note: Data disaggregated by insurance status for NH-NHPI are not reported because samples from these populations are too small to produce statistically stable estimates. Data for public insurance for NH-AI/AN are not reported because samples are too small to produce statistically stable estimates.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- In 2021, among racial and ethnic groups, NH-Asian groups (95.0%) were the most likely to have any health insurance, followed by NH-White (93.3%), NH-multiracial (92.1%), NH-Black (88.6%), and Hispanic (78.0%) (Figure 20).
- Insured people in all racial/ethnic groups were more likely to have private health insurance for at least part of the year. Having any private health insurance was most common among NH-Asian groups (77.1%), followed by NH-White (75.4%), NH-multiracial (59.3%), NH-Black (51.6%), and Hispanic (44.7%).
- Among location of residence, people in large fringe metro counties (i.e., “suburbs,” 91.9%) were most likely to have any health insurance, followed by people in small metro areas (89.6%), medium metro areas (89.4%), noncore counties (i.e., “rural,” 89.3%), large central metro areas (i.e., “cities,” 88.5%), and micropolitan areas (i.e., “small towns,” 87.3%).
- Having private health insurance was most common in metropolitan areas and tapered in less densely populated communities. Having any private health insurance was most common in large fringe metro counties (73.3%), followed by large central metro areas (65.2%), small metro counties (63.2%), medium metro counties (62.4%), noncore areas (58.5%), and micropolitan counties (57.0%).

Breakdowns for private and publicly sponsored insurance are unavailable for NH-AI/AN and NH-NHPI people because sample sizes are too small to report. But data for overall insurance coverage show that NH-AI/AN people, along with Hispanic people, are less likely to have any insurance coverage than other racial and ethnic groups (Figure 21). Additional disparities may also exist within racial and ethnic groups. For example, studies examining disaggregated data show inequitable levels of access for subgroups among NH-Asian people.^19^

Figure 21 People under age 65 years with any health insurance, by race/ethnicity, 2021

Key: NH = non-Hispanic.

Note: Data for NH-NHPI groups are not reported because samples are too small to produce statistically stable estimates.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2021.

- The percentage of people with any insurance coverage in 2021 was highest for NH-Asian people (95.0%), followed by NH-White (93.4%), NH-multiracial (92.5%), NH-Black (89.1%), NH-AI/AN (80.0%), and Hispanic (78.2%) people (Figure 21).

❖ Economic stability is associated with better health.

The Economic Stability domain accounts for a population’s ability to maintain steady employment and afford basic needs, such as housing, utilities, food, medical care, and medications. It also considers how health issues, such as arthritis or health-related disabilities, can limit a person’s ability to work, earn income, and accumulate wealth. Employment, income (the amount a person earns each year), and wealth (their net worth and assets) all enhance health.^ix^

The relationship between income and health outcomes has been studied for many years, and researchers have shown the positive relationship between more income and better health outcomes.^20,21,22,23^ One way to assess the relationship between income and healthcare quality is by examining the delivery of services in relationship to the poverty levels of households or communities.

Poverty is a state in which a person or household lacks sufficient financial resources to afford basic needs, such as food, shelter, or clothing. It also interferes with people’s ability to participate in community life, engage in healthy activities, or access healthcare services when needed. Thus, people who live in poverty are at higher risk for receiving poor quality care and experiencing undesirable outcomes.

Federal guidelines defining the poverty level are issued annually in the Federal Register by the Department of Health and Human Services, Assistant Secretary for Planning and Evaluation.^x^ The guidelines vary by family size and different family income criteria are used for the contiguous 48 states, Alaska, and Hawaii. The poverty guidelines are not defined for Puerto Rico, the U.S. Virgin Islands, American Samoa, Guam, the Republic of the Marshall Islands, the Federated States of Micronesia, the Commonwealth of the Northern Mariana Islands, or Palau.^24^

Figure 22 U.S. household Income distribution by percent population, 2020

Note: Percentiles add to 100. Ranges represent quartiles but each quartile may represent less than or more than 25% of the population. The last quartile is divided into two groups, showing 15.7% and 10.3% of the population, respectively.

Source: U.S. Census Bureau. American Community Survey, Table HINC06, 2020.

- In 2020, the lowest quartile of individual households earned less than $35,000 each year; the highest quartile of households earned $120,000 or more annually (Figure 22).

The Census estimates that 12.8% of the population lives below the federal poverty guideline (PG) but percentages can vary more than twofold among states (Figure 23).

Figure 23 Population with household income less than the poverty guideline, 2020-2022

U.S. map showing percentage of population with income below the poverty guideline; Utah and Vermont have the lowest percentages. New Mexico and Mississippi have the highest; key points are in the text below

Source: U.S. Census Bureau. Current Population Survey, Annual Social and Economic Supplements, Table B-5, 2020-2022.

- The percentage of state population with household income less than PG ranges from 7.1% to 18.2%. The median percentage of state population living in poverty is 10.7% (Figure 23).

For most measures, the NHQDR tracks disparities data based on the ratio of household income to the PG for the household’s size. For measures drawn from AHRQ’s Healthcare Cost and Utilization Project (HCUP), income is defined using the median income of the patient’s residential ZIP Code.^xi^ In 2020, the median household income was $64,994. More than one-quarter of households (26.2%) earned less than $35,000 per year; the top 10% of households earned $200,000 or more per year.

The NHQDR uses the ratio of household income to PG^24^ to characterize the relationship between poverty and healthcare delivery. Figure 24 shows the percentage of the U.S. population that lives below PG thresholds commonly used in this report.

Figure 24 Cumulative percentage of U.S. households with different ratios of income to poverty, 2020

Note: In 2020, the PG, which is used to determine income-to-PG ratios, was $12,760 for a one-person household, $17,240 for a two-person household, $21,720 for a three-person household, and $26,200 for a four-person household.

Source: American Community Survey, 5-year estimates, 2020, Table S1701, 2020.

- In 2020, 12.8% of the population had annual household incomes equal to or lower than 100% of the PG; 17.0% had household incomes between 100% and 199% of the PG; 29.7% had household incomes between 200% and 399% of the PG; and 59.5% of the population had household incomes at or lower than 400% of the PG (meaning that more than 40% had higher household incomes).

❖ Social connectedness is associated with better health.

The Social and Community Context domain accounts for the influence that positive and negative relationships with family, friends, coworkers, and the broader community can have on health. This domain includes the ability to communicate with healthcare providers and navigate social norms in healthcare delivery processes. Interpersonal relationships and rapport with clinicians are difficult to measure in a population. However, a few statistics provide a window on this domain.

Five-year estimates from the American Community Survey report that 86.5% of the population was born in the United States, and 93.0% of the population are U.S. citizens. Of the 13.5% born outside the United States, 6.9% are naturalized U.S. citizens and 6.6% are not naturalized U.S. citizens.^25^

More than one-fifth (21.5%) of the population age 5 years and over speaks a language other than English as their primary language at home, but the percentage of households with limited English proficiency varies among states. Spanish is the second most spoken language in the United States (13.2%). Asian and Pacific island languages account for 3.5%, other Indo-European languages for 3.7%, and other languages for 1.1%.^26^

Figure 25 Percentage of households with limited English proficiency, 2022

U.S. map showing percentage of households in each state with limited English proficiency; West Virginia has the lowest percentage and California has the highest; key points are in the text below

Source: U.S. Census Bureau. American Community Survey 1-year estimates, Table SI602, 2022.

- The percentage of state population from households with limited English proficiency ranges from 0.4% to 8.4%. The median is 2.0% (Figure 25).

Most communities appear to have relatively stable populations, with the vast majority (86.2%) staying in the same place the previous year. Fewer than 1 in 7 people reported moving in the previous year.^25^ Specifically:

- 7.7% moved within the same county.
- 3.2% moved to a different county but remained in the same state.
- 2.3% moved to a different state.
- 0.6% moved abroad.

Nationally, in 2022, 13.9% of people in the United States were foreign born. Just over half (7.4%) were either naturalized citizens or Americans born abroad, while the remaining people (6.5%) were not U.S. citizens. But immigration patterns vary widely among states and local communities. Because publicly sponsored healthcare and social service programs often exclude people who are not American citizens, communities where noncitizens live may receive fewer resources than needed, leading to socioeconomic disadvantage for the healthcare systems that serve them.

Figure 26 Percentage of people who are not U.S. citizens, 2022

U.S. map showing percentage of people who are not U.S. citizens; West Virginia has the lowest percentage and California has the highest; key points are in the text below

Source: U.S. Census Bureau. American Community Survey 1-year estimates, Table B05001, 2022.

- The percentage of state population who are not U.S. citizens ranges from 0.8% to 12.2%. The median is 3.6% (Figure 26).

❖ Access to high-quality education is associated with better health.

The Education Access and Quality domain accounts for the association between having a higher level of education and living a longer, healthier life. Access to high-quality formal education can improve economic stability, enhance the likelihood of engaging in healthy behaviors, and improve a person’s ability to understand and adhere to medical treatment.

Just under half of children between 3 and 4 years old are enrolled in school, but nearly all children between 5 and 8 years are. School enrollment declines steadily after age 18 years.

Figure 27 Percentage of people in the United States enrolled in school, by age, 2020

Source: American Community Survey, 5-year estimates, 2020, Table S1401, 2020.

- Among the population age 3 years and over and enrolled in kindergarten to 12th grade (Figure 27):
  ■ 7.5% are enrolled in kindergarten.
  ■ 29.8% are enrolled in grade 1 to grade 4.
  ■ 31.1% are enrolled in grade 5 to grade 8.
  ■ 31.6% are enrolled in grade 9 to grade 12.

Most adults age 25 years and over in the United States (88.5%) have a high school diploma. Approximately one-third have a bachelor’s degree, and about 13% have a graduate or professional degree. About 20% of adults attended college but did not get a degree, and about 9% have an associate’s degree. About 5% of the adult population did not attend school beyond eighth grade.^27^

❖ Health quality is influenced by community characteristics.

The Neighborhood and Built Environment domain accounts for the influence physical infrastructure (e.g., access to transportation, access to healthy food options, spaces for engaging in physical activity, access to high-speed internet) and the environment (e.g., air quality, water quality) have on health.

Neighborhood and built environment often interact with health and healthcare delivery in bidirectional and reinforcing ways. For example, studies show that unstable housing and lack of transportation can influence a person’s ability to access healthcare services, adhere to treatment recommendations, and recover from an illness or injury. In addition, the consequences of poor health can limit a person’s ability to obtain housing or afford transportation.

Broadband internet access is another example of the built environment as a social determinant of health. With healthcare delivery organizations expanding telehealthcare services, a person’s access to healthcare services may come to depend on having access to high-speed internet. From 2015 to 2020, 85.5% of people in the United States had a broadband internet subscription, up from 78.7% from 2013 to 2017.

Many people still lack access, particularly those in lower income households and those in nonmetropolitan areas (Figure 28).^28^ AHRQ offers a data visualization on poverty and broadband access to help readers explore this issue.

Public libraries (a third example of the built environment) may offer a way to partially offset lack of individual access to broadband internet. Libraries are actively exploring opportunities to provide people with public access to private spaces equipped with computers and broadband for patrons to access telehealth services.^29^

Figure 28 Percentage of households with any broadband service subscription, 2013-2017

U.S. map showing percentage of households in each county with broadband access; percentage ranges from 0 to 100, with metropolitan areas having higher percentages and rural areas having lower percentages

Source: U.S. Census Bureau, American Communities Survey 5-year estimates, 2013-2017. https://www.census.gov/librarv/stories/2018/12/rural-and-lower-income-coiinties-lag-nation-internetsubscription.html.

❖ The Social Vulnerability Index is a tool to help assess the relationship between social determinants of health and healthcare delivery.

The Social Vulnerability Index (SVI) is a tool that can enable users to account for social factors that contribute to healthcare delivery and outcomes. The SVI is a composite index that combines indicators of social vulnerability from four domains (Figure 29) using geographically linked indicators from the Census Bureau’s American Community Survey and other sources.

Figure 29 Social Vulnerability Index domains

Diagram showing Social Vulnerability Index components; overall vulnerability has four domains with specific elements: Socioeconomic status (e.g., below 150% poverty, unemployed, no high school diploma) Household characteristics (e.g., 65 and older, disability) Racial and ethnic minority status (e.g., Hispanic or Latino, Black, Asian) Housing type and transportation (e.g., mobile home, crowding, no vehicle)

Source: Centers for Disease Control and Prevention, Agency for Toxic Substances and Disease Registry, CDC/ATSDR SVI 2020 Documentation - 8/5/2022. https://www.atsdr.cdc.gov/placeandhealth/svi/documentation/pdf/SVI2020Documentation 08.05.22.pdf.

The SVI rates communities with a summary score that indicates whether a community has high social vulnerability (i.e., more likely to experience undesirable outcomes due to socioeconomic risks), low social vulnerability (i.e., less likely to experience undesirable outcomes), or in-between. Health systems, policymakers, and others can use the SVI in several ways, including:

- Identifying populations vulnerable to social, economic, and environmental stressors that can affect their ability to access healthcare services or adhere to treatment plans.
- Informing resource allocation decisions to increase the likelihood that vulnerable communities can access the services most appropriate for their needs.
- Guiding planning and development of healthcare services.
- Evaluating healthcare delivery policies and interventions.

Mapping tools and other SVI resources are available from the Centers for Disease Control and Prevention (CDC) (Figure 30).

Figure 30 County-level SVI score in continental United States, 2020

Note: People in high SVI counties (darker shading) have more socioeconomic vulnerability and are at greater risk for experiencing unfavorable outcomes than people in in low SVI counties (lighter shading).

U.S. map displaying county SVI scores in four tiers: low, low-medium, medium-high, and high; scores tend to be high in the South and parts of the West Coast states

Source: Centers for Disease Control and Prevention, Agency for Toxic Substances and Disease Registry, Social Vulnerability Index. Accessed at https://www.atsdr.cdc.gov/placeandhealth/svi/interactive_map.html on September 1, 2023.

### Summary

Social determinants of health (SDOH) shape a person’s well-being and health and thus have a crucial role in determining both the need for healthcare services and how successfully people respond to treatment. In fact, such determinants often have a stronger influence on health and use of healthcare services than care provided by healthcare systems. SDOH that can affect health include health insurance coverage, household income, education, employment opportunities, housing availability and quality, access to broadband internet, culture, and language.

Prevalence of social vulnerability related to SDOH varies widely within the population and among states. Thus, state and local efforts to improve socioeconomic conditions within communities play an essential role in improving healthcare quality and eliminating health disparities.

## Healthcare Delivery Systems

The United States must have an adequate healthcare delivery infrastructure to meet population needs. Americans receive healthcare from a complex ecosystem of people, institutions, organizations, and resources. The healthcare workforce includes more than 60 occupations that provide direct care to patients, as well as many other administrative, technological, and support occupations.

Healthcare infrastructure includes diverse organizations, such as medical offices; dental offices; hospitals; long-term care facilities; home care services; ambulatory surgery centers; public health departments; health insurance plans; and various industries that produce medications, medical devices, and healthcare technological applications.

❖ The healthcare workforce plays a key role in healthcare delivery.

Delivering high-quality care often requires that the right number and combination of healthcare workers are available and can work together effectively. For example, routine surgical procedures can be delayed if only a surgeon is present. Safe, high-quality procedures may require anesthesiologists, nurses, pharmacy staff, laboratory technicians, staff who clean operating rooms, staff to sterilize and safely store instruments, and other professions.

Reports of hospital, nursing home, and community-based healthcare staff shortages due to increased healthcare worker turnover, burnout, lack of support for dependent family members, illness, and death during the COVID-19 PHE have raised concerns about whether the United States has the capacity to deliver safe, high-quality care. Data from the Bureau of Labor Statistics (BLS) offer support for these concerns but also highlight important nuances.

The BLS classifies healthcare delivery “establishments” into major types of settings: ambulatory healthcare, hospitals, and nursing and residential care facilities.^xii^ Its Standard Occupational Classifications lists more than 60 different healthcare occupations that provide direct care services in those settings. Other, non-direct care occupations, such as managers, security, and catering, also work in healthcare settings.

This section uses data from the BLS Current Employment Survey and BLS Current Population Survey to describe overall workforce trends and trends for seven types of healthcare occupations: physicians, advanced practice registered nurses (APRNs), registered nurses, mental health workers, and three sets of other groups of healthcare occupations, classified by level of education needed to enter the profession (Figure 31).^xiii,30^

Figure 31 Distribution of race and ethnicity in different healthcare occupations, 2021

Source: U.S. Census, American Community Survey, 2021.

❖ Postpandemic employment has improved in many sectors but workforce participation in the nursing and residential care sector continues to shrink.

The healthcare workforce grew approximately 15.5% over the past decade, with most rapid growth occurring in the ambulatory sector. Although workforce size decreased sharply at the beginning of the COVID-19 PHE, there were approximately 16.6 million workers as of January 2023, which was 1.2% higher than it had been in January 2020. This increase signals that overall healthcare workforce participation had returned to levels reported immediately before the PHE in January 2020. However, the recovery has been uneven among different healthcare settings and worker groups.

Figure 32 Number of workers employed and at work in ambulatory healthcare, hospitals, and nursing and residential care facilities, January 2013-January 2023

Source: Bureau of Labor Statistics, Current Employment Statistics (National), January 2013-January 2023. Accessed at https://www.bls.gov/ces/data/ on August 2, 2023.

- Workforce participation in the ambulatory healthcare sector was 8.3 million workers in January 2023, up 5.7% from levels reported in January 2020 (Figure 32).^xiv^
- Workforce participation in the hospital sector was 5.3 million workers in January 2023, statistically unchanged from levels reported in January 2020.
- Workforce participation in the nursing home and residential care sector was 3.1 million workers in January 2023, down 8.4% from levels reported in January 2020.

Data from the BLS Current Population Survey provide less statistically stable estimates due to smaller sample sizes but allow examination of employment trends by occupation and worker demographic characteristics. The data show similar levels of workforce participation by physicians, nurses, and APRNs in December 2022 as in January 2020.

Figure 33 Number of physicians, advanced practice registered nurses, nurses, and mental health workers employed and at work in any healthcare setting, January 2020-December 2022

Key: APRN = advanced practice registered nurse.

Source: U.S. Bureau of Labor Statistics, Current Population Survey, monthly data, January 2020-December 2022.

- Approximately 3,139,000 nurses participated in the workforce in December 2022, unchanged from the 3,125,000 nurses reported in January 2020 (Figure 33).
- Approximately 921,000 physicians participated in the workforce in December 2022, unchanged from the 1,067,000 physicians reported in January 2020.
- Approximately 719,000 mental health workers participated in the workforce in December 2022, unchanged from the 637,000 workers reported in January 2020.
- Approximately 260,000 APRNs participated in the workforce in December 2022, unchanged from the 256,000 APRNs reported in January 2020.

Current Population Survey data also show approximately 100,000 fewer workers in December 2022 than in January 2020 for nonphysician, non-nurse healthcare professions that typically require an associate’s degree or less education (such as medical assistants, paramedics, and pharmacy assistants). Numbers were also lower for professions that typically require a doctoral degree or clinical internship (such as podiatrists, physical therapists, and pharmacists). Although not statistically significant, the size of these gaps signals a less robust recovery for these worker categories and warrants monitoring.

Figure 34 Number of workers in other healthcare occupations employed and at work in any healthcare setting, by education needed to enter the occupation, January 2020-December 2022

Source: U.S. Bureau of Labor Statistics, Current Population Survey, monthly data. Accessed on July 3, 2023.

- In December 2022, approximately 2,150,000 workers were employed in roles requiring an associate’s degree or less education, unchanged from the 2,259,000 workers reported in January 2020 (Figure 34).
- In December 2022, approximately 1,466,000 workers were employed in roles requiring a bachelor’s or master’s degree, unchanged from the 1,446,000 workers reported in January 2020.
- In December 2022, approximately 760,000 workers were employed in roles requiring a doctoral degree or more education, unchanged from the 819,000 workers reported in January 2020.

❖ In a complex U.S. healthcare system, medical offices remain by far the setting most commonly visited for care.

In any given year, most people in the United States interact with healthcare delivery systems through routine office-based physician visits. A smaller percentage of people seek emergency care services, and even fewer require hospitalization. In 2020, 83.4% of adults and 94.0% of children had an office visit with a physician or other healthcare professional in the past year.^31^ For comparison, 19.0% of adults had an emergency department visit that year. In 2018, only 7.4% of people in the United States required an overnight hospital stay.^32^

### Ambulatory Medical and Surgical Offices

In 2018, there were 860.4 million medical physician office visits, or 267.1 visits per 100 people. Just over half (136.6 visits per 100 people) were with a primary care provider. Approximately one-quarter of encounters (67.1 visits per 100 people) were with medical specialists, while the remaining encounters (63.3 visits per 100 people) were with surgical specialists.

Figure 35 Major reasons for office-based physician visits, by patient age in years, 2018

Note: Analysis is based on the National Ambulatory Medical Care Survey, which annually surveys 3,000 physician practices in nonfederal, office-based settings. Some of the surveyed offices provide telehealthcare services.

Source: Ashman JJ, Santo L, Okeyode T. Characteristics of Office-Based Physician Visits, 2018. NCHS Data Brief. 2021 May;408:1-8. https://www.cdc.gov/nchs/products/databriefs/db408.htm.

- Overall, most office visits (39.0%) were for managing one or more chronic conditions, followed by evaluating a new problem (24.0%), providing preventive care services (23.0%), and performing pre- or postoperative evaluation (8%) (Figure 35).
- Only 6.0% of ambulatory healthcare visits were for evaluation or management of an injury.
- Among children less than 18 years old, this overall pattern of visits differs, giving greater emphasis to visits for new problems and preventive services.

The 10 leading principal reasons for visits account for less than half (42.3%) of all reasons for all office visits in 2019. The list illustrates the wide scope of healthcare services delivered in ambulatory settings. It also highlights primary care offices’ counseling, medication maintenance, and followup activities, which are central to successfully managing chronic diseases.^33^

The top reasons for visits in 2019 were:

- Progress visit, not otherwise specified (21.3%).^xv^
- General medical examination (5.8%).
- Postoperative visit (2.7%).
- Gynecological examination (2.4%),
- Counseling, not otherwise specified (2.2%),
- Medication (prescribing or refill), other and unspecified kinds (1.8%),
- Shoulder symptoms (1.6%),
- Hypertension (1.5%),
- Well baby examination (1.5%),
- Cough (1.5%).

Living near primary care services could improve a person’s likelihood of receiving high-quality care for chronic disease. However, many communities in the United States report limited or no access to primary care, especially nonmetropolitan communities. The Health Resources and Services Administration (HRSA) has designated 7,955 locations, population groups, and healthcare facilities as Primary Care Health Professional Shortage Areas (HPSAs).

More equitable distribution of primary care providers may reduce the number of primary care HPSAs. HRSA reports that there were 256,220 full-time-equivalent primary care providers in 2018^34^ and estimates that 16,461 additional practitioners would fulfill the needs of existing HPSAs.^35^

Figure 36 Counties where all, part, or none of the county is a primary care HPSA

U.S. map showing counties where none of the county is a shortage area, part of the county is a shortage area, and all of county is a shortage area; key points are in the text below

Source: Rural Health Information Hub. Population in Primary Care HPSAs (Health Professional Shortage Area) for Metro and Nonmetro Counties, 2022. https://www.inralhealthinfo.org/charts/5. Accessed July 20, 2023.

- Overall, 2,002 (63.7%) of 3,143 counties and county equivalents are classified as “whole county shortage areas” in 2023. Of these, 566 (28.3%) are metropolitan counties and 1,436 (71.7%) are nonmetropolitan counties (Figure 36).

- In contrast, only 144 (4.6%) counties and county equivalents are classified as having “no primary care shortage area” in 2023. More than two-thirds (103 or 71.5%) are metropolitan counties while only 41 (28.5%) are nonmetropolitan counties.
- More rural counties have primary care HPSAs than metropolitan counties. However, most people who live in areas designated as primary care HPSAs live in metropolitan counties because those counties are more densely populated.
  ■ Of the approximately 79 million people who live in counties where the entire county has been designated a primary care HPSA, 51 million (64.6%) are in metropolitan counties and 28 million (35.4%) are in nonmetropolitan counties.^36^
  ■ Of the approximately 226 million people who live in counties where part of the county has been designated a primary care HPSA, 210 million (92.9%) are in metropolitan counties, and 16 million (7.1%) live in nonmetropolitan counties.^35^
  ■ Approximately 22.6 million people live in counties where none of the county has been designated a primary care HPSA. Nearly all (21 million or 92.9%) live in metropolitan counties.^35^

### Emergency Departments

Emergency departments (EDs) play a critical role in healthcare delivery systems as a provider of acute care and an important gateway for hospitalization.^37^ Their central role in healthcare delivery is supported in part by the Emergency Medical Treatment and Labor Act, which requires hospitals to provide acute medical care to all patients, regardless of their demographic characteristics or ability to pay.^38^

In 2021, there were approximately 139.8 million ED visits, or 42.7 visits per 100 people. Among visits with triage data available, almost half (45.2%) of visits were classified as “urgent” or higher acuity, 18.3% were classified as “semiurgent,” and a small portion (2.5%) was deemed “nonurgent.” The remaining visits were not triaged or had unknown triage status^39^ (Figure 37).

Figure 37 Triage status of emergency department visits, 2019-2021

Note: Data for the 2020 and 2021 Not Triaged groups and the 2021 Level 1: Immediate group not shown because estimates are statistically unreliable.

Source: Centers for Disease Control and Prevention, National Hospital Ambulatory Medical Care Survey, 2019-2021.

The eight most common ED diagnoses recorded in 2021 account for more than three-fourths of all diagnoses made in this setting. The broadly defined diagnoses reflect EDs’ importance as a source of care for conditions that lack a definitive diagnosis or may require urgent treatment. These diagnoses are:

- Symptoms, signs, and abnormal clinical laboratory findings, not classified elsewhere (26.0%),
- Injury, poisoning, and certain other consequences of external causes (16.9%),
- Diseases of the respiratory system (7.3%),
- Diseases of the musculoskeletal system and connective tissue (6.8%),
- Diseases of the digestive system (6.0%),
- Diseases of the genitourinary system (5.5%),
- Mental, behavioral, and neurodevelopmental disorders (4.2%), and
- Diseases of the circulatory system (3.9%).

Although the number of freestanding EDs (defined as EDs that are not physically attached to a hospital) has increased in recent years, most EDs are located within hospitals.^40^

### Hospitals

Hospitals are organizations that bring together different types of healthcare professionals, diagnostic and therapeutic equipment, and services, typically to provide medical and surgical care for short-term (acute) illnesses.^41^ In 2022, the American Hospital Association (AHA) counted 6,093 hospitals with a total 920,531 staffed beds in the United States. Most are community hospitals.

More specifically:

- Nearly half (48.6%) are not-for-profit, nongovernment community hospitals.
- About one-fifth (20.2%) are for-profit, nongovernment community hospitals.
- Close to one-sixth (15.6%) are state and local government community hospitals.
- About one-tenth (10.4%) are nonfederal psychiatric hospitals.
- A small portion (3.4%) are federal government hospitals, and the remaining 1.8% are other types.

Most hospitals (3,483 or 57.2%) are affiliated with a health system, which the AHA defines as “a central organization linking either two or more hospitals, or a hospital and three or more nonacute care entities, such as a multispecialty outpatient office or a skilled nursing facility.”^xvi^ Health systems have the potential to extend the efficiencies hospitals offer by linking them to a broader network of resources and services than any individual hospital can provide onsite.

## Hospitals Serving Communities That Experience Higher Risk for Poor Health Outcomes

The NHQDR focuses additional attention to care delivered by three types of hospitals that play an important role in rural areas and other at-risk communities. The Healthcare Cost and Utilization Project (HCUP), which supplies data for many NHQDR measures, defines minority serving hospitals (MSHs) as hospitals with the 25% highest number of discharges for people who are not identified as non-Hispanic White. HCUP similarly defines safety net hospitals (SNHs) as hospitals that have the highest 25% of hospital discharges paid for by Medicaid or uninsured people. (Academic literature offers varying definitions of SNHs.)

MSHs and SNHs are often large, located in metropolitan centers, and classified as teaching hospitals. Although the MSH and SNH designations do not confer additional resources on hospitals, they provide a useful window for understanding differences in hospital performance.

Critical access hospitals (CAHs) are facilities that meet certain statutory and regulatory criteria. Such criteria include having 25 or fewer acute care inpatient beds, providing 24/7 emergency care services, being located more than 35 miles from another hospital or CAH (with exceptions), and maintaining an annual average length of stay of 96 hours or less.^42^ CAHs are thus smaller than most hospitals, and most are located in rural communities (Figure 38).

The Centers for Medicare & Medicaid Services (CMS) certifies a facility as a CAH if a facility (1) is located in a state that has established a Medicare rural hospital flexibility program; (2) is designated as a CAH by the state in which it is located; and (3) meets other criteria as CMS may require.

Figure 38 Distribution of critical access hospitals in the United States, 2022

Note: Alaska and Hawaii are not to scale.

U.S. map showing locations of critical access hospitals; a large cluster is in the upper Midwest, as well as Kansas, Mississippi, and Texas

Source: Rural Health Information Hub, using data.HRSA.gov, U.S. Department of Health and Human Services, April 2022.

Hospital availability in nonmetropolitan (rural) communities is of particular interest to the nation’s health. In sparsely populated communities, hospitals may be the only source of routine and specialized services that would otherwise be unavailable. In addition, they are often the only source of emergency and after-hours care. Thus, when rural hospitals are unavailable or stop providing services, access to healthcare services may be hindered.

For example, 174 rural hospitals closed between 2005 and 2020.^xvii^ The Government Accountability Office (GAO) recently examined the effects of rural hospital closures on healthcare services. GAO found that people who lived in a closed hospital’s service area had to travel considerably farther to access dental, mental health, substance use, and obstetric services, as well as services typically associated with hospital care^43^ (Figure 39).

Figure 39 Median distance people in the service area of a rural hospital that offered a selected healthcare service traveled to receive the service after the hospital closed, 2012 and 2018

Source: Rural Hospital Closures: Affected Residents Had Reduced Access to Healthcare Services. GAO-21-93. Washington, DC: U.S. Government Accountability Office; December 2020. https://www.gao.gov/products/gao-21-93.

National data compiled by the North Carolina Rural Health Research Program show that rural hospitals had been closing at an accelerating pace in the years leading up to the first year of the COVID-19 PHE, but fewer hospital closures occurred in 2021 and 2022 (Figure 40). This finding might be related to financial support provided to rural hospitals in the first year of the PHE.

Figure 40 Number of rural hospital closures across the United States by year, 2005-2022

Source: North Carolina Rural Health Research Program. Rural Health Closures, 2005-2022. Accessed at https://www.shepscenter.unc.edu/programs-projects/rural-health/rural-hospital-closures/. on December 7, 2023.

## Hospital Bed Capacity

Although hospitals provide a wide range of services, not every hospital provides every service, and not every staffed bed may be appropriate for every need. The AHA notes that 789,354 (85.7%) staffed beds are in community hospitals, and 696,223 (75.6%) beds are in hospitals affiliated with health systems.^44^ However, only some support general healthcare activities, while many staffed beds are intended for specialized purposes, such as intensive care, care for children, or labor and delivery (Figure 41).

For example, the AHA estimates that 112,359 (12.2%) of all staffed hospital beds are designated for providing intensive care services. However, the specific types of critical care services they provide vary. While a hospital where the need for medical-surgical intensive care beds has exceeded capacity may realistically reallocate a cardiac intensive care bed to treat an adult with pneumonia-induced respiratory failure, it would be much more challenging to reallocate neonatal intensive care beds for the same purpose.

Figure 41 Types of staffed intensive care beds in community hospitals, 2020

Source: American Hospital Association, Fast Facts on U.S. Hospitals, 2022, updated January 2022. https://www.aha.org/system/files/media/file/2022/01/fast-facts-on-US-hospitals-2022.pdf.

The number and type of hospital beds available in a community, especially in relation to specific needs, may provide a more meaningful way to assess the United States’ capacity to anticipate and meet demand for hospital services. During the COVID-19 PHE, the Centers for Disease Control and Prevention’s (CDC) National Healthcare Safety Network established a system for estimating general medical and intensive care bed capacity at national and state levels. The system allowed estimates to be updated biweekly to provide federal decision makers with timely guidance. Although no longer updated after July 2020, the hospital capacity dashboard (https://www.cdc.gov/nhsn/covid19/report-overview.html) still provides valuable information about the distribution of acute care services in the United States.

### Postacute and Long-Term Care

A diverse patchwork of healthcare delivery systems supports people who need help because they have limited ability to self-manage their health. They may face barriers to self-care because of aging; chronic illness; physical, cognitive, or mental disability; or other health-related conditions. In some cases, people may need support for a limited time to successfully recover after an acute illness. In other cases, they may need long-term support for weeks, months, or years.

The Patient Protection and Affordable Care Act uses the term “long-term services and supports” (LTSS) to describe a broad range of paid and unpaid services that support people with limited capacity for self-care.^45^ LTSS encompasses paid services delivered in healthcare facilities, paid “home and community-based services” (HCBS), and unpaid services provided by family, friends, or neighbors.

Data for this report come from the National Post-acute and Long-term Care Study (NPALS),^46^ which gathers data on paid, regulated entities in institutional and HCBS healthcare delivery systems and is an important source of national estimates on postacute services and paid LTSS. As NPALS includes only paid, regulated services, the NHQDR uses “long-term care” when referring to paid services delivered in healthcare facilities, in people’s homes, or in community-based settings and “LTSS” to describe both paid and unpaid services. The NHQDR also uses “HCBS” to describe a subset of LTSS that occurs outside of healthcare facilities.

NPALS reports on healthcare delivery systems that provide two types of care: postacute care and long-term care. Although the specific services provided by entities described in NPALS vary and sometimes overlap, they often include one or more of the following:

- Health maintenance tasks, such as changing wound dressing or administering medications;
- Therapeutic tasks, such as engaging people in rehabilitation exercises;
- Assistance with activities of daily living (ADLs), such as eating, dressing, bathing, or toileting; and
- Assistance with instrumental activities of daily living (IADLs), such as organizing medications or housekeeping.

Postacute care refers to services that people receive after hospital discharge to help them successfully transition from inpatient care to home. HCUP data indicate that just over one-fifth of hospitalized people were discharged to postacute care in 2013,^47^ and an analysis of Medicare data found that 26.3% of beneficiaries were discharged to postacute care in 2015.^48^

Some patients need a period of rehabilitation to fully recover function. Some need help managing a chronic illness so they can transition from hospital to home successfully. Others require months or years of 24-hour nursing care, including ventilator management, after experiencing critical illnesses or complex traumatic injuries. Still others have a terminal illness that requires palliative services.

Over the past two decades, hospitals have increasingly relied on discharging people to postacute care settings to support patients after hospitalization, reduce length of stay, and increase their capacity to admit new patients.^46^ When access to postacute care declines, hospitals may struggle to maintain their capacity to treat people.^49^

Medicare pays for postacute care on a time-limited basis as long as people meet specific criteria for receiving services. The most common conditions associated with discharge to postacute care in 2014 were:

1. Total hip/knee joint replacement,
2. Sepsis,
3. Heart failure with shock,
4. Stroke,
5. Simple pneumonia,
6. Renal failure,
7. Kidney and urinary tract infection,
8. Chronic obstructive pulmonary disease,
9. Hip and femur procedure other than major joint procedure, and
10. Cellulitis.^45^

Long-term care refers to a range of services that help people with functional limitations perform daily activities and that provide supervision to avoid unsafe outcomes. In contrast to postacute care services, long-term care typically provides nonmedical support to help people live as independently as possible instead of medical services. Although paid, regulated long-term care entities support younger people with one or more disabilities, most recipients of long-term care are age 65 years and over.

The current capacity of paid long-term care services (Table 5) appears insufficient to meet projected LTSS needs. The Administration on Community Living estimates that 69% of people age 65 years and over will require LTSS for an average of 3 years before they die.^50^ It also projects that the need for services will grow with the increased prevalence of disability and an aging population.

Finding a way to pay for long-term care is a growing concern for many people. Of the more than $400 billion spent on long-term care in 2020, 13% was paid for with out-of-pocket spending, 8% by private insurance, 25% by other public and private payers, and 54% by Medicaid. ^51^

As Medicare does not cover the cost of long-term care, older adults and other people needing LTSS (e.g., people who become disabled) must often spend retirement funds, mortgage their homes, or use personal savings to afford it. In many cases, people reduce their personal wealth to near or below poverty guidelines to qualify for Medicaid, which does pay for LTSS.^52^

When people needing LTSS lack the financial means to access long-term care, they must instead rely on family, friends, and neighbors to support them. AARP estimates that the number of people who provided unpaid care for an adult in the previous 12 months increased from 39.8 million (16.6% of the adult population) in 2015 to 47.9 million (19.2%) in 2020.

While caregiving can be personally rewarding, many caregivers experience worse physical and mental health and reduced financial prospects because of caregiving. Twenty-three percent of caregivers agreed that caregiving made it difficult to attend to their own health needs, 36% reported feeling some or high emotional stress, 23% felt that caregiving made their health worse, and 45% experienced at least one financial impact (e.g., stopped saving, left bills unpaid/paid them late, borrowed money).^53^

Lack of access to paid long-term care also has broader economic implications for the nation because unpaid caregivers often cannot participate in the workforce, engage in commerce, or accumulate wealth. A substantial portion of caregivers in 2020 were in their prime working years (26% were 18-49 years old; 25% were 50-65 years old), and approximately 1 in 4 (24%) caregivers supported more than one adult. AARP estimates the economic value of unpaid caregiving in 2021 was approximately $600 billion.

NPALS describes seven types of services that provide postacute care, long-term care, or both:

- Adult day services are programs that provide care and companionship for adults who need assistance or supervision during the day. They provide people with an alternative to institutionalized care, encourage socialization, and support health. They also provide relief for family members and caregivers, enabling them to work and attend to personal business. Medicare does not pay for adult day services, but Medicaid does in some cases.
- Home health agencies provide part-time, intermittent nursing, medical, and social work services in a person’s home to help people address medical needs and live as independently as possible. Home health agencies also help them recover from an acute illness or injury, such as after discharge from the hospital. Medicare covers home care if a physician certifies that a person requires part-time care and would have difficulty leaving home to obtain it in an ambulatory setting. Medicaid supports home health services as part of its HCBS program.
- Residential care communities, which include assisted living facilities, are community-based housing units that offer support for ADLs, including tasks such as building maintenance and housekeeping, as well as dressing, bathing, cooking, and taking medicines. Residential care communities do not provide 24-hour nursing supervision but are intended to help people with functional limitations live as independently as possible. Medicare does not cover the cost of residential care.
- Nursing homes are facilities for people who need inpatient LTSS or rehabilitative services but do not require hospital care. They support ADLs and provide limited healthcare services to people who do not have an acute illness but still need 24/7 support for a condition that prevents them from living at home (e.g., advanced dementia).

Many nursing homes are dual certified as skilled nursing facilities (SNFs), enabling them to provide medical services as well as rehabilitative care. SNFs employ registered nurses, rehabilitation specialists, and medical doctors who often provide limited medical services to people transitioning between hospital care and home. Medicare covers up to 100 days of SNF services per benefit period provided that beneficiaries enter the SNF after a qualifying 3-night hospital admission and require extended services related to the hospital admission. Medicare does not cover long-term care services provided by nursing homes.

The NHQDR uses the CMS Minimum Data Set to report separate quality of care measures for services delivered in the long-term components of nursing homes (reported as “long-stay nursing homes,” in which people have cumulative days in the facility of 101 days or more) and their skilled nursing facility components (reported as “short-stay nursing homes, in which people have cumulative days in the facility of 100 days or less).

- Inpatient rehabilitation facilities provide postacute nursing care and inpatient physical, occupational, and speech therapy services to help people recover from an illness, injury, or surgery. They provide both short-term services similar to the postacute care offered by SNFs, as well as long-term services that serve as a bridge between acute hospital care and transition to home. Medicare covers inpatient rehabilitation services. Compared with SNFs, inpatient rehabilitation facilities typically offer more intensive rehabilitation services. They also must meet specific criteria established by Medicare, such as ensuring 60% of patients are treated for one of 13 primary conditions.
- Long-term care hospitals, sometimes referred to as long-term acute care hospitals or LTACHs, are certified acute care hospitals that provide extended hospital-level care to people with serious illnesses. People often transfer from an acute care hospital to a long-term care hospital from an intensive care unit because of a continued need for services such as ventilator management or management of complex chronic comorbidities. Many had received prolonged care in an intensive care unit during their acute care hospital admission. Medicare covers long-term care hospital services through the inpatient prospective payment system if patients meet eligibility criteria.
- Hospice services are programs that support people and their caregivers at the end of life, by focusing on managing symptoms and offering pain relief instead of seeking to treat or cure a person’s illness. Medicare covers hospice services, as do some Medicaid programs.

Table 5 provides data on the number of organizations and employees in each sector.

Table 5 Characteristics of postacute and long-term care facility services in the United States, 2018

Service | Number of Facilities/Services | Average Maximum Capacity per Facility/Service | Average People per Program | Provides Postacute Care | Provides Long-Term Care | Total Workers^*^
Adult day services | 4,200 | 68 | 65 per day | | X | 24,300
Home health agencies | 11,500 | Not available | 458 per year | X | X | 139,200
Residential care communities | 31,400 | 38 | 32 per day | | X | 474,200
Nursing homes | 15,600 | 106 | 85 per day | (X)^†^ | X | 660,000
Inpatient rehabilitation facilities | 1,200 | 298 | 348 per year | X | X | 263,000
Long-term care hospitals | 400 | 68 | 293 per year | X | X | 13,600
Hospice services | 4,700 | Not available | 356 per year | | X | 91,300

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, Post-Acute and Long-Term Care Providers and Services Users in the United States, 2017–2018.

* Nursing and social work full-time-equivalent workers.

† Medicare only covers qualifying postacute care services provided by home care agencies and by skilled nursing facilities co-located with nursing homes. Medicare does not cover long-term care services from home care agencies or nursing homes.

### Summary

Multiple healthcare delivery systems provide overlapping but distinct services to address the U.S. population’s diverse needs. The descriptive statistics in this report provide an outline of health systems’ capacity to deliver services, but more work is needed to understand how each system aligns with its counterparts and how they work together as a whole.

Short-term labor trends show that workforce participation in the ambulatory and hospital sectors, which had declined during the COVID-19 PHE, has returned to or exceeded levels reported before the pandemic. But workforce participation in the nursing home sector continues to decline, even as demand from an aging population grows.

Although concerns about shortages of physicians and nurses have received prominent attention, labor data suggest that much of the decrease in workforce participation occurred among people in occupations that require lower levels of educational attainment, many of which are held by women and people in racial and ethnic minority groups.

Longer labor trends signal a shift toward more outpatient healthcare delivery, as employment in the ambulatory sector has grown rapidly, while employment in hospitals and nursing homes has remained flat or decreased.

Data characterizing healthcare delivery settings show that each delivers distinct types of services and that service lines within each setting are often fragmented and unevenly distributed across populations. These findings imply that people, and the providers who guide them, must be able to identify which services they need and where to find services to meet those needs. However, research suggests many people have difficulty navigating the healthcare system.^54^

## National Healthcare Expenditures

Where a nation spends its limited resources often reflects its needs and priorities. Two measures from the National Health Expenditure Accounts characterize the nation’s healthcare delivery spending. “Personal healthcare expenditures” measures the total amount spent to treat individuals with specific medical conditions. It includes spending for all medical goods and services, such as:

- Hospital care;
- Healthcare professional services;
- Home health care;
- Long-term nursing care;
- Continuing care retirement communities;
- Medical products sold in retail outlets; and
- Other health, residential, and personal care services.^55^

“National healthcare consumption” measures the amount the nation spends on healthcare and related activities. It includes all personal healthcare expenditures plus spending for public health activities, government administration of healthcare programs, and, for private insurers, the difference between earnings from premiums and costs or liabilities they incur. It does not include investments in noncommercial medical research or capital spending on structures or equipment.

❖ Medicare and Medicaid expenditures now account for a larger share of healthcare consumption than private health insurance expenditures.

Over the past two decades, Medicare and Medicaid have assumed an increasing share of the nation’s healthcare expenditures, accounting for approximately 40% of healthcare consumption in 2021. Over the same period, private health insurance and out-of-pocket spending have decreased (Figure 42). In addition, expenditures for government healthcare programs and public health have declined, except for a significant increase in spending during the COVID-19 PHE in 2020 and 2021.

Figure 42 Contributions of payment sources to national healthcare consumption, 1960-2021

Note: “Other Payer” includes Children’s Health Insurance Program (Titles XIX and XXI) and programs available through the Department of Defense and the Department of Veterans Affairs. “Third-Party Payer/Public Health” may include worksite healthcare, other private venues, Indian Health Service, workers’ compensation, general assistance, maternal and child health programs, vocational rehabilitation programs, other federal programs, Substance Abuse and Mental Health Services Administration, other state and local programs, and school health programs.

Source: Centers for Medicare & Medicaid Services, National Health Expenditure Accounts (NHEA) by source of funds, CY 1960-2021; and NHEA Table 3. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html.

❖ Hospital care accounts for nearly 40% of personal healthcare spending, but its share of national spending has decreased as healthcare delivery transitions to nonacute care settings.

Although relatively few people in the United States require hospitalization, the people who do often need care that is complex, labor intensive, and expensive. Thus, hospital services represent the largest sector of healthcare spending, accounting for 37.3% of the nation’s personal healthcare expenditures in 2021 (Figure 43).

Figure 43 Distribution of personal healthcare expenditures by type of spending, 2021

Key: CCRCs = continuing care retirement communities.

Note: Other Professional Services covers services provided in establishments operated by health practitioners other than physicians and dentists. These professional services include those provided by private-duty nurses, chiropractors, podiatrists, optometrists, and physical, occupational, and speech therapists, among others. Other Healthcare Spending refers to other health, residential, and personal care expenses; durable medical equipment; and nondurable medical products.

Source: Centers for Medicare & Medicaid Services, National Health Expenditure Accounts, by type of service and source of funds, CY 2021. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html.

The healthcare system is transitioning toward an emphasis on ambulatory care, postacute care, and residential care services. Accordingly, hospital care has decreased as a percentage of personal healthcare expenditures from its peak at 48% in 1982, while relative spending for prescription drugs, home care, nonphysician professional services, and durable and nondurable medical equipment has increased (Figure 44).

Figure 44 Personal healthcare expenditures by type of spending, 1960-2021

Key: CCRCs = continuing care retirement communities.

Note: Percentages do not add to 100 due to rounding. Personal healthcare expenditures are outlays for goods and services related directly to patient care. These expenditures are total national health expenditures minus expenditures for investment, health insurance program administration and the net cost of insurance, and public health activities. Other Healthcare Spending refers to durable medical equipment, nondurable medical products, and other health, residential, and personal care expenses.

Source: Centers for Medicare & Medicaid Services, National Health Expenditures by type of service and source of funds, CY 1960-2021. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html.

### Summary

The National Healthcare Expenditure Accounts show that publicly sponsored health insurance spending for healthcare services has grown over the past two decades, while coverage by private health insurance has declined as a percentage of overall spending. At the same time, out-of-pocket spending by Americans has also declined.

Notably, data also show a steady decline in public health spending over the 60 years before the COVID-19 PHE, providing context to concerns about the public health system’s readiness to address the pandemic or future threats.

Other trends identified in these data include a decrease in hospital spending as a percentage of personal health expenditures. This decrease is accompanied by a proportional increase in spending for prescription drugs, physician and other clinical services, home health care, and other professional services. Other professional services include care delivered by private duty nurses and physical, occupational, and speech therapy.

Together with the growth in ambulatory sector employment reported earlier in this section of the report, these data lend further evidence that healthcare delivery is shifting away from care in centralized acute care settings toward care delivery in diverse ambulatory settings as well as in people’s homes.

## Geographic Variations in Care

States have been described as “laboratories of democracy”^56^; and data suggest they may also be viewed as laboratories for healthcare policy. State-level data show that healthcare quality and disparities vary widely, depending on state and region. Although a state may perform well in overall quality, the same state may face significant disparities in healthcare access or disparities within specific areas of quality.

State-level analysis included 179 measures for which state data were available. Of these measures, 137 are core measures and 42 are supplemental measures from the National CAHPS Benchmarking Database (NCBD), which provides state data for core measures with Medical Expenditure Panel Survey national data only. The state healthcare quality analysis included all 179 measures, and the state disparities analysis included 110 measures for which state-by-race or state-by-ethnicity data were available.

State-level data are also available for 110 supplemental measures. These data are available from the Data Query tool on the NHQDR website but are not included in data analysis.

❖ Quality varied between states, but in some regions nearby states had similar quality scores.

Figure 45 Overall quality of care, by state, 2016-2021

Note: All state-level measures with data were used to compute an overall quality score for each state based on the number of quality measures above, at, or below the average across all states. States were ranked and quartiles are shown on the map. The states with the worst quality scores are in the fourth quartile, and states with the best quality scores are in the first quartile. Historically, the NHQDR has included state-specific estimates for selected AHRQ Quality Indicators based on Healthcare Cost and Utilization Project data.

U.S. map showing quality by state in quartiles; key points are in the text below

- Overall quality of care varied across the United States (Figure 45):
  ■ Four states in the Northeast region (Maine, New Hampshire, Pennsylvania, and Rhode Island), five in the Midwest region (Iowa, Minnesota, Nebraska, South Dakota, and Wisconsin), one state in the South region (Delaware), and two states in the West region (Idaho and Utah) had the highest overall quality scores.
  ■ Eight states in the West region (Alaska, Arizona, California, Nevada, New Mexico, Oregon, Washington, a nd Wyoming), and five states in the South region ( District of Columbia,^xviii^ Georgia, Mississippi, Oklahoma, and Texas) had the lowest overall quality scores.

The disparities map (Figure 46) shows average differences in quality of care for AI/AN, Asian, Black, Hispanic, NHPI, and multiracial people co mpared with the reference group, non-Hispanic White or White people. States with fewer than 50 data points are excluded.

❖ Many factors may account for the variation in disparities between states.

Figure 46 Average differences in quality of care for American Indian or Alaska Native, Asian, Black, Hispanic, Native Hawaiian/Pacific Islander, and multiracial people compared with non-Hispanic White or White people, by state, 2018-2021

Note: More information about the measures and data sources included in the creation of the quality and disparities maps can be found in Appendix C. Specific information about healthcare quality in each state can be found on the NHQDR Data Tools website, https://datatools.ahrq.gov/nhqdr. All measures in this report that had state-level data to assess racial and ethnic disparities were used. Separate quality scores were computed for AI/AN, Asian, Black, Hispanic, multiracial, NHPI, and White people. For each state, the average of the AI/AN, Asian, Black, Hispanic, multiracial, and NHPI scores was divided by the White score. States were ranked on this ratio, and quartiles are shown on the map. The states with the worst disparity scores are in the fourth quartile, and states with the best disparity scores are in the first quartile. Disparity scores were not risk adjusted for population characteristics in each state, so these findings do not take into account population differences between states. Historically, the NHQDR has included state-specific estimates for selected AHRQ Quality Indicators based on Healthcare Cost and Utilization Project data. States with fewer than 50 data points were excluded. More information is available in Appendix A.

- Racial and ethnic disparities varied across the United States (Figure 46). Factors may include differences in prevalence of chronic conditions, policies that limit behavioral risk factors, and the availability of infrastructure that allows easy access to quality healthcare:
  ■ Five states in the West region (Hawaii, Idaho, Montana, Oregon, and Washington), four states in the South region (Arkansas, Kentucky, Virginia, and West Virginia), and two states in the Midwest region (Kansas and Nebraska) had the fewest racial and ethnic healthcare disparities overall.
  ■ Three states in the Northeast region (Massachusetts, New York, and Pennsylvania), three states in the Midwest region (Illinois, Indiana, and Minnesota), one state in the South region (North Carolina), and one state in the West region (Colorado) had the most racial and ethnic healthcare disparities overall.

i In this report, “Census” refers to the decennial census.

ii Comparisons of racial and ethnic data between the 2020 and 2010 Census should be made with caution, taking into account improvements in how the Census asks respondents about Hispanic origin and race. See https://www.census.gov/library/stories/2021/08/improved-race-ethnicity-measures-reveal-united-states-population-much-more-multiracial.html for more details.

iii The 2013 NCHS Urban-Rural classification scheme is the most recent version available. NCHS anticipates releasing updated specifications for classifying urban and rural populations in 2024.

iv For comparisons across residence locations, large fringe MSAs (large city suburbs) are used as the reference group since these counties have the lowest levels of poverty and typically have the best quality and access to healthcare.

v Compared with averaged data for Japan (life expectancy in 2021: 84.5 years), Switzerland (84.0 years), Australia (83.4 years), Sweden (83.2 years), France (82.5 years), Belgium (81.9 years), the Netherlands (81.5 years), Austria (81.3 years), Germany (80.9 years), the United Kingdom (80.8 years), and Canada (not included in 2021).

vi Examples of chronic diseases include: diseases of the brain, such as stroke and traumatic brain injury; affective disorders, such as depression, bipolar disorder, and schizophrenia; vascular diseases, such as high blood pressure, high cholesterol, heart disease, and complications from stroke; metabolic disorders, such as diabetes and thyroid disease; digestive diseases, such as Crohn’s disease; liver diseases, such as cirrhosis; kidney diseases, such as chronic kidney disease; diseases of the joints, such as arthritis; and diseases of the blood, such as thalassemia and sickle cell disease. Given the diverse range of these conditions, measures of chronic disease often count different specific diseases when defining the concept. The NHQDR reports on “chronic disease” as defined by data sources.

vii The NHQDR includes multiple measures characterizing access to healthcare services and quality of those services later in the report.

viii The National Health Interview Survey (NHIS) estimates of the overall percentage of people with health insurance coverage are slightly larger than the sum of the percentage of people with any private health insurance coverage and the percentage of people with publicly sponsored insurance. The overall percentage includes people with other sources of health insurance, such as coverage provided under state and local programs established through the Ryan White Act or through special programs for farm workers and refugees. More information is available in National Health Interview Survey 2021 CAPI Manual for NHIS Field Representatives, https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Survey_Questionnaires/NHIS/2021/frmanual-508.pdf.

ix The NHQDR frequently examines healthcare delivery and outcomes in relation to household income. However, income is not the same as wealth, which can include assets other than income. Wealth is disproportionately dispersed among higher income categories, and research also shows a positive association between greater wealth and better health outcomes.

x Federal guidelines for determining poverty thresholds based on income, size of household, and other considerations are available online at https://aspe.hhs.gov/topics/poverty-economic-mobility/poverty-guidelines/prior-hhs-poverty-guidelines-federal-register-references/2020-poverty-guidelines.

xi Measures using HCUP data analyze health outcomes by community-level household income. In 2020, the median households in the lowest earning quartile of ZIP Codes earned $49,999 or less each year, while the median households in the highest earning quartile of ZIP Codes earned $86,000 or more. More detail can be found at https://www.hcup-us.ahrq.gov/db/vars/zipinc_qrtl/nisnote.jsp.

xii The NHQDR uses the North American Industry Classification System (NAICS) to describe trends in workforce participation. NAICS groups establishments into business sectors and more specific industries according to similarity in the processes used to produce goods or deliver services. NAICS groupings do not necessarily align with clinical taxonomies for organizing healthcare services. For example, within the “Health Care and Social Assistance” sector (NAICS 62xxxx), “nursing care facilities (skilled nursing facilities)” (NAICS 623110) are grouped with long-term institutional services such as “continuing care retirement communities” (NAICS 623311) and “assisted living facilities for the elderly” (NAICS 623312) in the “Nursing and Residential Care Facilities” subsector (NAICS 623xxx), but “home health care services” (NAICS 621610) are grouped with outpatient services, such as “offices of physicians” (NAICS 621111) and “kidney dialysis centers” (NAICS 621492) in the “Ambulatory Health Care Services” subsector (NAICS 621xxx). Readers may find more information at https://www.census.gov/programs-surveys/economic-census/year/2022/guidance/understanding-naics.html.

xiii The NHQDR’s analysis uses the Standard Occupational Classification system (SOC codes 29-xxxx and 31-xxxx) and the BLS Occupational Outlook Handbook to group healthcare occupations into three categories according to the level of education typically required to enter a profession. Examples of occupations requiring an associate’s degree or less education are dental hygienist, medical assistant, phlebotomist, and paramedic. Examples of occupations requiring a bachelor’s or master’s degree are dietitian and laboratory technician. Examples of occupations requiring a doctorate or equivalent training are pharmacist and podiatrist.

xiv Changes in workforce participation data from the Current Employment Statistics and the Current Population Survey are based on the Bureau of Labor Statistics methodology, which calculates differences at the 90% level of confidence. See the Handbook of Methods at https://www.bls.gov/opub/hom/ces/calculation.htm#reliabiliity and https://www.bls.gov/opub/hom/cps/calculation.htm for more detail.

xv Terms in this list are based on the National Ambulatory Medical Care Survey’s Reason for Visit Classification for Ambulatory Care (RVC), defined in the National Ambulatory Medical Care Survey 2019 National Summary Tables, available at https://www.cdc.gov/nchs/data/ahcd/namcs_summary/2019-namcs-web-tables-508.pdf.

xvi The AHRQ Comparative Health System Performance Initiative similarly defines a health system as “an organization that includes at least one hospital and at least one group of physicians that provides comprehensive care (including primary and specialty care) who are connected with each other and with the hospital through common ownership or joint management.” More information and additional resources for examining health systems may be found in the AHRQ Compendium of Health Systems at https://www.ahrq.gov/chsp/dataresources/compendium.html.

xvii The Cecil G. Sheps Center for Health Services Research, which provides data on rural hospital closures, includes two types of status changes when defining hospital closures: (1) “Complete” closures, in which facilities no longer provide healthcare services, and (2) “Converted’ closures, in which facilities no longer provide inpatient care but continue to provide some healthcare services, such as primary care or skilled nursing care (https://www.shepscenter.unc.edu/programs-projects/rural-health/rural-hospital-closures/).

xviii For purposes of the NHQDR, the District of Columbia is treated as a state.

## References

1 U.S. Census Bureau. Quick Facts, United States (v2021). https://www.census.gov/quickfacts/. Accessed October 23, 2023.
2 Johnson RW. ASPE Research Brief. What Is the Lifetime Risk of Needing and Receiving Long-Term Services and Supports? Washington, DC: Office of the Assistant Secretary for Planning and Evaluation; April 2019. https://aspe.hhs.gov/reports/what-lifetime-risk-needing-receiving-long-term-services-supports-0. Accessed October 23, 2023.
3 Fulmer T, Reuben DB, Auerbach J, Fick DM, Galambos C, Johnson KS. Actualizing better health and health care for older adults. Health Aff (Millwood). 2021 Feb;40(2):219–225. 10.1377/hlthaff.2020.01470. Accessed October 23, 2023.33476185
4 Smith AS, Trevelyan E. The Older Population in Rural America: 2012-2016. American Community Survey Reports. ACS-41. Washington, DC: U.S. Census Bureau; September 2019. https://www.census.gov/content/dam/Census/library/publications/2019/acs/acs-41.pdf. Accessed October 23, 2023.
5 Hill L, Ndugga N, Artiga S. Key Data on Health and Health Care by Race and Ethnicity. Kaiser Family Foundation; March 15, 2023. https://www.kff.org/racial-equity-and-health-policy/report/key-data-on-health-and-health-care-by-race-and-ethnicity/. Accessed October 23, 2023.
6 Dobis EA, Krumel TP Jr, Cromartie J, Conley KL, Sanders A, Ortiz R. Rural America at a Glance. 2021 Edition. Economic Information Bulletin Number 230. Washington, DC: U.S. Department of Agriculture, Economic Research Service; November 2021. https://www.ers.usda.gov/webdocs/publications/102576/eib-230.pdf?v=4409. Accessed October 23, 2023.
7 Centers for Disease Control and Prevention. NCHS Urban-Rural Classification Scheme for Counties. Last reviewed June 2017. https://www.cdc.gov/nchs/data_access/urban_rural.htm. Accessed October 23, 2023.
8 Kurani N, Wager E. How does the quality of the U.S. health system compare to other countries? Peterson-KFF Health System Tracker; September 30, 2021. https://www.healthsystemtracker.org/chart-collection/quality-u-s-healthcare-system-compare-countries/. Accessed October 23, 2023.
9 Arias E, Tejada-Vera B, Kochanek KD, Ahmad FB. Provisional life expectancy estimates for 2021. Vital Statistics Rapid Release; no 23. Hyattsville, MD: National Center for Health Statistics; August 2022. 10.15620/cdc:118999. Accessed October 23, 2023.
10 National Academies of Sciences, Engineering, and Medicine; Division of Behavioral and Social Sciences and Education; Committee on National Statistics; Committee on Population; Committee on Rising Midlife Mortality Rates and Socioeconomic Disparities. High and Rising Mortality Rates Among Working-Age Adults. Becker T, Majmundar MK, Harris KM, eds. Washington, DC: National Academies Press; 2021. https://nap.nationalacademies.org/catalog/25976/high-and-rising-mortality-rates-among-working-age-adults.Accessed October 23, 2023.
11 Buxbaum JD, Chernew ME, Fendrick AM, Cutler DM. Contributions of public health, pharmaceuticals, and other medical care to U.S. life expectancy changes, 1990-2015. Health Aff (Millwood). 2020 Sep;39(9):1546–1556. 10.1377/hlthaff.2020.00284. Accessed October 23, 2023.32897792
12 Magnan S. Social Determinants of Health 101 for Health Care: Five Plus Five. NAM Perspectives. Discussion Paper. Washington, DC: National Academy of Medicine; 2017. https://nam.edu/social-determinants-of-health-101-for-health-care-five-plus-five/. Accessed October 23, 2023.
13 Sommers BD, Gawande AA, Baicker K. Health insurance coverage and health - what the recent evidence tells us. N Engl J Med. 2017 Aug 10;377(6):586–593. https://www.nejm.org/doi/10.1056/NEJMsb1706645.Accessed October 23, 2023.28636831
14 Allen H, Baicker K, Finkelstein A, Taubman S, Wright BJ; Oregon Health Study Group. What the Oregon Health Study can tell us about expanding Medicaid. Health Aff (Millwood). 2010 Aug;29(8):1498–1506. https://www.healthaffairs.org/doi/10.1377/hlthaff.2010.0191. Accessed October 23, 2023.20679654
15 James J. The Oregon Health Insurance Experiment. Health Affairs Health Policy Brief; July 16, 2015. https://www.healthaffairs.org/do/10.1377/hpb20150716.236899/. Accessed October 23, 2023.
16 Sommers BD, Blendon RJ, Orav EJ, Epstein AM. Changes in utilization and health among low-income adults after Medicaid expansion or expanded private insurance. JAMA Intern Med. 2016 Oct 1;176(10):1501–1509. 10.1001/jamainternmed.2016.4419. Accessed October 23, 2023.27532694
17 American Hospital Association. Importance of Health Coverage. October 2019. https://www.aha.org/guidesreports/report-importance-health-coverage. Accessed October 23, 2023.
18 Institute of Medicine Committee on the Consequences of Uninsurance. 4. The Difference Coverage Could Make to the Health of Uninsured Adults. In: Care Without Coverage: Too Little, Too Late. Washington, DC: National Academies Press; 2002. https://www.ncbi.nlm.nih.gov/books/NBK220633/. Accessed October 23, 2023.
19 Oh EG, Huang AW, Nguyen KH. Inequities in patient access to care among Asian American, Native Hawaiian, and Pacific Islander adults in Medicaid. J Racial Ethn Health Disparities. 2023 Jul 25. 10.1007/s40615-023-01719-x. Accessed November 17, 2023.
20 Khullar D, Chokshi DA. Health, Income, & Poverty: Where We Are & What Could Help. Health Affairs Health Policy Brief; October 4, 2018. https://www.healthaffairs.org/do/10.1377/hpb20180817.901935/full/. Accessed October 23, 2023.
21 Larrimore J. Does a higher income have positive health effects? Using the earned income tax credit to explore the income-health gradient. Milbank Q. 2011 Dec;89(4):694–727. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3250638/. Accessed October 23, 2023.22188352
22 Shaw KM, Theis KA, Self-Brown S, Roblin DW, Barker L. Chronic disease disparities by county economic status and metropolitan classification, Behavioral Risk Factor Surveillance System, 2013. Prev Chronic Dis. 2016 Sep 1;13:E119. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5008860/. Accessed October 23, 2023.27584875
23 Bor J, Cohen GH, Galea S. Population health in an era of rising income inequality: USA, 1980-2015. Lancet. 2017 Apr 8;389(10077):1475–1490. 10.1016/S0140-6736(17)30571-8. Accessed October 23, 2023.28402829
24 Office of the Assistant Secretary for Planning and Evaluation, U.S. Department of Health and Human Services. U.S. Federal Poverty Guidelines Used To Determine Financial Eligibility for Certain Programs. https://aspe.hhs.gov/topics/poverty-economic-mobility/poverty-guidelines. Accessed October 23, 2023.
25 American Community Survey, 5-year estimates, 2020, Table DP02. https://data.census.gov/table?q=United+States&g=010XX00US&tid=ACSDP5Y2020.DP02. Accessed October 23, 2023.
26 American Community Survey, 5-year estimates, 2020, Table S1601. https://data.census.gov/table?q=United+States&g=010XX00US&tid=ACSST5Y2020.S1601. Accessed October 23, 2023.
27 American Community Survey, 5-year estimates, 2020, Table S1501. https://data.census.gov/table?q=United+States&g=010XX00US&tid=ACSST5Y2020.S1501. Accessed October 23, 2023.
28 American Community Survey, 5-year estimates, 2020, Table S2801. https://data.census.gov/table?q=internet&tid=ACSST5Y2020.S2801. Accessed October 23, 2023.
29 National Library of Medicine. Telehealth 101: What Libraries Need To Know. https://www.nnlm.gov/training/class-catalog/telehealth-101-what-libraries-need-know. Accessed November 13, 2023.
30 U.S. Bureau of Labor Statistics. Occupational Outlook Handbook. https://www.bls.gov/ooh/. Accessed October 23, 2023.
31 Adjaye-Gbewonyo D, Boersma P. Early Release of Selected Estimates Based on Data From the 2021 National Health Interview Survey. Hyattsville, MD: National Center for Health Statistics; April 2022. https://www.cdc.gov/nchs/data/nhis/earlyrelease/earlyrelease202204.pdf. Accessed October 23, 2023.
32 Summary Health Statistics: National Health Interview Survey. Table P-10a. Age-adjusted percent distribution (with standard errors) of number of overnight hospital stays during the past 12 months, by selected characteristics: United States, 2018. Hyattsville, MD: National Center for Health Statistics; 2018. https://ftp.cdc.gov/pub/Health_Statistics/NCHS/NHIS/SHS/2018_SHS_Table_P-10.pdf. Accessed October 23, 2023.
33 National Ambulatory Medical Care Survey: 2018 National Summary Tables. Hyattsville, MD: National Center for Health Statistics. https://www.cdc.gov/nchs/data/ahcd/namcs_summary/2018-namcs-web-tables-508.pdf.Accessed October 23, 2023.
34 Health Resources and Services Administration. Primary Care Workforce Projections. Last reviewed August 2022. https://bhw.hrsa.gov/data-research/projecting-health-workforce-supply-demand/primary-health. Accessed October 23, 2023.
35 Health Resources and Services Administration. Health Professional Shortage Area Dashboard. https://data.hrsa.gov/topics/health-workforce/shortage-areas. Accessed October 23, 2023.
36 Rural Health Information Hub. Population in Primary Care HPSAs (Health Professional Shortage Area) for Metro and Nonmetro Counties, 2022. https://www.ruralhealthinfo.org/charts/6.
37 Schuur JD, Venkatesh AK. The growing role of emergency departments in hospital admissions. N Engl J Med. 2012;367(5): 391–393. https://www.nejm.org/doi/10.1056/NEJMp1204431. Accessed October 23, 2023.22784039
38 Fields WW, Asplin BR, Larkin GL, Marco CA, Johnson LA, Yeh C, Ghezzi KT, Rapp M. The Emergency Medical Treatment and Labor Act as a federal health care safety net program. Acad Emerg Med. 2001;8 (11):1064–1069. https://pubmed.ncbi.nlm.nih.gov/11691669/. Accessed October 23, 2023.11691669
39 National Hospital Ambulatory Medical Care Survey: 2021 Emergency Department Summary Tables. Hyattsville, MD: National Center for Health Statistics. https://www.cdc.gov/nchs/data/nhamcs/web_tables/2021-nhamcs-ed-web-tables-508.pdf. Accessed October 23, 2023.
40 Gutierrez C, Lindor RA, Baker O, Cutler D, Schuur JD. State regulation of freestanding emergency departments varies widely, affecting location, growth, and services provided. Health Aff (Millwood). 2016 Oct 1;35(10):1857–1866. https://www.healthaffairs.org/doi/10.1377/hlthaff.2016.0412. Accessed October 23, 2023.27702960
41 Liu JB, Kelz RR. Types of hospitals in the United States. JAMA. 2018 Sep 11;320(10):1074. 10.1001/jama.2018.9471. Accessed October 23, 2023.30208457
42 Rural Health Information Hub. Critical Access Hospitals (CAHs). Last reviewed September 2021. https://www.ruralhealthinfo.org/topics/critical-access-hospitals. Accessed October 23, 2023.
43 Rural Hospital Closures: Affected Residents Had Reduced Access to Healthcare Services. GAO-21-93. Washington, DC: U.S. Government Accountability Office; December 2020. https://www.gao.gov/products/gao-21-93. Accessed October 23, 2023.
44 Fast Facts: U.S. Health Systems. Chicago, IL: American Hospital Association; 2020. https://www.aha.org/system/files/media/file/2022/06/Fast-Facts-US-Health-Systems-2022-with-FY20-Data.pdf. Accessed October 23, 2023.
45 Patient Protection and Affordable Care Act, P.L. 111-148. Accessed at https://www.govinfo.gov/content/pkg/PLAW-111publ148/pdf/PLAW-111publ148.pdf on 11/13/2023.
46 National Center for Health Statistics. NPALS – About the National Post-acute and Long-term Care Study. Accessed on 11/13/2023. https://www.cdc.gov/nchs/npals/about_npals.htm
47 Tian W. An All-Payer View of Hospital Discharge to Postacute Care, 2013. HCUP Statistical Brief #205. Rockville, MD: Agency for Healthcare Research and Quality; May 2016. http://www.hcup-us.ahrq.gov/reports/statbriefs/sb205-Hospital-Discharge-Postacute-Care.pdf. Accessed October 23, 2023.
48 Werner RM, Konetzka RT. Trends in post-acute care use among Medicare beneficiaries: 2000 to 2015. JAMA. 2018 Apr 17;319(15):1616–1617. 10.1001/jama.2018.2408. Accessed October 23, 2023.29677292
49 Massachusetts Health & Hospital Association. A Clogged System: Keeping Patients Moving Through Their Care Journey. June 2023. https://mhalink.informz.net/mhalink/data/images/ACloggedSystemMHAReport.pdf. Accessed October 23, 2023.
50 Johnson RW. What Is the Lifetime Risk of Needing and Receiving Long-Term Services and Supports? Washington, DC: U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation; April 3, 2019. https://aspe.hhs.gov/reports/what-lifetime-risk-needing-receiving-long-term-services-supports-0. Accessed October 23, 2023.
51 Chidambaram P. and Burns A. 10 things about long-term services and supports (LTSS). Kaiser Family Foundation. September 15, 2022. Accessed at https://www.kff.org/medicaid/issue-brief/10-things-about-long-term-services-and-supports-ltss/#:~:text=The%20U.S.%20spent%20over%20%24400,payers%20paid%20the%20remaining%2026%25 on 8/15/2023
52 Johnson RW, Favreault MM. Economic Hardship and Medicaid Enrollment in Later Life: Assessing the Impact of Disability, Health, and Marital Status Shocks. Washington, DC: U.S. Department of Health and Human Services, Assistant Secretary for Planning and Evaluation. January 31, 2021. https://aspe.hhs.gov/reports/economic-hardship-medicaid-enrollment-later-life. Accessed October 23, 2023.
53 AARP and National Alliance for Caregiving. Caregiving in the United States 2020. Washington, DC:AARP. May 2020. Accessed at https://www.aarp.org/ppi/info-2020/caregiving-in-the-united-states.html on 8/15/2023.
54 Tang KL, Ghali WA. Patient navigation-exploring the undefined. JAMA Health Forum. 2021 Nov 2;2(11):e213706. 10.1001/jamahealthforum.2021.3706. Accessed October 23, 2023.36218850
55 Centers for Medicare & Medicaid Services. National Health Expenditure Accounts: Methodology Paper, 2018: Definitions, Sources, and Methods. https://www.cms.gov/files/document/definitions-sources-and-methods.pdf. Accessed October 23, 2023.
56 Sutherland G; and Supreme Court of the United States. U.S. Reports: New State Ice Co. v. Liebmann, 285 U.S. 262 (1932). https://www.loc.gov/item/usrep285262/. Accessed October 23, 2023.