# Appendix E Definitions and Abbreviations Used in the 2023 National Healthcare Quality and Disparities Report

## Definitions

### Racial and Ethnic Groups

Racial and ethnic groups are defined according to Standards for the Classification of Federal Data on Race and Ethnicity, issued by the Office of Management and Budget (available at https://www.gpo.gov/fdsys/granule/FR-1997-10-30/97-28653).

The basic racial and ethnic categories for federal statistics and program administrative reporting are defined as follows:

1. American Indian or Alaska Native (AI/AN). A person having origins in any of the original peoples of North and South America (including Central America) and who maintains tribal affiliation or community attachment.
2. Asian. A person having origins in any of the original peoples of the Far East, Southeast Asia, or the Indian subcontinent, including, for example, Cambodia, China, India, Japan, Korea, Malaysia, Pakistan, the Philippine Islands, Thailand, and Vietnam.
3. Black or African American. A person having origins in any of the Black racial groups of Africa. Terms such as “Haitian” can be used in addition to “Black or African American.”
4. Hispanic or Latino. A person of Cuban, Mexican, Puerto Rican, Central or South American, or other Spanish culture or origin, regardless of race. The term “Spanish origin” can be used in addition to “Hispanic or Latino.”
5. Native Hawaiian/Pacific Islander (NHPI). A person having origins in any of the original peoples of Hawaii, Guam, Samoa, or other Pacific Islands.
6. White. A person having origins in any of the original peoples of Europe, the Middle East, or North Africa.

### Income

Income groups are most commonly based on the poverty guideline (PG) for a family of four:

❖ Less than 100% of PG
❖ 100% to less than 200% of PG
❖ 200% to less than 400% of PG
❖ 400% or more of PG

The poverty guidelines are available at https://aspe.hhs.gov/poverty-guidelines.

### Education

Education groups are most commonly the following categories:

❖ People with less than a high school education.^i^
❖ High school graduate or equivalent.
❖ People with any college education.

Some data sources provide education information for individuals age 18 years and over while other data sources provide education information for individuals age 25 years and over.

### Urban-Rural Areas

Urban and rural areas are defined based on the National Center for Health Statistics 2013 Urban-Rural Classification Scheme.

Figure 1 Map showing 2013 NCHS Urban-Rural County Classifications in the United States

U.S. map showing county designations

- Metropolitan counties:
  - Large central metro counties in metropolitan statistical area (MSA) of 1 million or more population that: (1) contain the entire population of the largest principal city of the MSA, or (2) are completely contained within the largest principal city of the MSA, or (3) contain at least 250,000 residents of any principal city in the MSA.
  - Large fringe metro counties in MSA of 1 million or more population that do not qualify as large central.
  - Medium metro counties in MSA of 250,000-999,999 population.
  - Small metro counties in MSAs of less than 250,000 population.
- Nonmetropolitan counties:
  - Micropolitan: Counties in a micropolitan statistical area.
  - Noncore: Nonmetropolitan counties that are not in a micropolitan statistical area.

More information is available at https://www.cdc.gov/nchs/data_access/urban_rural.htm.

### Disabilities

Disability status is defined by following the methodology of the American Community Survey, which is different from the Activity Limitation used in the 2007-2018 NHQDR.

❖ Adults age 18 and over are defined as with disability if one reported with serious difficulty in hearing, serious difficulty in vision, serious cognitive difficulty, serious difficulty in walking or climbing stairs, difficulty in dressing or bathing, and difficulty in doing errands.
❖ Children with special health care needs (CSHCN): Children ages 0-17 with activity limitations or need or use of more healthcare or other services than is usual for most children of the same age. Question sequences^ii^ are asked about the following five health consequences: the need or use of medicines prescribed by a doctor; the need or use of more medical care, mental health care, or education services than is usual for most children; limitations or inability to do things most children can do; the need or use of special therapy, such as physical, occupational, or speech therapy; and the need or use of treatment or counseling for emotional, developmental, or behavioral problems. Children with responses to at least one of the five health consequences were identified as having a special health care need.

## Abbreviations Used in the NHQDR

### Terms

- AAC: average annual change
- AAPC: average annual percentage change
- ADL: activities of daily living
- AI/AN: American Indian or Alaska Native
- AJCC: American Joint Committee on Cancer
- API: Asian or Pacific Islander
- APRN: advanced practice registered nurse
- BRFSS: Behavioral Risk Factor Surveillance System
- CAH: critical access hospital
- CAHPS: Consumer Assessment of Healthcare Providers and Systems
- CARES: Coronavirus Aid Relief and Economic Security
- CAUTI: catheter-associated urinary tract infections
- CCRC: continuing care retirement community
- CD4: cluster of differentiation 4
- CLABSI: central line-associated bloodstream infection (also referred to as central venous catheter-related bloodstream infection)
- COPD: Chronic obstructive pulmonary disease
- COVID-19: coronavirus disease-2019
- CRCCP: Colorectal Cancer Control Program
- CSHCN: children with special health care needs
- CT: computed tomography
- DSMES: Diabetes Self-Management Education and Support
- ECG: electrocardiogram
- ED: emergency department
- EHR: electronic health record
- EUA: emergency use authorization
- HAC: hospital-acquired conditions
- HAI: healthcare-associated infections
- HCUP: Healthcare Cost & Utilization Project
- HHS: U.S. Department of Health and Human Services
- HIPAA: Health Insurance Portability and Accountability Act
- HIQR: Hospital Inpatient Quality Reporting
- HIV: human immunodeficiency virus
- HOQR: Hospital Outpatient Quality Reporting
- HPSA: health professional shortage area
- HPV: human papillomavirus
- HRSA: Health Resources and Services Administration
- IADL: instrumental activities of daily living
- ICD-9-CM: International Classification of Diseases, Ninth Revision, Clinical Modification
- ICD-10-CM: International Classification of Diseases, Tenth Revision, Clinical Modification
- IDD: intellectual/developmental disabilities
- IOM: Institute of Medicine ((formally changed its name to the National Academy of Medicine)
- LOS: length of stay
- LTACH: long-term acute care hospital
- LTSS: long-term services and supports
- MDE: major depressive episode
- MDS: Minimum Data Set
- MEPS: Medical Expenditure Panel Survey
- MERS-CoV: Middle East respiratory syndrome virus
- MOUD: medication for opioid use disorder
- MRI: magnetic resonance imaging
- MRSA: methicillin-resistant Staphylococcus aureus
- MSA: metropolitan statistical area
- MSH: minority serving hospital
- NAM: National Academy of Medicine
- NAMCS: National Ambulatory Medical Care Survey
- NBCCEDP: National Breast and Cervical Cancer Early Detection Program
- NCBD: National CAHPS Benchmarking Database
- NCCCP: National Comprehensive Cancer Control Program
- NCDB: National Cancer Data Base
- NEHRS: National Electronic Health Records Survey
- NH: non-Hispanic
- NHAMCS: National Hospital Ambulatory Medical Care Survey
- NHANES: National Health and Nutrition Examination Survey
- NHEA: National Health Expenditure Accounts
- NHIS: National Health Interview Survey
- NHPI: Native Hawaiian/Pacific Islander
- NHQDR: National Healthcare Quality and Disparities Report
- NHSS: National HIV Surveillance System
- NHW: non-Hispanic White
- NIS: National Immunization Survey
- NIS-ACM: National Immunization Survey—Adult COVID Module
- NPALS: National Post-acute and Long-term Care Study
- NPCR-USCS: National Program of Cancer Registries – U.S. Cancer Statistics
- NSDUH: National Survey on Drug Use and Health
- NTSS: National Tuberculosis Surveillance System
- NVSS-L: National Vital Statistics System—Linked Birth and Infant Death Data
- NVSS-M: National Vital Statistics System—Mortality
- NVSS-N: National Vital Statistics System—Natality
- OASIS: Home Health Outcome and Assessment Information Set
- OECD: Organisation for Economic Co-operation and Development
- OHIE: Oregon Health Insurance Experiment
- OWS: Operation Warp Speed
- PCC: post-COVID-19 condition
- PG: federal poverty guideline
- PHE: public health emergency
- PL: federal poverty level
- PPE: personal protective equipment
- PREP: Public Readiness and Emergency Preparedness
- QRP: Quality Reporting Program
- QSRS: Quality and Safety Review System
- RECOVER: Researching COVID to Enhance Recovery
- RVC: Reason for Visit Classification for Ambulatory Care
- S-CHIP: State Children’s Health Insurance Program
- SARS-CoV-2: severe acute respiratory syndrome coronavirus-2
- SDOH: social determinants of health
- SID: State Inpatient Databases
- SIR: standardized infection ratio
- SNH: safety net hospital
- SNF: skilled nursing facility
- SVI: Social Vulnerability Index
- TEDS: Substance Use Disorder Treatment Episode Data Set
- UDS: Uniform Data System
- USC: Usual source of care
- USRDS: United States Renal Data System
- WHO: World Health Organization
- WISQARS: Web-based Injury Statistics Query and Reporting System

### Agencies and Offices in the U.S. Department of Health and Human Services

- AHRQ: Agency for Healthcare Research and Quality
  - CFACT: Center for Financing, Access, and Cost Trends
  - CQuIPS: Center for Quality Improvement and Patient Safety
  - OC: Office of Communications
  - OEREP: Office of Extramural Research, Education, and Priority Populations
- ASPE: Office of the Assistant Secretary for Planning and Evaluation
- CDC: Centers for Disease Control and Prevention
  - ATSDR: Agency for Toxic Substances and Disease Registry
  - NCHS: National Center for Health Statistics
  - NPCR: National Program of Cancer Registries
- CMS: Centers for Medicare & Medicaid Services
- FDA: Food and Drug Administration
- HRSA: Health Resources and Services Administration
- IHS: Indian Health Service
- NIH: National Institutes of Health
  - NCI: National Cancer Institute
- OASH: Office of the Assistant Secretary for Health
- SAMHSA: Substance Abuse and Mental Health Services Administration

### Other Federal Agencies

- BLS: Bureau of Labor Statistics
- GAO: Government Accountability Office
- VHA: Veterans Health Administration

### Private and Academic Organizations

- ACS NSQIP: American College of Surgeons National Surgical Quality Improvement Program
- AHA: American Hospital Association
- MPSMS-Yale: Medicare Patient Safety Monitoring System
- UMKECC: University of Michigan Kidney Epidemiology and Cost Center

i Less than a high school education refers to people who did not complete high school.

ii A CSHCN Screener instrument was developed through a national collaborative process as part of the Child and Adolescent Health Measurement Initiative coordinated by the Foundation for Accountability. For more information, refer to Bethell CD, Read D, Stein REK, Blumberg SJ, Wells N, Newacheck PW. Identifying children with special health care needs: development and evaluation of a short screening instrument. Ambul Pediatr. 2002 Feb;2(1):38-48. https://www.ncbi.nlm.nih.gov/pubmed/11888437. Accessed October 9, 2023.