# Appendix D Quality and Disparities Summary Charts

This appendix presents summary charts showing the number of measures that had better, worse, and same performance for various groups compared with the reference group (e.g., Black people vs. White people, uninsured people vs. people with private insurance). The charts show disparities in access, disparities in quality by priority area (e.g., person-centered care, patient safety), and trends in quality. In addition, disparities in quality and trends in disparities are shown for selected groups by race, ethnicity, income, insurance status, and residence location.

## Snapshot of Disparities in Access to Care

Figure 1 Number and percentage of access measures for which members of selected race and ethnicity groups experienced better, same, or worse access to care compared with non-Hispanic White or White people for the most recent data year, 2019, 2020, or 2021

Key: n = number of measures, AI/AN = American Indian or Alaska Native, NHPI = Native Hawaiian/Pacific Islander.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, Hispanic people had worse access to care than non-Hispanic White people for 86% of access measures (Figure 1).
- American Indian and Alaska Native people had worse access to care than White people for 60% of access measures.
- Asian people had worse access to care than White people for 36% of access measures and better access to care for another 36% of access measures.
- Black people had worse access to care than White people for 47% of access measures.
- Native Hawaiian/Pacific Islander people had worse access to care than White people for 25% of access measures.
- Multiracial^i^ people had worse access to care than White people for 21% of access measures and better access to care for 7% of access measures.

Figure 2 Number and percentage of access measures for which members of selected age groups and with selected insurance status experienced better, same, or worse access to care compared with adults ages 18-44 years or individuals with private insurance for the most recent data year, 2019, 2020, or 2021

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, children ages 0-17 years had worse access to care than adults ages 18-44 years for 13% of access measures and better access to care for 88% of access measures (Figure 2).
- Adults ages 45-64 years had worse access to care than adults ages 18-44 years for 8% of access measures and better access to care for 75% of access measures.
- Adults age 65 years and over had worse access to care than adults ages 18-44 years for 25% of access measures and better access to care for 63% of access measures.
- People with only public insurance had worse access to care than people with private insurance for 45% of access measures.
- People with no insurance had worse access to care than people with private insurance for all access measures.

Figure 3 Number and percentage of access measures for which members of selected gender, income, and disability status groups experienced better, same, or worse access to care compared with males, people in households with incomes 400% or more of the poverty guideline, or people without disabilities for the most recent data year, 2019, 2020, or 2021

Key: n = number of measures; PG = federal poverty guideline.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, females had better access to care than males for 50% of access measures (Figure 3).
- People in households with incomes less than 100% of the federal poverty guideline (PG) had worse access to care than people in households with incomes 400% or more of the PG for 86% of access measures.
- People in households with incomes 100%-199% the PG had worse access to care than people in households with incomes 400% or more the PG for 86% of access measures.
- People in households with incomes 200%-399% of the PG had worse access to care than people in households with incomes 400% or more of the PG for 71% of access measures.
- People with disabilities had worse access to care than people without disabilities for 33% of access measures and better access to care for 50% of access measures.

Figure 4 Number and percentage of access measures for which members of selected geographic locations experienced better, same, or worse access to care compared with people in large fringe metro areas for the most recent data year, 2019, 2020, or 2021

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year. The geographic locations are based on the 2013 National Center for Health Statistics Urban-Rural Classification Scheme (https://www.cdc.gov/nchs/data_access/):

- Large central metropolitan refers to counties in a metropolitan statistical area (MSA) of 1 million or more population that contain the entire population of the largest principal city of the MSA, whose entire population is contained within the largest principal city of the MSA, or that contain at least 250,000 residents of any principal city in the MSA.
- Large fringe metropolitan refers to counties in MSAs of 1 million or more population that do not qualify as large central, described as suburban areas.
- Medium metropolitan refers to counties in MSAs of 250,000 to 999,999 population.
- Small metropolitan refers to counties in MSAs of less than 250,000 population.
- The two nonmetropolitan county designations are micropolitan, which are counties in a micropolitan statistical area, and noncore, which are nonmetropolitan counties that are not in a micropolitan statistical area.

- For the most recent data year, people in large central metro areas had worse access to care than people in large fringe metro areas for 36% of access measures (Figure 4).
- People in medium metro areas had worse access to care than people in large fringe metro areas for 36% of access measures.
- People in small metro areas had worse access to care than people in large fringe metro areas for 17% of access measures.
- People in micropolitan areas had worse access to care than people in large fringe metro areas for 33% of access measures.
- People in noncore areas had worse access to care than people in large fringe metro areas for 18% of access measures and better access to care for another 18% of measures.

## Person-Centered Care Quality Measures by Setting of Care

Figure 5 Number and percentage of all person-centered care measures improving, not changing, or worsening from 2002 to 2021, by setting of care

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p<0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p<0.10.

- From 2002 to 2021, 41% of person-centered care measures improved (Figure 5).
- From 2002 to 2021, 67% of person-centered care measures in the ambulatory setting, 44% of person-centered care measures in the home health setting, and 14% of person-centered care measures in the hospice setting improved.

## Patient Safety Quality Measures by Setting of Care

Figure 6 Number and percentage of all patient safety measures improving, not changing, or worsening from 2002 to 2021, by setting of care

Key: n = number of measures.

Note: Patient safety measures include measures related to nursing home resident safety. For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p≤0.10.

- From 2002 to 2021, 57% of patient safety measures improved and 4% of patient safety measure worsened (Figure 6).
- From 2002 to 2021, 100% of patient safety measures in the ambulatory setting, 25% of patient safety measures in the home health setting, 57% of patient safety measures in the hospital setting, and 100% of patient safety measures in the nursing home setting improved.
- From 2002 to 2021, 13% of patient safety measures in the home health setting worsened.

## Care Coordination Quality Measures by Topic Areas

Figure 7 Number and percentage of all care coordination measures improving, not changing, or worsening from 2002 to 2021, by sub-area

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p<0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p<0.10.

- From 2002 to 2021, 39% of care coordination measures improved and 11% of care coordination measures worsened (Figure 7).
- From 2002 to 2021, the one medication information measure, 50% of potentially avoidable admissions, 17% of preventable emergency department visits, 43% of preventable hospitalizations, 50% of supportive and palliative care, and 50% of transitions of care measures improved.
- From 2002 to 2021, 29% of preventable hospitalizations measures and 50% of transitions of care measures worsened.

## Affordable Care Quality Measures by Sub-Areas

Figure 8 Number and percentage of all affordable care measures improving, not changing, or worsening from 2002 to 2020, by sub-area

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p<0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p<0.10.

- From 2002 to 2020, the two affordable care measures, one about usual source of care and the other about financial burden, had no statistically significant changes (Figure 8).

## Effectiveness of Care Measures by Sub-Areas

Figure 9 Number and percentage of all effective treatment measures improving, not changing, or worsening from 2000 to 2021 by disease category

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p<0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p<0.10.

- From 2000 to 2021, 39% of effective treatment measures improved and 11% of effective treatment measures worsened (Figure 9).
- From 2000 to 2021, 83% of cancer measures, 43% of cardiovascular disease measures, 20% of chronic kidney disease measures, 14% of diabetes measures, 80% of HIV measures, and 50% of respiratory disease measures improved.
- From 2000 to 2021, 14% of diabetes measures and 60% of mental health and substance abuse measures worsened.

## Healthy Living Measures by Topic Areas

Figure 10 Number and percentage of all healthy living measures improving, not changing, or worsening from 2000 to 2021, by topic area

Key: n = number of measures.

Note: National Health Interview Survey measures that have been included in previous years were unavailable for this report. For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p<0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p<0.10.

- From 2000 to 2021, 47% of healthy living measures improved and 7% of healthy living measures worsened (Figure 10).
- From 2000 to 2021, 35% of clinical preventive services measures, 67% of functional status preservation and rehabilitation measures, 60% of supportive and palliative care measures, 80% of lifestyle modification measures, and 33% of maternal and child health measures improved.
- From 2000 to 2021, 10% of clinical preventive services measures and 20% of lifestyle modification measures worsened.

Figure 11 Number and percentage of all clinical preventive services measures improving, not changing, or worsening from 2000 to 2021, by sub-area

Key: n = number of measures.

Note: National Health Interview Survey measures that have been included in previous years were unavailable for this report. For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p<0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p<0.10.

- From 2000 to 2021, 17% of adult preventive care measures, 67% of childhood immunization measures, 30% of other childhood preventive care measures, and 17% of overall preventive care measures improved (Figure 11).
- From 2000 to 2021, 50% of overall preventive care measures worsened.

## Disparities by Race and Ethnicity

### Disparities in Quality of Care by Race and Ethnicity

Figure 12 Number and percentage of quality measures for which members of selected groups experienced better, same, or worse quality of care compared with White people for the most recent data year, 2019, 2020, or 2021

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander; n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, American Indian and Alaska Native people received worse care than White people for 44% of quality measures and better care for 13% of quality measures (Figure 12).
- Asian people received worse care than White people for 35% of quality measures and better care for 29% of quality measures.
- Black people received worse care than White people for 52% of quality measures and better care for 11% of quality measures.
- Native Hawaiian/Pacific Islander people received worse care than White people for 36% of quality measures and better care for 22% of quality measures.
- Hispanic people received worse care than non-Hispanic White people for 37% of quality measures and better care for 19% of quality measures.

### Changes in Disparities by Race and Ethnicity

Figure 13 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time, 2000 to 2021

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander; n = number of measures.

Note: Different data sources have different data years for most recent data year.

- From 2000 to 2021, disparities between American Indian or Alaska Native people and White people narrowed for 3% of measures (Figure 13).
- From 2000 to 2021, disparities between Asian people and White people narrowed for 3% of measures.
- From 2000 to 2021, disparities between Black people and White people narrowed for 8% of measures and worsened for 3% of measures.
- From 2000 to 2021, disparities between Native Hawaiian/Pacific Islander people and White people had no statistically significant changes.
- From 2000 to 2021, disparities between Hispanic people and non-Hispanic White people narrowed for 10% of measures.

### Disparities for American Indian and Alaska Native Populations

#### Disparities in Quality of Care for American Indian and Alaska Native Populations

Figure 14 Number and percentage of quality measures for which American Indian and Alaska Native people experienced better, same, or worse quality of care compared with White people for the most recent data year, 2019, 2020, or 2021

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, American Indian or Alaska Native people had worse quality of care than White people for 44% of quality measures and better quality of care for 13% of quality measures (Figure 14).

#### Trends in Quality of Care for American Indian and Alaska Native Populations

Figure 15 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2021

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

- Among the 109 quality measures with trend data for American Indian or Alaska Native people, 33% of quality measures were improving and 8% of quality measures were worsening from 2000 to 2021 (Figure 15).

#### Changes in Disparities for American Indian and Alaska Native Populations

Figure 16 Number and percentage of all quality measures with disparity at baseline for which disparities between American Indian and Alaska Native people and White people were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2021

Key: n = number of measures.

Note: Different data sources have different data years.

- From 2000 to 2021, disparities between American Indian and Alaska Native people and White people narrowed for 3% of quality measures (Figure 16).

### Disparities for Asian Populations

#### Disparities in Quality of Care for Asian Populations

Figure 17 Number and percentage of quality measures for which Asian people experienced better, same, or worse quality of care compared with White people for the most recent data year, 2019, 2020, or 2021

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, Asian people had worse quality of care than White people for 35% of quality measures and better quality of care for 29% of quality measures (Figure 17).

#### Trends in Quality of Care for Asian Populations

Figure 18 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2021

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

- Among the 113 quality measures with data for Asian people, 51% of quality measures were improving and 6% of quality measures were worsening from 2000 to 2021 (Figure 18).

#### Changes in Disparities for Asian Populations

Figure 19 Number and percentage of all quality measures with disparity at baseline for which disparities between Asian people and White people were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2021

Key: n = number of measures.

Note: Different data sources have different data years.

- From 2000 to 2021, disparities between Asian people and White people narrowed for 3% of quality measures (Figure 19).

### Disparities for Black Populations

#### Disparities in Quality of Care for Black Populations

Figure 20 Number and percentage of quality measures for which Black people experienced better, same, or worse quality of care compared with White people for the most recent data year, 2019, 2020, or 2021

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, Black people had worse quality of care than White people for 52% of quality measures and better quality of care for 11% of quality measures (Figure 20).

#### Trends in Quality of Care for Black Populations

Figure 21 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2021

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

- Among the 168 quality measures with data for Black people, 40% of quality measures were improving and 9% of quality measures were worsening from 2000 to 2021 (Figure 21).

#### Changes in Disparities for Black Populations

Figure 22 Number and percentage of quality measures with disparity at baseline for which disparities between Black people and White people were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2021

Key: n = number of measures.

Note: Different data sources have different data years.

- From 2000 to 2021, disparities between Black people and White people narrowed for 8% of quality measures and worsened for 3% of quality measures (Figure 22).

### Disparities for Native Hawaiian/Pacific Islander Populations

#### Disparities in Quality of Care for Native Hawaiian/Pacific Islander Populations

Figure 23 Number and percentage of quality measures for which Native Hawaiian/Pacific Islander groups experienced better, same, or worse quality of care compared with White groups for the most recent data year, 2019, 2020, or 2021

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, Native Hawaiian/Pacific Islander people had worse quality of care than White people for 36% of quality measures and better quality of care for 22% of quality measures (Figure 23).

#### Trends in Quality of Care for Native Hawaiian/Pacific Islander Populations

Figure 24 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2001 to 2021

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

- Among the 77 quality measures with data for Native Hawaiian/Pacific Islander people, 35% of quality measures were improving and 10% of quality measures were worsening from 2001 to 2021 (Figure 24).

#### Changes in Disparities for Native Hawaiian/Pacific Islander Populations

Figure 25 Number and percentage of all quality measures with disparity at baseline for which disparities between Native Hawaiian/Pacific Islander people and White people were improving, not changing, or worsening over time, total and by priority area, from 2008 to 2021

Key: n = number of measures.

Note: Different data sources have different data years.

- From 2008 to 2021, disparities between Native Hawaiian/Pacific Islander people and White people had no statistically significant changes (Figure 25).

### Disparities for Hispanic Populations

#### Disparities in Quality of Care for Hispanic Populations

Figure 26 Number and percentage of quality measures for which Hispanic groups experienced better, same, or worse quality of care compared with non-Hispanic White groups for the most recent data year, 2019, 2020, or 2021

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, Hispanic people had worse quality of care than non-Hispanic White people for 37% of quality measures and better quality of care for 19% of quality measures (Figure 26).

#### Changes in Quality of Care for Hispanic Populations

Figure 27 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total for Hispanic groups and by priority area, from 2000 to 2021

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

- Among the 162 quality measures with data for Hispanic people, 46% of quality measures were improving and 7% of quality measures were worsening from 2000 to 2021 (Figure 27).

#### Changes in Disparities for Hispanic Populations

Figure 28 Number and percentage of all quality measures with disparity at baseline for which disparities between Hispanic people and non-Hispanic White people were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2021

Key: n = number of measures.

Note: Different data sources have different data years.

- From 2000 to 2021, disparities between Hispanic people and non-Hispanic White people narrowed for 10% of quality measures (Figure 28).

## Disparities by Income

### Disparities in Access to Care Sub-Areas by Income Groups

Figure 29 Number and percentage of access measures for which people in households with an income less than 100% of the poverty guideline experienced better, same, or worse access to care compared with people in households with an income 400% or more of the poverty guideline, by sub-area, 2019, 2020, or 2021

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, people in households with an income less than 100% of the PG had worse access to care than people in households with an income 400% or more of the PG for 86% of access measures (Figure 29).

### Disparities in Quality of Care by Income Groups

Figure 30 Number and percentage of quality measures for which income groups experienced better, same, or worse quality of care compared with people in households with an income 400% or more of the poverty guideline for the most recent data year, 2019, 2020, or 2021

Key: n = number of measures; PG = federal poverty guideline.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, people in households with an income less than 100% the PG had worse quality of care than people in households with an income 400% or more of the PG for 61% of quality measures and better quality of care for 9% of quality measures (Figure 30).
- People in households with an income 100%-199% of the PG had worse quality of care than people in households with an income 400% or more of the PG for 53% of quality measures and better quality of care for 5% of quality measures.
- People in households with an income 200%-399% of the PG had worse quality of care than people in households with an income 400% or more of the PG for 43% of quality measures and better quality of care for 2% of quality measures.

### Trends in Quality of Care by Income Groups

Figure 31 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by income group, from 2000 to 2021

Key: n = number of measures; PG = federal poverty guideline.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

- For people in households with incomes less than 100% of the PG, 42% of quality measures were improving and 2% of quality measures were worsening from 2000 to 2021 (Figure 31).
- For people in households with incomes 100%-199% of the PG, 48% of quality measures were improving and 2% of quality measures were worsening from 2000 to 2021.
- For people in households with incomes 200%-399% of the PG, 48% of quality measures were improving and 4% of quality measures were worsening from 2000 to 2021.
- For people in households with incomes 400% or more of the PG, 41% of quality measures were improving and 5% of quality measures were worsening from 2000 to 2021.

### Changes in Disparities by Income Groups

Figure 32 Number and percentage of quality measures with disparity at baseline for which disparities related to income were improving, not changing, or worsening over time, 2000 to 2021

Key: n = number of measures; PG = poverty guideline.

Note: Different data sources have different data years.

- From 2000 to 2021, disparities between people in households with incomes less than 100% of the PG and people in households with incomes 400% or more of the PG had no statistically significant changes (Figure 32).
- From 2000 to 2021, disparities between people in households with incomes 100%-199% of the PG and people in households with incomes 400% or more of the PG had no statistically significant changes.
- From 2000 to 2021, disparities between people in households with incomes 200%-399% of the PG and people in households with incomes 400% or more of the PG had no statistically significant changes.

## Disparities by Insurance Status

### Disparities in Quality of Care by Insurance Status

Figure 33 Number and percentage of quality measures for which insurance groups experienced better, same, or worse quality of care compared with reference group (privately insured), 2019, 2020, or 2021

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, people with public insurance had worse quality of care than people with private insurance for 39% of quality measures and better quality of care for 7% of quality measures (Figure 33).
- People without insurance had worse quality of care than people with private insurance for 56% of quality measures and better quality of care for 5% of quality measures.

### Changes in Quality of Care by Insurance Status

Figure 34 Number and percentage of all quality measures that were improving, not changing, or worsening, total and by insurance status, from 2000 to 2021

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

- For people with private insurance, 40% of quality measures were improving and 3% of quality measures were worsening from 2000 to 2021 (Figure 34).
- For people with public insurance, 37% of quality measures were improving and 8% of quality measures were worsening from 2000 to 2021.
- For people without insurance, 31% of quality measures were improving and 2% of quality measures were worsening from 2000 to 2021.

### Changes in Disparities by Insurance Status

Figure 35 Number and percentage of quality measures with disparity at baseline for which disparities related to insurance were improving, not changing, or worsening, 2000 to 2021

Key: n = number of measures.

Note: Different data sources have different data years.

- From 2000 to 2021, disparities between people with public insurance and people with private insurance had no statistically significant changes (Figure 35).
- From 2000 to 2021, disparities between people without insurance and people with private insurance had no statistically significant changes.

## Disparities by Residence Location

### Disparities in Quality of Care by Residence Location

Figure 36 Number and percentage of quality measures for which residents of selected locations experienced better, same, or worse quality of care compared with large fringe metropolitan areas, 2019, 2020, or 2021

Key: n = number of measures.

Note: Definitions of residence locations are available at https://www.cdc.gov/nchs/data_access/urban_rural.htm and in Figure 4. The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

- For the most recent data year, people in large central metro areas had worse quality of care than people in large fringe metro areas for 21% of quality measures and better quality of care for 4% of quality measures (Figure 36).
- People in medium metro areas had worse quality of care than people in large fringe metro areas for 21% of quality measures and better quality of care for 1% of quality measures.
- People in small metro areas had worse quality of care than people in large fringe metro areas for 22% of quality measures and better quality of care for 1% of quality measures.
- People in micropolitan areas had worse quality of care than people in large fringe metro areas for 32% of quality measures and better quality of care for 2% of quality measures.
- People in noncore areas had worse quality of care than people in large fringe metro areas for 40% of quality measures and better quality of care for 7% of quality measures.

### Changes in Quality of Care by Residence Location

Figure 37 Number and percentage of all quality measures that were improving, not changing, or worsening, by residence location, from 2002 to 2021

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

- For people in large central metro areas, 50% of quality measures were improving and 9% of quality measures were worsening from 2000 to 2021 (Figure 37).
- For people in large fringe metro areas, 38% of quality measures were improving and 9% of quality measures were worsening from 2000 to 2021.
- For people in medium metro areas, 38% of quality measures were improving and 9% of quality measures were worsening from 2000 to 2021.
- For people in small metro areas, 36% of quality measures were improving and 7% of quality measures were worsening from 2000 to 2021.
- For people in micropolitan areas, 32% of quality measures were improving and 7% of quality measures were worsening from 2000 to 2021.
- For people in noncore areas, 36% of quality measures were improving and 10% of quality measures were worsening from 2000 to 2021.

### Changes in Disparities by Residence Location

Figure 38 Number and percentage of quality measures with disparity at baseline for which disparities related to residence location were improving or not changing, 2002 to 2021

Key: n = number of measures.

Note: Different data sources have different data years.

- From 2002 to 2021, disparities between people living in large central metro areas and people living in large fringe metro areas narrowed for 9% of quality measures (Figure 38).
- From 2002 to 2021, disparities between people living in medium metro areas and people living in large fringe metro areas worsened for 9% of quality measures.
- From 2002 to 2021, disparities between people living in small metro areas and people living in large fringe metro areas worsened for 6% of quality measures.
- From 2002 to 2021, disparities between people living in micropolitan areas and people living in large fringe metro areas worsened for 5% of quality measures.
- From 2002 to 2021, disparities between people living in noncore areas and people living in large fringe metro areas narrowed for 4% of quality measures and worsened for 8% of quality measures.

i Multiracial is defined as people indicating they were two or more of the following races: American Indian or Alaska Native, Asian, Black, Native Hawaiian/Pacific Islander, and White.