# Appendix B Quality Trends and Disparities Tables

## COVID-19 Experiences

SARS-CoV-2, the virus that causes COVID-19, spreads through respiratory droplets transmitted by an infected person when they sneeze, cough, speak, sing, laugh, or breathe. The virus enters the human body by invading epithelial cells in exposed mucous membranes, such as in the respiratory tract. Once infected, people may respond in different ways, ranging from having no symptoms to dying from it.

A small percentage of infected people would go on to develop severe disease, which manifested as severe shortness of breath, need for supplemental oxygen, or pneumonia requiring hospitalization. An even smaller percentage would develop critical symptoms that required transfer to an intensive care unit for interventions such as life support on a mechanical ventilator.

Of 1.3 million U.S. cases reported to the Centers for Disease Control and Prevention through May 2020, 14% were hospitalized, 2% were admitted to an intensive care unit, and 5% died.

In addition to its direct effects, COVID-19’s transmissibility produced a surge in demand for healthcare services by people with severe and critical illness that overwhelmed many healthcare delivery organizations in communities affected by the disease. In addition, care for severe cases of COVID-19 strained hospital capacity and hindered their ability to treat people with other illnesses.

### Importance

#### Mortality

COVID-19 Deaths (2022).................................................244,986^1^

#### Prevalence

COVID-19 Cases.......................104 million^2^

#### Cost

Lost GDP...................................................................................$7.6 billion

Health Loss

Premature Death .............................................................................................................. $4.4 billion

Long-Term Health Impairment ....................................................................................... $2.6 billion

Mental Health Impairment ............................................................................................ $1.6 billion^iii^

#### Key Findings

COVID-19 measures that showed large disparities include:

- COVID-19 deaths per 100,000 population.
- Inability to access needed care for substance use treatment due to the COVID-19 pandemic, resulting in moderate to severe impact on health.
- Not receiving needed care from a family member or friend because of the COVID-19 pandemic.
- Delayed prescriptions for substance use treatment due to the COVID-19 pandemic.
- Not receiving nurse or professional home health care because of the COVID-19 pandemic.

COVID-19 measures were not trended over time or assessed for overall improvement or worsening or worsening disparities.

### References

1 Ahmad FB, Cisewski JA, Xu J, Anderson RN. Provisional mortality data - United States, 2022. MMWR Morb Mortal Wkly Rep. 2023 May 5;72(18):488–492. https://www.cdc.gov/mmwr/volumes/72/wr/mm7218a3.htm?s_cid=mm7218a3_w. Accessed October 10, 2023.37141156
2 Silk BJ, Scobie HM, Duck WM, COVID-19 Surveillance After Expiration of the Public Health Emergency Declaration ― United States, May 11, 2023. MMWR Morb Mortal Wkly Rep. 2023;72:523–528. https://www.cdc.gov/mmwr/volumes/72/wr/mm7219e1.htm?s_cid=mm7219e1_w. Accessed October 10, 2023.37167154
3 Cutler DM, Summers LH. The COVID-19 Pandemic and the $16 Trillion Virus. JAMA. 2020;324(15):1495–1496. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7604733/. Accessed October 10, 2023.33044484

### Measure Category: 1. COVID-19 Experiences, Subcategory: 1. COVID-19 Infection and Death

Appendix Table 1.1.1 COVID-19 cases per 100,000 population

Appendix Table 1.1.2 COVID-19 cases with hospital admissions

Appendix Table 1.1.3 Hospital admissions for COVID-19 per 100,000 population

Appendix Table 1.1.4 Adults who ever had COVID-19

Appendix Table 1.1.5 Children who ever had COVID-19

Appendix Table 1.1.6 Adults with COVID-19 infection who described having moderate or severe symptoms at their worst

Appendix Table 1.1.7 Children with COVID-19 infection who described having moderate or severe symptoms at their worst

Appendix Table 1.1.8 COVID-19 Death per 100,000 population

Appendix Table 1.1.9 Deaths per 1,000 COVID-19 cases

### Measure Category: 1. COVID-19 Experiences, Subcategory: 2. COVID-19 Vaccination

Appendix Table 1.2.1 Adults who received recommendation to receive a COVID-19 vaccine from a doctor, nurse, or other health professional

Appendix Table 1.2.2 Adults who received recommendation to receive a COVID-19 booster from a doctor, nurse, or other health professional

Appendix Table 1.2.3 Adults who received at least one dose of COVID-19 vaccination

Appendix Table 1.2.4 Adults who received two doses of COVID-19 vaccinations

Appendix Table 1.2.5 Adults who received three or more doses of COVID-19 vaccinations

Appendix Table 1.2.6 Children ages 12–17 who received at least one dose of COVID-19 vaccination

Appendix Table 1.2.7 Children ages 12–17 who received two doses of COVID-19 vaccinations

Appendix Table 1.2.8 Adults who received at least one dose of COVID-19 vaccine who experienced any difficulty obtaining the vaccine

Appendix Table 1.2.9 Adults who did not receive any COVID-19 vaccine who experienced any difficulty obtaining the vaccine

Appendix Table 1.2.10 Adults who received COVID-19 booster vaccine who experienced any difficulty obtaining the booster

Appendix Table 1.2.11 Adults who did not receive COVID-19 booster vaccine who experienced any difficulty obtaining the booster

Appendix Table 1.2.12 Adults who had difficulty getting an online appointment for the COVID-19 booster

Appendix Table 1.2.13 Adults who had difficulty knowing where to get the COVID-19 booster

Appendix Table 1.2.14 Adults who had difficulty getting to a vaccination site to get the COVID-19 booster

Appendix Table 1.2.15 Adults who had difficulty getting the COVID-19 booster because vaccination sites were not open at convenient times

Appendix Table 1.2.16 Adults who had difficulty knowing if they were eligible for the COVID-19 booster

Appendix Table 1.2.17 Adults who had difficulty with getting the COVID-19 booster because of a reaction to a previous dose of the COVID-19 vaccine

Appendix Table 1.2.18 Adults who had difficulty with the cost of getting the COVID-19 booster

Appendix Table 1.2.19 Adults who provide direct medical care services who received at least one COVID-19 vaccination

Appendix Table 1.2.20 Adults who provide direct medical care services who received two COVID-19 vaccinations

Appendix Table 1.2.21 Adults who provide direct medical care services who received three or more COVID-19 vaccinations

Appendix Table 1.2.22 Adults who work in healthcare settings but do not provide direct medical care services who received at least one COVID-19 vaccination

Appendix Table 1.2.23 Adults who work in healthcare settings but do not provide direct medical care services who received two COVID-19 vaccinations

Appendix Table 1.2.24 Adults who work in healthcare settings but do not provide direct medical care services who received three or more COVID-19 vaccinations

### Measure Category: 1. COVID-19 Experiences, Subcategory: 3. Access During COVID-19

Appendix Table 1.3.1 Adults who did not get medical care because of COVID-19

Appendix Table 1.3.2 Children who did not get medical care because of COVID-19

Appendix Table 1.3.3 Adults receiving treatment for cancer who changed, delayed, or canceled cancer treatment because of COVID-19

Appendix Table 1.3.4 Adults who ever had cancer receiving medical care for other conditions related to cancer who changed, delayed, or canceled treatment because of COVID-19

Appendix Table 1.3.5 Adults who received home healthcare services in the past 12 months

Appendix Table 1.3.6 Adults who needed home healthcare services who did not receive nurse or professional home healthcare because of COVID-19

Appendix Table 1.3.7 Adults who received care at home from a family member or friend in the past 12 months

Appendix Table 1.3.8 Adults who had a family member or friend provide care that a professional home healthcare provider did not because of COVID-19

Appendix Table 1.3.9 Adults who needed care from a family member or friend but did not get it because of COVID-19

Appendix Table 1.3.10 Adults who had a virtual medical appointment in the past 12 months whose virtual appointment was because of COVID

Appendix Table 1.3.11 Children who had a virtual medical appointment in the past 12 months whose virtual appointment was because of COVID

Appendix Table 1.3.12 Practices planning to continue using telemedicine visits when appropriate once the coronavirus disease pandemic is over

### Measure Category: 1. COVID-19 Experiences, Subcategory: 4. Mental Health and Substance Use During COVID-19

Appendix Table 1.4.1 Adolescents ages 12–17 who had serious thoughts of suicide because of the COVID-19 pandemic in the past 12 months

Appendix Table 1.4.2 Adults who had serious thoughts of suicide because of the COVID-19 pandemic in the past 12 months

Appendix Table 1.4.3 Adolescents ages 12–17 who made any suicide plans because of the COVID-19 pandemic in the past 12 months

Appendix Table 1.4.4 Adults who made any suicide plans because of the COVID-19 pandemic in the past 12 months

Appendix Table 1.4.5 Adolescents ages 12–17 who attempted suicide because of the COVID-19 pandemic in the past 12 months

Appendix Table 1.4.6 Adults who attempted suicide because of the COVID-19 pandemic in the past 12 months

Appendix Table 1.4.7 Adults who perceived the COVID-19 pandemic had quite a bit or a lot of negative effect on their emotional or mental health

Appendix Table 1.4.8 Adults who perceived the COVID-19 pandemic had at least a little negative effect on their emotional or mental health

Appendix Table 1.4.9 Adults with a major depressive episode (MDE) in the past 12 months who perceived the COVID-19 pandemic had at least a little negative effect on their emotional or mental health

Appendix Table 1.4.10 Adults with a major depressive episode (MDE) in the past 12 months who perceived the COVID-19 pandemic had quite a bit or a lot negative effect on their emotional or mental health

Appendix Table 1.4.11 Adults with a major depressive episode (MDE) with severe impairment in the past 12 months who perceived the COVID-19 pandemic had at least a little negative effect on their emotional or mental health

Appendix Table 1.4.12 Adults with a major depressive episode (MDE) with severe impairment in the past 12 months who perceived the COVID-19 pandemic had quite a bit or a lot negative effect on their emotional or mental health

Appendix Table 1.4.13 Adults without a major depressive episode (MDE) in the past 12 months who perceived the COVID-19 pandemic had at least a little negative effect on their emotional or mental health

Appendix Table 1.4.14 Adults without a major depressive episode (MDE) in the past 12 months who perceived the COVID-19 pandemic had quite a bit or a lot negative effect on their emotional or mental health

Appendix Table 1.4.15 Adults with diabetes who feel more overwhelmed by the demands of living with diabetes compared to before the COVID-19 public health emergency

Appendix Table 1.4.16 Adults who received less social and emotional support in the past 12 months than they had previously

Appendix Table 1.4.17 People age 12 and over with alcohol use in the past 12 months who used alcohol a little less or much less than before the COVID-19 pandemic

Appendix Table 1.4.18 People age 12 and over with alcohol use in the past 12 months who used alcohol a little more or much more than before the COVID-19 pandemic

Appendix Table 1.4.19 People age 12 and over with drug or prescription psychotherapeutics use in the past 12 months who used drugs a little less or much less than before the COVID-19 pandemic

Appendix Table 1.4.20 People age 12 and over with drug or prescription psychotherapeutics use in the past 12 months who used drugs a little more or much more than before the COVID-19 pandemic

Appendix Table 1.4.21 People age 12 and over who were unable to access needed care for substance use treatment due to the COVID-19 pandemic resulting in moderate to severe impact on health

Appendix Table 1.4.22 People age 12 and over with illicit drug or alcohol use in the past 12 months who were unable to access needed care for substance use treatment due to the COVID-19 pandemic resulting in moderate to severe impact on health

Appendix Table 1.4.23 People age 12 and over with illicit drug or alcohol use disorder in the past 12 months who were unable to access needed care for substance use treatment due to the COVID-19 pandemic resulting in moderate to severe impact on health

Appendix Table 1.4.24 People age 12 and over who delayed getting prescriptions for substance use treatment due to the COVID-19 pandemic

Appendix Table 1.4.25 People age 12 and over with illicit drug or alcohol use in the past 12 months who delayed getting prescriptions for substance use treatment due to the COVID-19 pandemic

Appendix Table 1.4.26 People age 12 and over with illicit drug or alcohol use disorder in the past 12 months who delayed getting prescriptions for substance use treatment due to the COVID-19 pandemic

Appendix Table 1.4.27 People age 12 and over who had appointments for substance use treatment that were delayed or cancelled due to the COVID-19 pandemic

Appendix Table 1.4.28 People age 12 and over with illicit drug or alcohol use in the past 12 months who had appointments for substance use treatment that were delayed or cancelled due to the COVID-19 pandemic

Appendix Table 1.4.29 People age 12 and over with illicit drug or alcohol use disorder in the past 12 months who had appointments for substance use treatment that were delayed or cancelled due to the COVID-19 pandemic

Appendix Table 1.4.30 People age 12 and over who had appointments for substance use treatment that was moved from in-person to telehealth due to the COVID-19 pandemic

Appendix Table 1.4.31 People age 12 and over with illicit drug or alcohol use in the past 12 months who had appointments for substance use treatment that was moved from in-person to telehealth due to the COVID-19 pandemic

Appendix Table 1.4.32 People age 12 and over with illicit drug or alcohol use disorder in the past 12 months who had appointments for substance use treatment that was moved from in-person to telehealth due to the COVID-19 pandemic

## Access to Care

Access to healthcare means having "the timely use of personal health services to achieve the best health outcomes."^1^

### Importance

Access to comprehensive, quality healthcare services is important for promoting and maintaining health, preventing and managing disease, reducing unnecessary disability and premature death, and achieving health equity for all Americans.^2^ Attaining good access to care means having:

- Health insurance that facilitates entry into the healthcare system.
- Timely access to needed care.
- A usual source of care with whom the patient can develop a relationship.
- The ability to receive care when there is a perceived need for care.

### Key Findings

Access to care measures that improved overall include:

- People under age 65 who were uninsured all year.
- People under age 65 with any period of uninsurance during the year.
- Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed.

No key access to care measures worsened overall.

Access to care measures that showed large disparities include:

- People under age 65 with any private health insurance.
- People under age 65 with health insurance.

No key access to care measures showed worsening disparities.

### References

1 Institute of Medicine, Committee on Monitoring Access to Personal Health Care Services. Access to Health Care in America. Millman M, ed. Washington, DC: National Academies Press; 1993. https://www.ncbi.nlm.nih.gov/books/NBK235882/. Accessed October 10, 2023.
2 Office of Disease Prevention and Health Promotion. HealthyPeople 2030. Health Care Access and Quality. https://health.gov/healthypeople/objectives-and-data/browse-objectives/health-care-access-and-quality. Accessed October 10, 2023.

### Measure Category: 2. Access, Subcategory: 1. Getting Appointments for Care

Appendix Table 2.1.1 Adults who had any appointments for routine health care in the last 12 months who sometimes or never got an appointment for routine care as soon as needed

Appendix Table 2.1.2 Children who had any appointments for routine health care in the last 12 months who sometimes or never got an appointment for routine care as soon as needed

Appendix Table 2.1.3 Adults who needed care right away for an illness, injury, or condition in the last 12 months who sometimes or never got care as soon as needed

### Measure Category: 2. Access, Subcategory: 2. Waiting Time

Appendix Table 2.2.1 Adults who reported getting the help or advice they needed the same day they contacted their home health care providers

Appendix Table 2.2.2 Emergency department visits triaged as immediate or emergent at which patients waited to see a physician for 1 hour or more

Appendix Table 2.2.3 Emergency department visits triaged as urgent at which patients waited to see a physician for 1 hour or more

Appendix Table 2.2.4 Emergency department visits where the patient was transferred or admitted to the hospital and length of visit was 6 hours or more

Appendix Table 2.2.5 Median time in minutes spent in the emergency department (ED) from admission decision to ED departure for admitted patients

Appendix Table 2.2.6 Median time in minutes outpatients spent at emergency department (ED) from ED arrival to ED departure

Appendix Table 2.2.7 Median time in minutes outpatients with psychiatric or mental health conditions spent at emergency department (ED) from ED arrival to ED departure

### Measure Category: 2. Access, Subcategory: 3. Health Insurance

Appendix Table 2.3.1 People under age 65 with health insurance

Appendix Table 2.3.2 People under age 65 with any private health insurance

Appendix Table 2.3.3 Adults age 65 and over with any private health insurance

Appendix Table 2.3.4 People under age 65 who were uninsured all year

Appendix Table 2.3.5 People under age 65 with any period of uninsurance during the year

Appendix Table 2.3.6 People under age 65 without health insurance

Appendix Table 2.3.7 People under age 65 with public health insurance only

Appendix Table 2.3.8 People under age 65 with any period of public insurance during the year

Appendix Table 2.3.9 People under age 65 with any period of private dental insurance during the year

Appendix Table 2.3.10 Adults age 65 and over with any Medicare Advantage health insurance

Appendix Table 2.3.11 Adults age 65 and over with any dual-eligible health insurance plan

### Measure Category: 2. Access, Subcategory: 4. Usual Source of Care

Appendix Table 2.4.1 People with a specific source of ongoing care

Appendix Table 2.4.2 People in fair or poor health with a specific source of ongoing care

Appendix Table 2.4.3 People who identified a hospital, emergency room, or clinic as a source of ongoing care

### Measure Category: 2. Access, Subcategory: 5. Patient Perception of Need

Appendix Table 2.5.1 People with a usual source of care, excluding hospital emergency rooms, who has office hours at night or on weekends

Appendix Table 2.5.2 People with a usual source of care who is somewhat to very difficult to contact over the telephone during regular business hours

Appendix Table 2.5.3 Adults who tried to make an appointment to see a specialist in the last 12 months who sometimes or never found it easy to get the appointment

Appendix Table 2.5.4 Children who needed to see a specialist in the last 12 months who sometimes or never found it easy to see a specialist

## Affordable Care

The goal of the Affordable Care Act was to establish quality, affordable healthcare for Americans. The law also created a platform to test new healthcare payment and delivery models through the Centers for Medicare & Medicaid Services. Tracking this quality domain helps healthcare professionals, researchers, and policymakers better understand the status of affordable care.

Reducing the cost of healthcare will support two related goals under this quality domain. The first includes ensuring affordable and accessible high-quality healthcare for people, families, caregivers, employers, and governments. The second is supporting and enabling communities to ensure accessible, high-quality care while reducing waste and fraud.

### Importance

Affordability of care remains a central barrier to access for many individuals, families, and caregivers. Several financial and nonfinancial barriers contribute to the inaccessibility of care. Financial barriers include high premiums and copays, lack of insurance, and underinsurance. Nonfinancial barriers include transportation challenges, negative interactions with care teams, delayed access to a healthcare provider, and inability to access care due to competing demands (e.g., childcare, work schedules).^1^ Past research continues to show that lack of insurance and inaccessible care are linked to patient mortality.^2,3^

### Key Findings

No key affordable care measures showed overall improvement or worsening or worsening disparities.

Affordable care measures that showed large disparities include:

- People under age 65 whose family's health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income.
- People without a usual source of care who indicated a financial or insurance reason for not having a source of care.

### References

1 Kullgren JT, McLaughlin CG, Mitra N, Armstrong K. Nonfinancial barriers and access to care for U.S. adults. Health Serv Res. 2012;47(1 Pt 2):462–85. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3393009/. Accessed October 10, 2023.22092449
2 Wilper AP, Woolhandler S, Lasser KE, McCormick D, Bor DH, Himmelstein DU. Health insurance and mortality in U.S. adults. Am J Public Health. 2009;99(12):2289–95. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2775760/. Accessed October 10, 2023.19762659
3 Institute of Medicine; Committee on the Consequences of Uninsurance. Care Without Coverage: Too Little, Too Late. Washington, DC: National Academies Press; 2002. https://www.nap.edu/catalog/10367/carewithout-coverage-too-little-too-late. Accessed October 10, 2023.

### Measure Category: 3. Affordable Care, Subcategory: 1. Financial Burden of Healthcare

Appendix Table 3.1.1 People under age 65 whose family's health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income

### Measure Category: 3. Affordable Care, Subcategory: 2. Usual Source of Care

Appendix Table 3.2.1 People without a usual source of care who indicated a financial or insurance reason for not having a source of care

Appendix Table 3.2.2 Composite measure: People unable to get or delayed in getting needed medical care, dental care, or prescription medicines due to cost

Appendix Table 3.2.3 People unable to get or delayed in getting needed medical care due to cost

Appendix Table 3.2.4 People unable to get or delayed in getting needed dental care due to cost

Appendix Table 3.2.5 People unable to get or delayed in getting needed prescription medicines due to cost

Appendix Table 3.2.6 Adults age 18 and over who needed to see a doctor but could not because of cost in the past 12 months

## Effectiveness of Care

As better understanding of health has led to superior ways of preventing, diagnosing, and treating diseases, the health of most Americans has improved dramatically. However, more than half of all Americans are managing at least one chronic disease and many of them do not receive the full benefits of high-quality care.^1,2^

### Importance

Effective treatment interventions have been shown to reduce mortality and morbidity among people with chronic diseases. The following are some of the leading causes of death in the United States, showing number of deaths from those causes in 2021 and estimated healthcare costs to treat the conditions. Condition-specific costs are obtained from separate sources and methodologies may differ^3^:

- Heart disease: 695,547 deaths in 2021 and $239.9 billion annual average in 2018 to 2019.^4^
- Cancer: 605,213 deaths in 2021 and $183 billion in 2015.^5^
- COVID-19: 416,893 deaths in 2021.
- Accidents (unintentional injuries): 224,935 deaths in 2021 and $327 billion in 2019.^6^
- Stroke (cerebrovascular diseases): 162,890 deaths in 2021 and $45.5 billion annual average for 2014–2015.^7^
- Chronic lower respiratory diseases: 142,342 deaths in 2021, $49 billion for chronic obstructive pulmonary disease in 2020^7^ and $50 billion for asthma in 2013.^8^
- Alzheimer’s disease: 119,399 deaths in 2021 and $355 billion in 2021.^9^
- Diabetes: 103,294 deaths in 2021 and $237 billion in 2017.^10^
- Chronic liver disease and cirrhosis: 56,585 deaths in 2021.
- Nephritis, nephrotic syndrome, and nephrosis: 54,358 deaths in 2021 and $87.2 billion in Medicare for chronic kidney disease without end stage renal disease and $37.3 billion in Medicare for end stage renal disease in 2019.^11^

### Key Findings

Effective care measures that improved overall include:

- Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined.
- HIV infection deaths per 100,000 population.
- Deaths per 1,000 hospital admissions with percutaneous coronary intervention, age 40 years and over.
- Patients with tuberculosis who completed a curative course of treatment within 1 year of initiation of treatment.
- Deaths per 1,000 hospital admissions with heart failure, age 18 years and over.

Effective care measures that worsened overall include:

- Emergency department visits involving opioid-related diagnoses per 100,000 population.
- Hospital inpatient stays involving opioid-related diagnoses per 100,000 population.
- Suicide deaths among people age 12 and over per 100,000 population.
- Adults age 40 years and over with diagnosed diabetes who had their feet checked for sores or irritation in the calendar year.

Effective care measures that showed large disparities include:

- Lung cancer deaths per 100,000 population per year.
- Hospital admissions for heart failure per 100,000 population.
- Colorectal cancer deaths per 100,000 population per year.

Effective care measures that showed worsening disparities include:

- Emergency department visits involving opioid-related diagnoses per 100,000 population.
- Hospital inpatient stays involving opioid-related diagnoses per 100,000 population.

### References

1 Centers for Disease Control and Prevention, National Center for Chronic Disease Prevention and Health Promotion. Chronic Diseases in America. Last reviewed January 2021. https://www.cdc.gov/chronicdisease/resources/infographic/chronic-diseases.htm. Accessed October 11, 2023.
2 Raghupathi W, Raghupathi V. An empirical study of chronic diseases in the United States: a visual analytics approach. Int J Environ Res Public Health. 2018 Mar;15(3):431. https://doi.org/10.3390/ijerph15030431. Accessed October 11, 2023.29494555
3 Centers for Disease Control and Prevention. Leading Causes of Death. https://www.cdc.gov/nchs/fastats/leading-causes-of-death.htm Accessed October 11, 2023.
4 Tsao CW, Aday AW, Almarzooq ZI, Anderson CA M, and on behalf of the American Heart Association Council on Epidemiology and Prevention Statistics Committee and Stroke Statistics Subcommittee. Heart disease and stroke statistics—2023 update: a report from the American Heart Association Circulation. 2023 Feb 21;147(8):e93–e621. https://www.ahajournals.org/doi/10.1161/CIR.0000000000001123. Accessed October 11, 2023.36695182
5 Mariotto AB, Enewold L, Zhao J, Zeruto CA, Yabroff KR. Medical care costs associated with cancer survivorship in the United States. Cancer Epidemiol Biomarkers Prev. 2020 Jul;29(7):1304–1312. https://doi.org/10.1158/1055-9965.EPI-19-1534. Accessed October 11, 2023.32522832
6 Peterson C, Miller GF, Barnett SB, Florence C. Economic cost of injury — United States, 2019. MMWR Morb Mortal Wkly Rep. 2021;70:1655–1659. https://www.cdc.gov/mmwr/volumes/70/wr/mm7048a1.htm. Accessed October 11, 2023.34855726
7 Centers for Disease Control and Prevention. Chronic Obstructive Pulmonary Disease. COPD Costs. Last reviewed February 2018. https://www.cdc.gov/copd/infographics/copd-costs.html. Accessed October 11, 2023.
8 Nurmagambetov T, Kuwahara R, Garbe P. The economic burden of asthma in the United States, 2008–2013. Ann Am Thorac Soc. 2018 Mar;15(3):348–356. https://www.atsjournals.org/doi/10.1513/AnnalsATS.201703-259OC. Accessed October 11, 2023.29323930
9 2021 Alzheimer’s Disease Facts and Figures. Alzheimer’s Impact Movement; Alzheimer’s Association. March 2021. https://alz-journals.onlinelibrary.wiley.com/pb-assets/hub-assets/alz-journals/Facts-2021-Infographic-1623213302.png. Accessed October 11, 2023.
10 American Diabetes Association. Economic costs of diabetes in the U.S. in 2017. Diabetes Care. 2018;41(5):917–928. https://diabetesjournals.org/care/article/41/5/917/36518/Economic-Costs-of-Diabetes-in-the-U-S-in-2017. Accessed October 11, 2023.
11 Chronic Kidney Disease Basics. https://www.cdc.gov/kidneydisease/basics.html#print. Accessed October 11, 2023.

### Measure Category: 4. Effectiveness of Care, Subcategory: 1. Cancer

Appendix Table 4.1.1 Women with clinical Stage I-IIb breast cancer who received axillary node dissection or sentinel lymph node biopsy at the time of breast cancer surgery (lumpectomy or mastectomy)

Appendix Table 4.1.2 Women under age 70 treated for breast cancer with breast-conserving surgery who received radiation therapy to the breast within 1 year of diagnosis

Appendix Table 4.1.3 Breast cancer deaths per 100,000 female population per year

Appendix Table 4.1.4 Radiation therapy recommended or administered following any mastectomy within 1 year of diagnosis of breast cancer for women with 4 or more positive regional lymph nodes

Appendix Table 4.1.5 Tamoxifen or third generation aromatase inhibitor recommended or administered within 1 year of diagnosis for women with AJCC T1cN0M0 or stage IB to stage III hormone receptor-positive breast cancer

Appendix Table 4.1.6 Combination chemotherapy recommended or administered within 4 months of diagnosis for women under age 70 with AJCC T1cN0MO or Stage IB-III hormone receptor negative breast cancer

Appendix Table 4.1.7 Radiation therapy completed within 60 days of initiation of radiation among women diagnosed with any stage of cervical cancer

Appendix Table 4.1.8 Use of brachytherapy in patients treated with primary radiation with curative intent in any stage of cervical cancer

Appendix Table 4.1.9 Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined

Appendix Table 4.1.10 Colorectal cancer deaths per 100,000 population per year

Appendix Table 4.1.11 Adjuvant chemotherapy recommended or administered within 4 months of diagnosis for patients under age 80 with AJCC Stage III lymph node positive colon cancer

Appendix Table 4.1.12 Composite measure: Cancer deaths per 100,000 population per year for all cancers

Appendix Table 4.1.13 Lung cancer deaths per 100,000 population per year

### Measure Category: 4. Effectiveness of Care, Subcategory: 2. Cardiovascular Disease

Appendix Table 4.2.1 Adults with hypertension whose blood pressure is under control

Appendix Table 4.2.2 Deaths per 1,000 hospital admissions with acute myocardial infraction, age 18 and over, without transfer cases

Appendix Table 4.2.3 Median time in minutes from emergency department arrival to receipt of ECG for outpatients with chest pain or possible heart attack

Appendix Table 4.2.4 Outpatients with chest pain or possible heart attack who received fibrinolytic therapy within 30 minutes of arrival

Appendix Table 4.2.5 Median time in minutes before outpatients with chest pain or possible heart attack who needed specialized care and did not have contraindication to fibrinolytics were transferred to another hospital

Appendix Table 4.2.6 Hospital admissions for heart failure per 100,000 population, age 18 and over

Appendix Table 4.2.7 Deaths per 1,000 hospital admission with heart failure, age 18 and over

Appendix Table 4.2.8 Deaths per 1,000 hospital admissions with abdominal aortic aneurysm repair, age 18 and over

Appendix Table 4.2.9 Deaths per 1,000 hospital admissions with coronary artery bypass graft, age 40 and over

Appendix Table 4.2.10 Deaths per 1,000 hospital admissions with percutaneous coronary intervention, age 40 and over

Appendix Table 4.2.11 Receipt of interpretation of results within 45 minutes of emergency department (ED) arrival for ischemic or hemorrhagic stroke patients who came to the ED with stroke symptoms and received head CT or MRI

### Measure Category: 4. Effectiveness of Care, Subcategory: 3. Chronic Kidney Disease

Appendix Table 4.3.1 Adult end stage renal disease patients who saw a nephrologist at least 12 months prior to initiation of renal replacement therapy

Appendix Table 4.3.2 Dialysis patients under age 70 who were registered on a waiting list for transplantation or received a deceased donor kidney transplant within a year of initiation

Appendix Table 4.3.3 patients with treated chronic kidney failure who received a transplant within 3 years of date of renal failure

Appendix Table 4.3.4 Hemodialysis patients whose hemoglobin level is less than 10 g/dL

Appendix Table 4.3.5 Adult hemodialysis patients who use arteriovenous fistulas as the primary mode of vascular access

### Measure Category: 4. Effectiveness of Care, Subcategory: 4. Diabetes

Appendix Table 4.4.1 Composite measure: Adults age 40 and over with diagnosed diabetes who received all four recommended services for diabetes in the calendar year (two or more hemoglobin A1c measurements, dilated eye examination, foot examination, and flu vaccination)

Appendix Table 4.4.2 Adults age 40 and over with diagnosed diabetes who received at least two hemoglobin A1c measurements in the calendar year

Appendix Table 4.4.3 Adults age 40 and over with diagnosed diabetes who received a dilated eye examination in the calendar year

Appendix Table 4.4.4 Adults age 40 and over with diagnosed diabetes who had their feet checked for sores or irritation in the calendar year

Appendix Table 4.4.5 Adults age 40 and over with diagnosed diabetes who recived a flu vaccination in the calendar year

Appendix Table 4.4.6 Adults age 40 and over with diabetes whose condition was diagnosed

Appendix Table 4.4.7 Adults age 40 and over with diagnosed diabetes with hemoglobin A1c less than 8.0% (optimal control)

Appendix Table 4.4.8 Adults age 40 and over with diagnosed diabetes with hemoglobin A1c more than 9.0% (poor control)

Appendix Table 4.4.9 Adults age 40 and over with diagnosed diabetes with blood pressure less than 130/80 mm Hg

Appendix Table 4.4.10 Adjusted incident rates of end stage renal disease due to diabetes per million population

Appendix Table 4.4.11 Kidney failure due to diabetes among people with diabetes

### Measure Category: 4. Effectiveness of Care, Subcategory: 5. HIV/AIDS

Appendix Table 4.5.1 New AIDS cases per 100,000 population age 13 and over

Appendix Table 4.5.2 New HIV cases per 100,000 population age 13 and over

Appendix Table 4.5.3 People age 13 and over living with HIV who know their serostatus

Appendix Table 4.5.4 People age 13 and over living with diagnosed HIV who had at least two CD4 or viral load tests performed at least 3 months apart during the last year, among reporting jurisdictions

Appendix Table 4.5.5 People age 13 and over living with diagnosed HIV whose most recent viral load in the last 12 months was under 200 copies/ml

Appendix Table 4.5.6 HIV infection deaths per 100,000 population

Appendix Table 4.5.7 Adolescents and adults ages 16–64 with HIV testing

### Measure Category: 4. Effectiveness of Care, Subcategory: 6. Mental Health and Substance Use Disorder

Appendix Table 4.6.1 Adults with a major depressive episode in the past year who received treatment for depression in the past year

Appendix Table 4.6.2 Children ages 12–17 with a major depressive episode in the past year who received treatment for depression in the past year

Appendix Table 4.6.3 Suicide deaths among people age 12 and over per 100,000 population

Appendix Table 4.6.4 Long-stay nursing home residents with depression symptoms

Appendix Table 4.6.5 Short-stay nursing home patients given antipsychotic medication

Appendix Table 4.6.6 Long-stay nursing home patients given antipsychotic medication

Appendix Table 4.6.7 Composite measure: People age 12 and over who needed treatment for illicit drug use or an alcohol problem who received such treatment at a specialty facility in the past year

Appendix Table 4.6.8 People age 12 and over who needed treatment for illicit drug use who received such treatment at a specialty facility in the past year

Appendix Table 4.6.9 People age 12 and over who needed treatment for an alcohol problem who received such treatment at a specialty facility in the past year

Appendix Table 4.6.10 People age 12 and over treated for substance use disorder who completed treatment course

Appendix Table 4.6.11 Adults who filled an outpatient opioid prescription in the calendar year

Appendix Table 4.6.12 Adults who filled four or more outpatient opioid prescriptions in the calendar year

Appendix Table 4.6.13 People age 12 and over with opioid (either prescription opioid or heroin) use disorder in the past year

Appendix Table 4.6.14 Hospital inpatient stays involving opioid-related diagnoses per 100,000 population

Appendix Table 4.6.15 Emergency department visits involving opioid-related diagnoses per 100,000 population

Appendix Table 4.6.16 Drug overdose deaths involving any opioid per 100,000 resident population

Appendix Table 4.6.17 Drug overdose deaths involving natural and semisynthetic opioids per 100,000 resident population

Appendix Table 4.6.18 Drug overdose deaths involving other synthetic opioids (other than methadone) per 100,000 resident population

Appendix Table 4.6.19 People age 12 and over with opioid use disorder who received medication-assisted treatment for opioids in the past year

Appendix Table 4.6.20 People age 12 and over who received medication-assisted treatment for opioids in the past year

### Measure Category: 4. Effectiveness of Care, Subcategory: 7. Musculoskeletal Disease

Appendix Table 4.7.1 Adults with chronic joint symptoms who have ever seen a doctor or other health professional for joint symptoms

### Measure Category: 4. Effectiveness of Care, Subcategory: 8. Respiratory Diseases

Appendix Table 4.8.1 Deaths per 1,000 hospital admissions with pneumonia, age 18 and over

Appendix Table 4.8.2 Patients with tuberculosis who completed a curative course of treatment within 1 year of initiation of treatment

Appendix Table 4.8.3 People with current asthma who are now taking preventive medicine daily or almost daily (either oral or inhaler)

Appendix Table 4.8.4 People with current asthma who received written asthma management plans from their healthcare provider

Appendix Table 4.8.5 People with current asthma who received education about the appropriate response to an asthma episode

Appendix Table 4.8.6 People with current asthma who were advised to make changes to reduce exposure to irritants

Appendix Table 4.8.7 People with current asthma

Appendix Table 4.8.8 People with current asthma who were advised to make changes to reduce exposure to irritants

Appendix Table 4.8.9 People with current asthma

## Patient Safety

The Institute of Medicine (IOM), now the National Academy of Medicine (NAM), defines patient safety as “freedom from accidental injury due to medical care or medical errors.”^1^ In 1999, the IOM published their landmark report To Err Is Human: Building a Safer Health System,^1^ which called for a national effort to reduce medical errors and improve patient safety.

In 2015, NAM built on its initial report on patient safety by publishing Improving Diagnosis in Health Care, which identifies eight major goals for effecting progress on diagnostic error and improving patient safety outcomes.^2^ Although improving diagnostic safety and quality was not fully addressed in To Err is Human, the patient safety field has now established consensus that more attention needs to be placed on reducing diagnostic error.

In addition to providing reports and materials, AHRQ has identified three long-term goals related to improving patient safety. These are:

- Reducing preventable hospital admissions and readmissions,
- Reducing the incidence of adverse healthcare-associated conditions (HACs), and
- Reducing harm from inappropriate or unnecessary care.

To meet these goals, AHRQ supports research and quality improvement programs to reduce healthcare-associated infections (HAIs) and HACs, adverse drug events, and other preventable adverse events.

A common cause of adverse events is gaps in communication either between providers or with patients, their family members, or caregivers. Communication gaps may occur unintentionally and may result from implicit biases among healthcare providers.^3^ Thus, researchers, providers, and policymakers are considering patient safety and person-centered care together to better understand breakdowns in care so that patients experience safer care and better health outcomes.

### Importance

#### Mortality

Number of deaths in U.S. hospitals due to medical error each year (1999) ............. 44,000–98,000^1^

Age-standardized mortality rate due to adverse effects of medical treatment (2016) .................................................................................. 1.15 per 100,000 population^4^

#### Prevalence

Number of hospital-acquired conditions in U.S. hospitals (2017) ................................... 2,550,000^5^

All-payer 30-day readmission rate (2016) ...................................................... 13.9% of admissions^6^

Increase in ventilator-associated events during COVID-19 Delta surge (2021) ........ 60% increase^7^

#### Cost

Additional hospital inpatient costs due to hospital-acquired conditions (2014)^5^:

Central line-associated bloodstream infection (CLABSI) ....................................................$48,108

Ventilator-associated pneumonia ..........................................................................................$47,238

Surgical site infection (SSI) ..................................................................................................$28,219

Venous thromboembolism ....................................................................................................$17,367

### Key Findings

Patient safety measures that improved overall include:

- Short-stay nursing home patients with pressure ulcers that are new or worsened.
- Postoperative respiratory failure, prolonged mechanical ventilation, or reintubation per 1,000 elective-surgery admissions, age 18 and over.
- Long-stay nursing home residents with a urinary tract infection.
- Home health care patients whose management of oral medications improved.
- Hospital admissions with central venous catheter-related bloodstream infection per 1,000 medical and surgical discharges of length 2 or more days, age 18 and over or obstetric admissions.

Patient safety measures that worsened overall include:

- Adults who reported a home health care provider asking to see all the prescription and over-the-counter medicines they were taking, when they first started getting home health care.

Patient safety measures that showed large disparities include:

- Postoperative hip fracture per 1,000 surgical admissions who were not susceptible to falling.

Patient safety measures that showed worsening disparities include:

- Adults age 65 and over who received in the calendar year at least 1 of 33 potentially inappropriate prescription medications for older adults.

### References

1 Kohn LT, Corrigan JM, Donaldson MS, eds.; Committee on Quality of Health Care in America, Institute of Medicine. To Err Is Human: Building a Safer Health System. Washington, DC: National Academies Press; 2000. http://www.nap.edu/catalog/9728.html. Accessed October 10, 2023.
2 Committee on Diagnostic Error in Health Care; Board on Health Care Services; Institute of Medicine; National Academies of Sciences, Engineering, and Medicine. Improving Diagnosis in Health Care. Balogh EP, Miller BT, Ball JR, eds. Washington, DC: National Academies Press; December 2015. http://nap.edu/21794. Accessed October 10, 2023.
3 Hall WJ, Chapman MV, Lee KM, Merino YM, Thomas TW, Payne BK, Eng E, Day SH, Coyne-Beasley T. Implicit racial/ethnic bias among health care professionals and its influence on health care outcomes: a systematic review. Am J Public Health. 2015;105(12):e60–e76. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4638275/. Accessed October 10, 2023.
4 Sunshine JE, Meo N, Kassebaum NJ, Collison ML, Mokdad AH, Naghavi M. Association of adverse effects of medical treatment with mortality in the United States: a secondary analysis of the Global Burden of Diseases, Injuries, and Risk Factors Study. JAMA Netw Open. 2019;2(1):e187041. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6484545/. Accessed October 10, 2023.30657530
5 AHRQ National Scorecard on Hospital-Acquired Conditions: Final Results for 2014 Through 2017. https://www.ahrq.gov/sites/default/files/wysiwyg/professionals/quality-patient-safety/pfp/Updated-hacreportFInal2017data.pdf. Accessed October 10, 2023.
6 Bailey MK, Weiss AJ, Barrett ML, Jiang HJ. Characteristics of 30-day readmissions, 2010–2016. HCUP Statistical Brief #248. Rockville, MD: Agency for Healthcare Research and Quality; February 2019. https://hcup-us.ahrq.gov/reports/statbriefs/sb248-Hospital-Readmissions-2010-2016.jsp. Accessed October 10, 2023.
7 Lastinger L, Alvarez C, Kofman A, Konnor R, Kuhar D, Nkwata A, Patel P, Pattabiraman V, Xu S, Dudeck M. Continued increases in the incidence of healthcare-associated infection (HAI) during the second year of the coronavirus disease 2019 (COVID-19) pandemic. Infect Control Hosp Epidemiol. 2023 Jun;44(6):997–1001. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9237489/. Accessed October 10, 2023.35591782

### Measure Category: 5. Patient Safety, Subcategory: 1. Healthcare-Associated Infections

Appendix Table 5.1.1 Postoperative sepsis per 1,000 elective-surgery admissions, age 18 and over

Appendix Table 5.1.2 Hospital admissions with central venous catheter-related bloodstream infection per 1,000 medical and surgical discharges of length 2 or more days, age 18 and over or obstetric admissions

Appendix Table 5.1.3 Hospital admissions with central venous catheter-related bloodstream infection per 1,000 medical and surgical discharges of length 2 or more days, age less than 18 years

Appendix Table 5.1.4 Hospital admissions with pressure ulcers per 1,000 medical and surgical discharges of length 3 or more days, age 18 and over

Appendix Table 5.1.5 Adult inpatients with one or more pressure ulcer adverse events during hospital stay

### Measure Category: 5. Patient Safety, Subcategory: 2. Surgical Care

Appendix Table 5.2.1 Composite measure: Adult surgery patients with postoperative complications (postoperative pneumonia or venous thromboembolic events)

Appendix Table 5.2.2 Adult surgery patients with postoperative pneumonia events

Appendix Table 5.2.3 Adult surgery patients with postoperative venous thromboembolic events

Appendix Table 5.2.4 Perioperative hemorrhage or hematoma with surgical drainage or evacuation per 1,000 surgical admissions, age 18 and over

Appendix Table 5.2.5 Postoperative pulmonary embolism or deep vein thrombosis per 1,000 surgical admissions, age 18 and over

Appendix Table 5.2.6 Postoperative respiratory failure, prolonged mechanical ventilation, or reintubation per 1,000 elective-surgery admissions, age 18 and over

Appendix Table 5.2.7 Postoperative acute kidney injury requiring dialysis per 1,000 elective-surgery admissions, age 18 and over

Appendix Table 5.2.8 Postoperative hip fracture per 1,000 surgical admissions who were not susceptible to falling, age 18 and over

Appendix Table 5.2.9 Reclosure of postoperative abdominal wound dehiscence per 1,000 abdominopelvic-surgery admissions of length 2 or more days, age 18 and over

Appendix Table 5.2.10 Adult inpatient sustained one or more adverse outcomes from one or more operating room procedures or instance of anesthesia during stay

Appendix Table 5.2.11 Home health care patients whose surgical wound improved

### Measure Category: 5. Patient Safety, Subcategory: 3. Other Complications of Hospital Care

Appendix Table 5.3.1 Composite measure: Bloodstream infections or mechanical adverse events in adult patients receiving central venous catheter placement

Appendix Table 5.3.2 Bloodstream infection in adult patients receiving central venous catheter placement

Appendix Table 5.3.3 Accidental puncture or laceration during a procedure per 1,000 medical and surgical admissions, age 18 and over

Appendix Table 5.3.4 Accidental puncture or laceration during a procedure per 1,000 medical and surgical admissions, age less than 18 years

Appendix Table 5.3.5 Hospital admissions with iatrogenic pneumothorax per 1,000 medical and surgical admissions, age 18 and over

Appendix Table 5.3.6 Deaths per 1,000 elective-surgery admissions who developed serious treatable complications of care during hospitalization, ages 18–89 or obstetric admissions

Appendix Table 5.3.7 Deaths per 1,000 hospital admissions with expected low mortality, age 18 and over or obstetric admissions

Appendix Table 5.3.8 In-hospital deaths per 100,000 delivery hospitalizations, women ages 12–55

Appendix Table 5.3.9 Adult inpatients who sustained one or more adverse outcomes related to receipt of blood or blood product transfusion

Appendix Table 5.3.10 Adult inpatients with one or more falls during hospital stay

Appendix Table 5.3.11 Adult inpatients with a new diagnosis of deep vein thrombosis or pulmonary embolism not related to surgery, or that arose during hospital stay

### Measure Category: 5. Patient Safety, Subcategory: 4. Complications of Medication

Appendix Table 5.4.1 Adverse drug event with IV heparin in adult hospital patients who received an anticoagulant

Appendix Table 5.4.2 Hospital patients with an anticoagulant-related adverse drug event to low-molecular-weight heparin and factor Xa

Appendix Table 5.4.3 Hospital patients who received a hypoglycemic agent who had an adverse drug event with hypoglycemic agents

Appendix Table 5.4.4 Home health care patients whose management of oral medications improved

Appendix Table 5.4.5 Adults inpatients with an adverse event within 24 hours following opioid administration

### Measure Category: 5. Patient Safety, Subcategory: 5. Birth-Related Complications

Appendix Table 5.5.1 Birth trauma - injury to neonate per 1,000 live births

Appendix Table 5.5.2 Obstetric trauma per 1,000 vaginal deliveries without instrument assistance

Appendix Table 5.5.3 Obstetric trauma per 1,000 instrument-assisted vaginal deliveries

Appendix Table 5.5.4 Venous thromboembolism or pulmonary embolism per 1,000 delivery discharges, women ages 12–55

Appendix Table 5.5.5 Severe maternal morbidity per 1,000 delivery discharges, women ages 12–55

Appendix Table 5.5.6 Severe postpartum hemorrhage per 1,000 delivery discharges, women ages 12–55

Appendix Table 5.5.7 Eclampsia/preeclampsia per 1,000 delivery discharges, women ages 12–55

Appendix Table 5.5.8 Cesarean deliveries per 1,000 deliveries

Appendix Table 5.5.9 Vaginal birth after cesarean per 1,000 women with previous cesarean deliveries, uncomplicated

Appendix Table 5.5.10 First-time cesarean deliveries (identified by no previous cesarean delivery diagnosis on the record) per 1,000 deliveries

### Measure Category: 5. Patient Safety, Subcategory: 6. Inappropriate Treatment

Appendix Table 5.6.1 Adults age 65 and over who received in the calendar year at least 1 of 11 prescription medications that should be avoided in older adults

Appendix Table 5.6.2 Adults age 65 and over who received in the calendar year at least 1 of 33 potentially inappropriate prescription medications for older adults

### Measure Category: 5. Patient Safety, Subcategory: 7. Supportive and Palliative Care

Appendix Table 5.7.1 High-risk, long-stay nursing home patients with stages 2–4 pressure ulcer or unstable pressure ulcer

Appendix Table 5.7.2 Low-risk, long-stay nursing home residents with a catheter inserted and left in the bladder

Appendix Table 5.7.3 Long-stay nursing home residents with a urinary tract infection

Appendix Table 5.7.4 Long-stay nursing home patients experiencing one or more falls with major injury

Appendix Table 5.7.5 Short-stay nursing home patients with pressure ulcers that are new or worsened

### Measure Category: 5. Patient Safety, Subcategory: 8. Home Health Communication

Appendix Table 5.8.1 Adults who reported a home health care provider talking with them about how to set up their home so they can move around safely when they first started getting home health care

Appendix Table 5.8.2 Adults who reported a home health care provider talking with them about all the prescription and over-the-counter medicines they were taking when they first started getting home health care

Appendix Table 5.8.3 Adults who reported a home health care provider asking to see all the prescription and over-the-counter medicines they were taking, when they first started getting home health care

Appendix Table 5.8.4 Adults who reported that home health care providers talked with them about the purpose of taking their new or changed prescription medicines in the last 2 months of care

Appendix Table 5.8.5 Adults who reported that home health care providers talked with them about when to take medicines in the last 2 months of care

Appendix Table 5.8.6 Adults who reported that home health care providers talked with them about the side effects of medicines in the last 2 months of care

## Person-Centered Care

The National Academy of Medicine, formerly the Institute of Medicine (IOM), identifies patient centeredness as a core component of quality healthcare.^1^ Patient centeredness is defined as:

[H]ealth care that establishes a partnership among practitioners, patients, and their families (when appropriate) to ensure that decisions respect patients ’ wants, needs, and preferences and that patients have the education and support they need to make decisions and participate in their own care.^2^

### Importance

Person-centered decision making (when physicians consider the needs and circumstances of an individual) for planning an individual's care has been shown to improve healthcare outcomes.^3^ In addition, person-centered approaches to care have been shown to improve individuals' health status. These approaches rely on building a relationship between the individual and the provider, improving communication, fostering a positive atmosphere, and encouraging individuals to actively participate in interactions with their provider.^4^ Finally, person-centered care can reduce the chance of misdiagnosis due to poor communication.^5^

Person-centered care and successful communication help lead to increased individual and provider satisfaction, trust in the provider, and functional and psychological well-being. Effective communication also leads to improved outcomes, including:

- A small but significant absolute risk reduction of mortality from coronary artery disease,
- Improved control of diabetes and hyperlipidemia,
- Better adherence to antihypertensive medication,
- Bereavement adjustment in caregivers of cancer patients, and
- Higher self-efficacy of adherence to HIV medications.^6^

In addition to improved outcomes, research indicates that effective person-centered care may result in decreased healthcare costs:

- Poor communication, lack of collaboration, and lack of support for self-care are associated with suffering and waste in healthcare.^6^
- Person-centeredness has been shown to reduce overuse of medical care.^7^
- Improved communication methods can lower barriers to discussion about medication costs with individuals.^8^
- Improved communication between individuals and providers during medical decision making can reduce costs.^9^

### Key Findings

Person-centered care measures that improved overall include:

- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always gave them easy-to-understand instructions about what to do for a specific illness or health condition.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never spent enough time with them.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand.
- Adults who reported that home health care providers talked about pain in the last 2 months of care.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say.

No person-centered care measures worsened overall.

Person-centered care measures that showed large disparities include:

- Adults who reported that home health care providers always treated them with courtesy and respect in the last 2 months of care.
- Adults who had a doctor's office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand.
- Adults who reported that home health care providers always treated them as gently as possible in the last 2 months of care.

Person-centered care measures that showed worsening disparities include:

- Adults who had a doctor's office or clinic visit in the last 12 months whose health providers always offered help in filling out forms.

### References

1 Institute of Medicine Committee on Quality of Health Care in America. Crossing the Quality Chasm: A New Health System for the 21st Century. Washington, DC: National Academies Press; 2001. https://nap.nationalacademies.org/catalog/10027/crossing-the-quality-chasm-a-new-health-system-for-the . Accessed October 10, 2023.
2 Institute of Medicine Committee on the National Quality Report on Health Care Delivery. Envisioning the National Health Care Quality Report. Hurtado MP, Swift EK, Corrigan JM, eds. Washington, DC: National Academies Press; 2001. http://nap.edu/10073. Accessed October 10, 2023.
3 Holmes-Rovner M, Montgomery JS, Rovner DR, Scherer LD, Whitfield J, Kahn VC, Merkle EC, Ubel PA, Fagerlin A. Informed decision making: assessment of the quality of physician communication about prostate cancer diagnosis and treatment. Med Decis Mak. 2015;35(8):999–1009. https://doi.org/10.1177/0272989X15597226. Accessed October 10, 2023.
4 Weiner SJ, Schwartz A, Sharma G, Binns-Calvey A, Ashley N, Kelly B, Dayal A, Patel S, Weaver FM, Harris I. Patient-centered decision making and health care outcomes: an observational study. Ann Intern Med. 2013;158(8):573–579. https://www.acpjournals.org/doi/10.7326/0003-4819-158-8-201304160-00001. Accessed October 10, 2023.23588745
5 Okunrintemi V, Spatz ES, Di Capua P, Salami JA, Valero-Elizondo J, Warraich H, Virani SS, Blaha MJ, Blankstein R, Butt AA, Borden WB, Dharmarajan K, Ting H, Krumholz HM, Nasir K. Patient-provider communication and health outcomes among individuals with atherosclerotic cardiovascular disease in the United States: Medical Expenditure Panel Survey 2010 to 2013. Circ Cardiovasc Qual Outcomes. 2017;10(4):1–8. https://www.ahajournals.org/doi/full/10.1161/CIRCOUTCOMES.117.003635. Accessed October 10, 2023.
6 Chou C. Time to start using evidence-based approaches to patient engagement. NEJM Catalyst. 2018;4(2).
7 Øvretveit J. Do Changes to Patient-Provider Relationships Improve Quality and Save Money? A Review of the Evidence About Value Improvements Made by Changing Communication, Collaboration, and Support for Self-Care. London, UK: The Health Foundation; June 2012. https://www.health.org.uk/publications/do-changes-to-patient-provider-relationships-improve-quality-and-save-money. Accessed October 10, 2023.
8 Bertakis KD, Azari R. Patient-centered care is associated with decreased health care utilization. J Am Board Fam Med. 2011;24(3):229–39. https://www.jabfm.org/content/24/3/229.long. Accessed October 10, 2023.21551394
9 Slota C, Davis SA, Blalock SJ, Carpenter DM, Muir KW, Robin AL, Sleath B. Patient-physician communication on medication cost during glaucoma visits. Optom Vis Sci. 2017;94(12):1095–1101. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5726412/. Accessed October 10, 2023.29194229

### Measure Category: 6. Person-Centered Care, Subcategory: 1. Patient Experience of Care

Appendix Table 6.1.1 Composite measure: Adults who had a doctor's office or clinic visit in the last 12 months whose health providers sometimes or never listened carefully, explained things clearly, respected what they had to say, and spent enough time with them

Appendix Table 6.1.2 Adults who had a doctor's office or clinic visit in the last 12 months whose health providers sometimes or never listened carefully to them

Appendix Table 6.1.3 Adults who had a doctor's office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand

Appendix Table 6.1.4 Adults who had a doctor's office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say

Appendix Table 6.1.5 Adults who had a doctor's office or clinic visit in the last 12 months whose health providers sometimes or never spent enough time with them

Appendix Table 6.1.6 Adults who rated their healthcare received in the last 12 months as poor (0–6) on a scale of 0–10 (where 0 is the worst and 10 is the best)

Appendix Table 6.1.7 Adults with limited English proficiency and usual source of care (USC) whose USC had language assistance

Appendix Table 6.1.8 Adults with limited English proficiency who had a usual source of care

Appendix Table 6.1.9 People with a usual source of care whose providers sometimes or never asked them to help make decisions when there was a choice between treatments

Appendix Table 6.1.10 Adults who had a doctor's office or clinic visit in the last 12 months whose health providers always gave them easy-to-understand instructions about what to do for a specific illness or health condition

Appendix Table 6.1.11 Adults who had a doctor's office or clinic visit in the last 12 months whose health providers always asked them to describe how they would follow the instructions

Appendix Table 6.1.12 Adults who had a doctor's office or clinic visit in the last 12 months whose health providers always offered help in filling out forms

### Measure Category: 6. Person-Centered Care, Subcategory: 2. Hospital Communication

Appendix Table 6.2.1 Adult hospital patients who sometimes or never had good communication about medications they received in the hospital

### Measure Category: 6. Person-Centered Care, Subcategory: 3. Home Health Communication

Appendix Table 6.3.1 Adults who reported being told what care and services they would get when they first started getting home health care

Appendix Table 6.3.2 Adults who reported that home health care providers talked about pain in the last 2 months of care

Appendix Table 6.3.3 Adults who reported that home health care providers always kept them informed about when they would arrive at their home in the last 2 months of care

Appendix Table 6.3.4 Adults who reported that home health care providers always treated them as gently as possible in the last 2 months of care

Appendix Table 6.3.5 Adults who reported that home health care providers always explained things in a way that was easy to understand in the last 2 months of care

Appendix Table 6.3.6 Adults who reported that home health care providers always listened carefully to them in the last 2 months of care

Appendix Table 6.3.7 Adults who reported that home health care providers always treated them with courtesy and respect in the last 2 months of care

Appendix Table 6.3.8 Adults who reported getting the help or advice they needed when they contacted their home health care providers in the last 2 months of care

Appendix Table 6.3.9 Adults who did not have any problem with the care they received from their home health care providers in the last 2 months of care

### Measure Category: 6. Person-Centered Care, Subcategory: 4. Hospice Care

Appendix Table 6.4.1 Hospice patients whose hospice care team always communicated well with their family caregivers about taking care of them

Appendix Table 6.4.2 Hospice patients and family caregivers who always got help as soon as they needed from the hospice care team

Appendix Table 6.4.3 Hospice patients whose hospice care team always treated them with dignity and respect and really cared about them

Appendix Table 6.4.4 Hospice patients who always received enough help for pain, sadness, breathing, or constipation from the hospice care team

Appendix Table 6.4.5 Family members who definitely received training about taking care of their family member from the hospice care team

Appendix Table 6.4.6 Family caregivers who received the right amount of emotional and spiritual support from the hospice care team

Appendix Table 6.4.7 Family caregivers who rated the hospice care for their family member best (9–10) on a scale of 0–10 (where 0 is the worst and 10 is the best)

Appendix Table 6.4.8 Family caregivers who would definitely recommend this hospice to their friends and family

## Care Coordination

Care coordination is a conscious effort to ensure that all key information needed to make care decisions is available to patients and providers. It is defined as the deliberate organization of patient care activities between two or more participants involved in a patienťs care to facilitate appropriate delivery of healthcare services.^1^ Care coordination is multidimensional and essential to preventing adverse events, ensuring efficiency, and making care person centered.^2^

Patients in greatest need of care coordination include those with:

- Multiple chronic medical conditions,
- Concurrent care from several health professionals across care settings,
- Many medications,
- Extensive diagnostic workups, and
- Transitions from one care setting to another.

Effective care coordination requires well-defined multidisciplinary teamwork based on the principle that all who interact with a person must work together to ensure the delivery of safe, high-quality care in every setting.

### Importance

Care coordination interventions have been shown to:

- Reduce mortality among patients with heart failure,
- Reduce mortality and dependency among patients with stroke,
- Reduce symptoms among patients with depression and at the end of life, and
- Improve glycemic control among patients with diabetes.^1^

Care coordination interventions have also been shown to:

- Reduce hospitalizations among patients with heart failure,
- Reduce readmissions among patients with mental health conditions, and
- Be cost-effective when applied to the treatment of depression.^1^

### Key Findings

Care coordination measures that improved overall include:

- Hospital admissions for asthma per 100,000 population, ages 2–17 years.
- Hospital admissions with chronic obstructive pulmonary disease or asthma per 100,000 population, age 40 years and over.
- Hospital admissions for urinary tract infection per 100,000 population, ages 3 months to 17 years.
- Hospital admissions for asthma per 100,000 population, ages 18–39 years.
- Hospital admissions for urinary tract infection per 100,000 population, age 18 years and over.

Care coordination measures that worsened overall include:

- Hospital admissions with diabetes with short-term complications per 100,000 population, age 18 years and over.
- Lower extremity amputations among admissions for diabetes per 100,000 population, age 18 years and over.
- Adult hospital patients who strongly disagree or disagree that staff took their preferences and those of their family and caregiver into account when deciding what the patienťs discharge healthcare would be.

Care coordination measures that showed large disparities include:

- Hospitalizations and emergency department encounters for heart failure.
- Hospital admissions for urinary tract infection per 100,000 population.
- Hospital admissions for community-acquired pneumonia per 100,000 population.

Care coordination measures that showed worsening disparities include:

- Emergency department visits with a principal diagnosis related to dental conditions.
- Hospital admissions with chronic obstructive pulmonary disease or asthma per 100,000 population, age 40 years and over.

### References

1 Peterson K, Anderson J, Bourne D, Boundy E. Scoping Brief: Care Coordination Theoretical Models and Frameworks. Washington, DC: Department of Veterans Affairs; 2018. https://www.ncbi.nlm.nih.gov/books/NBK525002/. Accessed October 10, 2023.
2 Powell-Davies G, Williams AM, Larsen K, Perkins D, Roland M, Harris MF. Coordinating primary health care: an analysis of the outcomes of a systematic review. Med J Aust. 2008 Apr 21;188(8 Suppl):S65–68. https://www.ncbi.nlm.nih.gov/pubmed/18429740. Accessed October 10, 2023.18429740

### Measure Category: 7. Care Coordination, Subcategory: 1. Transitions of Care

Appendix Table 7.1.1 Adult hospital patients who did not receive good communication about discharge information

Appendix Table 7.1.2 Adult hospital patients who strongly disagree or disagree that staff took their preferences and those of their family and caregiver into account when deciding what the patients discharge health care would be

### Measure Category: 7. Care Coordination, Subcategory: 2. Medication Information

Appendix Table 7.2.1 People with a usual source of care who usually asks about prescrition medications and treatments from other doctors

### Measure Category: 7. Care Coordination, Subcategory: 3. Preventable Emergency Department Visits

Appendix Table 7.3.1 Emergency department visits with a principal diagnosis related to mental health only, per 100,000 population

Appendix Table 7.3.2 Emergency department visits with a principal diagnosis related to substance use disorder only, per 100,000 population

Appendix Table 7.3.3 Composite measure: Emergency department visits with a principal diagnosis related to co-occurring mental health, alcohol, and substance use disorder, per 100,000 population

Appendix Table 7.3.4 Emergency department visits with a principal diagnosis related to dental conditions

Appendix Table 7.3.5 Emergency department encounters for asthma, adults

Appendix Table 7.3.6 Emergency department encounters for asthma, children ages 2–17

Appendix Table 7.3.7 Emergency department visits for asthma per 10,000 population, ages 2–19

Appendix Table 7.3.8 Emergency department visits for asthma per 10,000 population, ages 2–9

Appendix Table 7.3.9 Emergency department visits for asthma per 10,000 population, ages 10–19

### Measure Category: 7. Care Coordination, Subcategory: 4. Preventable Hospitalizations

Appendix Table 7.4.1 Hospital admissions for uncontrolled diabetes without complications per 100,000 population, age 18 and over

Appendix Table 7.4.2 Hospital admissions with diabetes with short-term complications per 100,000 population, age 18 and over

Appendix Table 7.4.3 Hospital admissions with diabetes with short-term complications per 100,000 population, ages 6–17

Appendix Table 7.4.4 Hospital admissions with diabetes with long-term complications per 100,000 population, age 18 and over

Appendix Table 7.4.5 Lower extremity amputations among admissions for diabetes per 100,000 population, age 18 and over

Appendix Table 7.4.6 Composite measure: Hospital admissions for one or more diabetes complications (short-term complications, long-term complications, uncontrolled diabetes, or lower-extremity amputation) per 100,000 population, age 18 and over

Appendix Table 7.4.7 Hospital admissions for asthma per 100,000 population, ages 18 to 39

Appendix Table 7.4.8 Hospital admissions for asthma per 100,000 population, ages 2–17

### Measure Category: 7. Care Coordination, Subcategory: 5. Preventable Hospitalizations Among Home Health and Nursing Home Patients

Appendix Table 7.5.1 Hospitalizations and emergency department encounters for heart failure

Appendix Table 7.5.2 Home health care patients who had an emergency department visit and were then hospitalized

### Measure Category: 7. Care Coordination, Subcategory: 6. Supportive and Palliative Care

Appendix Table 7.6.1 Home health care patients who had an emergency department visit without a hospitalization

Appendix Table 7.6.2 Home health care patients who had to be admitted to the hospital

Appendix Table 7.6.3 Home health care patients who had timely initiation of care

Appendix Table 7.6.4 Adults who reported that home health care providers always seemed informed and up to date about all the care or treatment they got at home in the last 2 months of care

### Measure Category: 7. Care Coordination, Subcategory: 7. Potentially Avoidable Admissions

Appendix Table 7.7.1 Hospital admissions with hypertension per 100,000 population, age 18 and over

Appendix Table 7.7.2 Hospital admissions with chronic obstructive pulmonary disease or asthma per 100,000 population, age 40 and over

Appendix Table 7.7.3 Hospital admissions for community-acquired pneumonia per 100,000 population, age 18 and over

Appendix Table 7.7.4 Hospital admissions for urinary tract infection per 100,000 population, age 18 and over

Appendix Table 7.7.5 Hospital admissions for urinary tract infection per 100,000 population, ages 3 months to 17 years

Appendix Table 7.7.6 Hospital admissions for pediatric gastroenteritis per 100,000 population, ages 3 months to 17 years

## Healthy Living

Many illnesses associated with chronic conditions are related to unhealthy behaviors, environmental hazards, and poor social supports. These illnesses can be prevented by increasing access to effective clinical preventive services and promoting community interventions that advance public and population health. Working with communities is critical to ensure that immunizations and early detection and prevention services reach everyone who needs them and to build healthy neighborhoods and support networks.

### Importance

Promoting healthy lifestyles that prevent disease and disability is better for people and more efficient than treating conditions after organ damage has occurred. Healthy living is supported through preventive care strategies that cross all age groups and the care continuum. Among the most impactful preventive strategies are vaccinations for children and prenatal care.

Advances in medical science protect children against more diseases than ever before. Some diseases that once injured or killed thousands of children have been eradicated completely and others are close to eradication, primarily due to safe and effective vaccines. Polio is one example of the great impact vaccines have had in the United States. Polio was once America's most feared disease, causing death and paralysis across the country, but today, thanks to vaccination, there are no reports of polio in the United States.^i^

A strong body of research shows the cost-effectiveness of immunization; however, opportunities still exist for providers, patients, and systems to optimize immunization participation. It is less expensive to prevent a disease using immunization than to treat it. In a 2005 study on the economic impact of routine childhood immunization in the United States, researchers estimated that for every dollar spent, the vaccination program saved more than $5 in direct costs and approximately $11 in additional costs to society.^1,2^

### Key Findings

Healthy living measures that improved overall include:

- Long-stay nursing home residents with physical restraints.
- Adolescents ages 16-17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis since the age of 10 years.
- Adolescents ages 16-17 who received 1 or more doses of meningococcal conjugate vaccine.
- Home health care patients whose ability to get in and out of bed improved.
- Adolescents ages 16-17 who received 1 or more doses of meningococcal conjugate vaccine.

Healthy living measures that worsened overall include:

- Long-stay nursing home residents who were assessed for pneumococcal vaccination.
- Short-stay nursing home patients who had flu vaccination appropriately given.
- Home health care patients who had pneumococcal polysaccharide vaccination.
- Children ages 2–19 with obesity.

Healthy living measures that showed large disparities include:

- Children ages 19–35 months who received 3 or more doses of polio vaccine.
- Adults without hypertension who had their blood pressure measured in the past 2 years.
- Children ages 19–35 months who received 3 or more doses of hepatitis B vaccine.
- Children ages 19–35 months who received 1 or more doses of measles-mumps-rubella vaccine.

Healthy living measures that showed worsening disparities include:

- Home health care patients who had pneumococcal polysaccharide vaccination.

### References

1 Zhou F, Santoli J, Messonnier ML, Yusuf HR, Shefer A, Chu SY, Rodewald L, Harpaz R. Economic evaluation of the 7-vaccine routine childhood immunization schedule in the United States, 2001. Arch Pediatr Adolesc Med. 2005 Dec;159(12):1136–44. https://www.ncbi.nlm.nih.gov/pubmed/16330737. Accessed October 11, 2023.16330737
2 Leidner AJ, Murthy N, Chesson HW, Biggerstaff M, Stoecker C, Harris AM, Acosta A, Dooling K, Bridges CB. Cost-effectiveness of adult vaccinations: a systematic review. Vaccine. 2019;37(2):226–234. https://doi.org/10.1016/j.vaccine.2018.11.056. Accessed October 11, 2023.30527660

### Measure Category: 8. Healthy Living, Subcategory: 1. Maternal and Child Health

Appendix Table 8.1.1 Live-born infants with low birth weight (less than 2,500 g)

Appendix Table 8.1.2 Women with a live birth in the last 12 months who received early and at least adequate prenatal care

Appendix Table 8.1.3 Infant mortality per 1,000 live births, birth weight less than 1,500 grams

Appendix Table 8.1.4 Infant mortality per 1,000 live births, birth weight 1,500–2,499 grams

Appendix Table 8.1.5 Infant mortality per 1,000 live births, birth weight 2,500 grams or more

Appendix Table 8.1.6 Composite measure: Infant mortality per 1,000 live births, all birth weights

Appendix Table 8.1.7 Infants born in the calendar year who received breastfeeding exclusively through 3 months

### Measure Category: 8. Healthy Living, Subcategory: 2. Lifestyle Modification

Appendix Table 8.2.1 Adults who smoked and had a doctor's office or clinic visit in the last 12 months who received advice from their providers to quit smoking

Appendix Table 8.2.2 Adult smokers who received advice from health professional to quit

Appendix Table 8.2.3 Adult current smokers who tried to quit for at least 1 day

Appendix Table 8.2.4 Adult smokers who quit successfully

Appendix Table 8.2.5 Adults who do not smoke now

Appendix Table 8.2.6 People ages 2–19 years with obesity who had been told by a doctor or health professional that they were overweight

Appendix Table 8.2.7 Adults age 20 and over with obesity who had been told by a doctor or health professional that they were overweight

Appendix Table 8.2.8 Children ages 2–19 with obesity

Appendix Table 8.2.9 Adults with obesity who do not spend half an hour or more in moderate or vigorous physical activity at least five times a week

Appendix Table 8.2.10 Children ages 2–17 for whom a health provider gave advice within the past 2 years about the amount and kind of exercise, sports, or physically active hobbies they should have

Appendix Table 8.2.11 Children ages 2–17 for whom a health provider gave advice within the past 2 years about healthy eating

Appendix Table 8.2.12 Adults with obesity

Appendix Table 8.2.13 Adults age 20 and over with obesity

Appendix Table 8.2.14 Adults who do not now spend half an hour or more in moderate or vigorous physical activity at least five times a week

Appendix Table 8.2.15 Adults ages 18 and over with obesity who had a physician office visit for counseling or education related to diet or nutrition

### Measure Category: 8. Healthy Living, Subcategory: 3. Functional Status Preservation and Rehabilitation

Appendix Table 8.3.1 Home health care patients whose ability to walk or move around improved

Appendix Table 8.3.2 Home health care patients whose ability to get in and out of bed improved

Appendix Table 8.3.3 Home health care patients whose bathing improved

Appendix Table 8.3.4 Home health care patients who had improvement in toileting

Appendix Table 8.3.5 Long-stay nursing home residents whose need for help with daily activities increased

Appendix Table 8.3.6 Long-stay nursing home residents whose ability to move independently worsened

### Measure Category: 8. Healthy Living, Subcategory: 4. Supportive and Palliative Care

Appendix Table 8.4.1 Long-stay nursing home residents with moderate to severe pain

Appendix Table 8.4.2 Long-stay nursing home residents with too much weight loss

Appendix Table 8.4.3 Low-risk, long-stay nursing home residents with loss of control of bowels or bladder

Appendix Table 8.4.4 Long-stay nursing home residents with physical restraints

Appendix Table 8.4.5 Short-stay nursing home residents with moderate to severe pain

Appendix Table 8.4.6 Home health care patients whose shortness of breath decreased

Appendix Table 8.4.7 Home health care patients who stayed at home after an episode of home health care

Appendix Table 8.4.8 Home health care patients who had improvement in upper body dressing

Appendix Table 8.4.9 Home health care patients who had improvement in confusion frequency

Appendix Table 8.4.10 Home health care patients whose pain when moving around decreased

### Measure Category: 8. Healthy Living, Subcategory: 5. Clinical Preventive Services

Appendix Table 8.5.1 Women ages 50–74 who received a mammogram in the last 2 years

Appendix Table 8.5.2 Breast cancer diagnosed at advanced stage (regional, distant stage, or local stage with tumor greater than 2 cm) per 100,000 women age 40 and over

Appendix Table 8.5.3 Women ages 21–65 who received a Pap smear in the last 3 years or human papillomavirus vaccines in the last 5 years

Appendix Table 8.5.4 Cervical cancer diagnosed at advanced stage (all invasive tumors) per 100,000 women age 20 and over

Appendix Table 8.5.5 Composite measure: Adults ages 50–75 who received any type of colorectal cancer screening

Appendix Table 8.5.6 Colorectal cancer diagnosed at advanced stage (tumors diagnosed at regional or distant stage) per 100,000 population age 50 and over

Appendix Table 8.5.7 Adults without hypertension who had their blood pressure measured in the past 2 years

Appendix Table 8.5.8 Adults who received a blood cholesterol measurement in the last 5 years

Appendix Table 8.5.9 Adults age 18–64 at high risk (e.g., COPD) who received an influenza vaccination in the last flu season

Appendix Table 8.5.10 Adults ages 18 and over who received influenza vaccination in the last flu season

Appendix Table 8.5.11 Adults age 65 and over who received an influenza vaccination in the last flu season

Appendix Table 8.5.12 Hospital admissions for immunization-preventable influenza per 100,000 population, age 65 and over

Appendix Table 8.5.13 Adults ages 18–64 at high risk (e.g., COPD) who ever received pneumococcal vaccination

Appendix Table 8.5.14 Adults age 65 and over who ever received pneumococcal vaccination

Appendix Table 8.5.15 Adults with a dental visit in the calendar year

Appendix Table 8.5.16 Adults who received a preventive dental service in the calendar year

Appendix Table 8.5.17 Dentate adults age 20 and over with untreated dental caries in permanent teeth

Appendix Table 8.5.18 Composite measure: Children ages 19–35 months who received all recommended vaccines

Appendix Table 8.5.19 Children ages 19–35 months who received 4 or more doses of diphtheria-tetanus-pertussis vaccine

Appendix Table 8.5.20 Children ages 19–35 months who received 3 or more doses of polio vaccine

Appendix Table 8.5.21 Children ages 19–35 months who received 1 or more doses of measles-mumps-rubella vaccine

Appendix Table 8.5.22 Children ages 19–35 months who received 3 or more doses of hepatitis B vaccine

Appendix Table 8.5.23 Children ages 19–35 months who received 1 or more doses of varicella vaccine

Appendix Table 8.5.24 Children ages 19–35 months who received 4 or more doses of pneumococcal conjugate vaccine

Appendix Table 8.5.25 Children ages 19–35 months who received full series Haemophilus influenzae type B

Appendix Table 8.5.26 Adolescents ages 13–15 who received 1 or more doses of meningococcal conjugate vaccine

Appendix Table 8.5.27 Adolescents ages 16–17 who received 1 or more doses of meningococcal conjugate vaccine

Appendix Table 8.5.28 Adolescent females ages 13–15 who received 3 doses of human papillomavirus vaccine or 2 doses when the first dose was received before age 15

Appendix Table 8.5.29 Adolescent females ages 16–17 who received 3 doses of human papillomavirus vaccine or 2 doses when the first dose was received before age 15

Appendix Table 8.5.30 Adolescent males ages 13–15 who received 3 doses of human papillomavirus vaccine or 2 doses when the first dose was received before age 15

Appendix Table 8.5.31 Adolescent males ages 16–17 who received 3 doses of human papillomavirus vaccine or 2 doses when the first dose was received before age 15

Appendix Table 8.5.32 Adolescents ages 13–15 years who received 3 doses of human papillomavirus vaccine or 2 doses when the first dose was received before age 15

Appendix Table 8.5.33 Adolescents ages 16–17 years who received 3 doses of human papillomavirus vaccine or 2 doses when the first dose was received before age 15

Appendix Table 8.5.34 Adolescents ages 13–15 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis since the age of 10 years

Appendix Table 8.5.35 Adolescents ages 16–17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis since the age of 10 years

Appendix Table 8.5.36 Children ages 6 months to 17 years who received influenza vaccination in the last flu season

Appendix Table 8.5.37 Adolescents ages 13–15 years (excluding adolescents who have had varicella) vaccinated with at least 2 doses of varicella vaccine

Appendix Table 8.5.38 Adolescents ages 16–17 years (excluding adolescents who have had varicella) vaccinated with at least 2 doses of varicella vaccine

Appendix Table 8.5.39 Children who had their height and weight measure by a health provider within the past 2 years

Appendix Table 8.5.40 Children ages 2–17 who had a dental visit in the calendar year

Appendix Table 8.5.41 Children ages 2–19 with untreated dental caries

Appendix Table 8.5.42 Children ages 5–17 with untreated dental caries

Appendix Table 8.5.43 Children ages 3–19 received dental sealants on permanent teeth

Appendix Table 8.5.44 Children ages 2–17 who received a preventive dental service in the calendar year

Appendix Table 8.5.45 Children ages 3–5 who ever had their vision checked by a health provider

Appendix Table 8.5.46 Children for whom a health provider gave advice within the past 2 years about how smoking in the house can be bad for a child

Appendix Table 8.5.47 Children 0–40 lb for whom a health provider gave advice within the past 2 years about using a child safety seat while riding in the car

Appendix Table 8.5.48 Children 41–80 lb for whom a health provider gave advice within the past 2 years about using a booster seat when riding in the car

Appendix Table 8.5.49 Children over 80 lb for whom a health provider gave advice within the past 2 years about using lap or shoulder belts when riding in a car

Appendix Table 8.5.50 Children ages 2–17 for whom a health provider gave advice within the past 2 years about using a helment when riding a bicycle or motorcycle

Appendix Table 8.5.51 Children ages 0–17 with a wellness checkup in the past 12 months

Appendix Table 8.5.52 Long-stay nursing home patients who were assessed and appropriately given the seasonal influenza vaccine

Appendix Table 8.5.53 Long-stay nursing home residents who were assessed for pneumococcal vaccination

Appendix Table 8.5.54 Short-stay nursing home patients who had flu vaccination appropriately given

Appendix Table 8.5.55 Short-stay nursing home residents who were assessed for pneumococcal vaccination

Appendix Table 8.5.56 Home health care patients who had influenza vaccination during flu season

Appendix Table 8.5.57 Home health care patients who had pneumococcal polysaccharide vaccination

## Supplemental Measures

Measures used in the National Healthcare Quality and Disparities Report fall into two categories:

- Core measures are used in the main NHQDR, or “core report.” These summarize the status of overall quality, status of disparities, and trends in quality and disparities. Core measures are approved by the IWG for inclusion and are nationally representative. AHRQ receives these data regularly. •
- Supplemental measures are not discussed in the core report, except to highlight important topical issues. Supplemental measures are typically new measures and/or have limited data availability. These measures have not been approved by the IWG for inclusion in the core measure set and core measure summary analyses.

The supplemental measures in this section are grouped in six subcategories:

1. Access.
2. Person-Centered Care.
3. Care Coordination.
4. Effectiveness of Care.
5. Lifestyle Modification.
6. Affordable Care.

### Measure Category: 9. Supplemental Measures, Subcategory: 1. Access

Appendix Table 9.1.1 People delayed in getting medical care due to the coronavirus pandemic

Appendix Table 9.1.2 People delayed in getting dental treatment due to the coronavirus pandemic

Appendix Table 9.1.3 People delayed in getting prescription medicines due to the coronavirus pandemic

Appendix Table 9.1.4 People delayed in getting medical care, dental treatment, or prescription medicines due to the coronavirus pandemic

### Measure Category: 9. Supplemental Measures, Subcategory: 2. Person-Centered Care

Appendix Table 9.2.1 Composite measure: Children who had a doctor's office or clinic visit in the last 12 months whose health providers always listened carefully, explained things clearly, respected what they or their parents had to say, and spent enough time with them

Appendix Table 9.2.2 Children who had a doctor's office or clinic visit in the last 12 months whose health providers always listened carefully

Appendix Table 9.2.3 Children who had a doctor's office or clinic visit in the last 12 months whose health providers always explained things in a way they or their parents could understand

Appendix Table 9.2.4 Children who had a doctor's office or clinic visit in the last 12 months whose health providers always showed respect for what they or their parents had to say

Appendix Table 9.2.5 Children who had a doctor's office or clinic visit in the last 12 months whose health providers always spent enough time with them

Appendix Table 9.2.6 Adult hospital patients who always had good communication with doctors in the hospital

Appendix Table 9.2.7 Composite measure: Adult hospital patients who always had good communication with nurses in the hospital

Appendix Table 9.2.8 Adult hospital patients who strongly agree that they understood how to manage their health after discharge

Appendix Table 9.2.9 Adult hospital patients who strongly agree that they understood the purpose of taking each of their medications after discharge

### Measure Category: 9. Supplemental Measures, Subcategory: 3. Care Coordination

Appendix Table 9.3.1 Composite measure: Emergency department visits with a principal diagnosis related to mental health, alcohol, or substance use disorder, per 100,000 population

Appendix Table 9.3.2 Emergency department visits with any diagnosis of dementia, adults age 65 and over

Appendix Table 9.3.3 Emergency department visits with any diagnosis of dementia per 100,000 population, adults age 65 and over

Appendix Table 9.3.4 Composite measure: Hospitalizations for all conditions per 100,000 population, age 18 and over

Appendix Table 9.3.5 Composite measure: Hospital admissions for all conditions per 100,000 population, ages 6–17

Appendix Table 9.3.6 Composite measure: Hospital admissions for acute conditions per 100,000 population, age 18 and over

Appendix Table 9.3.7 Composite measure: Hospital admissions for acute conditions per 100,000 population, ages 6–17

Appendix Table 9.3.8 Composite measure: Hospital admissions for chronic conditions per 100,000 population, age 18 and over

Appendix Table 9.3.9 Composite measure: Hospital admissions for chronic conditions per 100,000 population, ages 6–17

Appendix Table 9.3.10 Perforated appendixes per 1,000 admissions with appendicitis, age 18 and over, in Indian Health Service, tribal, and contract hospitals

Appendix Table 9.3.11 Hospital admissions for urinary tract infections per 100,000 population age 18 and over in indian Health Service areas

Appendix Table 9.3.12 Hospitals with computerized system that supports medication lists

Appendix Table 9.3.13 Hospitals with computerized system that supports drug decision

Appendix Table 9.3.14 Hospitals with computerized system that allows electronic clinical documentation, including physician notes

Appendix Table 9.3.15 Hospitals with computerized system that allows electronic clinical documentation, including nursing notes

Appendix Table 9.3.16 Hospitals with computerized system that allows electronic clinical documentation, including problem lists

Appendix Table 9.3.17 Hospitals with computerized system that allows electronic clinical documentation, including medication lists

Appendix Table 9.3.18 Hospitals with computerized system that allows electronic clinical documentation, including discharge summaries

Appendix Table 9.3.19 Hospitals with computerized system that allows electronic clinical documentation, including advanced directives

Appendix Table 9.3.20 Hospitals with computerized system that allows electronic clinical documentation

Appendix Table 9.3.21 Hospitals with computerized system that allows results viewing, including laboratory reports

Appendix Table 9.3.22 Hospitals with computerized system that allows results viewing, including radiology reports

Appendix Table 9.3.23 Hospitals with computerized system that allows results viewing, including radiology images

Appendix Table 9.3.24 Hospitals with computerized system that allows results viewing, including diagnostic test results

Appendix Table 9.3.25 Hospitals with computerized system that allows results viewing, including diagnostic test images

Appendix Table 9.3.26 Hospitals with computerized system that allows results viewing, including consultant reports

Appendix Table 9.3.27 Hospitals with computerized system that allows decision support, including clinical guidelines

Appendix Table 9.3.28 Hospitals with computerized system that allows decision support, including clinical reminders

Appendix Table 9.3.29 Hospitals with computerized system that allows decision support, including drug allergy alerts

Appendix Table 9.3.30 Hospitals with computerized system that allows decision support, including drug-drug interaction alerts

Appendix Table 9.3.31 Hospitals with computerized system that allows decision support, including drug-lab interaction alerts

Appendix Table 9.3.32 Hospitals with computerized system that allows decision support, including drug dosing support

Appendix Table 9.3.33 Hospitals with computerized system that allows decision support

Appendix Table 9.3.34 Hospitals with computerized system that allows computerized provider order entry, including laboratory test

Appendix Table 9.3.35 Hospitals with computerized system that allows computerized provider order entry, including radiology tests

Appendix Table 9.3.36 Hospitals with computerized system that allows computerized provider order entry, including consultant requests

Appendix Table 9.3.37 Hospitals with computerized system that allows computerized provider order enter, including nursing orders

Appendix Table 9.3.38 Hospitals with computerized system that allows computerized provider order entry

Appendix Table 9.3.39 Hospitals with computerized system that allows results viewing

Appendix Table 9.3.40 Hospitals with computerized system that allows computerized provider order entry, including medications

Appendix Table 9.3.41 Hospitals with fully implemented electronic medical record system

Appendix Table 9.3.42 Office-based physicians with e-prescribing system for ordering prescriptions

Appendix Table 9.3.43 Office-based physicians with e-prescribing system for sending prescriptions electronically to pharmacy

Appendix Table 9.3.44 Office-based physicians who have computerized system (not including billing)

Appendix Table 9.3.45 Hospitals with computerized systems that are enabled for electronic prescribing of controlled substances

Appendix Table 9.3.46 Hospitals with computerized systems that provide outpatient care to patients

Appendix Table 9.3.47 Hospitals with two or more primary electronic medical record or electronic health record systems in use across outpatient sites

Appendix Table 9.3.48 Hospitals with computerized systems enabling patients to view their health information or medical information from their inpatient portals

Appendix Table 9.3.49 Hospitals with computerized systems enabling patients to view their health information or medical information from their outpatient portals

Appendix Table 9.3.50 Hospitals with computerized systems enabling patients to download health medical information from the their inpatient portals

Appendix Table 9.3.51 Hospitals with computerized systems enabling patients to download health medical information from the their outpatient portals

Appendix Table 9.3.52 Hospitals with computerized systems enabling patients to import their medical records from other organizations into their inpatient portals

Appendix Table 9.3.53 Hospitals with computerized systems enabling patients to import their medical records from other organizations into some or all their outpatient portals

Appendix Table 9.3.54 Hospitals with computerized systems enabling patients to electronically send health information or medical information in any format (including scanned or structured documents) to a third party from their inpatient portals

Appendix Table 9.3.55 Hospitals with computerized systems enabling patients to electronically send health information or medical information in any format to a third party from some or all their outpatient portals

Appendix Table 9.3.56 Hospitals with computerized systems enabling patients to electronically send health information or medical information in a structured format to a third party from their inpatient portals

Appendix Table 9.3.57 Hospitals with computerized systems enabling patients to electronically send health information or medical information in a structured format to a third party from some or all their outpatient portals

Appendix Table 9.3.58 Hospitals with computerized systems enabling patients to request an amendment to change or update their medical record on their inpatient portals

Appendix Table 9.3.59 Hospitals with computerized systems enabling patients to request an amendment to change or update their medical record on some or all their outpatient portals

Appendix Table 9.3.60 Hospitals with computerized systems enabling patients to designate family member or caregiver to access their health information or medical information on behalf of the patient on their inpatient portals

Appendix Table 9.3.61 Hospitals enabled patients to designate family members or caregivers to access their health information or medical information on behalf of the patient on some or all their outpatient portals

Appendix Table 9.3.62 Hospitals with computerized systems enabling patients to view their clinical notes in their inpatient portals

Appendix Table 9.3.63 Hospitals with computerized systems enabling patients to view their clinical notes in some or all their outpatient portals

Appendix Table 9.3.64 Hospitals with computerized systems enabling patients to access their health information or medical information using applications configured to meet the application programming interface specifications from their inpatient portals

Appendix Table 9.3.65 Hospitals with computerized systems enabling patients to access their health information or medical information using applications configured to meet the application programming interface specifications from some or all their outpatient portals

Appendix Table 9.3.66 Hospitals with computerized systems enabling patients to access their health information or medical information using applications configured to meet Fast Healthcare Interoperability Resource specifications from their inpatient portals

Appendix Table 9.3.67 Hospitals with computerized systems enabling patients to access their health information or medical information using applications configured to meet Fast Healthcare Interoperability Resource specifications from some or all their outpatient portals

Appendix Table 9.3.68 Hospitals with computerized systems enabling patients to submit patient generated data to their inpatient portals

Appendix Table 9.3.69 Hospitals with computerized systems enabling patients to submit patient generated data from some or all their outpatient portals

Appendix Table 9.3.70 Hospitals with computerized systems enabling patients to send or receive secure messages with inpatient providers

Appendix Table 9.3.71 Hospitals with computerized systems enabling patients to send or receive secure messages with providers from some or all their outpatient portals

Appendix Table 9.3.72 Hospitals with computerized systems enabling patients to pay bills online from their inpatient portals

Appendix Table 9.3.73 Hospitals with computerized systems enabling patients to pay bills online from some or all their outpatient portals

Appendix Table 9.3.74 Hospitals with computerized systems enabling patients to request refills for prescriptions online from some or all their outpatient portals

Appendix Table 9.3.75 Hospitals with computerized systems enabling patients to schedule appointments on-line from some or all their outpatient portals

Appendix Table 9.3.76 Hospitals currently participating in a state, regional, or local health information exchange or health information organization network

Appendix Table 9.3.77 Hospitals currently participating in CommonWell Health Alliance network

Appendix Table 9.3.78 Hospitals currently participating in e-Health Exchange network

Appendix Table 9.3.79 Hospitals currently participating in Strategic Health Information Exchange collaborative or Patient Centered Data Home network

Appendix Table 9.3.80 Hospitals currently participating in Carequality (network-to-network) trust or governance framework participation network

Appendix Table 9.3.81 Hospitals currently participating in electronic health records (EHR) vendor-based-network that enables record location and exchange within the EHR vendor's network of users

Appendix Table 9.3.82 Hospitals currently participating in other national health exchange networks

Appendix Table 9.3.83 Hospitals not currently participating in any national health information exchange networks (either via vendor or directly)

Appendix Table 9.3.84 Hospital emergency departments regularly providing electronic notification to their patients' primary care physicians

Appendix Table 9.3.85 Hospital emergency departments regularly providing electronic notification to their patients' primary care physicians inside the system

Appendix Table 9.3.86 Hospital emergency departments regularly providing electronic notification to their patients' primary care physicians outside the system

Appendix Table 9.3.87 Hospitals electronically submitting production data for public health reporting related to syndromic surveillance reporting

Appendix Table 9.3.88 Hospitals electronically submitting production data for immunization registry reporting

Appendix Table 9.3.89 Hospitals electronically submitting production data for public health reporting related to electronic case reporting

Appendix Table 9.3.90 Hospitals electronically submitting production data for public health reporting related to public health registry reporting

Appendix Table 9.3.91 Hospitals electronically submitting production data for public health reporting related to clinical data registry reporting

Appendix Table 9.3.92 Hospitals electronically submitting production data for public health reporting related to immunization registry reporting

Appendix Table 9.3.93 Doctor's office visits where the visits were televisits in the calendar year

Appendix Table 9.3.94 Televisits to doctor's offices where the visits were video visit in the calendar year

Appendix Table 9.3.95 Hospital outpatient department visits where the visits were televisits in the calendar year

Appendix Table 9.3.96 Televisits to Hospital outpatient department where the visits were video visit in the calendar year

Appendix Table 9.3.97 Practices that use telemedicine technology

Appendix Table 9.3.98 Practices that report at least 25% of patient visits occurring through telemedicine technology since March 2020

Appendix Table 9.3.99 Practices that use telephone audio for telemedicine visits

Appendix Table 9.3.100 Practices that use video conference software with audio for telemedicine visits

Appendix Table 9.3.101 Practices that use a telemedicine platfrom that is not integrated with an EHR system for telemedicine visits

Appendix Table 9.3.102 Practices that use a telemedicine platform that is integrated with an EHR system for telemedicine visits

Appendix Table 9.3.103 Practices that report limited internet access and/or speed issues as affecting their use of telemedicine for office visits

Appendix Table 9.3.104 Practices that report a telemedicine platform that is not easy to use or did not meet their needs as affecting their use of telemedicine for office visits

Appendix Table 9.3.105 Practices that report a telemedicine platform that is inappropriate for specialty/type of patients as affecting their use of telemedicine for office visits

Appendix Table 9.3.106 Practices that report improved reimbursement and relaxation of rules related to use of telemedicine visits as affecting their use of telemedicine for office visits

Appendix Table 9.3.107 Practices that report limitations in patients' access to technology (e.g., smartphone, computer, tablet, Internet) as affecting their use of telemedicine for office visits

Appendix Table 9.3.108 Practices that report patients' difficulty using technology/telemedicine platform as affecting their use of telemedicine for office visits

Appendix Table 9.3.109 Practices that describe being able to provide similar quality care during telemedicine visits as during in-person visits

Appendix Table 9.3.110 Practices very or somewhat satisfied with using telemedicine technology for patient visits

### Measure Category: 9. Supplemental Measures, Subcategory: 4. Effectiveness of Care

Appendix Table 9.4.1 Hospital admissions for uncontrolled diabetes per 100,000 population age 18 and over in Indian Health Service areas

Appendix Table 9.4.2 Hospital admissions for short-term complications of diabetes per 100,000 population age 18 and over in Indian Health Service areas

Appendix Table 9.4.3 Ryan White HIV/AIDS Program HIV positive patients with at least one outpatient ambulatory health service (OAHS) who also received a second OHAS at least 90 days later from the first service during the year

Appendix Table 9.4.4 Ryan White HIV/AIDS Program HIV positive patients with at least one outpatient ambulatory health service (OAHS) whose most recent viral load was <200 during the year

Appendix Table 9.4.5 Adults who received mental health treatment or counseling in the past year

Appendix Table 9.4.6 Adults who received outpatient mental health treatment or counseling in the past year

Appendix Table 9.4.7 Adults who received prescription medications for mental health treatment in the past year

Appendix Table 9.4.8 Adults who usually or always receive the social and emotional support they need

Appendix Table 9.4.9 People age 12 and over with alcohol use disorder who received medication-assisted treatment for alcohol use in the past 12 months

Appendix Table 9.4.10 Cesarean delivery of low risk births giving birth for first time

Appendix Table 9.4.11 Total cesarean births

Appendix Table 9.4.12 Total preterm births

Appendix Table 9.4.13 Late preterm or live births at 34 to 36 weeks of gestation

Appendix Table 9.4.14 Patients who received appropriate care for severe sepsis and septic shock

### Measure Category: 9. Supplemental Measures, Subcategory: 5. Lifestyle Modification

Appendix Table 9.5.1 Adults who received an influenza vaccination in the past 12 months

Appendix Table 9.5.2 Children who received an influenza vaccination in the past 12 months

### Measure Category: 9. Supplemental Measures, Subcategory: 6. Affordable Care

Appendix Table 9.6.1 Adults who did not get needed medical care because of cost in the past 12 months

Appendix Table 9.6.2 Children who did not get needed medical care because of cost in the past 12 months

Appendix Table 9.6.3 Adults who did not get needed mental health care because of cost in the past 12 months

Appendix Table 9.6.4 Adults who delayed getting mental health care because of cost in the past 12 months

Appendix Table 9.6.5 Adults in households that had problems paying or were unable to pay their medical bills in the past 12 months

Appendix Table 9.6.6 Children in households that had problems paying or were unable to pay their medical bills in the past 12 months

Appendix Table 9.6.7 Adults in households that currently have any medical bills they are unable to pay at all

Appendix Table 9.6.8 Children in households that currently have any medical bills they are unable to pay at all

Appendix Table 9.6.9 Adults taking prescription medications who skipped medication doses to save money in the past 12 months

Appendix Table 9.6.10 Adults taking prescription medications who took less medication to save money in the past 12 months

Appendix Table 9.6.11 Adults taking prescription medications who delayed filling a prescription to save money in the past 12 months

Appendix Table 9.6.12 Adults who needed a prescription but did not get it because of cost in the past 12 months

i One case was reported in New York in 2022, in an unvaccinated individual