# ACKNOWLEDGMENTS

The National Healthcare Quality and Disparities Report (NHQDR) is the product of collaboration among agencies from the U.S. Department of Health and Human Services (HHS), other federal departments, and the private sector. Many individuals guided and contributed to this effort. Without their magnanimous support, the report would not have been possible. Specifically, we thank:

Primary AHRQ Staff: Robert Valdez, David Meyers, Erin Grace, Karen Chaves, Darryl Gray, Barbara Barton, Romsai Boonyasai, Cecilia Hahn, and Doreen Bonnett.

HHS Interagency Workgroup (IWG) for the NHQDR: Chidera Agwu (HRSA), Girma Alemu (HRSA), Meredith Anderson (HRSA), Jill Ashman (CDC), Elizabeth Barfield (NIH), Barbara Barton (AHRQ), Troyana Benjamin (HRSA), Doreen Bonnett (AHRQ), Romsai Boonyasai (AHRQ), Christopher Cairns (CDC), Victoria Chau (SAMHSA), Karen Chaves (AHRQ), Xiuhua Chen (CVP Corp), Robin Cohen (CDC), Deborah Duran (NIH), Melissa Evans (CMS), Camille Fabiyi (AHRQ), William Freeman (AHRQ), Sabrina Frost (HRSA), Darryl Gray (AHRQ), Kirk Greenway (IHS), Monika Haugstetter (AHRQ), Rebecca Hawes (NIH), Kirk Henry (CDC), Sarah Heppner (HRSA), Roxana Hernandez (SAMHSA), Susan Jenkins (ACL), Christine Lee (FDA), Doris Lefkowitz (AHRQ), Lan Liang (AHRQ), Jesse Lichstein (HRSA), Shari Ling (CMS), Iris Mabry-Hernandez (AHRQ), Marlene Matosky (HRSA), Tracy Matthews (HRSA), Donna McCree (CDC), Christine Merenda (FDA), Kamila Mistry (AHRQ), Dawn Morales (NIH), Ernest Moy (VHA), Pradip Muhuri (AHRQ), Elizabeth Ochoa (HRSA), Benjamin Picillo (HRSA), Sarada Pyda (ASPE), Mary Roary (SAMHSA), Rajasri Roy (NIH), Dianne Rucinski (OASH), Asel Ryskulova (CDC), Michelle Schreiber (CMS), Yahtyng Sheu (HRSA), Adelle Simmons (ASPE), LaQuanta Smalley (HRSA), Loida Tamayo (CMS), Caroline Taplin (ASPE), Anjel Vahratian (CDC), Michelle Washko (HRSA), Tracy Wolff (AHRQ), Abigail Woodroffe (AIR), Ying Zhang (IHS), and Rachael Zuckerman (ASPE).

NHQDR Team: Barbara Barton (CQuIPS), Doreen Bonnett (OC), Romsai Boonyasai (CQuIPS), Xiuhua Chen, (CVP Corp), Camille Fabiyi (OEREP), William Freeman (OEREP), Erin Grace (CQuIPS), Darryl Gray (CQuIPS), Cecilia Hahn (CQuIPS), Lan Liang (CFACT), Kamila Mistry (OEREP), Margie Shofer (CQuIPS), Andrea Timaskenka (CQuIPS), Tselote Tilahun (CQuIPS), and Abigail Woodroffe (AIR).

HHS Data Experts: Cuong Bui (HRSA), Lara Bull (CDC), Christopher Cairns (CDC), Robin Cohen (CDC-NCHS), Joann Fitzell (CMS), Elizabeth Goldstein (CMS), Irene Hall (CDC-HIV), Katrina Hoadley (CMS), Jessica King (NPCR), Amanda Lankford (CDC), Lan Liang (AHRQ), Sharon Liu (SAMHSA), Marlene Matosky (HRSA), Tracy Matthews (HRSA), Robert Morgan (CMS), Richard Moser (NIH-NCI), Pradip Muhuri (AHRQ), Anthony Oliver (CMS), Robert Pratt (CDC), Asel Ryskulova (CDC-NCHS), LaQuanta Smalley (HRSA), Alek Sripipatana (HRSA), Lori Teichman (CMS), Reda Wilson (CDC-NCCDPHP-ONDIEH), and Xiaohong (Julia) Zhu (HRSA).

Other Data Experts: Valarie Ashby (University of Michigan), Mark Cohen (ACS NSQIP), Sheila Eckenrode (MPSMS-Yale), Clifford Ko (ACS NSQIP), Jill McCarty (IBM), Joe Messana (University of Michigan), Tammie Nahra (University of Michigan), Leticia Nogueira (American Cancer Society), Robin Padilla (University of Michigan), Rebecca Anhang Price (RAND), Jennifer Sardone (University of Michigan), Yun Wang (MPSMS-Yale), and Robin Yabroff (American Cancer Society).

Other AHRQ Contributors: Cindy Brach, Howard Holland, Edwin Lomotan, Corey Mackison, Karen Migdail, Milli O’Brien, Pamela Owens, Mary Rolston, Bruce Seeman, and Michele Valentine.

Data Support Contractors: AIR, CVP Corp.