# ORAL HEALTH

Maintaining oral health is important for overall health and well-being. Untreated oral disease can affect appetite, interfere with ability to eat, and lead to poor nutrition. Periodontitis (i.e., “gum disease”) and dental caries (i.e., “cavities”) lead to pain, impaired sleep, impaired academic performance, missed school and workdays, and decreased employability. Dental infections, left untreated, may lead to abscess (a severe infection) that may lead to life-threatening sepsis (the body’s extreme response to an infection). Poor oral health may also be associated with other chronic diseases, such as diabetes and heart-related conditions.

Findings in this report indicate that oral healthcare for children has improved, but the same gains have not occurred for adults. For example:

- The overall percentage of children ages 5-19 years with untreated dental caries decreased nearly 50% between 1988-1994 and 2015-2018 (from 24.3% to 13.2%). However, there was no statistically significant change in the percentage of adults with dental caries in the same period.
- In 2019, 14.3% of the population reported cost as a reason for being unable to get or delayed in getting needed dental care, which was higher than the 8.8% of people who reported cost as a barrier to getting needed medical care. The percentage of children ages 0-17 years for whom cost was a barrier to receiving needed dental care was approximately one-third that of adult groups.
- Disparities for children who had a dental visit in the calendar year narrowed significantly for children in racial and ethnic minority groups and for children in low-income households between 2002 and 2019. However, trends in disparities for these outcomes among adults show more modest improvement.
- From 2002 to 2019, the percentage of children with a dental visit increased both for nonmetropolitan communities (from 49.5% to 54.7%) and metropolitan communities (from 49.0% to 57.5%). However, the rate of improvement was faster for children in metropolitan locations, widening a disparity between these groups.
- During this period, disparities between adults in metropolitan and nonmetropolitan communities narrowed. The percentage of adults with a dental visit increased from 38.4% to 41.6% in nonmetropolitan communities, a small but significant increase, while the change in the percentage of adults with a dental visit in metropolitan communities was not statistically significant.

The Department of Health and Human Services has produced several reports and resources to support and improve the quality of oral healthcare delivery, including the Surgeon General’s 2000 report Oral Health in America; the National Institutes of Health (NIH) National Institute of Dental and Craniofacial Research’s (NIDCR) 2021 comprehensive update Oral Health in America: Advances and Challenges; and numerous other resources from the Centers for Disease Control and Prevention (CDC), Health Resources and Services Administration (HRSA), and Centers for Medicare & Medicaid Services (CMS).

## Importance

Maintaining oral health is important for overall health and well-being. However, cost may pose a barrier to achieving optimal oral health. In 2020, out-of-pocket (OOP) spending accounted for 12% of personal healthcare expenditures. Hospital services accounted for 3%, and physician services accounted for 7% of OOP expenditures, but dental services accounted for 37%.^1^

### Prevalence

Oral disease is prevalent in the United States. The prevalence of dental caries (i.e., “cavities”) in primary (baby) teeth was 23.3% among children ages 2-5 years and 52.1% among children ages 6-8 years in 2011-2016.^2^

The prevalence of dental caries in permanent teeth was 17.4% among children ages 6-11 years, 56.8% among adolescents ages 12-19 years, 89.9% among adults ages 20-64 years, and 96.2% among adults age 65 years and over in 2011-2016.^2^

Approximately 2.2% of adults ages 20-64 and 17.3% of adults age 65 and over are estimated to have lost their natural teeth in 2011-2016.^2^

### Morbidity and Mortality

Untreated oral disease can affect appetite, interfere with ability to eat, and lead to poor nutrition. Periodontitis (i.e., “gum disease”) and dental caries lead to pain, impaired sleep, impaired academic performance, missed school and workdays, and decreased employability.^3^ Left untreated, dental infections may lead to abscess (a severe infection) that may lead to life-threatening sepsis (the body’s extreme response to an infection). Poor oral health may also be associated with other chronic diseases, such as diabetes and heart-related conditions.^4^

### Cost

Oral diseases—which range from cavities and gum disease to oral cancer—cause pain and disability for millions of Americans and cost taxpayers billions of dollars each year. Research estimates that employed adults collectively lose more than 164 million work hours due to oral health problems or dental visits.^5^ People with visibly damaged or missing teeth can also face decreased opportunities for obtaining work. In addition, oral disease complications can undo the benefits of costly medical treatments covered by Medicare and Medicaid, such as heart valve replacement, radiation therapy, and hematopoietic stem cell replacement.^6^

### Effective Care for Oral Health

Fluoride has an important role in preventing and treating the most prevalent oral disease condition: dental caries. Community water fluoridation makes fluoride available to all community members, regardless of their age, demographic characteristics, income, or insurance status. Drinking fluoridated water reduces the risk of developing cavities by approximately 25%.^7^ An analysis conducted in 2016 estimated that adding fluoride to community water systems saves $6.5 billion per year by preventing the direct costs of dental caries and indirect costs of treating them.^7^

Oral health professionals can also apply fluoride varnishes and dental sealants, which are also effective ways to prevent cavities. Dental varnishes can prevent one-third of cavities in both primary and permanent teeth.^8^ The U.S. Preventive Services Task Force recommends (https://uspreventiveservicestaskforce.org/uspstf/recommendation/prevention-of-dental-caries-in-children-younger-than-age-5-years-screening-and-interventions1) that primary care providers prescribe oral fluoride supplements when children lack access to community water fluoridation and apply fluoride dental varnishes for all children up to 5 years. Dental sealants have been shown to reduce cavities in permanent molars by 80% 2 years after being applied, and they continue to protect against 50% of cavities 4 years after application.^9^

If cavities develop, they can be treated with noninvasive procedures to stop caries progression and remineralize teeth, in addition to relying on fillings or tooth extraction. Modern dental practice also includes improved techniques and materials for restoring teeth and performing dental implants.^3^

Beyond preventing and treating cavities, dentists and other oral health professionals can address risks traditionally associated with overall health. People who smoke are 3 times as likely as nonsmokers to lose all their teeth.^10^ HPV^i^-associated oral pharyngeal carcinoma is now more prevalent than HPV-associated cervical cancers. Thus, dental visits may provide people with opportunities to receive screening for tobacco and illicit drug use, tobacco cessation counseling, and HPV vaccination.^11^

Oral diseases are also exacerbated by diabetes, a prevalent chronic disease that often occurs with cardiovascular health conditions. Economic analyses conducted in 2014 estimated that the U.S. healthcare system could save up to $100 million if dental offices provided screening for diabetes, high blood pressure, and high cholesterol and, if needed, referred patients for treatment.^12^

## Findings

Data collected by the NHQDR include two indicators that summarize the status of oral healthcare delivery in the United States: (1) the prevalence of people with untreated dental caries, and (2) the rate of emergency department (ED) visits for a primary diagnosis associated with a dental condition. Both provide evidence that the nation’s investments in healthcare delivery have yielded benefits for children and adolescents, with possible downstream benefits on certain measures for younger adults. They also indicate little or no improvement in oral health outcomes for older adults.

Figure 1 shows that the percentage of children with untreated dental caries has decreased steadily since at least 2001, while the percentage of adults with untreated dental caries has remained relatively unchanged during the same time.^ii^ Figure 2 shows that rates of ED visits for dental concerns by younger adults (ages 18-44 years) decreased between 2016 and 2019, although ED visit rates for this age group remain far higher than for other age groups.

Viewed together, these measures indicate that oral healthcare for children has improved since the early 2000s. In addition, the improvements that began at that time may have generated downstream benefits in the form of reduced ED visits once children age into early adulthood. However, these indicators also show that one-fifth to one-fourth of adults continue to suffer from avoidable tooth decay.

Figure 1 People with untreated dental caries, by age, 1988-2018

Note: This chart uses data previously reported in the 2019 Health, United States report. The estimates shown are spaced at irregular intervals.

Line graph showing percentage; significant findings are in the text below the graph; in 2015-2018, percentages with untreated caries were 25.9, ages 20-44, 25.3, ages 45-64, 20.2, age 65+

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health and Nutrition Examination Survey, 1988-2018.

- The overall percentage of children ages 5-19 years with untreated dental caries decreased nearly 50% between 1988-1994 and 2015-2018 (from 24.3% to 13.2%) (Figure 1).
- During the same periods, there were no statistically significant differences in the percentage of adults with dental caries.

Figure 2 Emergency department visits with a principal diagnosis related to dental conditions per 100,000 population, overall and by age, 2016-2019

Line graph showing visits per 100,000 population; significant findings are in the text below the graph; rates for 2019 were 120.2, ages 0-17, 524.1, ages 18-44, 221.2, ages 45-64, 76.7, ages 65-84, 63.6, age 85+

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2016-2019.

- The rate of ED visits for dental conditions decreased overall from 312.3 per 100,000 population in 2016 to 202.8 per 100,000 population in 2019 (data not shown).
- Much of the decrease in the overall ED visit rate may be attributed to a decrease in ED visits among adults ages 18-44 years from 603.0 per 100,000 population in 2016 to 524.1 per 100,000 population in 2019 (Figure 2).

## How the Nation Can Improve Oral Healthcare Delivery

This special emphasis topic focuses on three potential opportunities for further improving quality of oral healthcare and outcomes and describes the nation’s progress toward realizing them:

1. Increasing water fluoridation in the public water supply.
2. Reducing financial barriers to dental services.
3. Reducing distance needed to access dental care services.

### Opportunity #1: Fluoridating Community Water Systems

Fluoridated water protects teeth and reduces cavities by about 25% in children and adults. Community water fluoridation has been shown to save money both for families and for the U.S. healthcare system by preventing cavities.^13^ Data from CDC show that public health efforts to fluoridate community water systems expanded in the latter half of the 20^th^ century, but these efforts have slowed in recent decades.

Figure 3 Percentage of population served by community water system that received fluoridated water, 2018

Map showing percentage with fluoridated water, higher percentages (79.6-100 were found in the North Central, Midwestern, and Southern Atlantic areas, as well as Arkansas, DC, Delaware, Connecticut, and Rhode Island; the next level (50-79.5%) was in most states in the West and Southwest, as well as Alabama, Florida, Maine, Massachusetts, Mississippi, New York, and Pennsylvania,; Alaska, Idaho, Louisiana, Montana, and New Hampshire had the next level (25-49.9%); Hawaii and New Jersey had the lowest percentages (less than 25)

Source: Centers for Disease Control and Prevention, Oral Health Data, Water Fluoridation, 2018.

- In 2018, 63.4% of people in the United States received fluoridated water and 73.0% of people with access to community water systems received water with the recommended amount of fluoride.^14^ The percentage of the population served by community water systems that received fluoridated water varied by state (Figure 3).
- The percentage in 2018 was similar to values reported in 2008, when 64.3% of the population received fluoridated water and 72.4% of the population with access to community water systems received optimally fluoridated water.
- The percentage of people with access to community water systems who receive optimally fluoridated water remains below the Healthy People 2030 target of 77.1%.

### Opportunity #2: Reducing Financial Barriers to Accessing Oral Healthcare Services

Fluoride varnish and dental sealants can protect teeth independent of community water fluoridation. Although these services can be delivered in school settings, most people receive them during a dental visit. For many Americans, the cost of dental services is a more important barrier to accessing services than the cost of medical care.

Figure 4 People unable to get or delayed in getting needed dental care or medical care due to cost, by age, 2019

Bar chart showing percentage Dental Care Medical Care Total 14.3 8.8 0-17 5.6 2.9 18-44 16.1 11.5 45-64 19 12.6 65+ 15.5 5.1

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2019.

- In 2019, 14.3% of the population reported cost as a reason for being unable to get or delayed in getting needed dental care (Figure 4), which was higher than the 8.8% of people who reported cost as a barrier to getting needed medical care.
- The percentage of children ages 0-17 years for whom cost was reported as a barrier to receiving needed dental care was approximately one-third that of adult groups.

While health insurance can mitigate the cost of healthcare services, health insurance plans often carve out separate coverage for certain types of care, including care for dental, vision, and hearing conditions. Thus, even when people have health insurance, they may still lack coverage for dental care and thus lack access to needed services. This distinction has relevance for understanding how different public health insurance programs have influenced healthcare delivery and oral health outcomes over the past two decades.

The Medicaid program and the Children’s Health Insurance Program (CHIP) have provided comprehensive coverage of dental care for all enrolled children since 1998. Medicaid treats dental care coverage for adults as an optional benefit, which a growing number of states have begun to offer in recent years. In 2018, immediately prior to the period shown in Figure 4, most states covered only limited benefits, such as coverage for tooth extractions and emergency services, six states covered no dental services, and only a few states offered comprehensive dental coverage.^15^

As of August 2022, 25 states plus the District of Columbia met the American Dental Association’s definition of offering “extensive” dental benefits, and only 3 states offered no dental benefits in their Medicaid plan. Traditional fee-for-service Medicare does not cover dental benefits outside a few exceptions, and Medicare Advantage plans vary widely in the types and comprehensiveness of services.

Figures 5–11 show that the percentage of people with private dental insurance has not changed but the percentage of people with health insurance coverage, including public health insurance coverage, has increased. They also show that access to dental services and outcomes have mostly improved for segments of the population for whom public insurance consistently covers dental services.

Figure 5 Percentage of people with any period of private dental insurance during the year, by age, 2006-2019

Line graph showing percentage; significant findings are in the text below the graph

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2006-2019.

- There were no statistically significant changes in the percentage of children and adults with private dental insurance between 2006 and 2019 (Figure 5). Between 44% and 63% of people reported having private dental health insurance.
- Rates of having private dental insurance were lowest for children ages 0-17 years, higher for adults ages 18-44 years, and highest for adults ages 45-64 years.

Figure 6 Percentage of people with any period of uninsurance during the year (top) and percentage of people with any period of public insurance only during the year (bottom), by age, 2006-2019

Line graph showing percentage; significant findings are in the text below the graph

Line graph showing percentage; significant findings are in the text below the graph

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2006-2019.

- The percentage of uninsured children decreased after implementation of the CHIP Reauthorization Act from a peak of 20.1% in 2008 to 9.9% in 2019 (Figure 6, top). The percentage of uninsured adults decreased after implementation of the Affordable Care Act (ACA), from 36.1% (ages 18-44 years) and 23.6% (ages 45-64 years) in 2013 to 23.7% (ages 18-44 years) and 14.6% (ages 45-64 years) in 2019.
- An increase in public health insurance coverage among all age groups (Figure 6, bottom) corresponded with the decrease in uninsurance shown in the top chart.

As shown in Figures 1 and 2, the percentage of children ages 5-19 years with untreated dental caries has decreased since 2001 and the rate of young adults ages 18-44 seeking emergency care for dental conditions has decreased since 2016. The improved outcomes occurred even though access to private dental insurance did not change (Figure 5). They also appear to coincide with the period when Medicaid/CHIP, which includes a dental benefit, expanded coverage for children, but not with the ACA’s health insurance expansion for adults (Figure 6).

Figures 7 to 11 reinforce the concept that inclusion of dental coverage in Medicaid/CHIP was linked to improved oral health outcomes for children. They show that disparities for these outcomes narrowed significantly for children in low-income households and for children in racial and ethnic minority groups between 2002 and 2019. In contrast, improvement in disparities for these outcomes among adults was more modest.

Figure 7 Children ages 2-17 years (top) and adults age 18 years and over (bottom) who had a dental visit in the calendar year, by ethnicity, 2002-2019

Line graph showing percentage; significant findings are in the text below the graph

Line graph showing percentage; significant findings are in the text below the graph

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2019.

- The percentage of children ages 2-17 who had a dental visit in the calendar year increased by 16.3% (from 49.1% to 57.1% of the population) between 2002 and 2019 but there was no statistically significant change for adults (data not shown).
- The data indicate improved access and narrowing disparities in access to dental services between Black and Hispanic groups and White groups (Figure 7).
- Between 2002 and 2019, the percentage of Black children with dental visits increased from 37.1% to 46.2%; and the percentage of Hispanic children with dental visits increased from 33.8% to 49.7% (Figure 7, top). The percentage of White children with dental visits increased at a slower rate, from 52.2% to 59.3%.
- During this time, the disparity between Black and White children in the percentage with dental visits decreased by 13.2% and the disparity between Hispanic and White children decreased by 47.8%.
- The percentage of Black adults with dental visits increased from 25.5% to 30.8%, and the percentage of Hispanic adults with dental visits increased from 24.6% to 28.9% (Figure 7, bottom). The percentage of White adults showed no statistically significant change (going from 46.2% to 46.8%).
- The disparity between Black and White adults in the percentage with dental visits decreased by 22.7% while the disparity between Hispanic and White adults in the percentage with dental visits decreased by 17.1%.
- Similar trends were seen for children and adults in Asian and multiple-race groups. Sample sizes for American Indian or Alaska Native and Native Hawaiian/Pacific Islander groups were too small to produce statistically reliable data and thus were not analyzed.

Figure 8 ED visits for dental conditions per 100,000 population, by median income of patient’s ZIP Code, 2016-2019

Line graph showing visits per 100,000 population; significant findings are in the text below the graph

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2016-2019.

- Between 2016 and 2019, the rate of ED visits for a dental condition decreased 6.1%, from 515.4 to 484.1 visits per 100,000 population for people who live in low-income counties (the 25% of counties with the lowest median household income). It decreased 11.5%, from 236.3 to 209.1 visits per 100,000, for people who live in not low-income counties (Figure 8).

Figure 9 Children with untreated dental caries (upper left) and adults with untreated dental caries (upper right and bottom), by race/ethnicity, 1988-2018

Note: This chart uses data previously reported in the 2019 Health, United States (https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/Health_US/hus19tables/table028.xlsx) report. The estimates shown are spaced at irregular intervals. Data for Asian race is not available prior to the 2011-2014 period; data for Hispanic ethnicity are available starting in 2007. This analysis does not include estimates for 2007 to 2010 because they were not reported in Health, United States.

Set of four line graphs showing percentages for ages 5-19, 20-44, 45-64, and 65+; significant findings are in the text below the graphs

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health and Nutrition Examination Survey, 1988-2018.

- Racial and ethnic disparities were narrowing for untreated dental caries among children ages 5-19 years, while disparities in untreated dental caries for adults ages 20-44, 45-64, and 65+ years showed no statistically significant changes (Figure 9).
- The percentage of children ages 5-19 years with untreated dental caries decreased for Black, Hispanic, and White groups between 1988-1994 and 2015-2018 (Figure 9, upper left). Between 1988-1994 and 2015-2018, the percentage decreased from 33.9% to 15.7% for Black children and from 19.4% to 11.9% for White children. Between 2011-2014 and 2015-2018, the percentage decreased from 21.7% to 14.1% for Hispanic children. There were no statistically significant changes in the percentage of Asian children with untreated dental caries.
- There were no statistically significant changes in the percentage of adults ages 20-44 years with untreated dental caries for any race or ethnicity between 1988-1994 and 2015-2018 (Figure 9, upper right).
- There were no statistically significant changes in the percentage of adults ages 45-64 years with untreated dental caries for any race or ethnicity between 1988-1994 and 2015-2018 (Figure 9, lower left).
- There were no statistically significant changes in the percentage of adults age 65 years and over with untreated dental caries for any race or ethnicity between 1988-1994 and 2015-2018 (Figure 9, lower right).

Figure 10 Children (top) and adults (bottom) who had a dental visit in the past year, by household income-to-poverty threshold ratio, 2002-2019

Set of two graphs showing percentages for ages 2017 and age 18+; significant findings are in the text below the graphs

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2019.

- From 2002 to 2019, the percentage of children ages 2-17 years with a dental visit increased from 33.0% to 42.5% in households with income less than 100% of the poverty threshold (“poor”), while the percentage of children with a dental visit grew at a slower pace (from 67.2% to 70.3%) in households with income at or above 400% of the poverty threshold (“high income”) (Figure 10, top).
- From 2002 to 2019, there was no statistically significant change in the percentage of adults age 18 years and over with a dental visit in either income group: 24.2% in 2002 to 24.8% in 2019 for households with income less than 100% of the poverty threshold and 57.2% in 2002 to 57.8% in 2019 for households with income at or above 400% of the poverty threshold (Figure 10, bottom).
- Although the percentage of children with dental visits increased in poor households, narrowing the gap between children in poor and high-income households, children in poor households remain significantly less likely to have a dental visit than either children or adults in high-income households.

Figure 11 Children (left) and adults (right) with untreated dental caries, by household income, 1988-2018

Note: This chart uses data previously reported in the 2019 Health, United States report. The estimates shown are spaced at irregular intervals. Income is expressed as a percentage of the poverty threshold. Data for the percentage of untreated dental caries for children in households with income at or above 400% of the poverty threshold in the 1988-1994 period are omitted from this analysis because the estimates are considered statistically unreliable.

Two line graphs showing percentages for ages 5-19 and ages 20 and over; significant findings are in the text below the graphs; in 2015-2018, percentages were 18.7, ages 5-19 with household income below 100% of the poverty threshold, 5.2, ages 5-19 with household income 400% or more of the poverty threshold; percentages for adults in 2015-2018 were 41.3, ages 20-44 below 100% of poverty threshold, 10.4, ages 20-44 at 400% or more of poverty threshold; 52.1, ages 45-64 below 100% of poverty threshold, 11.2, ages 45-64 at 400% or more of poverty threshold; 40.2, age 65+ below 100% of poverty threshold, 11.5, age 65+ at 400% or more of poverty threshold

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health and Nutrition Examination Survey, 1988-2018.

- Between 1999-2002 and 2015-2018, the percentage of children with untreated dental caries decreased from 31.9% to 18.7% among households with income less than 100% of the poverty threshold (Figure 11, left). During the same period, the percentage of children with untreated dental caries decreased from 8.9% to 5.2% in households with income at or above 400% of the poverty threshold. The disparity between children in poor and high-income households narrowed by 41.3%.
- Between 1988-1994 and 2015-2018, there were no statistically significant changes in the percentage of adults with untreated dental caries for any age group or income level (Figure 11, right).
- During the same years, there were no statistically significant changes in disparities between poor and high-income adults in any age group.

### Opportunity #3: Reducing the Distance Needed To Access Oral Healthcare Services

Although dental insurance may reduce cost-related barriers to accessing oral healthcare services, it may not ensure people can access oral healthcare services if the services are far from where they live or if available oral healthcare providers do not accept insurance. Lack of healthcare providers, geographic isolation, and lack of adequate transportation are frequently cited barriers to healthcare services in rural communities,^16^ which is also true for oral healthcare.

Increasing urbanization of the population has been associated with less financial stability among rural hospitals, hospital closures, and loss of access to the services they provide. The Government Accountability Office (GAO) documented 101 rural hospital closures from January 2013 through February 2020. Of these, 17 had offered oral healthcare services. The GAO estimates that the median distance people in the communities served by these hospitals needed to drive to access oral healthcare services increased from 2.4 to 36 miles.^17^

Rural communities also face greater challenges recruiting and supporting oral healthcare professionals. “Health Professional Shortage Area” (HPSA) is a designation HRSA assigns to areas that lack key types of healthcare practitioners, in order to prioritize support for those communities. HRSA has identified 7,018 geographic areas, population groups, and facilities as “dental HPSAs.”

Nearly three-quarters of dental HPSAs are in areas classified as rural or partially rural.

Figure 12 Dental Health Professional Shortage Areas in the United States and territories, 2022

Note: HPSA scores are developed for use by the National Health Service Corps to determine priorities for the assignment of clinicians. Scores range from 1 to 26 for dental health. The higher the score, the greater the priority.

Map showing dental health professional shortage areas; key points are noted in the text below the map

Source: Health Resources and Services Administration, Division of Data and Information Services, Office of Information Technology, July 13, 2022. https://data.hrsa.gov/maps/map-gallery.

- As of June 30, 2022, HRSA estimates that only 31.4% of dental HPSAs have met their need for practitioners, and an additional 11,694 dental professionals are needed to remove the remaining HPSA designations.^18^
- Figure 12 shows the distribution of counties with dental HPSAs. As of June 30, 2022, 4,692 of 7,018 (66.9%) dental HPSAs are classified as rural, 281 (4.0%) are classified as partially rural, and 2,044 (29.1%) are classified as nonrural.

Medical Expenditure Panel Survey data indicate that children and adults who live in micropolitan (“small town”) and noncore (“rural”) areas (i.e., nonmetropolitan counties) are less likely to have had a dental visit in the past year than similarly aged people who live in metropolitan locations (Figure 13).^iii^

Figure 13 Children who had a dental visit in the calendar year (top) and adults who had a dental visit in the calendar year (bottom), by location of residence, 2019

Two bar charts showing percentages for children ages 2-17 years and adults age 18 and over Percentages for ages 2-17 Large Central Metro, 56 Large Fringe Metro, 59.6 Medium Metro, 57.6 Small Metro, 56.1 Micropolitan, 55.5 Noncore, 53.6 Percentages for age 18+ Large Central Metro, 42.7 Large Fringe Metro, 46.6 Medium Metro, 44.5 Small Metro, 43.9 Micropolitan, 42.5 Noncore, 40.1

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2019.

- Children in noncore (53.6%) and micropolitan (55.5%) communities were less likely to have a dental visit than children in large fringe metropolitan areas (59.6%) (Figure 13, top).
- Adults in noncore (40.1%) and micropolitan (42.5%) counties were less likely to have a dental visit than those in large fringe metropolitan areas (46.6%) (Figure 13, bottom).

Figures 14 and 15 show trends for insurance coverage and dental visits for children and adults in metropolitan and nonmetropolitan locations between 2002 and 2019. They suggest value in having dental insurance coverage in this population but also hint at barriers unrelated to insurance coverage.

Figure 14 Overall percentage of people with private dental insurance (top), 2006-2019, and overall percentage of people with no insurance or public health insurance (bottom), by location of residence, 2002-2019

Two line graphs showing percentage; significant findings are in the text below the graphs

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2019.

- For metropolitan communities, the percentage of people with private dental insurance coverage decreased from 55.2% to 51.9% between 2006 and 2013, followed by a steady rise from 51.9% to 59.7% between 2013 and 2019 (Figure 14, top).
- For nonmetropolitan communities, a similar but delayed pattern in dental insurance coverage emerged, with a relatively rapid rise from 43.8% to 52.4% between 2016 and 2019.
- Overall, the percentage of people in metropolitan communities with public insurance rose from 16.6% to 26.5% and the percentage of uninsured people decreased from 25.3% to 16.9% between 2002 and 2019 (Figure 14, bottom).
- During the same period, the percentage of people in nonmetropolitan communities with public insurance rose from 20.2% to 32.4% and the percentage of uninsured people decreased from 26.2% to 19.3%.

Figure 15 Children who had a dental visit in the calendar year (top) and adults who had a dental visit in the calendar year (bottom), by location of residence, 2002-2019

Two line graphs showing percentage; significant findings are in the text below the graphs

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2019.

- From 2002 to 2019, the percentage of children with a dental visit increased both for nonmetropolitan communities (from 49.5% to 54.7%) and metropolitan communities (from 49.0% to 57.5%) (Figure 15, top). However, the rate of improvement was faster for children in metropolitan locations, widening a disparity between these groups.
- During this period, disparities between adults in metropolitan and nonmetropolitan communities narrowed (Figure 15, bottom). The percentage of adults with a dental visit increased from 38.4% to 41.6% in nonmetropolitan communities, a small but significant increase, while the change in the percentage of adults with a dental visit in metropolitan communities was not statistically significant.

Viewed together, Figures 14 and 15 suggest a potential correlation between a rise in private dental insurance coverage after 2016 and an increased percentage of adults who had a dental visit during the year in the same years. They also provide an indication that health insurance coverage is insufficient to address disparities between people in metropolitan and nonmetropolitan communities. While measures for children show an overall rise in dental visits in both metropolitan and nonmetropolitan locations, the faster rise in visits in metropolitan areas suggests those who live in nonmetropolitan communities may face barriers unrelated to insurance (e.g., lack of transportation).

Experts have proposed several strategies that could reduce dental workforce shortages and geographic distance as a barrier to receiving high-quality dental care.^16,19,20^ These include policies that:

- Prioritize students from rural areas for admission to dental schools, as they are more likely to return to rural areas to practice.
- Establish dental school curricula that emphasize rural dentistry.
- Recruit and retain dentists and other oral healthcare providers through financial and tax incentives, loan repayment/forgiveness, and community development programs.
- Establish programs that integrate oral and behavioral health services into primary care practices, thus enabling primary care providers to offer at least some dental services. As of September 2020, 14 states and several tribal nations had authorized care delivered by dental therapists.^21^
- Enable a wider range of health professional roles to safely deliver oral healthcare services. For example, dental therapists are licensed health professionals who provide preventive and restorative dental care as part of a broader dental care team, comparable to the role performed by physician assistants in delivering medical care.
- Expand capacity to deliver teledental services, including building broadband internet infrastructure and amending licensing regulations to permit teledentistry.

#### Limited Data for Oral Health Outcomes in Nonmetropolitan Communities

If demonstration projects to expand the rural workforce transition into national initiatives, it will become increasingly desirable to assess their impact on nonmetropolitan (i.e., micropolitan and rural) communities at state and national levels. Currently, the NHQDR has limited capacity to examine trends in this area.

For example, data showing less access to routine dental care services in nonmetropolitan communities raises concern for people who live in these communities. However, it is unclear if persistent disparities in dental visit rates are associated with similar trends for untreated dental caries for people in nonmetropolitan areas since data needed to examine differences in rate of untreated dental caries by location of residence are not available.

Data on ED visits for primary diagnosis of dental conditions by people in metropolitan and nonmetropolitan communities (Figure 16) show that disparities for this measure are narrowing. However, in the absence of corroborating data, it is unclear if this trend represents a desirable outcome (e.g., improved care and less need for emergency dental services) or an undesirable one (e.g., hospital closures leading to less access to needed emergency care).

Gathering data that would allow closer examination of oral health outcomes in nonmetropolitan counties would enhance our understanding of healthcare delivery in these communities and inform programs that seek to serve their needs.

Figure 16 Emergency department visits with a principal diagnosis related to dental conditions per 100,000 population, by location of residence, 2016-2019

Line graph showing visits per 100,000 population; significant findings are in the text below the graph

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2016-2019.

- The trend for people in large central metropolitan areas was statistically similar to those in large fringe metropolitan areas (going from 234.1 to 202.8 visits per 100,000 population in large central metropolitan areas and from 221.6 to 218.8 visits per 100,000 population in large fringe metropolitan counties) (Figure 16).
- The trend for people in medium and small metropolitan counties improved from 382.6 to 339.9 visits per 100,000 population, narrowing the disparity with large fringe metropolitan communities by 24.8%.
- The trend for people in nonmetropolitan counties improved from 482.9 to 442.2 visits per 100,000 population, narrowing the disparity with large fringe metropolitan communities by 14.5%.

## Conclusion

This special emphasis topic showcases NHQDR data that indicate improved dental care delivery for children and adolescents overall; decreased dental disparities between Asian, Black, Hispanic, and multiracial children and adolescents and White children and adolescents; and decreased dental disparities between children and adolescents in poor and high-income households. It also contrasts these gains with the dental healthcare experiences of adults, for whom trends in oral health outcomes and disparities show relatively little improvement.

The data point to comprehensive dental benefits in Medicaid for children and CHIP as important drivers for these trends and signal what could be achieved if dental coverage were similarly extended to adults. They also suggest the potential value of expanding coverage to include services that often are “carved out” from traditional health insurance coverage, such as care for vision and auditory conditions.

Our examination of oral healthcare trends in nonmetropolitan counties highlights how simply providing more comprehensive health insurance coverage has been insufficient for these communities. They indicate a need to bolster the dental workforce’s capacity to provide services in rural areas.

To monitor effectiveness of the many ongoing initiatives aimed at alleviating rural workforce shortages and their impact on oral health, the NHQDR team will seek measures that more fully assess quality of care in this area for future reports.

## Resources

The Department of Health and Human Services has produced several resources to support and improve the quality of oral healthcare delivery.

- NIH-NIDCR published the report Oral Health in America: Advances and Challenges (https://www.nidcr.nih.gov/research/oralhealthinamerica) in December 2021. This report describes and summarizes scientific advances and innovations in oral healthcare delivery since the original Surgeon General’s report on oral health, published 20 years earlier. It provides a detailed snapshot to inform policymakers and the public on this topic.
- CDC has compiled information, data, and other resources on their Oral Health (https://www.cdc.gov/OralHealth/index.html) website.
- HRSA has produced several resources intended to enhance dental health workforce capacity and support implementation of different types of oral healthcare delivery models. This information can be found on HRSA’s Oral Health (https://www.hrsa.gov/oral-health/index.html) website.
- CMS established the Oral Health Initiative (OHI) to improve Medicaid-enrolled children’s use of preventive dental care services. Through the OHI, CMS has helped states with outreach and quality improvement efforts by providing technical support in developing oral health action plans, hosting quality improvement learning collaboratives, and developing outreach materials for Medicaid beneficiaries.

## References

1 Centers for Medicare & Medicaid Services. National Health Expenditure Data. Last modified December 2021. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData. Accessed October 12, 2022.
2 Centers for Disease Control and Prevention. Oral Health Surveillance Report: Trends in Dental Caries and Sealants, Tooth Retention, and Edentulism, United States, 1999-2004 to 2011-2016. Atlanta, GA: U.S. Department of Health and Human Services; 2019. https://www.cdc.gov/oralhealth/publications/OHSR-2019-index.html. Accessed October 12, 2022.
3 National Institutes of Health, National Institute of Dental and Craniofacial Research. Oral Health in America: Advances and Challenges. Bethesda, MD: U.S. Department of Health and Human Services; 2021. https://www.nidcr.nih.gov/research/oralhealthinamerica. Accessed October 12, 2022.
4 Kelekar U, Naavaal S. Hours lost to planned and unplanned dental visits among U.S. adults. Prev Chronic Dis. 2018 Jan 11;15:E04. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5772383/. Accessed October 12, 2022.29324218
5 Leinbach LI, Willink A. Oral health in Medicare: considerations for 21st-century coverage. JAMA. 2020;324(13):1288–89. 10.1001/jama.2020.3003. Accessed October 12, 2022.32910164
6 Community Preventive Services Task Force. The Guide to Community Preventive Services. Dental Caries (Cavities): Community Water Fluoridation. https://www.thecommunityguide.org/findings/dental-caries-cavities-community-water-fluoridation. Accessed October 12, 2022.
7 O’Connell JM, Rockell J, Ouellet J, Tomar SL, Maas W. Costs and savings associated with community water fluoridation in the United States. Health Aff. 2016;35(12):2224–32. https://www.healthaffairs.org/doi/10.1377/hlthaff.2016.0881?url_ver=Z39.88-003&rfr_id=ori:rid:crossref.org&rfr_dat=cr_pub%20%200pubmed. Accessed October 12, 2022.
8 Marinho VC, Worthington HV, Walsh T, Clarkson JE. Fluoride varnishes for preventing dental caries in children and adolescents. Cochrane Database Syst Rev. 2013 Jul 11;(7):CD002279. 10.1002/14651858.cd002279.pub2. Accessed October 12, 2022.23846772
9 Community Preventive Services Task Force. The Guide to Community Preventive Services. Dental Caries (Cavities): School-Based Dental Sealant Delivery Programs: Task Force Findings and Rationale Statement. https://www.thecommunityguide.org/sites/default/files/assets/Oral-Health-Caries-School-based-Sealants_0.pdf. Accessed October 12, 2022.
10 Dietrich T, Walter C, Oluwagbemigun K, Bergmann M, Pischon T, Pischon N, Boeing H. Smoking, smoking cessation, and risk of tooth loss: the EPIC-Potsdam Study. J Dent Res. 2015 Oct;94(10):1369–75. https://pubmed.ncbi.nlm.nih.gov/26243734/. Accessed October 12, 2022.26243734
11 Centers for Disease Control and Prevention. HPV and Cancer. How Many Cancers Are Linked With HPV Each Year? https://www.cdc.gov/cancer/hpv/statistics/cases.htm. Accessed October 12, 2022.
12 Nasseh K, Greenberg B, Vujicic M, Glick M. The effect of chairside chronic disease screenings by oral health professionals on health care dollars. Am J Public Health. 2014;104(4):744–50. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4025684/. Accessed October 12, 2022.24524531
13 Centers for Disease Control and Prevention. Community Water Fluoridation. Last reviewed January 2020. https://www.cdc.gov/fluoridation/index.html. Accessed October 12, 2022.
14 Centers for Disease Control and Prevention. Oral Health Data, Water Fluoridation. https://nccd.cdc.gov/oralhealthdata/rdPage.aspx?rdReport=DOH_DATA.ExploreByTopic&islYear=2018&islTopic=WFR&go=GO. Accessed October 12, 2022.
15 Kaiser Family Foundation. Medicaid Benefits: Dental Services. https://www.kff.org/medicaid/state-indicator/dental-services/?currentTimeframe=0&sortModel=%7B%22colId%22:%22Location%22,%22sort%22:%22asc%22%7D. Accessed October 12, 2022.
16 Advisory Committee on Training in Primary Care Medicine and Dentistry. Improving Access to Care in Underserved Rural Communities: Eighteenth Annual Report to the Secretary of the U.S. Department of Health and Human Services and the U.S. Congress. Rockville, MD: Health Resources and Services Administration; November 2021. https://www.hrsa.gov/sites/default/files/hrsa/advisory-committees/primarycare-dentist/reports/actpcmd-18th-report.pdf. Accessed October 12, 2022.
17 Rural Hospital Closures: Affected Residents Had Reduced Access to Health Care Services. Washington, DC: Government Accountability Office; December 2020. Product No. GAO-21-93. https://www.gao.gov/products/gao-21-93. Accessed October 12, 2022.
18 Third Quarter of Fiscal Year 2022 Designated HPSA Quarterly Summary, as of June 30, 2022. Rockville, MD: Health Resources and Services Administration; July 2022..
19 Frogner BK, Fraher EP, Spetz J, Pittman P, Moore J, Beck AJ, Armstrong D, Buerhaus PI. Modernizing scopeof-practice regulations - time to prioritize patients. N Engl J Med. 2020 Feb 13;382(7):591–93. https://www.nejm.org/doi/10.1056/NEJMp1911077?url_ver=Z39.88-2003&rfr_id=ori:rid:crossref.org&rfr_dat=cr_pub%20%200pubmed. Accessed October 12, 2022.32053296
20 National Advisory Committee on Rural Health and Human Services. Improving Oral Health Care Services in Rural America: Policy Brief and Recommendations. Rockville, MD: U.S. Department of Health and Human Services; December 2018. https://www.hrsa.gov/sites/default/files/hrsa/advisory-committees/rural/2018-oral-health-policy-brief.pdf. Accessed October 12, 2022.
21 Oral Health Workforce Research Center. Authorization Status of Dental Therapists by State. Last updated September 2020. https://oralhealthworkforce.org/authorization-status-of-dental-therapists-by-state/. Accessed October 12, 2022.

i HPV = human papillomavirus.

ii The National Healthcare Quality and Disparities Report (NHQDR) has traditionally reported data for “Children ages 5-7 years with untreated dental caries” but not a similar measure for adults. Thus, this Special Emphasis Topic examines data originally reported in Table 28 of Health, United States 2019 (https://www.cdc.gov/nchs/data/hus/2019/028-508.pdf), which includes estimates of untreated dental caries for both children and adults. Appendix B of this report only displays data for untreated dental caries in children ages 5-17, which are data provided to the NHQDR. Future reports will collect and display data for both children and adults.

iii The NHQDR provides a more detailed explanation for how the report defines terms metropolitan, nonmetropolitan, and other rural-urban categories in the Portrait of American Healthcare section. Readers may also find category specifications in the Appendix A, Methods.