# SUBSTANCE USE DISORDERS

Substance use disorders (SUDs) occur when the recurrent, problematic use of alcohol or drugs causes clinically significant impairment, including health problems, disability, and failure to meet major responsibilities at work, school, or home. Alcohol misuse, illicit drug use, misuse of medications, and other SUDs are estimated to cost the United States more than $400 billion in lost workplace productivity (in part, due to premature mortality), healthcare expenses, law enforcement and other criminal justice costs (e.g., drug-related crimes), and losses from motor vehicle crashes.

Data show that receipt of needed treatment for SUDs and alcohol misuse remained low while adverse outcomes such as emergency department visits, hospitalizations, and mortality increased for nearly all population groups from 2015 to 2019. For example:

- In 2020, the percentage of people age 12 and over who needed treatment for alcohol misuse and who received such treatment at a specialty facility was less than 10% for people at all income levels.
- In 2020, the percentage of people age 12 and over who needed treatment for illicit drug use and who received such treatment at a specialty facility was less than 20% for people living in all geographic locations.
- The hospitalization rate for illnesses related to opioid use doubled overall and across all income groups.
- Emergency department visits involving opioid-related diagnoses more than doubled overall and across all income groups.
- Overall, the rate of drug overdose deaths involving natural and semisynthetic opioids increased fourfold, from 0.98 per 100,000 population in 1999 to 4.1 per 100,000 population in 2020. People ages 45-64 experienced a nearly fivefold increase.
- Among residents of large central metropolitan areas,^i^ the rate of drug overdose deaths involving synthetic opioids other than methadone increased from 9.7 per 100,000 population in 2018 to 19.1 per 100,000 population in 2020. Among residents of noncore areas,^ii^ the rate of drug overdose deaths involving synthetic opioids other than methadone increased from 5.0 per 100,000 population in 2018 to 10.6 per 100,000 population in 2020.

The Department of Health and Human Services and the White House have developed tools and provided funding for programs to reduce adverse outcomes related to alcohol misuse and SUDs. Examples includes the Overdose Prevention Strategy and the White House 2022 National Drug Control Strategy.

## Importance

SUDs meet criteria in the Diagnostic and Statistical Manual of Mental Disorders, 5th edition (DSM-5), for one or more illicit drugs or alcohol. SUDs can involve illicit drugs, prescription drugs, and alcohol or combinations of these substances.

Illicit drugs include marijuana, cocaine, heroin, hallucinogens, inhalants, and methamphetamine, as well as misuse of prescription psychotherapeutic drugs (e.g., pain relievers, tranquilizers, stimulants, sedatives).^1^ Opioid use disorders (OUDs) have become especially problematic in recent years. SUDs are linked to many health problems, and overdoses can lead to emergency department visits and deaths.^2^

### Prevalence

In 2020, among the 138.5 million people who were current alcohol users, 61.6 million were classified as binge drinkers and 17.7 million (28.8% of current binge drinkers and 12.8% of current alcohol users) were classified as heavy drinkers. Nearly 60 million people age 12 and over used illicit drugs in the past year, including close to 50 million who used marijuana.^3^

An estimated 26 million past-year users of alcohol and 11 million past-year users of drugs other than alcohol reported they were using these substances “a little more or much more” than they did before the COVID-19 public health emergency began.^4^

### Morbidity and Mortality

In 2020, 50% of people age 12 and over (or 138.5 million people) used alcohol in the past month.^4^ Vital statistics show that there has been a surge in alcohol-induced deaths, an increase from slightly over 39,000 deaths in 2019 to just over 49,000 deaths in 2020, or more than 25%. Provisional data from 2021 show the number of alcohol-induced deaths continued to increase, to more than 52,000, up 34% from prepandemic levels.^5^

The misuse of and addiction to opioids—including prescription pain relievers, heroin, and synthetic opioids such as fentanyl—have become common chronic illnesses in the United States. Although effective treatments exist for OUD, only about one in four people with this disorder receives any type of specialty treatment.^6^

Among people age 12 and over in 2020, 59.3 million people used illicit drugs in the past year. The most commonly used illicit drug in the past year was marijuana, which was used by 49.6 million people. The second most common type of illicit drug use in the past year was the misuse of prescription pain relievers, which were misused by 9.3 million people.^7^

Polysubstance use occurs when more than one drug is used, with or without the person’s knowledge. Rates of polysubstance use and polysubstance use disorders, particularly involving the co-use of stimulants and opioids, have increased in recent years. This growing issue also means that an opioid-involved overdose often occurs in combination with exposure to other opioids or other nonopioid substances. Some examples of polysubstance exposures found in combination in overdose deaths include illicitly manufactured fentanyl (IMF) and heroin; IMF and cocaine; IMF and methamphetamine; and prescription or illicit opioids and benzodiazepines.^8^

From May 2020 to April 2021, the estimated number of drug overdose deaths in the United States exceeded 100,000 over a 12-month period for the first time, with 64.0% of deaths involving synthetic opioids other than methadone, mainly IMFs, which include both fentanyl and illicit fentanyl analogs.^9^

Cocaine and heroin were the most commonly co-involved stimulant and opioid other than IMFs, respectively, among IMF-involved deaths in all regions of the United States except the West, where methamphetamine and prescription opioids were most common.^9^

People who experience nonfatal overdose (NFOD) are at high risk of subsequent overdose.^10^ NFODs are a significant cause of opioid-related morbidity in the United States and can result in opioid-induced respiratory depression and brain injury.^11^

### Cost

According to the Centers for Disease Control and Prevention, excessive alcohol use results in $249 billion in losses to the U.S. economy. Cost due to excessive drinking includes healthcare cost ($28 billion), loss of workplace productivity ($179 billion), collisions ($13 billion), and criminal justice ($25 billion).^12^

In 2017, alcohol-related emergency department visits cost $1.22 billion. Medicaid was the primary expected payer of 35% of the cost; private insurance and self-pay, 23% each; Medicare, 15%; and other primary expected payer, 4%.^13^

The monetary costs and collateral impact to society due to SUDs are very high. In 2017, the annual associated medical cost of SUDs in U.S. hospitals was $13.2 billion.^14^ Alcohol misuse, illicit drug use, misuse of medications, and SUDs are estimated to cost the United States more than $400 billion in lost workplace productivity (in part, due to premature mortality), healthcare expenses, law enforcement and other criminal justice costs (e.g., drug-related crimes), and losses from motor vehicle crashes.^15,16^

According to the Centers for Medicare & Medicaid Services, nearly 12% of Medicaid beneficiaries over age 18 have an SUD.^17^

### Barriers to Care

Many of the same kinds of barriers that existed to SUD treatment before the Affordable Care Act and parity laws remain, such as limits on the type of SUD treatment provided and the length of treatment.^18^

Medications for OUD, including buprenorphine, methadone, and naltrexone are safe and effective treatments.^19^ In the United States, in response to the COVID-19 public health emergency and its related safety restrictions, providers turned to telehealth to provide necessary healthcare to patients at a distance. State and federal policy changes implemented in response to the COVID-19 public health emergency aimed to increase access to medication for opioid use disorder (MOUD) through telehealth flexibilities, waiving restrictions on Medicaid/Medicare reimbursement for telehealth services, loosening restrictions on take-home doses of methadone, and lifting the in-person evaluation requirement for patients with OUD to begin buprenorphine treatment.^20^

Still, many barriers persist to widespread access to MOUD. Among the 2.5 million people age 12 and over with past year OUD, 11.2% received MOUD in the past year for opioid misuse.^7^

Barriers to preventing and treating SUDs include:

- A complex system of care that providers and patients alike may find difficult to navigate,
- A lack of interagency coordination and communication due to a shortage of facilities and providers and long distances between patients and providers,
- Limited resources and personnel,
- Lack of mental health services,
- Insufficient capacity,
- Lack of transportation,
- Homelessness and substandard housing,
- Stigma at the individual, practitioner, community, and policymaker level,
- Confidentiality concerns,
- Inadequate funding,
- Inadequate remuneration,
- Workforce shortages,
- Inadequate education at medical and professional schools, and
- Lack of pharmacy availability of buprenorphine.^21,22,23,24,25,26,27^

These challenges suggest that solutions will require cross-sector collaboration at all levels to begin to address access to and quality of care for SUDs.

In addition, a large percentage of people who need treatment for SUD do not seek treatment and fewer receive the help they need, especially among African American, Asian, and Hispanic groups. Barriers to care include lack of insurance, cost, stigmatization of substance use and mental illness, multicultural factors, and provider unwillingness to prescribe MOUD.^28,29,30,31^

## Findings

The figures in the substance use disorder section of the NHQDR illustrate significant trends over time and the most significant disparities in the most recent data year. For a deeper look at the disparities by geographic location, statistics about rural/urban location are also included where data are available. In addition, bivariate analyses are shown when such analyses are possible.

### Low Rates of Treatment for Substance Use Among All Residence Locations, Income Groups, and Gender Groups

Figure 1 People age 12 and over who needed treatment for illicit drug use or an alcohol problem and who received such treatment at a specialty facility in the last 12 months, by location, 2015-2019 (top) and by income and location, 2020 (bottom)

Line graph showing percentage; significant findings are in the text below the graph

Source: Substance Abuse and Mental Health Services Administration, National Survey on Drug Use and Health, 2015-2019.

Key: PG = poverty guideline.

Note: The 2020 data included quarters 1 and 4 only due to COVID. The criteria used to categorize substance use disorder (SUD) among National Survey on Drug Use and Health respondents changed from the fourth edition of the Diagnostic and Statistical Manual of Mental Disorders (DSM-IV) to the fifth edition (DSM-5), resulting in some differences in who is classified as having an SUD. Therefore, the DSM-5 SUD estimates from 2020 are not comparable with the DSM-IV SUD estimates from prior years. In 2020, data for noncore did not meet the criteria for statistical reliability, data quality, or confidentiality.

Columns showing percentage; significant findings are in the text below the chart

Source: Substance Abuse and Mental Health Services Administration, National Survey on Drug Use and Health, 2020, quarters 1 and 4.

- From 2015 to 2019, residents of micropolitan areas were the only group that showed an increase in the percentage of people who needed and received treatment for illicit drug use or an alcohol problem at a specialty facility in the last 12 months (Figure 1, top).
- In 2020, the percentage of people who needed and received treatment for illicit drug use or an alcohol problem at a specialty facility in the last 12 months was below 15% for all income groups and geographic locations (Figure 1, bottom).

Figure 2 People age 12 and over who needed treatment for an alcohol problem and who received such treatment at a specialty facility in the last 12 months, by income, 2015-2019 (top) and by sex and income, 2020 (bottom)

Key: PG = poverty guideline.

Line graph showing percentage; significant findings are in the text below the graph

Source: Substance Abuse and Mental Health Services Administration, National Survey on Drug Use and Health, 2015-2019.

Key: PG = poverty guideline.

Note: The 2020 data included quarters 1 and 4 only due to COVID. The criteria used to categorize substance use disorder (SUD) among National Survey on Drug Use and Health respondents changed from the fourth edition of the Diagnostic and Statistical Manual of Mental Disorders (DSM-IV) to the fifth edition (DSM-5), resulting in some differences in who is classified as having an SUD. Therefore, the DSM-5 SUD estimates from 2020 are not comparable with the DSM-IV SUD estimates from prior years.

Columns showing percentage Total, 3.8 Female, 2.8 Male, 4.6 <100% of PG (Lowest), 6.5 100-199% of PG, 4 200-399% of PG, 3.5 400%+ of PG (Highest), 3

Source: Substance Abuse and Mental Health Services Administration, National Survey on Drug Use and Health, 2020, quarters 1 and 4.

- From 2015 to 2019, among households with 100-199% of the PG, the percentage of people who needed and received treatment for an alcohol problem at a specialty facility in the last 12 months increased from 8.8% to 14.2% (Figure 2, top).
- In 2020, there were no statistically significant differences between income groups (Figure 2, bottom).

Figure 3 People age 12 and over who needed treatment for illicit drug use and who received such treatment at a specialty facility in the last 12 months, by geographic location, 2015-2019 (top) and by ethnicity and location, 2020 (bottom)

Note: Noncore data do not meet the criteria for statistical reliability, data quality, or confidentiality for 2016.

Line graph showing percentage; significant findings are in the text below the graph

Source: Substance Abuse and Mental Health Services Administration, National Survey on Drug Use and Health, 2015-2019.

Note: The 2020 data included quarters 1 and 4 only due to COVID. The criteria used to categorize substance use disorder (SUD) among National Survey on Drug Use and Health respondents changed from the fourth edition of the Diagnostic and Statistical Manual of Mental Disorders (DSM-IV) to the fifth edition (DSM-5), resulting in some differences in who is classified as having an SUD. Therefore, the DSM-5 SUD estimates from 2020 are not comparable with the DSM-IV SUD estimates from prior years. Micropolitan and noncore data for 2020 do not meet the criteria for statistical reliability, data quality, or confidentiality.

The geographic locations are based on the 2013 National Center for Health Statistics Urban-Rural Classification Scheme (https://www.cdc.gov/nchs/data/series/sr_02/sr02_166.pdf):

- Large central metropolitan refers to counties in a metropolitan statistical area (MSA) of 1 million or more population that contain the entire population of the largest principal city of the MSA, whose entire population is contained within the largest principal city of the MSA, or that contain at least 250,000 residents of any principal city in the MSA.
- Large fringe metropolitan refers to counties in MSAs of 1 million or more population that do not qualify as large central, described as suburban areas.
- Medium metropolitan refers to counties in MSAs of 250,000 to 999,999 population.
- Small metropolitan refers to counties in MSAs of less than 250,000 population.
- The two nonmetropolitan county designations are micropolitan, which are counties in a micropolitan statistical area, and noncore, which are nonmetropolitan counties that are not in a micropolitan statistical area.

Columns showing percentage Total, 9.9 Hispanic, 9.5 Non-Hispanic Black, 7 Non-Hispanic White, 10.8 Large Central Metro, 6.9 Large Fringe Metro, 5.9 Medium Metro, 16.7 Small Metro, 12.1

Source: Substance Abuse and Mental Health Services Administration, National Survey on Drug Use and Health, 2020, quarters 1 and 4.

- From 2015 to 2019, residents of the two nonmetropolitan areas, micropolitan and noncore, experienced different trends in the percentage of people who needed and received treatment for illicit drug use at a specialty facility (Figure 3, top). Residents of micropolitan areas showed an increase while residents of noncore areas showed a decrease.
- From 2015 to 2019, among residents of micropolitan areas, the percentage of people who needed and received treatment for illicit drug use at a specialty facility in the last 12 months increased from 14.5% to 25.3%.
- From 2015 to 2019, among residents of noncore areas, the percentage of people who needed and received treatment for illicit drug use at a specialty facility in the last 12 months decreased from 26.8% to 15.3%.
- In 2020, among people who needed and received treatment for illicit drug use at a specialty facility in the last 12 months, residents of medium metropolitan areas (16.7%) were more likely than residents of large fringe metropolitan areas (5.9%) to receive needed treatment (Figure 3, bottom).

### Low Rates of Treatment Completion for Substance Use Disorder Among All Racial and Ethnic Groups

Figure 4 People age 12 and over treated for substance use disorder who completed treatment course, by race and ethnicity (left) and Hispanic subgroups (right), 2019

Key: NHPI = Native Hawaiian/Pacific Islander.

Columns showing percentage; significant findings are in the text below the chart

Columns showing percentage; significant findings are in the text below the chart

Source: Substance Abuse and Mental Health Services Administration, Treatment Episode Data Set, 2019.

- The percentage of people treated for SUD who completed their treatment was below 50% for all racial/ethnic groups in 2019 (Figure 4).
- Non-Hispanic NHPI people had the lowest percentage who completed treatment (36.2%) (Figure 4, left).
- In 2019, 43.2% of Hispanic people of all races age 12 and over treated for substance use disorder completed the treatment course but the percentage varied by subgroup:
  ■ Mexican people, 36.3%,
  ■ Puerto Rican people and Cuban people, 45.2%, and
  ■ Other Hispanic groups, 46.5% (Figure 4, right).

### Increase in Opioid-Related Hospital Stays and Emergency Department Visits Among All Income Groups

Figure 5 Hospital inpatient stays involving opioid-related diagnoses per 100,000 population, by income, 2005-2019

Line graph showing rate per 100,000 population; significant findings are in the text below the graph

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Inpatient Databases, 2005-2019.

- From 2005 to 2019, the hospitalization rate related to opioid use doubled overall and for all income groups (Figure 5). The overall rate of hospital inpatient stays involving opioid-related diagnoses increased from 136.8 per 100,000 population to 275.0 per 100,000 population.
- From 2005 to 2019, among people in the lowest income group, the rate of hospital inpatient stays involving opioid-related diagnoses increased from 179.6 per 100,000 population to 359.9 per 100,000 population.
- From 2005 to 2019, among people in the second income group, the rate of hospital inpatient stays involving opioid-related diagnoses increased from 125.5 per 100,000 population to 277.4 per 100,000 population.
- From 2005 to 2019, among people in the third income group, the rate of hospital inpatient stays involving opioid-related diagnoses increased from 117.2 per 100,000 population to 243.4 per 100,000 population.
- From 2005 to 2019, among people in the highest income group, the rate of hospital inpatient stays involving opioid-related diagnoses increased from 98.1 per 100,000 population to 185.4 per 100,000 population.

Figure 6 Emergency department visits involving opioid-related diagnoses per 100,000 population, by income, 2005-2019

Line graph showing rate per 100,000 population; significant findings are in the text below the graph

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2005-2019.

- From 2005 to 2019, emergency department visits involving opioid-related diagnoses more than doubled overall and for all income groups (Figure 6).
- From 2005 to 2019, overall, the rate of emergency department visits related to opioid use increased from 89.1 per 100,000 population to 226.0 per 100,000 population.
- From 2005 to 2019, among people in the lowest income group, the rate of emergency department visits involving opioid-related diagnoses increased from 104.9 per 100,000 population to 308.1 per 100,000 population.
- From 2005 to 2019, among people in the second income group, the rate of emergency department visits involving opioid-related diagnoses increased from 90.2 per 100,000 population to 224.3 per 100,000 population.
- From 2005 to 2019, among people in the third income group, the rate of emergency department visits involving opioid-related diagnoses increased from 83.2 per 100,000 population to 190.6 per 100,000 population.
- From 2005 to 2019, among people in the highest income group, the rate of emergency department visits involving opioid-related diagnoses increased from 65.5 per 100,000 population to 147.7 per 100,000 population.

### Increases in Drug Overdose Deaths Involving Opioids Among All Racial/Ethnic and Income Groups

Figure 7 Drug overdose deaths involving any opioids per 100,000 population, by race/ethnicity, 2018-2020

Key: AI/AN = American Indian or Alaska Native.

Note: Race and Hispanic origin misclassification on death certificates results in substantial underestimation of mortality for non Hispanic AI/ANs (refer to https://www.cdc.gov/nchs/data/nvsr/nvsr70/NVSR70-12.pdf). Drug overdose deaths are identified using underlying cause-of-death codes from the 10th revision of the International Classification of Diseases (ICD-10-CM). Deaths involving any opioids use codes T40.0-T40.4 and T40.6. Rates are age adjusted.

Line graph showing rate per 100,000 population; significant findings are in the text below the graph

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 2018-2020. Data were downloaded from CDC WONDER, Multiple Cause of Death.

- From 2018 to 2020, overall, the rate of drug overdose deaths involving any opioids increased from 14.6 per 100,000 population to 21.4 per 100,000 population (Figure 7).
- From 2018 to 2020, among Hispanic people, the rate of drug overdose deaths involving any opioids increased from 7.5 per 100,000 population to 13.1 per 100,000 population.
- From 2018 to 2020, among non-Hispanic AI/AN people, the rate of drug overdose deaths involving any opioids increased from 13.8 per 100,000 population to 28.1 per 100,000 population.
- From 2018 to 2020, among non-Hispanic Black people, the rate of drug overdose deaths involving any opioids increased from 14.1 per 100,000 population to 26.6 per 100,000 population.
- From 2018 to 2020, among non-Hispanic White people, the rate of drug overdose deaths involving any opioids increased from 18.8 per 100,000 population to 25.5 per 100,000 population.

Figure 8 Drug overdose deaths involving natural and semisynthetic opioids per 100,000 population, by age, 1999-2020

Note: Natural opioid includes morphine and codeine; semisynthetic opioid includes drugs such as oxycodone, hydrocodone, hydromorphone, and oxymorphone. Drug overdose deaths are identified using underlying cause-of-death codes from the 10th revision of the International Classification of Diseases (ICD-10-CM). Deaths involving natural and semisynthetic opioids use code T40.2. Rates are crude rates. Rates were calculated based on the numbers of deaths and population of the downloaded 10-year age groups. Standard errors were calculated based on the rates and populations for the combined groups (square root of (p*(1-p)/N)). Deaths of missing age were excluded.

Line graph showing rate per 100,000 population; significant findings are in the text below the graph

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 1999-2020. Data were downloaded from CDC WONDER, Multiple Cause of Death.

- From 1999 to 2020, overall, the rate of drug overdose deaths involving natural and semisynthetic opioids increased fourfold, from 0.98 per 100,000 population to 4.1 per 100,000 population (Figure 8).
- From 1999 to 2020, among people ages 0-24, the rate of drug overdose deaths involving natural and semisynthetic opioids increased from 0.2 per 100,000 population to 0.7 per 100,000 population.
- From 1999 to 2020, among people ages 25-44, the rate of drug overdose deaths involving natural and semisynthetic opioids increased from 1.9 per 100,000 population to 6.8 per 100,000 population.
- From 1999 to 2020, among people ages 45-64, the rate of drug overdose deaths involving natural and semisynthetic opioids increased from 1.4 per 100,000 population to 6.8 per 100,000 population.
- From 1999 to 2020, among people age 65 and over, the rate of drug overdose deaths involving natural and semisynthetic opioids increased from 0.25 per 100,000 population to 1.9 per 100,000 population.

### Differences in Drug Overdose Deaths Involving Some Opioids in Certain Age and Ethnic Groups and Geographic Locations

Figure 9 Drug overdose deaths involving natural and semisynthetic opioids per 100,000 population, by age and ethnicity, 2020

Note: Natural opioid includes morphine and codeine; semisynthetic opioid includes drugs such as oxycodone, hydrocodone, hydromorphone, and oxymorphone. Rates are crude rates and are not age adjusted. Drug overdose deaths are identified using underlying cause-of-death codes from the 10^th^ revision of the International Classification of Diseases (ICD-10-CM). Deaths involving natural and semisynthetic opioids use codes T40.2.

Bar chart showing rate per 100,000 population Hispanic Non-Hispanic Black Non-Hispanic White Total 1.8 3.9 5.5 0-24 0.5 0.7 0.9 25-44 3.1 5.7 9.7 45-64 3.1 6.8 8.3 65+ 0.9 3.0 2.3

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 2020. Data were downloaded from CDC WONDER, Multiple Cause of Death.

- In 2020, overall, Hispanic and non-Hispanic Black people were less likely than non-Hispanic White people to die from a drug overdose involving natural and semisynthetic opioids (Figure 9).
- In 2020, among people age 25 and over, Hispanic people were less likely than non-Hispanic White people to die from a drug overdose involving natural and semisynthetic opioids.
- In 2020, among people ages 25-64, non-Hispanic Black people were less likely than non-Hispanic White people to die from a drug overdose involving natural and semisynthetic opioids.
- In 2020, among people age 65 and over, non-Hispanic Black people were more likely than non-Hispanic White people to die from a drug overdose involving natural and semisynthetic opioids.

Figure 10 Drug overdose deaths involving synthetic opioids other than methadone per 100,000 population, by geographic location, 2018-2020

Note: Rates are crude rates and are not age adjusted. Methadone is a synthetic opioid that can be prescribed for pain reduction or for use in medication-assisted treatment (MAT) for opioid use disorder (OUD). For MAT, methadone is used under direct supervision of a healthcare provider; synthetic opioid other than methadone includes drugs such as tramadol and fentanyl.

Drug overdose deaths are identified using underlying cause-of-death codes from the 10th revision of the International Classification of Diseases (ICD-10-CM). Deaths involving synthetic opioids other than methadone use code T40.4. The geographic locations are based on the 2013 National Center for Health Statistics Urban-Rural Classification Scheme (https://www.cdc.gov/nchs/data/series/sr_02/sr02_166.pdf):

- Large central metropolitan refers to counties in a metropolitan statistical area (MSA) of 1 million or more population that contain the entire population of the largest principal city of the MSA, whose entire population is contained within the largest principal city of the MSA, or that contain at least 250,000 residents of any principal city in the MSA.
- Large fringe metropolitan refers to counties in MSAs of 1 million or more population that do not qualify as large central, described as suburban areas.
- Medium metropolitan refers to counties in MSAs of 250,000 to 999,999 population.
- Small metropolitan refers to counties in MSAs of less than 250,000 population.
- The two nonmetropolitan county designations are micropolitan, which are counties in a micropolitan statistical area, and noncore, which are nonmetropolitan counties that are not in a micropolitan statistical area.

Line graph showing rate per 100,000 population; significant findings are in the text below the graph

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 2018-2020. Data were downloaded from CDC WONDER, Multiple Cause of Death.

- From 2018 to 2020, overall, the percentage of drug overdose deaths involving synthetic opioids increased from 9.6 per 100,000 population to 17.2 per 100,000 population (Figure 10).
- From 2018 to 2020, among residents of large central metropolitan areas, the rate of drug overdose deaths involving synthetic opioids other than methadone increased from 9.7 per 100,000 population to 19.1 per 100,000 population.
- From 2018 to 2020, among residents of large fringe metropolitan areas, the rate of drug overdose deaths involving synthetic opioids other than methadone increased from 12.0 per 100,000 population to 18.0 per 100,000 population.
- From 2018 to 2020, among residents of medium metropolitan areas, the rate of drug overdose deaths involving synthetic opioids other than methadone increased from 9.9 per 100,000 population to 18.2 per 100,000 population.
- From 2018 to 2020, among residents of small metropolitan areas, the rate of drug overdose deaths involving synthetic opioids other than methadone increased from 6.9 per 100,000 population to 13.3 per 100,000 population.
- From 2018 to 2020, among residents of micropolitan areas, the rate of drug overdose deaths involving synthetic opioids other than methadone increased from 7.1 per 100,000 population to 13.8 per 100,000 population.
- From 2018 to 2020, among residents of noncore areas, the rate of drug overdose deaths involving synthetic opioids other than methadone increased from 5.0 per 100,000 population to 10.6 per 100,000 population.

Figure 11 Drug overdose deaths involving synthetic opioids other than methadone per 100,000 population, by geographic location and ethnicity, 2020

Note: Rates are crude rates and are not age adjusted. Methadone is a synthetic opioid that can be prescribed for pain reduction or for use in medication-assisted treatment (MAT) for opioid use disorder (OUD). For MAT, methadone is used under direct supervision of a healthcare provider; synthetic opioid other than methadone includes drugs such as tramadol and fentanyl.

Drug overdose deaths are identified using underlying cause-of-death codes from the 10 revision of the International Classification of Diseases (ICD-10-CM). Deaths involving synthetic opioids other than methadone use code T40.4. The geographic locations are based on the 2013 National Center for Health Statistics Urban-Rural Classification Scheme (https://www.cdc.gov/nchs/data/series/sr_02/sr02_166.pdf):

- Large central metropolitan refers to counties in a metropolitan statistical area (MSA) of 1 million or more population that contain the entire population of the largest principal city of the MSA, whose entire population is contained within the largest principal city of the MSA, or that contain at least 250,000 residents of any principal city in the MSA.
- Large fringe metropolitan refers to counties in MSAs of 1 million or more population that do not qualify as large central, described as suburban areas.
- Medium metropolitan refers to counties in MSAs of 250,000 to 999,999 population.
- Small metropolitan refers to counties in MSAs of less than 250,000 population.
- The two nonmetropolitan county designations are micropolitan, which are counties in a micropolitan statistical area, and noncore, which are nonmetropolitan counties that are not in a micropolitan statistical area.

Bar chart showing rate per 100,000 population Hispanic Non-Hispanic Black Non-Hispanic White Large Central Metro 11.9 33.3 22.1 Large Fringe Metro 10.3 20.5 21.1 Medium Metro 10.9 21.2 21.1 Small Metro 7.7 15.6 14.4 Micropolitan 5.6 13.4 15.2 Noncore 5.8 7.8 11.4

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 2020.

- In 2020, among residents of all geographic locations, Hispanic people were less likely to die from a drug overdose involving synthetic opioids compared with non-Hispanic White people.
- In 2020, among residents of large central metropolitan areas, non-Hispanic Black people were more likely to die from a drug overdose involving synthetic opioids compared with non-Hispanic White people.

## Conclusion

From 2015 to 2019, there was little overall change in the percentage of people who needed and received treatment for illicit drugs or an alcohol problem and in 2020, rates remained below 20%. People with low income represented one of the few population groups who showed improvement in the receipt of needed treatment.

The need for specialty treatment is urgent. According to the National Institute on Drug Abuse (NIDA), drug overdoses have accelerated (https://www.cdc.gov/media/releases/2020/p1218-overdose-deaths-covid-19.html) during the COVID-19 public health emergency. The Centers for Disease Control and Prevention (CDC) National Center for Health Statistics estimated that 107,622 drug overdose deaths occurred in the United States in 2021. Overdose deaths rose 30% from 2019 to 2020 and continue to rise.

During this public health emergency, people in treatment for SUDs face unique challenges. Physical distancing, quarantine, and other public health measures have disrupted access to medication and other support services for many people. For example, people with OUD who rely on methadone dispensed at a clinic may be unable to access this daily medication while physically distancing.^32^

In the 2 years since the Substance Abuse and Mental Health Services Administration (SAMHSA) issued an exemption to opioid treatment programs (OTPs) allowing take-home doses of patient’s medication for OUD, increases have been seen in treatment engagement and patient satisfaction with care. In addition, few incidents of misuse or medication diversion have been observed. The evidence indicates the exemption has enhanced and encouraged use of OTP services.^33,34^

Data show that from 2017 to 2019, death rates involving opioids leveled off but were followed in 2020 by a sharp increase. In 2020, the rate of deaths involving synthetic opioids was highest among non-Hispanic Black people in large urban areas (31.9 per 100,000 population), nearly four times as high as non-Hispanic Black people in rural areas (8.0 per 100,000 population) and more than twice the rate of Hispanic people in urban areas (11.7 per 100,000 population).

## Resources

Efforts by the Department of Health and Human Services (HHS) are underway to prevent overdoses and save lives by ensuring equitable access to essential healthcare and support services without stigma. The Overdose Prevention Strategy (https://www.hhs.gov/overdose-prevention/) includes:

- Primary Prevention
  ■ Prevention is critical to reducing overdoses and overdose deaths. The strategy promotes tiered, multidisciplinary prevention activities, ranging from population-level strategies to targeted interventions aimed at high-risk individuals. These activities engage health and human services providers directly and facilitate cross-sector collaboration on prevention.
- Harm Reduction
  ■ Evidence-based harm reduction strategies minimize negative outcomes of drug use. These activities further expand access to harm reduction interventions and better integrate harm reduction into general medical care.
- Evidence-Based Treatment
  ■ Evidence-based treatments for SUDs can reduce substance use, related health harms (for example, infectious disease transmission), and overdose deaths. High-quality treatment can also increase social functioning. The strategy therefore focuses on reducing barriers to the most effective treatments, using motivational and cultural enhancements to encourage those who might be reluctant, advancing strategies to improve engagement and retention, and continuing to develop new therapeutic approaches.
- Recovery Support
  ■ Despite the demonstrated benefits of recovery support services, such as peer support, employment, and housing services, various challenges impede their availability and uptake. Enhancing coverage and integration of recovery support services is critical to promoting access to and use of these services. Strengthening the recovery support services workforce is also essential to promoting access and quality.

The White House 2022 National Drug Control Strategy (https://www.whitehouse.gov/wp-content/uploads/2022/04/National-Drug-Control-2022Strategy.pdf) focuses on two critical drivers of the epidemic: untreated addiction and drug trafficking. It instructs federal agencies to prioritize actions that will save lives, get people the care they need, go after drug traffickers’ profits, and make better use of data to guide all these efforts. The strategy aims to:

- Expand high-impact harm reduction interventions such as naloxone.
- Ensure those at highest risk of an overdose can access evidence-based treatment.
- Improve data systems and research that guide drug policy development.

The National Institutes of Health Helping to End Addiction Long-term (HEAL) Initiative is an aggressive, transagency effort to speed scientific solutions to stem the national opioid public health crisis. The initiative is funding hundreds of projects nationwide. Researchers are taking a variety of approaches to tackle the opioid epidemic through:

- Understanding, managing, and treating pain.
- Improving prevention and treatment for opioid misuse and addiction.

NIDAMED: Clinical Resources develop science-based resources for health professionals and those in training about screening, addressing, and treating addiction. Research shows that screening, brief intervention, and referral to treatment by clinicians in general medical settings can promote significant reductions in alcohol and tobacco use.

The Healthcare Professional’s Core Resource on Alcohol (https://www.niaaa.nih.gov/health-professionals-communities/core-resource-on-alcohol#:%7E:text=The%20Core%20Resource%20on%20Alcohol,care%20from%20screening%20through%20recovery.), developed by the National Institute on Alcohol Abuse and Alcoholism, helps clinicians provide care for people whose alcohol use may be affecting their health. In addition to providing foundational knowledge for understanding alcohol-related problems, this resource helps fill common gaps in healthcare provider training about addiction. It covers areas such as the neuroscience of addiction, evidence-based behavioral health care and medications for alcohol use disorder, strategies to reduce stigma associated with alcohol-related problems, and varied paths to recovery.

SAMHSA Funding Opportunities (https://www.samhsa.gov/grants) lists the current SAMHSA Funding Opportunities for SUD prevention and treatment as well as current grant awardees. SAMHSA Store (https://store.samhsa.gov/) is a compendium of publications and digital products that includes resources for SUD prevention, treatment, and recovery resources.

SAMHSA is committed to improving prevention, treatment, and recovery support services for mental and substance use disorders. The SAMHSA Evidence-Based Practices Resource Center (https://www.samhsa.gov/resource-search/ebp) provides communities, clinicians, policymakers, and others with the information and tools to incorporate evidence-based practices into their communities or clinical settings.

Behavioral Health Treatment Services Locator (https://findtreatment.samhsa.gov/) is a confidential and anonymous source of information for people seeking treatment facilities in the United States or U.S. territories for substance use, addiction, and mental health problems.

## References

1 Substance Abuse and Mental Health Services Administration. 2020 National Survey on Drug Use and Health (NSDUH): Methodological Summary and Definitions. https://www.samhsa.gov/data/sites/default/files/reports/rpt35330/2020NSDUHMethodSummDefs091721.pdf. Accessed October 11, 2022.
2 Office of Disease Prevention and Health Promotion, U.S. Department of Health and Human Services. Healthy People 2030. Drug and Alcohol Use. https://health.gov/healthypeople/objectives-and-data/browse-objectives/drug-and-alcohol-use. Accessed October 11, 2022.
3 Center for Behavioral Health Statistics and Quality. 2020 NSDUH Detailed Tables. Rockville, MD: Substance Abuse and Mental Health Services Administration; January 2022. https://www.samhsa.gov/data/report/2020-nsduh-detailed-tables. Accessed October 11, 2022.
4 Highlights for the 2020 National Survey on Drug Use and Health. Rockville, MD: Substance Abuse and Mental Health Services Administration. https://www.samhsa.gov/data/sites/default/files/2021-10/2020_NSDUH_Highlights.pdf. Accessed June 14, 2022.
5 Centers for Disease Control and Prevention, National Center for Health Statistics. Alcohol Deaths on the Rise and Suicide Declines. Last reviewed March 2022. https://www.cdc.gov/nchs/pressroom/podcasts/2022/20220318/20220318.htm. Accessed October 11, 2022.
6 Office of the Surgeon General. Facing Addiction in America: The Surgeon General’s Spotlight on Opioids. Washington, DC: U.S. Department of Health and Human Services; September 2018. https://addiction.surgeongeneral.gov/sites/default/files/OC_SpotlightOnOpioids.pdf. Accessed October 11, 2022.
7 Center for Behavioral Health Statistics and Quality. Key Substance Use and Mental Health Indicators in the United States: Results From the 2020 National Survey on Drug Use and Health. NSDUH Series H-56. Rockville, MD: Substance Abuse and Mental Health Services Administration; 2021. HHS Publication No. PEP21-07-01-00. https://www.samhsa.gov/data/sites/default/files/reports/rpt35325/NSDUHFFRPDFWHTMLFiles2020/2020NSDUHFFR1PDFW102121.pdf. Accessed October 11, 2022.
8 Centers for Disease Control and Prevention, Injury Center. Drug Overdose Deaths, Other Drugs. Last reviewed November 2021. https://www.cdc.gov/drugoverdose/deaths/other-drugs.html. Accessed October 11, 2022.
9 O’Donnell J, Tanz LJ, Gladden RM, Davis NL, Bitting J. Trends in and characteristics of drug overdose deaths involving illicitly manufactured fentanyls — United States, 2019-2020. MMWR Morb Mortal Wkly Rep. 2021;70:1740–46. https://www.cdc.gov/mmwr/volumes/70/wr/mm7050e3.htm?s_cid=mm7050e3_w. Accessed October 11, 2022.34914673
10 Shrestha S, Stopka TJ, Hughto JMW, Case P, Palacios WR, Reilly B, Green TC. Prevalence and correlates of non-fatal overdose among people who use drugs: findings from rapid assessments in Massachusetts, 2017-2019. Harm Reduct J. 2021 Aug 30;18:93. 10.1186/s12954-021-00538-9. Accessed October 11, 2022.34461922
11 Zibbell J, Howard J, Duhart Clarke S, Ferrell A, Karon SL. Non-Fatal Opioid Overdose and Associated Health Outcomes: Final Summary Report. (Prepared under Contract Number HHSP233201600021I from the Office of the Assistant Secretary for Planning and Evaluation to Research Triangle Institute). Washington, DC: U.S. Department of Health and Human Services; September 2019. https://aspe.hhs.gov/reports/non-fatal-opioid-overdose-associated-health-outcomes-final-summary-report-0. Accessed October 11, 2022.
12 Centers for Disease Control and Prevention. The Cost of Excessive Alcohol Use. Last reviewed December 2019. https://www.cdc.gov/alcohol/onlinemedia/infographics/cost-excessive-alcohol-use.html. Accessed October 11, 2022.
13 Karaca Z, Moore BJ. Costs of Emergency Department Visits for Mental and Substance Use Disorders in the United States, 2017. HCUP Statistical Brief #257. Rockville, MD: Agency for Healthcare Research and Quality; May 2020. www.hcup-us.ahrq.gov/reports/statbriefs/sb257-ED-Costs-Mental-Substance-Use-Disorders-2017.pdf. Accessed October 11, 2022.
14 Peterson C, Li M, Xu L, Mikosz CA, Luo F. Assessment of annual cost of substance use disorder in U.S. hospitals. JAMA Netw Open. 2021;4(3):e210242. 10.1001/jamanetworkopen.2021.0242. Accessed October 11, 2022.33666661
15 Sacks JJ, Gonzales KR, Bouchery EE, Tomedi LE, Brewer RD. 2010 national and state costs of excessive alcohol consumption. Am J Prev Med. 2015;49(5):e73–e79. https://pubmed.ncbi.nlm.nih.gov/26477807/. Accessed October 11, 2022.26477807
16 National Drug Intelligence Center. National Drug Threat Assessment, 2011. Washington, DC: U.S. Department of Justice; August 2011. Product No. 2011-Q0317-001. https://www.justice.gov/archive/ndic/pubs44/44849/44849p.pdf. Accessed October 11, 2022.
17 Centers for Medicare & Medicaid Services. Behavioral Health Services, Substance Use Disorders. https://www.medicaid.gov/medicaid/benefits/behavioral-health-services/substance-use-disorders/index.html. Accessed October 11, 2022.
18 Dickson-Gomez J, Weeks M, Green D, Boutouis S, Galletly C, Christenson E. Insurance barriers to substance use disorder treatment after passage of mental health and addiction parity laws and the Affordable Care Act: a qualitative analysis. Drug Alcohol Depend Rep. 2022 Jun;3: 100051. 10.1016/j.dadr.2022.100051. Accessed October 11, 2022.
19 National Academies of Sciences, Engineering, and Medicine; Health and Medicine Division; Board on Health Sciences Policy; Committee on Medication-Assisted Treatment for Opioid Use Disorder; Mancher M, Leshner AI, eds. Medications for Opioid Use Disorder Save Lives. Washington, DC: National Academies Press; March 2019. https://www.ncbi.nlm.nih.gov/books/NBK538936/. Accessed October 11, 2022.
20 Telehealth and Substance Use Disorder Services in the Era of COVID-19: Review and. Recommendations. Washington, DC: Legislative Analysis and Public Policy Association; June 2022. https://www.whitehouse.gov/wp-content/uploads/2022/06/Telehealth-and-Substance-Use-Disorder-Services-in-the-Era-of-COVID-19-FINAL.pdf. Accessed October 11, 2022.
21 Rural Health Information Hub. Barriers to Preventing and Treating Substance Use Disorders in Rural Communities. https://www.ruralhealthinfo.org/toolkits/substance-abuse/1/barriers. Accessed October 11, 2022.
22 Khan A, Khan Q, Kolb E. Supportive alternate site provision of buprenorphine: overcoming barriers and improving patient outcomes. J Subst Abuse Treat. 2021 Apr;123:108256. https://pubmed.ncbi.nlm.nih.gov/33612191/. Accessed October 11, 2022.33612191
23 Madden EF, Prevedel S, Light T, Sulzer SH. Intervention stigma toward medications for opioid use disorder: a systematic review. Subst Use Misuse. 2021;56(14):2181–2201. https://pubmed.ncbi.nlm.nih.gov/34538213/. Accessed October 11, 2022.34538213
24 National Academies of Sciences, Engineering, and Medicine; Health and Medicine Division; Board on Health Sciences Policy; Committee on Medication-Assisted Treatment for Opioid Use Disorder; Mancher M, Leshner AI, eds. Medications for Opioid Use Disorder Save Lives. Washington, DC: National Academies Press; March 2019 Mar 30. 5, Barriers to Broader Use of Medications to Treat Opioid Use Disorder. https://www.ncbi.nlm.nih.gov/books/NBK541389/. Accessed October 11, 2022.
25 Hodgkin D, Horgan C, Bart G. Financial sustainability of payment models for office-based opioid treatment in outpatient clinics. Addict Sci Clin Pract. 2021 Jul 5;16(1):45. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC8256208/. Accessed October 11, 2022.34225785
26 HRSA Health Workforce. Behavioral Health Workforce Projections, 2017-2030. Rockville, MD: Health Resources and Services Administration. https://bhw.hrsa.gov/sites/default/files/bureau-health-workforce/data-research/bh-workforce-projections-fact-sheet.pdf. Accessed October 11, 2022.
27 Tong ST, Hochheimer CJ, Peterson LE, Krist AH. Buprenorphine provision by early career family physicians. Ann Fam Med. 2018 Sep;16(5):443–46. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6130986/. Accessed October 11, 2022.30201642
28 2020 National Survey on Drug Use and Health: African Americans. Rockville, MD: Substance Abuse and Mental Health Services Administration; July 2022. https://www.samhsa.gov/data/sites/default/files/reports/slides-2020-nsduh/2020NSDUHAfricanAmSlides072522.pdf. Accessed October 12, 2022.
29 2020 National Survey on Drug Use and Health: Asian/Native Hawaiians and Other Pacific Islanders (NHOPI). Rockville, MD: Substance Abuse and Mental Health Services Administration; July 2022. https://www.samhsa.gov/data/sites/default/files/reports/slides-2020-nsduh/2020NSDUHAsianSlides072522.pdf. Accessed October 12, 2022.
30 2020 National Survey on Drug Use and Health: Hispanics. Rockville, MD: Substance Abuse and Mental Health Services Administration; July 2022. https://www.samhsa.gov/data/sites/default/files/reports/slides-2020-nsduh/2020NSDUHHispanicSlides072522.pdf. Accessed October 12, 2022.
31 Lagisetty PA, Ross R, Bohnert A, Clay M, Maust DT. Buprenorphine treatment divide by race/ethnicity and payment. JAMA Psychiatry. 2019;76(9):979–81. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6506898/. Accessed October 12, 2022.31066881
32 National Institute on Drug Abuse. COVID-19 & Substance Use. February 25, 2022. https://nida.nih.gov/research-topics/comorbidity/covid-19-substance-use. Accessed October 12, 2022.
33 Substance Abuse and Mental Health Services Administration. Methadone Take-Home Flexibilities Extension Guidance. Last updated March 2022. https://www.samhsa.gov/medication-assisted-treatment/statutes-regulations-guidelines/methadone-guidance. Accessed October 12, 2022.
34 Amram O, Amiri S, Panwala V, Lutz R, Joudrey PJ, Socias E. The impact of relaxation of methadone take-home protocols on treatment outcomes in the COVID-19 era. Am J Drug Alcohol Abuse. 2021 Nov.

i Large central metro counties in metropolitan statistical area (MSA) of 1 million or more population that: (1) contain the entire population of the largest principal city of the MSA, or (2) are completely contained within the largest principal city of the MSA, or (3) contain at least 250,000 residents of any principal city in the MSA.

ii Noncore areas are nonmetropolitan counties that are not in a micropolitan statistical area.