# MATERNAL HEALTH

The United States has the highest maternal mortality rate of industrialized countries and this rate is increasing. Pregnant people from historically marginalized racial and ethnic groups have higher rates of maternal mortality and morbidity.

Many cases of maternal mortality and morbidity are preventable. However, barriers to timely and effective maternal healthcare exist at multiple levels: community, health facility, patient/family, provider, and system.

Findings showed that, despite efforts to improve the quality of maternal care, maternal morbidity increased across nearly all population groups in the years assessed for this report (2016-2019). For example:

- Rates of cesarean deliveries in first time, low-risk pregnancies were higher for non-Hispanic Black people than for non-Hispanic White people and the disparity widened with the age of the mother.
- Rates for severe maternal morbidity, eclampsia/preeclampsia, severe postpartum hemorrhage, and venous thromboembolism or pulmonary embolism were increasing over time across all deliveries. In addition, disparities related to racial/ethnic categories were common.
- Rates of severe maternal morbidity, eclampsia/preeclampsia, and venous thromboembolism or pulmonary embolism were significantly worse for non-Hispanic Black individuals compared with non-Hispanic White individuals.
- Rates of severe postpartum hemorrhage were significantly worse for non-Hispanic Asian or Pacific Islander (API) individuals compared with non-Hispanic White individuals, and the disparity was growing larger over time.
- In addition to assessing disparities across various characteristics, maternal health was trended over time. Results showed that, despite efforts to improve the quality of maternal care, most morbidities increased across nearly all population groups in the years assessed for this report.

HHS has developed tools, resources, and programs to improve maternal health, which is a priority of the Biden-Harris Administration. These include the White House Blueprint for Addressing the Maternal Health Crisis, the Healthy Start Initiative, and the Perinatal Improvement Collaborative.

## Importance

### Prevalence

In 2020, 3,613,647 births occurred in the United States^1^ and the total fertility rate was 1.6.^i,^ ^2^ Maternal health encompasses the physical, emotional, and mental health of individuals giving birth during the pregnancy, childbirth, and postnatal period.

### Morbidity and Mortality

Across the United States in 2020, 861 maternal deaths occurred during delivery or within 42 days of delivery. The maternal mortality rate in 2020 was 23.8 deaths per 100,000 live births, an increase from 2019 (20.1 deaths per 100,000 live births) and 2018 (17.4 deaths per 100,000 live births).^3,4^ In addition, in 2020, the United States had the highest maternal mortality rate among 11 developed countries.^5^

The Centers for Disease Control and Prevention (CDC) states that “severe maternal morbidity includes unexpected outcomes of labor and delivery that result in significant short- or long-term consequences to a woman’s health.”^6^ More than 25,000 deliveries each year involve severe maternal morbidity, including conditions such as intravascular coagulation, hysterectomy, renal failure, sepsis, and adult respiratory distress syndrome.

When deliveries with receipt of blood transfusions are included, the number of deliveries with severe maternal morbidity more than doubles.^7,8,9^ Additional types of maternal morbidity include preeclampsia and obstetric trauma.^10,11^ Similar to the increasing rate of maternal mortality, many types of maternal morbidity are also on the rise.^5^

Maternal mental health issues are common; 10% to 25% of postpartum women develop a depressive disorder.^12^ The risk of suicide increases among depressed people during the perinatal period and up to 20% of postpartum deaths are due to suicide.^13^ However, the percentage of providers who ask about depression during postpartum visits varies widely, from 51% to 96%.^13^

Violence against pregnant people and those who recently gave birth is also of concern. Homicide is the leading cause of death during pregnancy and within 42 days postpartum in the United States.^14^

About half of all births are to people from racial and ethnic minority groups. Research indicates that pregnant people from these groups often experience the highest rates of adverse health outcomes.^15^ Even when accounting for risk factors such as maternal age, income, and receipt of prenatal care, racial and ethnic minority individuals continue to have significantly worse outcomes.^16^

Black^ii^ individuals, in particular, are disproportionately affected by pregnancy-related morbidity and mortality.^14,17,18,19,20^ Studies of military service members show that, despite members’ equal access to healthcare and similar socioeconomic levels, non-Hispanic Black women were disproportionately affected by adverse health outcomes.^21,22^

Rates of adverse maternal outcomes vary across hospitals,^23^ and Black individuals are more likely to give birth in lower performing hospitals due to location and access issues. In addition, within similar hospitals, Black individuals continue to have higher rates of adverse outcomes.^24^ For example, Black individuals who gave birth at hospitals serving a high percentage of Black people (high Black-serving hospitals) had higher rates of severe maternal morbidity than both White individuals who gave birth at high Black-serving hospitals and Black individuals who gave birth at low Black-serving hospitals. White individuals who gave birth in low Black-serving hospitals had the lowest rates of severe maternal morbidity.^25^

Like Black individuals, some subgroups of Asian, Hispanic, and American Indian or Alaska Native (AI/AN) individuals experience higher rates of pregnancy-related complications and are at higher risk of delivering an infant with adverse health outcomes.^20,26,27^ Studies suggest that the physiological effects caused by the stress of racism lead to negative effects on the birthing person and infant, and structural racism, discrimination, and resulting mistrust of the healthcare system contribute to systemic disparities in maternal health outcomes.^19,28,29,30^

Maternal morbidity and mortality also vary substantially by age. Studies have shown that older women are more likely to have severe maternal morbidity.^31^ In addition, individuals under 18 years old are at risk for certain complications. Research shows that teenagers and women in their 40s and 50s are more likely to have eclampsia/preeclampsia^32^ or severe postpartum hemorrhage.^33,34^

Studies have also cited variation in maternal health by geographic location. Individuals in rural communities have higher rates of some types of maternal mortality and morbidity.^20,35,36^ Severe maternal morbidity varies by region, with states in the Northeast often having the highest rates and states in the Northwest often having the lowest rates.^37^ Evidence also shows that some immigrant populations in high-income countries, including immigrants to the United States, have worse maternal outcomes than individuals born in the high-income country.^38,39^

Additional disparities noted in the literature suggest that food insecurity,^40^ COVID-19,^41,42^ substance use disorders,^43^ and pollution^44,45^ negatively affect maternal and infant health outcomes.

### Cost

It was estimated that total maternal morbidity costs in the United States from conception through the child’s fifth birthday were $32.3 billion in 2019, nearly $9,000 for each parent-child pair.^46^

### Barriers to Care

Many cases of maternal mortality and morbidity are preventable.^47^ CDC estimated that between 2008 and 2017, about two-thirds of pregnancy-related deaths during delivery and in the first year postpartum were preventable and preventability did not vary by race or ethnicity.^48^ Many of the strategies for preventing maternal mortality also reduce maternal morbidity, and timely and appropriate prenatal, delivery, and postpartum care is associated with better maternal health outcomes.

Petersen, et al.,^11^ identified contributing factors to care for five levels:

- Community (e.g., inadequate access to clinical care),
- Health facility (e.g., limited experience with obstetric emergencies),
- Patient/family (e.g., lack of knowledge of warning signs or need to seek care),
- Provider (e.g., missed or delayed diagnosis), and
- System (e.g., inadequate receipt of care).

Additional studies have supported the need to address such factors, including:

- Existing healthcare needs,
- Lack of insurance/inability to afford care,
- Closures and service reductions at rural hospitals,
- Maternal healthcare workforce shortages,
- Long travel times due to lack of transportation or nearby provider, and
- Long wait times for an appointment and limited appointment times.^49,50,51,52^

Figure 1 shows the locations of maternity care deserts, defined as counties with no hospital offering obstetric care and no obstetric providers. It also presents limited access to maternity care (LAMC) counties, defined as counties with fewer than two hospitals offering obstetric care and fewer than 60 obstetric/gynecologic (OB-GYN) providers per 10,000 births.

The counties are separated into LAMC level 1, where 10% or more of women ages 18-64 lack health insurance, and LAMC level 2, where less than 10% of women ages 18-64 lack health insurance.^53^ Only 6% of OB-GYNs are located in rural areas and the ratio of OB-GYNs per 10,000 women is lower in nonmetropolitan areas than in metropolitan areas.^54^

Figure 1 Access to maternity care in U.S. counties, 2016

Map showing maternity care deserts (1,085), LAMC level 1 (367), LAMC level 2 (273), and access to maternity care (1,4110; maternity care deserts are prominent in the South and west of the Mississippi River, as well as Alaska. Areas on the coasts have better access to maternity care

Source: U.S. Health Resources and Services Administration, Area Health Resources Files, 2019.

## Findings

The figures in the maternal health section of the NHQDR illustrate significant trends over time and the most significant disparities in the most recent data year. For a deeper look at the disparities by geographic location, statistics about rural/urban location are also included where data are available. In addition, bivariate analyses are shown when such analyses are possible.

### Large Racial and Ethnic Disparities in Prenatal Care

Figure 2 Individuals with a live birth in the last 12 months who received early and at least adequate prenatal care, by race/ethnicity and geographic location, 2020

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Columns showing percentage; significant findings are in the text below the chart

Source: Centers for Disease Control and Prevention, National Vital Statistics System - Natality, 2020.

- In 2020, there were large racial/ethnic differences in the percentage of individuals with a live birth in the last 12 months who received early and adequate prenatal care (Figure 2). There was also a significant difference by geographic location. However, the disparities by race/ethnicity (41% relative difference between the groups with the highest and lowest percentages) were much larger than by geographic location (6% relative difference between the groups with the highest and lowest percentages).
- In 2020, the percentage of individuals with a live birth in the last 12 months who received early and adequate prenatal care was lower for Hispanic (69.5%), non-Hispanic AI/AN (59.1%), non-Hispanic Asian (76.5%), non-Hispanic Black (67.3%), and non-Hispanic Native Hawaiian/Pacific Islander (47.1%) individuals than for non-Hispanic White individuals (79.6%).
- In 2020, the percentage of individuals with a live birth in the last 12 months who received early and adequate prenatal care was lower for individuals in large central metro areas (71.9%) compared with individuals in large fringe metro areas (75.9%) (Figure 2).

### Higher Rates of Low-Risk Cesarean Deliveries for Black Women and Older Women

Figure 3 Cesarean deliveries of low-risk births among individuals giving birth for the first time, by age and race/ethnicity, 2020 (lower rates are better)

Key: AI/AN = American Indian or Alaska Native, NHPI = Native Hawaiian/Pacific Islander.

Note: Low-risk cesarean rate is defined as the number of singleton, term (37 or more weeks of gestation based on obstetric estimate), cephalic, cesarean deliveries to women having a first birth per 100 women delivering singleton, term, cephalic, first births.

Race and Hispanic origin data are reported separately on birth certificates. Mother’s race is defined by a single race reported on the birth certificate. People of Hispanic origin may be any race. Mother’s ethnicity classifies non-Hispanic women by single race. Race categories are consistent with 1997 Office of Management and Budget standards. These data are not comparable with bridged-race data published in previous reports.

Columns showing percentage; significant findings are in the text below the chart

Source: Centers for Disease Control and Prevention, National Vital Statistics System - Natality, 2020.

- In 2020, within all age groups, the percentage of cesarean deliveries of low-risk births among people giving birth for the first time was higher for non-Hispanic Black individuals than for non-Hispanic White individuals (Figure 3). In addition, the disparity between non-Hispanic Black and non-Hispanic White individuals was greater for higher age groups. The relative difference was 22% for individuals ages 15-19 years, 41% for individuals ages 30-34 years, and 30% for individuals age 35 years and over.
- In 2020, within all racial and ethnic groups, the percentage of cesarean deliveries of low-risk births among individuals giving birth for the first time was lower for individuals ages 15-19 years than for individuals ages 20-24 years.
- In 2020, within all racial and ethnic groups, the percentage of cesarean deliveries of low-risk births among individuals giving birth for the first time was higher for individuals ages 25-29 years, 30-34 years, and 35 years and over than for individuals ages 20-24 years.
- In 2020, the percentage of cesarean deliveries of low-risk births among women giving birth for the first time was lower in large central metro areas (26.2%), medium metro areas (25.6%), small metro areas (24.5%), micropolitan areas (25.0%), and noncore areas (25.5%) compared with individuals in large fringe metro areas (26.6%) (data not shown).

Figure 4 Cesarean deliveries of low-risk births among individuals giving birth for the first time, by age, 2007-2020 (lower rates are better)

Note: Low-risk cesarean rate is defined as the number of singleton, term (37 or more weeks of gestation based on obstetric estimate), cephalic, cesarean deliveries to women having a first birth per 100 women delivering singleton, term, cephalic, first births.

Race and Hispanic origin data are reported separately on birth certificates. Mother’s race is defined by a single race reported on the birth certificate. People of Hispanic origin may be any race. Mother’s ethnicity classifies non-Hispanic women by single race. Race categories are consistent with 1997 Office of Management and Budget standards. These data are not comparable with bridged-race data published in previous reports.

Line graphs showing percentage; significant findings are in the text below the graph

Source: Centers for Disease Control and Prevention, National Vital Statistics System - Natality, 2020.

- From 2007 to 2020, within all age groups, the percentage of cesarean deliveries decreased (Figure 4). However, the percentage of all cesarean deliveries did not decline significantly (from 27.5% to 25.9%) since the ages of individuals giving birth increased and older birthing individuals have higher rates of cesarean deliveries.

### Worsening Rates and Large Racial and Ethnic Disparities in Maternal Morbidity

Figure 5 Severe maternal morbidity per 1,000 deliveries, by race/ethnicity (left) and hospital delivery volume (right), 2016-2019 (lower rates are better)

Key: API = Asian or Pacific Islander.

Note: Severe maternal morbidity is an overall measure of unexpected health outcomes for multiple conditions as defined by the Centers for Disease Control and Prevention: https://www.cdc.gov/reproductivehealth/maternalinfanthealth/severematernalmorbidity.html. This figure uses data from HCUP Fast Stats for hospital delivery volume: http://datatools.ahrq.gov//hcup-fast-stats?type=subtab&tab=hcupfsse&count=3.

Line graph showing rate per 1,000 deliveries; significant findings are in the text below the graph

Line graph showing rate per 1,000 deliveries; significant findings are in the text below the graph

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project (HCUP), State Inpatient Databases weighted to provide national estimates, 2016-2019.

- In 2019, the rate of deliveries with severe maternal morbidity was 87% higher for non-Hispanic Black individuals than for non-Hispanic White individuals (Figure 5, left).
- In 2019, the rate of deliveries with severe maternal morbidity was higher for Hispanic (8.2 per 1,000 deliveries), non-Hispanic API (8.7 per 1,000 deliveries), and non-Hispanic Black (12.3 per 1,000 deliveries) individuals than for non-Hispanic White individuals (6.6 per 1,000 deliveries).
- From 2016 to 2019, the rate of deliveries with severe maternal morbidity increased for Hispanic individuals (from 7.1 per 1,000 deliveries to 8.2 per 1,000 deliveries) and non-Hispanic Black individuals (from 11.3 per 1,000 deliveries to 12.3 per 1,000 deliveries).
- In 2019, the rate of deliveries with severe maternal morbidity was lower in hospitals with fewer than 500 deliveries (4.9 per 1,000 deliveries) and 500 to 1,000 deliveries (5.6 per 1,000 deliveries) than in hospitals with more than 1,000 deliveries (8.6 per 1,000 deliveries) (Figure 5, right).
- From 2016 to 2019, the rate of deliveries with severe maternal morbidity increased for hospitals with more than 1,000 deliveries (from 7.6 per 1,000 deliveries to 8.6 per 1,000 deliveries).
- In 2019, the rate of deliveries with severe maternal morbidity was higher for deliveries to individuals from large central metro areas (9.8 per 1,000 deliveries) compared with large fringe metro areas (7.2 per 1,000 deliveries). The rate of deliveries with severe maternal morbidity was lower for deliveries to individuals from small metro areas (6.0 per 1,000 deliveries), micropolitan areas (5.2 per 1,000 deliveries), and noncore areas (5.1 per 1,000 deliveries) compared with large fringe metro areas (7.2 per 1,000 deliveries) (data not shown).

Figure 6 Eclampsia/preeclampsia per 1,000 deliveries, by race/ethnicity (left) and by hospital characteristics (right), 2016-2019 (lower rates are better)

Key: API = Asian or Pacific Islander, CAH = critical access hospital.

Note: Eclampsia/preeclampsia is a complication of pregnancy characterized by high blood pressure that can progress to kidney and liver dysfunction, blood cell destruction, seizures, and death.

Line graph showing rate per 1,000 deliveries; significant findings are in the text below the graph

Line graph showing rate per 1,000 deliveries; significant findings are in the text below the graph

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Inpatient Databases weighted to provide national estimates, 2016-2019.

- Between 2016 and 2019, the rate of deliveries with eclampsia/preeclampsia increased 30% across all deliveries. The increase was significant for all racial/ethnic groups (Figure 6, left) and most of the hospital characteristics examined (Figure 6, right).
- There were also significant racial/ethnic disparities. In 2019, deliveries to non-Hispanic Black individuals had a 58% higher rate of eclampsia/preeclampsia (99.2 per 1,000 deliveries) compared with deliveries to non-Hispanic White individuals (62.8 per 1,000 deliveries).
- In 2019, deliveries to non-Hispanic API individuals (49.3 per 1,000 deliveries) had a lower rate of eclampsia/preeclampsia than deliveries to non-Hispanic White individuals (62.8 per 1,000 deliveries).
- In 2019, deliveries to Hispanic individuals (69.7 per 1,000 deliveries) had a higher rate of eclampsia/preeclampsia than deliveries to non-Hispanic White individuals (62.8 per 1,000 deliveries).
- From 2016 to 2019, the rate of deliveries with eclampsia/preeclampsia increased for Hispanic individuals (from 53.8 per 1,000 deliveries to 69.7 per 1,000 deliveries), non-Hispanic API individuals (from 34.8 per 1,000 deliveries to 49.3 per 1,000 deliveries), non-Hispanic Black individuals (from 77.0 per 1,000 deliveries to 99.2 per 1,000 deliveries), and non-Hispanic White individuals (from 45.8 per 1,000 deliveries to 62.8 per 1,000 deliveries).
- Differences were also seen by hospital characteristics. For example, in 2019, the rate of deliveries with eclampsia/preeclampsia was nearly 40% lower at critical access hospitals (CAHs) compared with deliveries at non-CAHs (43.4 per 1,000 deliveries vs. 69.8 per 1,000 deliveries).
- In 2019, minority-serving hospitals had an 18% higher rate of deliveries with eclampsia/preeclampsia than non-minority-serving hospitals (75.9 per 1,000 deliveries vs. 64.4 per 1,000 deliveries).
- From 2016 to 2019, the rate of deliveries with eclampsia/preeclampsia increased for non-CAHs (from 53.6 per 1,000 deliveries to 69.8 per 1,000 deliveries), minority-serving hospitals (from 58.1 per 1,000 deliveries to 75.9 per 1,000 deliveries), and non-minority-serving hospitals (from 49.7 per 1,000 deliveries to 64.4 per 1,000 deliveries).
- In 2019, the rate of deliveries with eclampsia/preeclampsia was higher for individuals from large central metro areas (73.9 per 1,000 deliveries) compared with large fringe metro areas (66.2 per 1,000 deliveries) (data not shown).

Figure 7 Severe postpartum hemorrhage per 1,000 deliveries, by race/ethnicity (left) and hospital ownership (right), 2016-2019 (lower rates are better)

Key: API = Asian or Pacific Islander.

Note: Severe postpartum hemorrhage is dangerous amounts of bleeding that can occur after delivery: placenta accreta, placenta increta, placenta percreta, third-stage hemorrhage, other immediate postpartum hemorrhage, delayed and secondary postpartum hemorrhage, and postpartum coagulation defects.

Line graph showing rate per 1,000 deliveries; significant findings are in the text below the graph

Line graph showing rate per 1,000 deliveries; significant findings are in the text below the graph

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Inpatient Databases weighted to provide national estimates, 2016-2019.

- Between 2016 and 2019, the rate of deliveries with severe postpartum hemorrhage increased 27% across all deliveries (Figure 7). The increase was significant for all racial/ethnic groups and most hospital ownership categories examined.
- Significant disparities were observed (Figure 7, left). In 2019, deliveries to non-Hispanic API individuals had a 45% higher rate of severe postpartum hemorrhage compared with deliveries to non-Hispanic White individuals, and the disparity had worsened over time. In addition, the rate of severe postpartum hemorrhage for public hospitals was more than double that of private, for-profit hospitals in 2019.
- In 2019, Hispanic individuals (48.0 per 1,000 deliveries) and non-Hispanic API individuals (57.3 per 1,000 deliveries) were more likely than non-Hispanic White individuals (39.6 per 1,000 deliveries) to have a severe postpartum hemorrhage.
- From 2016 to 2019, the disparity in severe postpartum hemorrhage rates worsened for deliveries to API individuals compared with deliveries to non-Hispanic White individuals.
- From 2016 to 2019, the rate of deliveries with severe postpartum hemorrhage increased for Hispanic individuals (from 38.6 per 1,000 deliveries to 48.0 per 1,000 deliveries), non-Hispanic API individuals (from 43.8 per 1,000 deliveries to 57.3 per 1,000 deliveries), non-Hispanic Black individuals (from 33.8 per 1,000 deliveries to 43.5 per 1,000 deliveries), and non-Hispanic White individuals (from 30.9 per 1,000 deliveries to 39.6 per 1,000 deliveries).
- In 2019, the rate of deliveries with severe postpartum hemorrhage at public hospitals (53.0 per 1,000 deliveries) and private, not-for-profit hospitals (45.1 per 1,000 deliveries) was higher compared with private, for-profit hospitals (25.7 per 1,000 deliveries) (Figure 7, right).
- From 2016 to 2019, the rate of deliveries with severe postpartum hemorrhage increased for public hospitals (from 44.9 per 1,000 deliveries to 53.0 per 1,000 deliveries), private, not-for-profit hospitals (from 35.2 per 1,000 deliveries to 45.1 per 1,000 deliveries), and private, for-profit hospitals (from 19.7 per 1,000 deliveries to 25.7 per 1,000 deliveries).
- In 2019, the rate of deliveries with severe postpartum hemorrhage was higher for individuals from large central metro areas (49.0 per 1,000 deliveries) compared with large fringe metro areas (42.8 per 1,000 deliveries). The rate of deliveries with severe postpartum hemorrhage was lower for individuals from small metro areas (37.6 per 1,000 deliveries) and micropolitan areas (37.0 per 1,000 deliveries) compared with large fringe metro areas (42.8 per 1,000 deliveries) (data not shown).

Figure 8 Venous thromboembolism or pulmonary embolism per 1,000 delivery discharges, by race/ethnicity (left) and bed size (right), 2016-2019 (lower rates are better)

Key: API = Asian or Pacific Islander.

Note: Venous thromboembolism/pulmonary embolism refers to development of blood clots, a potentially fatal risk that can increase during pregnancy.

Line graph showing rate per 1,000 deliveries; significant findings are in the text below the graph

Line graph showing rate per 1,000 deliveries; significant findings are in the text below the graph

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Inpatient Databases weighted to provide national estimates, 2016-2019.

- From 2016 to 2019, the rate of deliveries with venous thromboembolism or pulmonary embolism increased nearly 10% across all deliveries (Figure 8). The percentage increase was highest in hospitals with fewer than 100 beds (54% increase) (Figure 8, right).
- In 2019, Hispanic individuals (0.23 per 1,000 deliveries) and non-Hispanic API individuals (0.12 per 1,000 deliveries) giving birth were less likely than non-Hispanic White individuals (0.31 per 1,000 deliveries) giving birth to have a venous thromboembolism or pulmonary embolism (Figure 8, left).
- In 2019, non-Hispanic Black individuals (0.35 per 1,000 deliveries) giving birth were more likely than non-Hispanic White individuals (0.31 per 1,000 deliveries) giving birth to have a venous thromboembolism or pulmonary embolism.
- In 2019, hospitals with fewer than 100 beds (0.20 per 1,000 deliveries), 100-299 beds (0.21 per 1,000 deliveries), and 300-499 (0.28 per 1,000 deliveries) had lower rates of venous thromboembolism or pulmonary embolism than hospitals with 500 or more beds (0.39 per 1,000 deliveries).
- In 2019, the rate of deliveries with venous thromboembolism or pulmonary embolism did not vary by geographic location of the birthing person (data not shown).

## Conclusion

The findings from data collected and analyzed for the NHQDR mirror some conclusions reported by the literature and provide additional insights. For most maternal health measures included in the NHQDR, disparities are significant for comparisons by race/ethnicity, age, and hospital characteristics.

For prenatal care, the findings are consistent with those from the research community in that Hispanic, AI/AN, Black, and Native Hawaiian/Pacific Islander individuals are less likely than White and non-Hispanic White individuals to receive prenatal care. However, there was no evidence of large differences in prenatal care by urban/rural location.

The NHQDR findings also showed that the rate of cesarean deliveries for first time, low-risk pregnancies was higher for non-Hispanic Black individuals than for non-Hispanic White individuals and the disparity widened with maternal age. In addition, the rate of cesarean deliveries within each age group decreased, but because maternal age is increasing, the overall rate of cesarean deliveries did not change significantly.

The results also indicated that rates of the four pregnancy-related complications examined (severe maternal morbidity, eclampsia/preeclampsia, severe postpartum hemorrhage, venous thromboembolism or pulmonary embolism) were increasing over time across all deliveries. In addition, disparities related to racial/ethnic categories were common.

Rates of severe maternal morbidity, eclampsia/preeclampsia, and venous thromboembolism or pulmonary embolism were significantly worse for non-Hispanic Black individuals compared with non-Hispanic White individuals. Rates of severe postpartum hemorrhage were significantly worse for non-Hispanic API individuals compared with non-Hispanic White individuals, and the disparity was growing larger over time.

Differences were also seen by hospital characteristics. Hospitals with fewer beds (for severe maternal morbidity, venous thromboembolism or pulmonary embolism), private, for-profit hospitals (for severe postpartum hemorrhage), minority-serving hospitals^iii^ (for eclampsia/preeclampsia), and CAHs (for eclampsia/preeclampsia) had fewer complications. Although rural/urban location is associated with these hospital characteristics, none are a proxy for rural/urban location. For example, more than 80% of rural hospitals have fewer than 100 beds, but just over half of the hospitals with fewer than 100 beds are located in rural areas.^55,56^

In addition to assessing disparities across various characteristics, maternal health was trended over time. Results showed that, despite efforts to improve the quality of maternal care, most morbidities increased across nearly all population groups in the years assessed for this report.

## Resources

The Department of Health and Human Services (HHS) has identified maternal health as a national priority to address factors that contribute to maternal mortality and are disproportionately higher for Black and AI/AN women regardless of income or education. HHS is also working to address factors contributing to women living in rural areas experiencing higher pregnancy-related mortality than women in nonrural areas, such as social determinants of health, mental health, and substance use as they relate to maternal healthcare.

The White House Blueprint for Addressing the Maternal Health Crisis (https://www.whitehouse.gov/wp-content/uploads/2022/06/Maternal-Health-Blueprint.pdf) addresses five maternal health-related priorities:

- Increasing access to and coverage of comprehensive high-quality maternal health services, including behavioral health services.
- Ensuring that individuals giving birth are heard and are decision makers in accountable systems of care.
- Advancing data collection, standardization, harmonization, transparency, and research.
- Expanding and diversifying the perinatal workforce.
- Strengthening economic and social supports for people before, during, and after pregnancy.

The administration intends to address the priorities through:

- Extended postpartum coverage,
- Investments in rural maternal care,
- A maternal mental health hotline,
- Substance use services,
- Elimination of surprise bills,
- Improved maternal health data,
- A more diverse maternal care workforce,
- Better access to doulas and midwives,
- Expanded social services, and
- Stronger workplace protections for mothers.

In September 2021, HHS announced $350 million in awards to support maternal health. The programs included the Maternal, Infant, and Early Childhood Home Visiting (MIECHV) Program (https://mchb.hrsa.gov/maternal-child-health-initiatives/home-visiting-overview) and the Healthy Start Initiative (https://mchb.hrsa.gov/maternal-child-health-initiatives/healthy-start). The latter focuses on Community-Based Doulas (https://www.hrsa.gov/grants/find-funding/hrsa-21-121), Infant Health Equity (https://www.hrsa.gov/grants/find-funding/hrsa-21-120), and the State Systems Developmental Initiative (https://www.hrsa.gov/grants/find-funding/hrsa-21-130). In April 2022, HHS announced additional funds for MIECHV and the State Maternal Health Innovation and Implementation Program. HHS funding is also aimed at maternal health initiatives in rural communities, implicit bias training for healthcare providers, pregnancy medical home demonstration projects, perinatal health disparities, data collection and evaluation, and behavioral health disorders.

In addition, HHS’s Office on Women’s Health is funding the Maternal Morbidity and Mortality Data and Analysis Initiative (https://www.womenshealth.gov/about-us/what-we-do/programs-and-activities/owh-maternal-morbidity-and-mortality-data-and-analysis). The initiative improves maternal health data by creating a network of more than 200 hospitals to deploy clinical, evidence-based best practices in maternity care. As part of the contract, Maternal Mortality and Morbidity Advocates’ (MoMMA’s) Voices, a coalition of many organizations, will focus on the patient experience to ensure patients’ voices are heard. The Perinatal Improvement Collaborative (https://www.hhs.gov/about/news/2021/11/08/hhs-announces-200-hospitals-participating-new-maternal-and-infant-care-collaborative.html) is part of the initiative. Each of the more than 200 participating hospitals will capture more than 150 clinical and nonclinical measures that affect health outcomes (e.g., clinical data pertaining to hypertension, infection, and COVID-19).

The following links provide information on additional initiatives aimed at improving maternal health:

- Surgeon General’s Call to Action to Improve Maternal Health (https://www.hhs.gov/sites/default/files/call-to-action-maternal-health.pdf)
- HHS Rural Action Plan (https://www.hhs.gov/sites/default/files/hhs-rural-action-plan.pdf)
- HHS Hypertension Innovator Award Competition (https://www.womenshealth.gov/about-us/what-we-do/programs-and-activities/hhs-hypertension-innovator-award-competition)
- Public-Private Partnership to Improve Maternal Outcomes for Black Mothers (https://www.hhs.gov/about/agencies/iea/initiatives/index.html)
- Initiative to Improve Maternal Health Data and Drive Quality Improvement (https://www.womenshealth.gov/blog/hhs-awards-contract-improve-maternal-health-data-collection-and-drive-clinical-quality)
- State Data for Conducting Patient Centered Outcomes Research to Improve Maternal Health: Stakeholder Discussions Summary Report (https://aspe.hhs.gov/sites/default/files/private/pdf/259016/state-data-for-pcor-mh.pdf)

The literature presents and, in some cases, assesses strategies to address factors related to maternal health. At the provider level, those with fewer deliveries appear to have higher rates of adverse outcomes. Therefore, the recommendation was made to refer to higher volume providers or improve training for low-volume providers.^57^ Another study assessed the state-level earned income tax credit (EITC) and found that EITC overall was associated with better birth outcomes, with increasing effects the more generous an EITC was.^58^ Additional strategies include allowing presumptive eligibility for Medicaid^59^ and requiring implicit bias training for providers.^16^

## References

1 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final Data for 2020. Natl Vital Stat Rep. 2021 Feb;70(17):1–50. https://www.cdc.gov/nchs/data/nvsr/nvsr70/nvsr70-17.pdf. Accessed October 3, 2022.
2 Hamilton BE, Martin JA, Osterman MJK. Births: Provisional Data for 2021. Vital Statistics Rapid Release No. 20. Hyattsville, MD: National Center for Health Statistics; 2022. 10.15620/cdc:116027. Accessed October 3, 2022.
3 Hoyert DL. Maternal mortality rates in the United States, 2019. NCHS Health E-Stats. 2021. 10.15620/cdc:103855. Accessed October 3, 2022.
4 Hoyert DL. Maternal mortality rates in the United States, 2020. NCHS Health E-Stats. 2022. 10.15620/cdc:113967. Accessed October 3, 2022.
5 Maternal Mortality and Maternity Care in the United States Compared to 10 Other Developed Countries. Issue Brief. New York, NY: The Commonwealth Fund; November 2020. https://www.commonwealthfund.org/publications/issue-briefs/2020/nov/maternal-mortality-maternity-care-us-compared-10-countries. Accessed October 3, 2020.
6 Centers for Disease Control and Prevention. Severe Maternal Morbidity in the United States. Last reviewed February 2021. https://www.cdc.gov/reproductivehealth/maternalinfanthealth/severematernalmorbidity.html. Accessed October 3, 2022.
7 Severe Maternal Morbidity in the United States: A Primer. Issue Brief. New York, NY: The Commonwealth Fund; October 2021. https://www.commonwealthfund.org/publications/issue-briefs/2021/oct/severe-maternal-morbidity-united-states-primer. Accessed October 3, 2022.
8 Centers for Disease Control and Prevention. How Does CDC Identify Severe Maternal Morbidity? Last reviewed December 2019. https://www.cdc.gov/reproductivehealth/maternalinfanthealth/smm/severe-morbidity-ICD.htm. Accessed October 3, 2022.
9 Office of the Surgeon General. The Surgeon General’s Call to Action to Improve Maternal Health. Washington, DC: U.S. Department of Health and Human Services; December 2020. https://www.hhs.gov/sites/default/files/call-to-action-maternal-health.pdf. Accessed October 3, 2022.
10 Gestational Hypertension and Preeclampsia: ACOG Practice Bulletin Summary, Number 222. Obstet Gynecol. 2020 Jun;135(6):1492–95. https://pubmed.ncbi.nlm.nih.gov/32443077/. Accessed October 3, 2022.32443077
11 Committee on Practice Bulletins-Obstetrics. ACOG Practice Bulletin No. 198: Prevention and Management of Obstetric Lacerations at Vaginal Delivery. Obstet Gynecol. 2018 Sep;132(3):e87–e102. https://pubmed.ncbi.nlm.nih.gov/30134424/. Accessed October 3, 2022.30134424
12 Bauman BL, Ko JY, Cox S, D’Angelo DV, Warner L, Folger S, Tevendale HD, Coy KC, Harrison L, Barfield WD. Vital signs: postpartum depressive symptoms and provider discussions about perinatal depression — United States, 2018. MMWR Morb Mortal Wkly Rep 2020;69:575–81. 10.15585/mmwr.mm6919a2. Accessed October 3, 2022.32407302
13 Lindahl V, Pearson JL, Colpe L. Prevalence of suicidality during pregnancy and the postpartum. Arch Womens Ment Health. 2005 Jun;8(2):77–87. https://pubmed.ncbi.nlm.nih.gov/15883651/. Accessed October 3, 2022.15883651
14 Wallace M, Gillispie-Bell V, Cruz K, Davis K, Vilda D. Homicide during pregnancy and the postpartum period in the United States, 2018-2019. Obstet Gynecol. 2021 Nov 1;138(5):762–769. Erratum in: Obstet Gynecol. 2022 Feb 1;139(2):347. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC9134264/. Accessed October 3, 2022.34619735
15 Centers for Disease Control and Prevention. CDC WONDER. Last reviewed August 2022. https://wonder.cdc.gov/. Accessed October 3, 2022.
16 Howell EA. Reducing disparities in severe maternal morbidity and mortality. Clin Obstet Gynecol. 2018 Jun;61(2):387–99. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5915910/. Accessed October 3, 2022.29346121
17 Petersen EE, Davis NL, Goodman D, Cox S, Mayes N, Johnston E, Syverson C, Seed K, Shapiro-Mendoza CK, Callaghan WM, Barfield W. Vital signs: pregnancy-related deaths, United States, 2011-2015, and strategies for prevention, 13 states, 2013-2017. MMWR Morb Mortal Wkly Rep 2019;68:423–29. 10.15585/mmwr.mm6818e1. Accessed October 3, 2022.31071074
18 Howell EA, Zeitlin J. Quality of care and disparities in obstetrics. Obstet Gynecol Clin North Am. 2017;44(1):13–25. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5300700/. Accessed October 3, 2022.28160890
19 Glazer KB, Zeitlin J, Howell EA. Intertwined disparities: applying the maternal-infant dyad lens to advance perinatal health equity. Semin Perinatol. 2021 Jun;45(4):151410. 10.1016/j.semperi.2021.151410. Accessed October 3, 2022.33865629
20 Shah LM, Varma B, Nasir K, Walsh MN, Blumenthal RS, Mehta LS, Sharma G. Reducing disparities in adverse pregnancy outcomes in the United States. Am Heart J. 2021 Dec;242:92–102. 10.1016/j.ahj.2021.08.019. Accessed October 3, 2022.34481757
21 Hall C, Bukowinski AT, McGill AL, You WB, Gumbs GR, Wells NY, Conlin AMS. Racial disparities in prenatal care utilization and infant small for gestational age among active duty U.S. military women. Matern Child Health J. 2020 Jul;24(7):885–93. 10.1007/s10995-020-02941-3. Accessed October 3, 2022.32356127
22 Hamilton JL, Shumbusho D, Cooper D, Fletcher T, Aden J, Weir L, Keyser E. Race matters: maternal morbidity in the Military Health System. Am J Obstet Gynecol. 2021 May;224(5):512.e1–512.e6. 10.1016/j.ajog.2021.02.036. Accessed October 3, 2022.
23 Bailit JL, Grobman WA, Rice MM, Spong CY, Wapner RJ, Varner MW, Thorp JM, Leveno KJ, Caritis SN, Shubert PJ, Tita AT, Saade G, Sorokin Y, Rouse DJ, Blackwell SC, Tolosa JE, Van Dorsten JP; Eunice Kennedy Shriver National Institute of Child Health and Human Development Maternal–Fetal Medicine Units Network. Risk-adjusted models for adverse obstetric outcomes and variation in risk-adjusted outcomes across hospitals. Am J Obstet Gynecol. 2013;209(5):446.e1–446.e30. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4030746/. Accessed October 3, 2022.
24 Creanga AA, Bateman BT, Mhyre JM, Kuklina E, Shilkrut A, Callaghan WM. Performance of racial and ethnic minority-serving hospitals on delivery-related indicators. Am J Obstet Gynecol. 2014 Dec;211(6):647.e1–16. https://pubmed.ncbi.nlm.nih.gov/24909341/. Accessed October 3, 2022.
25 Howell EA, Egorova N, Balbierz A, Zeitlin J, Hebert PL. Black-white differences in severe maternal morbidity and site of care. Am J Obstet Gynecol. Jan; 2016 214(1):122, e121–127. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4698019/. Accessed October 3, 2022.
26 Parchem JG, Gupta M, Chen HY, Wagner S, Mendez-Figueroa H, Chauhan SP. Adverse infant and maternal outcomes among low-risk term pregnancies stratified by race and ethnicity. Obstet Gynecol. 2020 Apr;135(4):925–34. 10.1097/AOG.0000000000003730. Accessed October 3, 2022.32168221
27 Testa A, Jackson DB. Race, ethnicity, WIC participation, and infant health disparities in the United States. Ann Epidemiol. 2021 Jun;58:22–28. 10.1016/j.annepidem.2021.02.005. Accessed October 3, 2022.33626410
28 Vedam S, Stoll K, Taiwo TK, Rubashkin N, Cheyney M, Strauss N, McLemore M, Cadena M, Nethery E, Rushton E, Schummers L, Declercq E; GVtM-US Steering Council. The Giving Voice to Mothers study: inequity and mistreatment during pregnancy and childbirth in the United States. Reprod Health. 2019 Jun 11;16(1):77. 10.1186/s12978-019-0729-2. Accessed October 3, 2022.31182118
29 Ekeke P, Mendez DD, Yanowitz TD, Catov JM. Racial differences in the biochemical effects of stress in pregnancy. Int J Environ Res Public Health. 2020 Sep 23;17(19):6941. 10.3390/ijerph17196941. Accessed October 3, 2022.32977397
30 Riggan KA, Gilbert A, Allyse MA. Acknowledging and addressing allostatic load in pregnancy care. J Racial Ethn Health Disparities. 2021 Feb;8(1):69–79. 10.1007/s40615-020-00757-z. Accessed October 3, 2022.32383045
31 Lisonkova S, Potts J, Muraca GM, Razaz N, Sabr Y, Chan WS, Kramer MS. Maternal age and severe maternal morbidity: a population-based retrospective cohort study. PLoS Med. 2017 May 30;14(5):e1002307. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5448726/. Accessed October 3, 2022.28558024
32 Aoyama K, Pinto R, Ray JG, Hill AD, Scales DC, Lapinsky SE, Hladunewich MA, Seaward GR, Fowler RA. Association of maternal age with severe maternal morbidity and mortality in Canada. JAMA Netw Open. 2019 Aug 2;2(8):e199875. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6714030/. Accessed October 3, 2022.31441937
33 Liu CN, Yu FB, Xu YZ, Li JS, Guan ZH, Sun MN, Liu CA, He F, Chen DJ. Prevalence and risk factors of severe postpartum hemorrhage: a retrospective cohort study. BMC Pregnancy Childbirth. 2021 Apr 26;21(1):332. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC8077797/. Accessed October 3, 2022.33902475
34 Freeman, H. Austinn MD; Salmeen, Kirsten MD; Shirazi, Aida PhD; Morocco, Sarah MD. Postpartum hemorrhage and very advanced maternal age [28M]. Obstetr Gynecol. 2020 May;135:142S. 10.1097/01.AOG.0000664820.70051.60. Accessed October 3, 2022.
35 Kozhimannil KB, Interrante JD, Henning-Smith C, Admon LK. Rural-urban differences in severe maternal morbidity and mortality in the U.S., 2007-15. Health Aff (Millwood). 2019 Dec;38(12):2077–85. 10.1377/hlthaff.2019.00805. Accessed October 3, 2022.31794322
36 Lisonkova S, Haslam MD, Dahlgren L, Chen I, Synnes AR, Lim KI. Maternal morbidity and perinatal outcomes among women in rural versus urban areas. CMAJ. 2016;188(17–18):E456–E465. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5135522/. Accessed October 3, 2022.27672220
37 Agency for Healthcare Research and Quality. HCUP Fast Stats - Map of Severe Maternal Morbidity (SMM) Among In-Hospital Deliveries. Last modified May 2022. https://www.hcup-us.ahrq.gov/faststats/SMMMap. Accessed October 3, 2022.
38 van den Akker T, van Roosmalen J. Maternal mortality and severe morbidity in a migration perspective. Best Pract Res Clin Obstet Gynaecol. 2016 Apr;32:26–38. https://pubmed.ncbi.nlm.nih.gov/26427550/. Accessed October 3, 2022.26427550
39 Urquia ML, Glazier RH, Mortensen L, Nybo-Andersen AM, Small R, Davey MA, Rööst M, Essén B; ROAM (Reproductive Outcomes and Migration. An International Collaboration). Severe maternal morbidity associated with maternal birthplace in three high-immigration settings. Eur J Public Health. 2015 Aug;25(4):620–5. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4512956/. Accessed October 3, 2022.25587005
40 Di Renzo GC, Tosto V. Food insecurity, food deserts, reproduction, and pregnancy: we should alert from now. J Matern Fetal Neonatal Med. 2021 Dec 17:1–3. 10.1080/14767058.2021.2016052. Accessed October 3, 2022.
41 Dongarwar D, Ajewole VB, Oduguwa E, Ngujede A, Harris K, Ofili TU, Olaleye OA, Salihu HM. Role of social determinants of health in widening maternal and child health disparities in the era of COVID-19 pandemic. Int J MCH AIDS. 2020;9(3):316–19. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7397329/. Accessed October 18, 2022.32765962
42 Chmielewska B, Barratt I, Townsend R, Kalafat E, van der Meulen J, Gurol-Urganci I, O’Brien P, Morris E, Draycott T, Thangaratinam S, Le Doare K, Ladhani S, von Dadelszen P, Magee L, Khalil A. Effects of the COVID-19 pandemic on maternal and perinatal outcomes: a systematic review and meta-analysis. Lancet Glob Health. 2021 Jun;9(6):e759–e772. 10.1016/S2214-109X(21)00079-6. Accessed October 3, 2022.33811827
43 Jarlenski M, Krans EE, Chen Q, Rothenberger SD, Cartus A, Zivin K, Bodnar LM. Substance use disorders and risk of severe maternal morbidity in the United States. Drug Alcohol Depend. 2020 Nov 1;216:108236. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7606664/. Accessed October 3, 2022.32846369
44 Benmarhnia T, Huang J, Basu R, Wu J, Bruckner TA. Decomposition analysis of black-white disparities in birth outcomes: the relative contribution of air pollution and social factors in California. Environ Health Perspect. 2017 Oct 4;125(10):107003. 10.1289/EHP490. Accessed October 3, 2022.28977781
45 Qiu X, Fong KC, Shi L, Papatheodorou S, Di Q, Just A, Kosheleva A, Messerlian C, Schwartz JD. Prenatal exposure to particulate air pollution and gestational age at delivery in Massachusetts neonates 2001-2015: a perspective of causal modeling and health disparities. Environ Epidemiol. 2020 Sep 14;4(5):e113. 10.1097/EE9.0000000000000113. Accessed October 3, 2022.33154990
46 The High Costs of Maternal Morbidity Show Why We Need Greater Investment in Maternal Health. Issue Brief. New York, NY: The Commonwealth Fund; November 2021. https://www.commonwealthfund.org/publications/issue-briefs/2021/nov/high-costs-maternal-morbidity-need-investment-maternal-health. Accessed October 3, 2022.
47 Centers for Disease Control and Prevention. Preventing Pregnancy-Related Deaths. Last reviewed April 2022. https://www.cdc.gov/reproductivehealth/maternal-mortality/preventing-pregnancy-related-deaths.html. Accessed October 3, 2022.
48 Davis NL, Smoots AN, Goodman DA. Pregnancy-Related Deaths: Data From 14 U.S. Maternal Mortality Review Committees, 2008-2017. Atlanta, GA: Centers for Disease Control and Prevention; 2019. https://www.cdc.gov/reproductivehealth/maternal-mortality/erase-mm/MMR-Data-Brief_2019-h.pdf. Accessed October 14, 2022.
49 Thomas SR, Pink GH, Reiter O. Trends in Risk of Financial Distress Among Rural Hospitals, 2015 to 2019. Chapel Hill: North Carolina Rural Health Research Program, Cecil G. Sheps Center for Health Services Research, .University of North Carolina; April 2019. https://www.shepscenter.unc.edu/wp-content/uploads/dlm_uploads/2019/04/FDI-Trends-1.pdf. Accessed October 3, 2022.
50 National Advisory Council on the National Health Service Corps. Recommendations for Priorities to Support National Health Service Corps Efforts to Address the U.S. Health Care Workforce Shortage 2021-2023. Rockville, MD: Health Resources and Services Administration; 2021. https://www.hrsa.gov/sites/default/files/hrsa/advisory-committees/national-health-service-corps/nhsc-healthcare-shortage-2021-2023.pdf. Accessed October 3, 2022.
51 Holcomb DS, Pengetnze Y, Steele A, Karam A, Spong C, Nelson DB. Geographic barriers to prenatal care access and their consequences. Am J Obstet Gynecol MFM. 2021 Sep;3(5):100442. https://www.ajogmfm.org/article/S2589-9333(21)00137-3/fulltext. Accessed October 3, 2022.34245930
52 Kozhimannil KB, Hung P, Henning-Smith C, Casey MM, Prasad S. Association between loss of hospital-based obstetric services and birth outcomes in rural counties in the United States. JAMA. 2018 Mar 27;319(12):1239–47. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5885848/. Accessed October 3, 2022.29522161
53 Nowhere To Go: Maternity Care Deserts Across the U.S. Arlington, VA: March of Dimes; 2018. https://www.marchofdimes.org/materials/Nowhere_to_Go_Final.pdf. Accessed October 3, 2022.
54 Health Disparities in Rural Women Committee Opinion Number 586. Washington, DC: American College of Obstetricians and Gynecologists; February 2014. https://www.acog.org/clinical/clinical-guidance/committee-opinion/articles/2014/02/health-disparities-in-rural-women/. Accessed October 3, 2022.
55 Trendwatch. The Opportunities and Challenges for Rural Hospitals in an Era of Health Reform. Chicago: American Hospital Association; April 2011. https://www.aha.org/system/files/2018-03/11apr-tw-rural.pdf. Accessed October 3, 2022.
56 Fast Facts: U.S. Rural Hospitals. Chicago: American Hospital Association. https://www.aha.org/infographics/2021-05-24-fast-facts-us-rural-hospitals-infographic. Accessed October 3, 2022.
57 Janakiraman V, Lazar J, Joynt KE, Jha AK. Hospital volume, provider volume, and complications after childbirth in U.S. hospitals. Obstet Gynecol. 2011;118(3):521–27. https://pubmed.ncbi.nlm.nih.gov/21826039/. Accessed October 3, 2022.21826039
58 Komro KA, Markowitz S, Livingston MD, Wagenaar AC. Effects of state-level earned income tax credit laws on birth outcomes by race and ethnicity. Health Equity. 2019 Mar 12;3(1):61–67. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6419088/. Accessed October 3, 2022.30886942
59 Deadly delivery: the maternal health care crisis in the USA. New York, NY: Amnesty International; March 12, 2010. Index Number: AMR 51/007/2010. https://www.amnesty.org/en/documents/amr51/007/2010/en/. Accessed October 3, 2022.

i The total fertility rate of a population is the average number of children a hypothetical cohort of women would have at the end of their reproductive period if they were subject during their whole lives to the fertility rates of a given period and if they were not subject to mortality. It is expressed as children per woman. More information is available from the World Health Organization at https://www.who.int/data/gho/indicator-metadata-registry/imr-details/123#:~:text=Total%20fertility%20rate%20is%20directly,in%20five%2Dyear%20age%20groups.

ii Some studies assessed rates for Black women while others assessed rates for non-Hispanic Black women.

iii Hospitals providing Heathcare Cost and Utilization Project data were ranked in descending order according to the percentage of total hospital discharges with a minority race/ethnicity (Black, Hispanic, Asian or Pacific Islander, American Indian or Alaska Native, other). The top 25% of hospitals (i.e., with the highest percentage of minority patients) were designated as minority serving.