# APPENDIX F DEFINITIONS AND ABBREVIATIONS USED IN 2022 NHQDR

## Definitions

### Racial and Ethnic Groups

Racial and ethnic groups are defined according to Standards for the Classification of Federal Data on Race and Ethnicity, issued by the Office of Management and Budget (available at https://www.gpo.gov/fdsys/granule/FR-1997-10-30/97-28653).

The basic racial and ethnic categories for federal statistics and program administrative reporting are defined as follows:

1. American Indian or Alaska Native (AI/AN). A person having origins in any of the original peoples of North and South America (including Central America) and who maintains tribal affiliation or community attachment.
2. Asian. A person having origins in any of the original peoples of the Far East, Southeast Asia, or the Indian subcontinent, including, for example, Cambodia, China, India, Japan, Korea, Malaysia, Pakistan, the Philippine Islands, Thailand, and Vietnam.
3. Black or African American. A person having origins in any of the Black racial groups of Africa. Terms such as “Haitian” can be used in addition to “Black or African American.”
4. Hispanic or Latino. A person of Cuban, Mexican, Puerto Rican, Central or South American, or other Spanish culture or origin, regardless of race. The term “Spanish origin” can be used in addition to “Hispanic or Latino.”
5. Native Hawaiian/Pacific Islander (NHPI). A person having origins in any of the original peoples of Hawaii, Guam, Samoa, or other Pacific Islands.
6. White. A person having origins in any of the original peoples of Europe, the Middle East, or North Africa.

### Income

Income groups are based on the poverty guideline (PG) for a family of four:

- Less than 100% of PG
- 100% to less than 200% of PG
- 200% to less than 400% of PG
- 400% or more of PG

The poverty guidelines are available at https://aspe.hhs.gov/poverty-guidelines.

### Urban-Rural Areas

Urban and rural areas are defined based on the National Center for Health Statistics 2013 Urban-Rural Classification Scheme.

Figure F-1 Map showing 2013 NCHS Urban-Rural County Classifications in the United States

Map showing metropolitan and nonmetropolitan areas; classifications are noted in the text below the map

- Metropolitan counties:
  ■ Large central metro counties in metropolitan statistical area (MSA) of 1 million or more population that: (1) contain the entire population of the largest principal city of the MSA, or (2) are completely contained within the largest principal city of the MSA, or (3) contain at least 250,000 residents of any principal city in the MSA
  ■ Large fringe metro counties in MSA of 1 million or more population that do not qualify as large central.
  ■ Medium metro counties in MSA of 250,000-999,999 population.
  ■ Small metro counties in MSAs of less than 250,000 population.
- Nonmetropolitan counties:
  ■ Micropolitan: Counties in a micropolitan statistical area.
  ■ Noncore: Nonmetropolitan counties that are not in a micropolitan statistical area.

More information is available at https://www.cdc.gov/nchs/data_access/urban_rural.htm.

### Disabilities

Disability status is defined by following the methodology of the American Community Survey, which is different from the Activity Limitation used in the 2007-2018 NHQDR.

- Adults age 18 and over are defined as with disability if one reported with serious difficulty in hearing, serious difficulty in vision, serious cognitive difficulty, serious difficulty in walking or climbing stairs, difficulty in dressing or bathing, and difficulty in doing errands.
- Children with special health care needs (CSHCN): Children ages 0-17 with activity limitations or need or use of more healthcare or other services than is usual for most children of the same age. Question sequences^i^ are asked about the following five health consequences: the need or use of medicines prescribed by a doctor; the need or use of more medical care, mental health care, or education services than is usual for most children; limitations or inability to do things most children can do; the need or use of special therapy, such as physical, occupational, or speech therapy; and the need or use of treatment or counseling for emotional, developmental, or behavioral problems. Children with responses to at least one of the five health consequences were identified as having a special health care need.

## Abbreviations Used in the NHQDR

- ACA: Affordable Care Act
- AHA: American Hospital Association
- AI/AN: American Indian or Alaska Native
- API: Asian and Pacific Islander
- APRN: advanced practice registered nurse
- CAH: critical access hospital
- CAHPS: Consumer Assessment of Healthcare Providers and Systems
- CCRC: continuing care retirement community
- CHIP: Children’s Health Insurance Program
- DSM-5: Diagnostic and Statistical Manual of Mental Disorders, fifth edition
- ED: emergency department
- EITC: earned income tax credit
- EMT: emergency medical technician
- HCUP: Healthcare Cost & Utilization Project
- HHS: U.S. Department of Health and Human Services
- HPSA: health professional shortage area
- HPV: human papillomavirus
- ICD-9-CM: International Classification of Diseases, Ninth Revision, Clinical Modification
- ICD-10-CM: International Classification of Diseases, Tenth Revision, Clinical Modification
- IMF: illicitly manufactured fentanyl
- IOM: Institute of Medicine
- IWG: Interagency Work Group
- LAMC: limited access to maternity care
- LPN/LNV: licensed practical nurse/licensed vocational nurse
- MAT: medication-assisted treatment
- MEPS: Medical Expenditure Panel Survey
- MIECHV: Maternal, Infant, and Early Childhood Home Visiting Program
- MOUD: medication for opioid use disorder
- MPSMS: Medicare Patient Safety Monitoring System
- MSA: metropolitan statistical area
- MSH: minority serving hospital
- NHPI: Native Hawaiian/Pacific Islander
- NHQDR: National Healthcare Quality and Disparities Report
- NIDA: National Institute on Drug Abuse
- NPCR-USCS: National Program of Cancer Registries – U.S. Cancer Statistics
- OB-GYN: obstetric-gynecologic; obstetrician-gynecologist
- OECD: Organisation for Economic Co-operation and Development
- OOP: out of pocket
- OTP: opioid treatment program
- PG: poverty guideline
- SDOH: social determinants of health
- SNH: safety net hospital
- SUD: substance use disorder
- YPLL: years of potential life lost

### Agencies and Offices in the U.S. Department of Health and Human Services

- AHRQ: Agency for Healthcare Research and Quality
  ■ CFACT: Center for Financing, Access, and Cost Trends
  ■ CQuIPS: Center for Quality Improvement and Patient Safety
  ■ OC: Office of Communications
  ■ OEREP: Office of Extramural Research, Education, and Priority Populations
- ACL: Administration for Community Living
- ASPE: Office of the Assistant Secretary for Planning and Evaluation
- CDC: Centers for Disease Control and Prevention
  ■ NCCDPHP-ONDIEH: National Center for Chronic Disease Prevention and Health Promotion, Office of Noncommunicable Diseases, Injury, and Environmental Health
  ■ NCHS: National Center for Health Statistics
  ■ NCI: National Cancer Institute
  ■ NPCR: National Program of Cancer Registries
- CMS: Centers for Medicare & Medicaid Services
- FDA: Food and Drug Administration
- HRSA: Health Resources and Services Administration
- IHS: Indian Health Service
- NIH: National Institutes of Health
  ■ NCI: National Cancer Institute
  ■ NIDA: National Institute on Drug Abuse
  ■ NIDCR: National Institute of Dental and Craniofacial Research
  ■ NIMHD: National Institute on Minority Health and Health Disparities
  ■ OD-ORWH: Office of the Director-Office of Research on Women’s Health
- OASH: Office of the Assistant Secretary for Health
- SAMHSA: Substance Abuse and Mental Health Services Administration

### Other Federal Agencies

- BLS: Bureau of Labor Statistics
- GAO: Government Accountability Office
- OMB: Office of Management and Budget
- VHA: Veterans Health Administration

### Private Organizations

- ACS NSQIP: American College of Surgeons National Surgical Quality Improvement Program

i A CSHCN Screener instrument was developed through a national collaborative process as part of the Child and Adolescent Health Measurement Initiative coordinated by the Foundation for Accountability. For more information, refer to Bethell CD, Read D, Stein REK, Blumberg SJ, Wells N, Newacheck PW. Identifying children with special health care needs: development and evaluation of a short screening instrument. Ambul Pediatr. 2002 Feb;2(1):38–48. https://www.ncbi.nlm.nih.gov/pubmed/11888437. Accessed October 25, 2022 11888437 .