# APPENDIX E PRELIMINARY ANALYSES OF HCUP DATA

To provide access to the most recent information, this report includes preliminary data from the Healthcare Cost and Utilization Project in the areas of maternal health, child and adolescent mental health, and substance use disorder. These estimates are being published prior to final data editing and final weighting and should not be extrapolated to the national level.

For maternal health, this appendix provides estimates for data from nine states for data years 2019-2021. The states included in the dataset are Arizona, Colorado, Hawaii, Iowa, Kansas, Kentucky, Mississippi, Montana, and West Virginia. For child mental health and substance use disorder, this appendix provides estimates for data from seven states for data years 2019-2021: Arizona, Iowa, Kansas, Kentucky, Mississippi, Montana, and South Dakota.

## Maternal Health

Figure 1 Severe maternal morbidity per 1,000 deliveries for 9 states, by race/ethnicity (left) and hospital bed size (right), 2019-2021 (lower rates are better)

Key: API = Asian or Pacific Islander.

Note: Estimates are not weighted or risk adjusted.

Bar chart showing rate per 1,000 deliveries; significant findings are in the text below the chart

Bar chart showing rate per 1,000 deliveries; significant findings are in the text below the chart

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Inpatient Databases, 2019-2021.

- In 2021, overall, the rate of severe maternal morbidity was 8.2 per 1,000 delivery discharges (data not shown):
  ■ Among deliveries to Hispanic individuals: 8.9 per 1,000 delivery discharges (Figure 1).
  ■ Among deliveries to non-Hispanic Asian and Pacific Islander individuals: 10.1 per 1,000 delivery discharges.
  ■ Among deliveries to non-Hispanic Black individuals: 11.5 per 1,000 delivery discharges.
  ■ Among deliveries to non-Hispanic White individuals: 7.0 per 1,000 delivery discharges.
  ■ Among deliveries in hospitals with fewer than 100 beds: 4.5 per 1,000 delivery discharges.
  ■ Among deliveries in hospitals with 100-299 beds: 6.3 per 1,000 delivery discharges.
  ■ Among deliveries in hospitals with 300-499 beds: 8.1 per 1,000 delivery discharges.
  ■ Among deliveries in hospitals with 500 or more beds: 13.1 per 1,000 delivery discharges.

Figure 2 Eclampsia/preeclampsia per 1,000 deliveries for 9 states, by race/ethnicity (left) and critical access hospital status (right), 2019-2021 (lower rates are better)

Key: API = Asian or Pacific Islander; CAH = critical access hospital.

Note: Estimates are not weighted or risk adjusted.

Bar chart showing rate per 1,000 deliveries; significant findings are in the text below the chart

Bar chart showing rate per 1,000 deliveries; significant findings are in the text below the chart

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Inpatient Databases, 2019-2021.

- In 2021, overall, the rate of eclampsia/preeclampsia was 72.4 per 1,000 delivery discharges (data not shown):
  ■ Among deliveries to Hispanic individuals: 74.1 per 1,000 delivery discharges (Figure 2).
  ■ Among deliveries to non-Hispanic Asian and Pacific Islander individuals: 70.9 per 1,000 delivery discharges.
  ■ Among deliveries to non-Hispanic Black individuals: 92.2 per 1,000 delivery discharges.
  ■ Among deliveries to non-Hispanic White individuals: 67.8 per 1,000 delivery discharges.
  ■ Among deliveries in critical access hospitals: 43.6 per 1,000 delivery discharges.
  ■ Among deliveries in not critical access hospitals: 73.7 per 1,000 delivery discharges.

Figure 3 Severe postpartum hemorrhage per 1,000 deliveries for 9 states, by race/ethnicity (left) and hospital ownership (right), 2019-2021 (lower rates are better)

Key: API = Asian or Pacific Islander.

Note: Estimates are not weighted or risk adjusted.

Bar chart showing rate per 1,000 deliveries; significant findings are in the text below the chart

Bar chart showing rate per 1,000 deliveries; significant findings are in the text below the chart

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Inpatient Databases, 2019-2021.

- In 2021, overall, the rate of postpartum hemorrhage was 43.5 per 1,000 delivery discharges (data not shown):
  ■ Among deliveries to Hispanic individuals: 56.3 per 1,000 delivery discharges (Figure 3).
  ■ Among deliveries to non-Hispanic Asian and Pacific Islander individuals: 61.1 per 1,000 delivery discharges.
  ■ Among deliveries to non-Hispanic Black individuals: 36.7 per 1,000 delivery discharges.
  ■ Among deliveries to non-Hispanic White individuals: 38.5 per 1,000 delivery discharges.
  ■ Among deliveries in public hospitals: 64.3 per 1,000 delivery discharges.
  ■ Among deliveries in private, not-for-profit hospitals: 42.2 per 1,000 delivery discharges.
  ■ Among deliveries in private, for-profit hospitals: 31.7 per 1,000 delivery discharges.

Figure 4 Venous thromboembolism or pulmonary embolism per 1,000 delivery discharges for 9 states, by race/ethnicity (left) and hospital bed size (right), 2019-2021 (lower rates are better)

Key: API = Asian or Pacific Islander.

Note: Estimates are not weighted or risk adjusted.

Bar chart showing rate per 1,000 deliveries; significant findings are in the text below the charts

Bar chart showing rate per 1,000 deliveries; significant findings are in the text below the charts

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Inpatient Databases, 2019-2021.

- In 2021, overall, the rate of venous thromboembolism or pulmonary embolism was 0.30 per 1,000 delivery discharges (data not shown):
  ■ Among deliveries to Hispanic individuals: 0.27 per 1,000 delivery discharges (Figure 4).
  ■ Among deliveries to non-Hispanic Asian and Pacific Islander individuals: 0.18 per 1,000 delivery discharges.
  ■ Among deliveries to non-Hispanic Black individuals: 0.30 per 1,000 delivery discharges.
  ■ Among deliveries to non-Hispanic White individuals: 0.34 per 1,000 delivery discharges.
  ■ Among deliveries in hospitals with fewer than 100 beds: 0.25 per 1,000 delivery discharges.
  ■ Among deliveries in hospitals with 100-299 beds: 0.22 per 1,000 delivery discharges.
  ■ Among deliveries in hospitals with 300-499 beds: 0.24 per 1,000 delivery discharges.
  ■ Among deliveries in hospitals with 500 or more beds: 0.51 per 1,000 delivery discharges.

## Child and Adolescent Mental Health

Figure 5 Emergency department visits with a principal diagnosis related to mental health only per 100,000 population, by age, 2019-2021

Note: Estimates are based on seven states and are not weighted or risk adjusted.

Line graph showing rate per 100,000 population; significant findings are in the text below the charts

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2019-2021.

- From 2019 to 2021, the rates of ED visits with a principal diagnosis related to mental health only increased for children ages 0-17 years, from 711.3 per 100,000 population to 785.1 per 100,000 population (Figure 5). The rate for the 0-17 age group dropped in 2020 due to the COVID-19 public health emergency, but in 2021, the rate went up higher than in 2019. This age group is the only one for which the rate went higher than in 2019 after a dip in 2020.
- From 2019 to 2021, the rates of ED visits with a principal diagnosis related to mental health only decreased for adults age 85 years and over, from 917.6 per 100,000 population to 744.4 per 100,000 population. The rates for adults 85 years and over for 7 states are much closer to the overall rates than the rates for other age groups.

## Substance Use Disorders

Figure 6 Emergency department visits related to substance use disorder per 100,000 population, by income, 2019-2021

Key: PG = poverty guideline.

Note: Estimates are not weighted or risk adjusted.

Bar graph showing visits per 100,000 population; significant findings are in the text below the charts

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Emergency Department Databases, 2019-2021.

- In 2019, overall, the rate of emergency department visits related to substance use disorder was 395.2 per 100,000 population (data not shown):
  ■ Among residents of communities with the lowest income: 491.4 per 100,000 population (Figure 6).
  ■ Among residents of communities with income 100-199% of the poverty guideline (PG): 362.3 per 100,000 population.
  ■ Among residents of communities with income 200-399% of the PG: 308.7 per 100,000 population.
  ■ Among residents of communities with income 400% or more of the PG: 204.7 per 100,000 population.
- In 2020, overall, the rate of emergency department visits related to substance use disorder was 374.9 per 100,000 population (data not shown):
  ■ Among residents of communities with the lowest income: 476.3 per 100,000 population.
  ■ Among residents of communities with income 100-199% of the PG: 358.8 per 100,000 population.
  ■ Among residents of communities with income 200-399% of the PG: 252.5 per 100,000 population.
  ■ Among residents of communities with income 400% or more of the PG: 187.8 per 100,000 population.
- In 2021, overall, the rate of emergency department visits related to substance use disorder was 382.6 per 100,000 population (data not shown):
  ■ Among residents of communities with the lowest income: 481.9 per 100,000 population.
  ■ Among residents of communities with income 100-199% of the PG: 359.6 per 100,000 population.
  ■ Among residents of communities with income 200-399% of the PG: 279.7 per 100,000 population.
  ■ Among residents of communities with income 400% or more of the PG: 184.2 per 100,000 population.

Figure 7 Emergency department visits related to substance use disorder per 100,000 population, by location, 2019-2021

Note: Estimates are not weighted or risk adjusted.

Bar chart showing visits per 100,000 population; significant findings are in the text below the charts

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Emergency Department Databases, 2019-2021.

- In 2019, overall, the rate of emergency department visits related to substance use disorder was 395.2 per 100,000 population (data not shown):
  ■ Among residents of large central metropolitan areas: 395.9 per 100,000 population (Figure 7).
  ■ Among residents of large fringe metropolitan areas: 329.1 per 100,000 population.
  ■ Among residents of medium metropolitan areas: 407.8 per 100,000 population
  ■ Among residents of small metropolitan areas: 485.3 per 100,000 population.
  ■ Among residents of micropolitan areas: 377.4 per 100,000 population.
  ■ Among residents of noncore areas: 313.7 per 100,000 population.
- In 2020, overall, the rate of emergency department visits related to substance use disorder was 374.9 per 100,000 population (data not shown):
  ■ Among residents of large central metropolitan areas: 355.4 per 100,000 population.
  ■ Among residents of large fringe metropolitan areas: 303.3 per 100,000 population.
  ■ Among residents of medium metropolitan areas: 395.7 per 100,000 population.
  ■ Among residents of small metropolitan areas: 458.0 per 100,000 population.
  ■ Among residents of micropolitan areas: 375.3 per 100,000 population.
  ■ Among residents of noncore areas: 298.0 per 100,000 population.
- In 2021, overall, the rate of emergency department visits related to substance use disorder was 382.6 per 100,000 population (data not shown):
  ■ Among residents of large central metropolitan areas: 352.6 per 100,000 population.
  ■ Among residents of large fringe metropolitan areas: 301.6 per 100,000 population.
  ■ Among residents of medium metropolitan areas: 402.5 per 100,000 population
  ■ Among residents of small metropolitan areas: 458.6 per 100,000 population.
  ■ Among residents of micropolitan areas: 390.8 per 100,000 population.
  ■ Among residents of noncore areas: 325.7 per 100,000 population.

Figure 8 Emergency department visits related to opioid use per 100,000 population, by income, 2019-2021

Key: PG = poverty guideline.

Note: Estimates are not weighted or risk adjusted.

Bar chart showing visits per 100,000 population; significant findings are in the text below the charts

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Emergency Department Databases, 2019-2021.

- In 2019, overall, the rate of emergency department visits related to opioid use was 201.3 per 100,000 population (data not shown):
  ■ Among residents of communities with the lowest income: 250.7 per 100,000 population (Figure 8).
  ■ Among residents of communities with income 100-199% of the poverty guideline (PG): 193.8 per 100,000 population.
  ■ Among residents of communities with income 200-399% of the PG: 155.8 per 100,000 population.
  ■ Among residents of communities with income 400% or more of the PG: 105.9 per 100,000 population.
- In 2020, overall, the rate of emergency department visits related to opioid use was 192.0 per 100,000 population (data not shown):
  ■ Among residents of communities with the lowest income: 250.4 per 100,000 population.
  ■ Among residents of communities with income 100-199% of the PG: 173.2 per 100,000 population.
  ■ Among residents of communities with income 200-399% of the PG: 146.2 per 100,000 population.
  ■ Among residents of communities with income 400% or more of the PG: 99.1 per 100,000 population.
- In 2021, overall, the rate of emergency department visits related to opioid use was 195.2 per 100,000 population (data not shown):
  ■ Among residents of communities with the lowest income: 249.7 per 100,000 population.
  ■ Among residents of communities with income 100-199% of the PG: 186.5 per 100,000 population.
  ■ Among residents of communities with income 200-399% of the PG: 140.9 per 100,000 population.
  ■ Among residents of communities with income 400% or more of the PG: 92.2 per 100,000 population.

Figure 9 Emergency department visits related to opioid use per 100,000 population, by location, 2019-2021

Note: Estimates are not weighted or risk adjusted.

Bar chart showing visits per 100,000 population; significant findings are in the text below the charts

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Emergency Department Databases, 2019-2021.

- In 2019, overall, the rate of emergency department visits related to opioid use was 201.3 per 100,000 population (data not shown):
  ■ Among residents of large central metropolitan areas: 276.0 per 100,000 population (Figure 9).
  ■ Among residents of large fringe metropolitan areas: 240.1 per 100,000 population.
  ■ Among residents of medium metropolitan areas: 204.5 per 100,000 population.
  ■ Among residents of small metropolitan areas: 141.2 per 100,000 population.
  ■ Among residents of micropolitan areas: 144.0 per 100,000 population.
  ■ Among residents of noncore areas: 159.7 per 100,000 population.
- In 2020, overall, the rate of emergency department visits related to opioid use was 192.0 per 100,000 population (data not shown):
  ■ Among residents of large central metropolitan areas: 250.1 per 100,000 population.
  ■ Among residents of large fringe metropolitan areas: 223.2 per 100,000 population.
  ■ Among residents of medium metropolitan areas: 198.3 per 100,000 population.
  ■ Among residents of small metropolitan areas: 125.3 per 100,000 population.
  ■ Among residents of micropolitan areas: 147.1 per 100,000 population.
  ■ Among residents of noncore areas: 165.3 per 100,000 population.
- In 2021, overall, the rate of emergency department visits related to opioid use was 195.2 per 100,000 population (data not shown).
  ■ Among residents of large central metropolitan areas: 238.0 per 100,000 population.
  ■ Among residents of large fringe metropolitan areas: 207.0 per 100,000 population.
  ■ Among residents of medium metropolitan areas: 207.8 per 100,000 population.
  ■ Among residents of small metropolitan areas: 129.9 per 100,000 population.
  ■ Among residents of micropolitan areas: 157.4 per 100,000 population.
  ■ Among residents of noncore areas: 181.7 per 100,000 population.