# APPENDIX D QUALITY TRENDS AND DISPARITIES SUMMARY CHARTS

This appendix presents summary charts showing the number of measures that had better, worse, and the same performance for various groups compared with the reference group (e.g., Black people vs. White people, uninsured people vs. people with private insurance). The charts show disparities in access, disparities in quality by priority area (e.g., person-centered care, patient safety), and trends in quality. In addition, disparities in quality and trends in disparities are shown for selected groups by race, ethnicity, income, insurance status, and residence location.

## Disparities in Access to Care

Figure 1 Number and percentage of access measures for which members of selected ethnic and racial groups experienced better, same, or worse access to care compared with non-Hispanic White or White people, 2018, 2019, or 2020

Key: n = number of measures, AI/AN = American Indian or Alaska Native, NHPI = Native Hawaiian/Pacific Islander.

Stacked bar chart showing number of measures in each category Hispanic vs. non-Hispanic White (n=15), 4 same, 11 worse AI/AN vs. White (n=10), 6 same, 4 worse Asian vs. White (n=14), 5 better, 4 same, 5 worse Black vs. White (n=15), 6 same, 9 worse NHPI vs. White (n=4), 4 same >1 Race vs. White (n=14), 11 same, 3 worse

- For the most recent year, Hispanic people had worse access to care than non-Hispanic White people for 73% of access measures (Figure 1).
- American Indian and Alaska Native (AI/AN) people had worse access to care than White people for 40% of access measures.
- Asian people had worse access to care than White people for 36% of access measures and better access to care for 36% of access measures.
- Black people had worse access to care than White people for 60% of access measures.
- Native Hawaiian/Pacific Islander (NHPI) people had the same access to care as White people for all four access measures.
- Multiracial^i^ people had worse access to care than White people for 21% of access measures.

Figure 2 Number and percentage of access measures for which members of selected age groups and with selected insurance status experienced better, same, or worse access to care compared with adults ages 18-44 years or individuals with private insurance, 2018, 2019, or 2020

Key: n = number of measures.

Stacked bar chart showing number of measures in each category 45-64 vs. 18-44 (n=12), 9 better, 1 same, 2 worse 65+ vs. 18-44 (n=8), 5 better, 1 same, 2 worse Public vs. Private (n=11), 6 same, 5 worse Uninsured vs. Private (n=9), 2 same,7 worse

- For the most recent year, children ages 0-17 years had worse access to care than adults ages 18-44 years for 20% of access measures and better access to care for 70% of access measures (Figure 2).
- Adults ages 45-64 years had worse access to care than adults ages 18-44 years for 17% of access measures and better access to care for 75% of access measures.
- Adults age 65 years and over had worse access to care than adults ages 18-44 years for 25% of access measures and better access to care for 63% of access measures.
- People with public insurance had worse access to care than people with private insurance for 45% of access measures.
- People with no insurance had worse access to care than people with private insurance for 78% of access measures.

Figure 3 Number and percentage of access measures for which members of selected gender, income, and disability status groups experienced better, same, or worse access to care compared with males, people in households with incomes 400% or more of the poverty guideline, or people without disabilities, 2018, 2019, or 2020

Key: n = number of measures; PG = poverty guideline.

Stacked bar chart showing number of measures in each category Female vs. Male (n=14), 7 better, 7 same <100% PG vs. 400%+ PG (n=14), 2

- For the most recent year, females had better access to care than males for 50% of access measures (Figure 3).
- People in households with incomes less than 100% of the poverty guideline (PG) had worse access to care than people in households with incomes 400% or more of the PG for 86% of access measures.
- People in households with incomes 100%-199% of the PG had worse access to care than people in households with incomes 400% or more of the PG for 86% of access measures.
- People in households with incomes 200%-399% of the PG had worse access to care than people in households with incomes 400% or more of the PG for 64% of access measures.
- People with disabilities had worse access to care than people without disabilities for 33% of access measures and better access to care for 50% of access measures.

Figure 4 Number and percentage of access measures for which residents of selected geographic locations experienced better, same, or worse access to care compared with people in large fringe metro areas, 2018, 2019, or 2020

Key: n = number of measures.

Note: The geographic locations are based on the 2013 National Center for Health Statistics Urban-Rural Classification Scheme (https://www.cdc.gov/nchs/data_access/urban_rural.htm):

- Large central metropolitan refers to counties in a metropolitan statistical area (MSA) of 1 million or more population that contain the entire population of the largest principal city of the MSA, whose entire population is contained within the largest principal city of the MSA, or that contain at least 250,000 residents of any principal city in the MSA.
- Large fringe metropolitan refers to counties in MSAs of 1 million or more population that do not qualify as large central, described as suburban areas.
- Medium metropolitan refers to counties in MSAs of 250,000-999,999 population.
- Small metropolitan refers to counties in MSAs of less than 250,000 population.
- The two nonmetropolitan county designations are micropolitan, which are counties in a micropolitan statistical area, and noncore, which are nonmetropolitan counties that are not in a micropolitan statistical area.

Stacked bar chart showing number of measures in each category Large Central Metro vs. Large Fringe Metro (n=14), 5 same, 9 worse Medium Metro vs. Large Fringe Metro (n=14), 11 same, 3 worse Small Metro vs. Large Fringe Metro (n=12), 9 same, 3 worse Micropolitan vs. Large Fringe Metro (n=12), 7 same, 5 worse Noncore vs. Large Fringe Metro (n=12), 2 better, 7 same, 3 worse

- For the most recent year, people in large central metro areas had worse access to care than people in large fringe metro areas for 64% of access measures (Figure 4).
- People in medium metro areas had worse access to care than people in large fringe metro areas for 21% of access measures.
- People in small metro areas had worse access to care than people in large fringe metro areas for 25% of access measures.
- People in micropolitan areas had worse access to care than people in large fringe metro areas for 42% of access measures.
- People in noncore areas had worse access to care than people in large fringe metro areas for 25% of access measures and better access to care for 17% of access measures.

## Trends in Quality of Care

### Patient Safety Quality Measures by Setting of Care

Figure 5 Number and percentage of all patient safety measures improving, not changing, or worsening from 2002 to 2020, by setting of care

Key: n = number of measures.

Note: Patient safety measures include measures related to nursing home resident safety. For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p≤0.10.

Stacked bar chart showing number of measures in each category Total (n=29), 17 improving, 11 not changing, 1 worsening Hospital (n=14), 9 improving, 5 not changing Ambulatory (n=2), 2 improving Home Health (n=8), 2 improving, 5 not changing, 1 worsening Nursing Home (n=5), 4 improving, 1 not changing

- From 2002 to 2020, 59% of patient safety measures improved and 3% of patient safety measures worsened (Figure 5).
- From 2002 to 2020, 64% of patient safety measures in the hospital setting, 100% of patient safety measures in the ambulatory setting, 25% of patient safety measures in the home health setting, and 80% of patient safety measures in the nursing home setting improved.
- From 2000 to 2020, 13% of patient safety measures in the home health setting worsened.

### Person-Centered Care Quality Measures by Setting of Care

Figure 6 Number and percentage of all person-centered care measures improving, not changing, or worsening from 2002 to 2020, by setting of care

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p<0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p<0.10.

Stacked bar chart showing number of measures in each category Total (n=27), 10 improving, 17 not changing Hospital (n=1), 1 not changing Ambulatory (n=9), 6 improving, 3 not changing Home Health (n=9), 3 improving, 6 not changing Hospice Care (n=8), 1 improving, 7 not changing

- From 2002 to 2020, 37% of person-centered care measures improved (Figure 6).
- From 2002 to 2020, 67% of person-centered care measures in the ambulatory setting, 33% of person-centered care measures in the home health setting, and 13% of person-centered care measures in the hospice care setting improved.

### Care Coordination Quality Measures by Topic Area

Figure 7 Number and percentage of all care coordination measures improving, not changing, or worsening from 2002 to 2020, by sub-area

Key: n = number of measures; hosp = hospitalizations.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p<0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p<0.10.

Stacked bar chart showing number of measures in each category Total (n=28), 10 improving, 13 not changing, 5 worsening Medication Information (n=1), 1 improving Potentially Avoidable Admissions (n=6), 2 improving, 4 not changing Preventable Emergency Department (n=6), 1 improving, 5 not changing Preventable Hospitalizations (n=7), 3 improving, 1 not changing, 3 worsening Preventable Hospitalizations Among Home Health and Nursing Home Patients (n=2), 2 not changing Supportive and Palliative Care (n=4), 2 improving, 1 not changing, 1 worsening Transitions of Care (n=2), 1 improving, 1 worsening

- From 2002 to 2020, 36% of care coordination measures improved and 18% of care coordination measures worsened (Figure 7).
- From 2000 to 2020, the one medication information measure, 33% of potentially avoidable admission measures, 17% of preventable emergency department visit measures, 43% of preventable hospitalization measures, 50% of supportive and palliative care measures, and 50% of transitions of care measures improved.
- From 2000 to 2020, 43% of preventable hospitalization measures, 25% of supportive and palliative care measures, and 50% of transitions of care measures worsened.

### Effective Treatment Measures by Sub-Areas

Figure 8 Number and percentage of all effective treatment measures improving, not changing, or worsening from 2000 to 2020, by disease category

Key: n = number of measures.

Stacked bar chart showing number of measures in each category Total (n=38), 12 improving, 21 not changing, 5 worsening Cancer (n=6), 5 improving, 1 not changing Cardiovascular Disease (n=7),12 improving, 5 not changing, 1 worsening Chronic Kidney Disease (n=5), 1 improving, 4 not changing Diabetes (n=7), 6 not changing, 1 worsening HIV/AIDS (n=5), 3 improving, 2 not changing Mental Health and Substance Abuses (n=5), 2 not changing, 3 worsening Musculoskeletal Disease (n=1), 1 not changing Respiratory Diseases (n=2), 2 improving

- From 2002 to 2020, 32% of effective treatment measures improved and 13% of effective treatment measures worsened (Figure 8).
- From 2000 to 2020, 83% of cancer measures, 14% of cardiovascular disease measures, 20% of chronic kidney disease measures, 60% of HIV/AIDS measures, and 100% of respiratory disease measures improved.
- From 2000 to 2020, 14% of cardiovascular disease measures, 14% of diabetes measures, and 60% of mental health and substance abuse measures worsened.

### Healthy Living Quality Measures by Topic Area

Figure 9 Number and percentage of all healthy living measures improving, not changing, or worsening from 2000 to 2020, by topic area

Key: n = number of measures.

Note: National Health Interview Survey measures that have been included in previous years were unavailable for this report.

Stacked bar chart showing number of measures improving, not changing, and worsening Total (n=55), 30 improving, 23 not changing, 2 worsening Clinical Preventive Services (n=31), 13 improving, 17 not changing,1 worsening Functional Status Preservation and Rehabilitation (n=6), 5 improving, 1 not changing Supportive and Palliative Care (n=10), 7 improving, 3 not changing Lifestyle Modification (n=5), 4 improving, 1 worsening Maternal and Child Health (n=3), 1 improving, 2 not changing

- From 2002 to 2020, 55% of healthy living measures improved and 4% of healthy living measures worsened (Figure 9).
- From 2000 to 2020, 42% of clinical preventive services, 83% of functional status preservation and rehabilitation, 70% of supportive and palliative care, 80% of lifestyle modification, and 33% of maternal and child health measures improved.
- From 2000 to 2020, 3% of clinical preventive services and 20% of lifestyle modification measures worsened.

Figure 10 Number and percentage of all clinical preventive services measures improving, not changing, or worsening from 2000 to 2020, by sub-area

Key: n = number of measures.

Note: National Health Interview Survey measures that have been included in previous years were unavailable for this report. For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p<0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p<0.10.

Stacked bar chart showing number of measures improving, not changing, and worsening Adult Preventive Care (n=6), 2 improving, 4 not changing Childhood Immunization (n=9), 6 improving, 3 not changing Other Childhood Preventive Care (n=10), 3 improving, 7 not changing Overall Preventive Care (n=6), 2 improving, 3 not changing, 1 worsening

- From 2000 to 2020, 33% of adult preventive care measures, 67% of childhood immunization measures, 30% of other childhood preventive care measures, and 33% of overall preventive care measures improved (Figure 10).
- From 2000 to 2020, 17% of overall preventive care measures worsened.

### Affordable Care Quality Measures by Sub-Area

Figure 11 Number and percentage of all affordable care measures improving, not changing, or worsening from 2002 to 2019, by sub-area

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p<0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p<0.10.

Stacked bar chart showing number of measures in each category Total (n=2), 2 not changing Usual Source of Care (n=1), 1 not changing Financial Burden (n=1), 1 not changing

- From 2002 to 2020, the two affordable care measures, one about usual source of care and the other about financial burden, did not have any statistically significant changes (Figure 11).

## Disparities by Race and Ethnicity

### Disparities in Access to Care by Race and Ethnicity

Figure 12 Number and percentage of access measures for which members of selected racial groups experienced better, same, or worse access to care compared with White people for the most recent data year, 2019, 2020, or 2021

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander; n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of measures in each category AI/AN vs. White (n=10), 6 same, 4 worse Asian vs. White (n=14), 5 better, 4 same, 5 worse Black vs. White (n=15), 6 same, 9 worse NHPI vs. White (n=4), 4 same Hispanic vs. non-Hispanic White (n=15), 4 same, 11 worse

- AI/AN people had worse access to care than White people for 40% of access measures (Figure 12).
- Asian people had worse access to care than White people for 36% of access measures and received better care for another 36% of access measures.
- Black people had worse access to care than White people for 60% of access measures.
- NHPI people had the same access to care as White people for all access measures.
- Hispanic people had worse access to care than non-Hispanic White people for 73% of access measures.

### Disparities in Quality of Care by Race and Ethnicity

Figure 13 Number and percentage of quality measures for which members of selected groups experienced better, same, or worse quality of care compared with White people for the most recent data year, 2017, 2018, 2019, or 2020

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander; n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of measures in each category AI/AN vs. White (n=110), 13 better, 50 same, 47 worse Asian vs. White (n=172),48 better,76 same, 48 worse Black vs. White (n=190), 19 better, 86 same, 85 worse NHPI vs. White (n=73), 13 better, 33 same, 27 worse Hispanic vs. non-Hispanic White (n=190), 33 better, 8 4 same, 73 worse

- AI/AN people received worse care than White people for 43% of quality measures and better care for 12% of quality measures (Figure 13).
- Asian people received worse care than White people for 28% of quality measures and better care for another 28% of quality measures.
- Black people received worse care than White people for 45% of quality measures and better care for 10% of quality measures.
- NHPI people received worse care than White people for 37% of quality measures and better care for 18% of quality measures.
- Hispanic people received worse care than non-Hispanic White people for 38% of quality measures and better care for 17% of quality measures.

### Changes in Disparities by Race and Ethnicity

Figure 14 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time, 2000 to 2020

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander; n = number of measures.

Note: Different data sources have different data years for most recent data year.

Stacked bar chart showing number of quality measures AI/AN (n=38), Improving, 3, Not Changing, 35 Asian (n=43), Improving, 1, Not Changing, 42 Black (n=72), Improving, 5, Not Changing, 62, Worsening,5 NHPI (n=18), Improving, 1, Not Changing, 17 Hispanic (n=58), Improving, 5, Not Changing, 53

- Disparities between AI/AN people and White people improved for 8% of measures (Figure 14).
- Disparities between Asian people and White people improved for 2% of measures.
- Disparities between Black people and White people improved for 7% of measures and worsened for another 7% of measures.
- Disparities between NHPI people and White people improved for 6% of measures.
- Disparities between Hispanic people and non-Hispanic White people improved for 9% of measures.

### Disparities for American Indian and Alaska Native Populations

#### Disparities in Quality of Care for American Indian and Alaska Native Populations

Figure 15 Number and percentage of quality measures for which American Indian and Alaska Native people experienced better, same, or worse quality of care compared with White people for the most recent data year, total and by priority area, 2017, 2018, 2019, or 2020

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of quality measures Total (n=110), Better, 13, Same, 50, Worse, 47 Person-Centered Care (n=24), Better, 1, Same, 10, Worse, 13 Patient Safety (n=13), Better, 1, Same, 9, Worse,36 Healthy Living (n=43), Better, 6, Same, 18, Worse, 19 Effective Treatment (n=21), Better, 5, Same, 11, Worse, 5 Care Coordination (n=8), Same, 1, Worse, 7 Affordable Care (n=1), Same, 1

- Data for the most recent year show that quality of care was worse for AI/AN people than for White people for 43% of all quality measures and better for 12% of all quality measures (Figure 15).

#### Trends in Quality of Care for American Indian and Alaska Native Populations

Figure 16 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2020

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

Stacked bar chart showing number of quality measures in each category Total (n=105), Improving, 40, Not Changing, 59, Worsening, 6 Person-Centered Care (n=24), Improving, 3, Not Changing, 20, Worsening, 1 Patient Safety (n=13), Improving, 4, Not Changing, 8, Worsening,1 Healthy Living (n=43), Improving, 25, Not Changing, 17, Worsening,1 Effective Treatment (n=16), Improving, 5, Not Changing,9, Worsening, 2 Care Coordination (n=8), Improving, 3, Not Changing, 4, Worsening, 1 Affordable Care (n=1), Not changing, 1

- Among the 105 quality measures with data for AI/AN people, 38% of quality measures were improving and 6% of quality measures were getting worse from 2000 through 2020 (Figure 16).

#### Changes in Disparities for American Indian and Alaska Native Populations

Figure 17 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2020

Key: n = number of measures.

Note: Different data sources have different data years.

Stacked bar chart showing number of quality measures in each category Total (n=38), Improving, 3, Not Changing, 35 Person-Centered Care (n=12), Not Changing, 12 Patient Safety (n=3), Not Changing, 3 Healthy Living (n=13), Improving, 2, Not Changing, 11 Effective Treatment (n=4), Improving, 1, Not Changing, 3 Care Coordination (n=6), Not Changing, 6 Affordable Care (n=0)

- From 2000 to 2020, disparities between AI/AN people and White people narrowed in 8% of quality measures (Figure 17).

### Disparities for Asian Populations

#### Disparities in Quality of Care for Asian Populations

Figure 18 Number and percentage of quality measures for which Asian people experienced better, same, or worse quality of care compared with White people for the most recent data year, total and by priority area, 2017, 2018, 2019, or 2020

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of quality measures in each category Total (n=172), Better, 48, Same, 76, Worse, 48 Person-Centered Care (n=29), Better, 1, Same, 9, Worse, 19 Patient Safety (n=25), Better, 7, Same, 13, Worse, 5 Healthy Living (n=62), Better, 16, Same, 30, Worse, 16 Effective Treatment (n=33), Better, 8, Same, 20, Worse, 5 Care Coordination (n=21),Better, 16, Same, 2, Worse, 3 Affordable Care (n=2), Same, 2

- Data for the most recent year show that quality of care was worse for Asian people than for White people for 28% of all quality measures and better for another 28% of all quality measures (Figure 18).

#### Trends in Quality of Care for Asian Populations

Figure 19 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2020

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

Stacked bar chart showing number of quality measures in each category Total (n=151), Improving, 75, Not Changing, 71, Worsening, 5 Person-Centered Care (n=27), Improving, 18, Not Changing, 9 Patient Safety (n=26), Improving, 11, Not Changing, 14, Worsening, 1 Healthy Living (n=49), Improving, 32, Not Changing, 17 Effective Treatment (n=26), Improving, 8, Not Changing, 16, Worsening, 2 Care Coordination (n=21), Improving, 6, Not Changing, 13, Worsening, 2 Affordable Care (n=2), Not Changing, 2

- Among the 151 quality measures with data for Asian people, 50% of quality measures were improving and 3% of quality measures were getting worse from 2000 through 2020 (Figure 19).

#### Changes in Disparities for Asian Populations

Figure 20 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2020

Key: n = number of measures.

Note: Different data sources have different data years.

Stacked bar chart showing number of quality measures in each category Total (n=43), Improving, 1, Not Changing, 42 Person-Centered Care (n=19), Not Changing, 19 Patient Safety (n=4), Not Changing, 4 Healthy Living (n=14), Not Changing, 14 Effective Treatment (n=3), Improving, 1, Not Changing, 2 Care Coordination (n=3), Not Changing, 3 Affordable Care (n=0)

- From 2000 to 2020, disparities between Asian people and White people narrowed for 2% of quality measures (Figure 20).

### Disparities for Black Populations

#### Disparities in Quality of Care for Black Populations

Figure 21 Number and percentage of quality measures for which Black people experienced better, same, or worse quality of care compared with White people for the most recent data year, total and by priority area, 2017, 2018, 2019, or 2020

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of quality measures Total (n=190), Better, 19, Same, 86, Worse, 85 Person-Centered Care (n=27), Better, 3, Same, 17, Worse, 7 Patient Safety (n=28), Better, 5, Same, 13, Worse, 10 Healthy Living (n=71), Better,4, Same, 32, Worse, 35 Effective Treatment (n=40), Better, 5, Same, 19, Worse, 16 Care Coordination (n=22),Better, 1, Same, 4, Worse, 17 Affordable Care (n=2), Better,1, Same, 1

- Data for the most recent year show that quality of care was worse for Black people than for White people for 45% of all quality measures and better for 10% of all quality measures (Figure 21).

#### Trends in Quality of Care for Black Populations

Figure 22 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2020

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

Stacked bar chart showing number of quality measures in each category Total (n=164, Improving, 69, Not Changing, 83, Worsening, 12 Person-Centered Care (n=27), Improving, 10, Not Changing, 17 Patient Safety (n=29), Improving, 13, Not Changing, 14, Worsening, 2 Healthy Living (n=53), Improving, 29, Not Changing, 21, Worsening,3 Effective Treatment (n=31), Improving, 9, Not Changing, 18, Worsening, 4 Care Coordination (n=22), Improving, 8, Not Changing,11, Worsening, 3 Affordable Care (n=2), Not Changing, 2

- Among the 164 quality measures with data for Black people, 42% of quality measures were improving and 7% of quality measures were getting worse from 2000 through 2020 (Figure 22).

#### Changes in Disparities for Black Populations

Figure 23 Number and percentage of quality measures with disparity at baseline for which disparities between Black people and White people were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2020

Key: n = number of measures.

Note: Different data sources have different data years.

Stacked bar chart showing number of quality measures improving; not changing; and worsening Total (n=72, Improving, 5, Not Changing, 62, Worsening, 5 Person-Centered Care (n=8), Not Changing, 8 Patient Safety (n=7), Not Changing, 7 Healthy Living (n=27), Not Changing, 27 Effective Treatment (n=14), Improving, 2, Not Changing, 11, Worsening, 1 Care Coordination (n=16), Improving, 3, Not Changing, 9, Worsening, 4 Affordable Care (n=0)

- From 2000 to 2020, disparities between Black people and White people narrowed in 7% of quality measures and expanded in 7% of quality measures (Figure 23).

### Disparities for Native Hawaiian and Pacific Islander Populations

#### Disparities in Quality of Care for Native Hawaiian and Pacific Islander Populations

Figure 24 Number and percentage of quality measures for which Native Hawaiian/Pacific Islander groups experienced better, same, or worse quality of care compared with White groups for the most recent data year, total and by priority area, 2018, 2019, or 2020

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of quality measures in each category Total (n=73), Better, 13, Same, 33, Worse, 27 Person-Centered Care (n=10), Better, 1, Same, 5, Worse, 4 Patient Safety (n=12), Better, 2, Same, 7, Worse,3 Healthy Living (n=5), Better, 5, Same, 13, Worse, 12 Effective Treatment (n=13), Better, 4, Same, 4, Worse, 5 Care Coordination (n=7), Better, 1, Same, 3, Worse,3 Affordable Care (n=1, Same, 1)

- Data for the most recent year show that quality of care was worse for NHPI people than for White people for 37% of all quality measures and better for 18% of all quality measures (Figure 24).

#### Trends in Quality of Care for Native Hawaiian and Pacific Islander Populations

Figure 25 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2001 to 2020

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

Stacked bar chart showing number of quality measures in each category Total (n=69), Improving, 31, Not Changing, 33, Worsening, 5 Person-Centered Care (n=12), Improving, 2, Not Changing, 10 Patient Safety (n=12), Improving, 6, Not Changing, 5, Worsening, 1 Healthy Living (n=28), Improving, 18, Not Changing, 9, Worsening, 1 Effective Treatment (n=8), Improving, 2, Not Changing, 4, Worsening, 2 Care Coordination (n=8), Improving, 3, Not Changing, 4, Worsening, 1 Affordable Care (n=1), Not Changing, 1

- Among the 69 quality measures with data for NHPI people, 45% of quality measures were improving and 7% of quality measures were getting worse from 2001 through 2020 (Figure 25).

#### Changes in Disparities for Native Hawaiian and Pacific Islander Populations

Figure 26 Number and percentage of all quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time, total and by priority area, from 2008 to 2020

Key: n = number of measures.

Note: Different data sources have different data years.

Stacked bar chart showing number of quality measures in each category Total (n=18), Improving, 1, Not Changing, 17 Person-Centered Care (n=5), Not Changing, 5 Patient Safety (n=1), Not Changing, 1 Healthy Living (n=5), Not Changing, 5 Effective Treatment (n=3), Improving, 1, Not Changing, 2 Care Coordination (n=4), Not Changing,4 Affordable Care (n=0)

- From 2008 to 2020, disparities between NHPI people and White people narrowed for 6% of quality measures (Figure 26).

### Disparities for Hispanic Populations

#### Disparities in Quality of Care for Hispanic Populations

Figure 27 Number and percentage of quality measures for which Hispanic groups experienced better, same, or worse quality of care compared with non-Hispanic White groups for the most recent data year, total and by priority area, 2017, 2018, 2019, or 2020

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of quality measures in each category Total (n=190), Better, 33, Same, 84, Worse, 73 Person-Centered Care (n=27), Better, 2, Same, 12, Worse, 13 Patient Safety (n=28), Better, 6, Same, 17, Worse, 5 Healthy Living (n=70), Better, 11, Same, 26, Worse, 33 Effective Treatment (n=41), Better, 8, Same, 21, Worse, 12 Care Coordination (n=22), Better,5, Same,8, Worse, 9 Affordable Care (n=2), Better, 1, Worse, 1

- Data for the most recent year show that quality of care was worse for Hispanic people than for White people for 38% of all quality measures and better for 17% of all quality measures (Figure 27).

#### Changes in Quality of Care for Hispanic Populations

Figure 28 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2020

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

Stacked bar chart showing number of quality measures in each category Total (n=156), Improving, 77, Not Changing, 70, Worsening, 9 Person-Centered Care (n=27), Improving, 7, Not Changing, 20 Patient Safety (n=28), Improving, 14, Not Changing, 12, Worsening, 2 Healthy Living (n=49), Improving, 38, Not Changing, 10, Worsening, 1 Effective Treatment (n=28), Improving, 11, Not Changing, 15, Worsening, 2 Care Coordination (n=22), Improving, 7, Not Changing, 11, Worsening, 4 Affordable Care (n=2), Not Changing, 2

- Among the 156 quality measures with data for Hispanic people, 49% of quality measures were improving and 6% of quality measures were getting worse from 2000 through 2020 (Figure 28).

#### Changes in Disparities for Hispanic Populations

Figure 29 Number and percentage of all quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time, total and by priority area, from 2000 to 2020

Key: n = number of measures.

Note: Different data sources have different data years.

Stacked bar chart showing number of quality measures Total (n=58), Improving, 5, Not Changing, 53 Person-Centered Care (n=15), Not Changing,15 Patient Safety (n=7), Not Changing, 7 Healthy Living (n=19), Improving, 3, Not Changing, 16 Effective Treatment (n=9), Improving, 1, Not Changing, 8 Care Coordination (n=7), Improving 1, Not Changing, 6 Affordable Care (n=1), Not Changing, 1

- From 2000 to 2020, disparities between Hispanic people and White people narrowed for 9% of quality measures (Figure 29).

### Disparities by Income

#### Disparities in Access to Care by Income Group

Figure 30 Number and percentage of access measures for which members of selected income groups experienced better, same, or worse access to care compared with people in households with an income 400% or more of the poverty guideline, 2018, 2019, or 2020

Key: n = number of measures; PG = poverty guideline.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of measures in each category <100% PG vs. 400%+ PG (n=14), same, 2, worse, 12 100%-199% PG vs. 400%+ PG (n=14), same, 2, worse, 12 200%-399% PG vs. 400%+ PG (n=14), same, 5, worse, 9

- Data for the most recent year show that access to care was worse for people in households with income less than 100% of the PG than for people in households with income 400% or more of the PG for 86% of all access measures (Figure 30).
- Data for the most recent year show that access to care was worse for people in households with income 100%-199% of the PG than for people in households with income 400% or more of the PG for 86% of all access measures.
- Data for the most recent year show that access to care was worse for people in households with income 200%-399% of the PG than for people in households with income 400% or more of the PG for 64% of all access measures.

#### Disparities in Access to Care for Income Groups by Sub-Area

Figure 31 Number and percentage of access measures for which people in households with income less than 100% of the poverty guideline experienced better, same, or worse access to care compared with people in households with income 400% or more of the poverty guideline, by sub-area, 2018, 2019, or 2020

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of measures in each category Access, Total (n=14), same, 2, worse, 12 Health Insurance (n=5), worse, 5 Source of Ongoing Care (n=2), worse, 2 Timely Access to Care (n=3), worse, 3 Patient Perception of Need (n=4), same, 2, worse, 2

- Data for the most recent year show that access to care was worse for people in households with income less than 100% of the PG than for people in households with income 400% or more of the PG for 86% of all access measures (Figure 31).

#### Disparities in Quality of Care by Income Groups

Figure 32 Number and percentage of quality measures for which income groups experienced better, same, or worse quality of care compared with people in households with income 400% or more of the poverty guideline for the most recent data year, 2018, 2019, or 2020

Key: n = number of measures; PG = poverty guideline.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of measures in each category Total (n=351), better, 7, same, 163, worse, 181 <00% PG (n=116), better, 4, same, 44, worse, 68 100%-199% PG (n=117), better, 2, same,50, worse, 65 200%-399% PG (n=118), better, 1, same, 69, worse, 48

- Data for the most recent year show that quality of care was worse for people in households with income less than 100% of the PG than for people in households with income 400% or more of the PG for 59% of all quality measures and better for 3% of all quality measures (Figure 32).
- Data for the most recent year show that quality of care was worse for people in households with income 100%-199% of the PG than for people in households with income 400% or more of the PG for 56% of all quality measures and better for 2% of all quality measures.
- Data for the most recent year show that quality of care was worse for people in households with income 200%-399% of the PG than for people in households with income 400% or more of the PG for 41% of all quality measures and better for 1% of all quality measures.

#### Trends in Quality of Care by Income Groups

Figure 33 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by income group, from 2000 to 2020

Key: n = number of measures; PG = poverty guideline.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

Stacked bar chart showing number of quality measures Total (n=375), Improving, 161, Not Changing, 182, Worsening, 32 <100% PG (n=94), Improving, 41, Not Changing, 44, Worsening, 9 100%-199% PG (n=94), Improving, 41, Not Changing,44, Worsening, 9 200%-399% PG (n=94), Improving, 42, Not Changing, 44, Worsening, 8 400%+ PG (n=93), Improving, 37, Not Changing, 50, Worsening, 6

- For people in households with incomes less than 100% of the PG, 44% of quality measures were improving and 10% of quality measures were getting worse from 2000 through 2020 (Figure 33).
- For people in households with incomes 100%-199% of the PG, 44% of quality measures were improving and 10% of quality measures were getting worse from 2000 through 2020.
- For people in households with incomes 200%-399% of the PG, 45% of quality measures were improving and 9% of quality measures were getting worse from 2000 through 2020.
- For people in households with incomes 400% or more of the PG, 40% of quality measures were improving and 6% of quality measures were getting worse from 2000 through 2020.

#### Changes in Disparities by Income Groups

Figure 34 Number and percentage of quality measures with disparity at baseline for which disparities related to income were improving, not changing, or worsening over time, 2000 to 2020

Key: n = number of measures; PG = poverty guideline.

Note: Different data sources have different data years.

Stacked bar chart showing number of quality measures Total (n=181), Improving, 9, Not Changing, 160, Worsening, 12 <100% PG (n=63), Improving, 6, Not Changing, 50, Worsening, 7 100%-199% PG (n=61), Improving, 2, Not Changing, 55, Worsening,4 200%-399% PG (n=57), Improving, 1, Not Changing,55, Worsening, 1

- From 2000 to 2020, disparities between people in households with incomes less than 100%of the PG and people in households with incomes 400% or more of the PG narrowed for 10%of quality measures and expanded for 11% of quality measures (Figure 34).
- From 2000 to 2020, disparities between people in households with incomes 100%-199% of the PG and people in households with incomes 400% or more of the PG narrowed for 3% of quality measures and expanded for 7% of quality measures.
- From 2000 to 2020, disparities between people in households with incomes 200%-399% of the PG and people in households with incomes 400% or more of the PG narrowed for 2% of quality measures and expanded for 2% of quality measures.

### Disparities by Insurance Status

#### Disparities in Quality of Care by Insurance Status

Figure 35 Number and percentage of quality measures for which insurance groups experienced better, same, or worse quality of care compared with reference group (privately insured), 2018, 2019, or 2020

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of quality measures Total (n=156), better,11, same, 70, worse, 75 Public (n=86), better, 9, same, 44, worse, 33 Uninsured (n=70), better, 2, same, 26, worse, 42

- Data for the most recent year show that quality of care was worse for people with public insurance than for people with private insurance for 38% of all quality measures and better for 10% of all quality measures (Figure 35).
- Data for the most recent year show that quality of care was worse for people without insurance than for people with private insurance for 60% of all quality measures and better for 3% of all quality measures.

#### Changes in Quality of Care by Insurance Status

Figure 36 Number and percentage of all quality measures that were improving, not changing, or worsening, total and by insurance status, from 2000 to 2020

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

Stacked bar chart showing number of quality measures Total (n=168), Improving, 65, Not Changing, 99, Worsening, 4 Private (n=57), Improving, 24, Not Changing, 32, Worsening, 1 Public (n=57), Improving, 28, Not Changing, 27, Worsening, 2 Uninsured (n=54), Improving, 13, Not Changing, 40, Worsening, 1

- For people with private insurance, 42% of quality measures were improving and 2% of quality measures were getting worse from 2000 through 2020 (Figure 36).
- For people with public insurance, 49% of quality measures were improving and 4% of quality measures were getting worse from 2000 through 2020.
- For people without insurance, 24% of quality measures were improving and 2% of quality measures were getting worse from 2000 through 2020.

#### Changes in Disparities by Insurance Status

Figure 37 Number and percentage of quality measures with disparity at baseline for which disparities related to insurance were improving, not changing, or worsening, 2000 to 2020

Key: n = number of measures.

Note: Different data sources have different data years.

Stacked bar chart showing number of quality measures Total (n=51), Improving, 2, Not Changing, 49 Public (n=26), Improving, 1, Not Changing, 25 Uninsured (n=25), Improving, 1, Not Changing, 24

- From 2000 to 2020, disparities between people with public insurance and people with private insurance narrowed in 4% of quality measures (Figure 37).
- From 2000 to 2020, disparities between people without insurance and people with private insurance narrowed in 4% of quality measures.

### Disparities by Residence Location

#### Disparities in Quality of Care by Residence Location

Figure 38 Number and percentage of quality measures for which residents of selected locations experienced better, same, or worse quality of care compared with large fringe metropolitan areas, 2018, 2019, or 2020

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value≤0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Different data sources have different data years for most recent data year.

Stacked bar chart showing number of quality measures Total Measures (n=481), Better, 22, Same, 321, Worse, 118 Large Central Metro (n=96), Better, 7, Same, 73, Worse, 16 Medium Metro (n=94), Better, 2, Same, 73, Worse, 19 Small Metro (n=93), Better, 1, Same, 70, Worse, 22 Micropolitan (n=90), Better, 6, Same, 53, Worse, 31 Noncore (n=88), Better, 6, Same, 52, Worse, 30

- Data for the most recent year show that quality of care was worse for people in large central metro areas than for people in large fringe metro areas for 17% of all quality measures and better for 7% of all quality measures (Figure 38).
- Data for the most recent year show that quality of care was worse for people in medium metro areas than for people in large fringe metro areas for 20% of all quality measures and better for 2% of all quality measures.
- Data for the most recent year show that quality of care was worse for people in small metro areas than for people in large fringe metro areas for 24% of all quality measures and better for 1% of all quality measures.
- Data for the most recent year show that quality of care was worse for people in micropolitan areas than for people in large fringe metro areas for 34% of all quality measures and better for 7% of all quality measures.
- Data for the most recent year show that quality of care was worse for people in noncore areas than for people in large fringe metro areas for 34% of all quality measures and better for 7% of all quality measures.

#### Changes in Quality of Care by Residence Location

Figure 39 Number and percentage of all quality measures that were improving, not changing, or worsening, by residence location, from 2002 to 2020

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percent change is 1% or greater in the desirable direction, and p≤0.10.
- Not Changing = The average annual percent change is ≤1% in either the desirable or undesirable direction or p>0.10.
- Worsening = The average annual percent change is 1% or greater in the undesirable direction, and p≤0.10.

Different data sources have different data years.

Stacked bar chart showing number of quality measures Total (n=492), Improving, 170, Not Changing, 273, Worsening, 49 Large Central Metro (n=82), Improving, 37, Not Changing,37, Worsening, 8 Large Fringe Metro (n=82), Improving, 34, Not Changing, 39, Worsening, 9 Medium Metro (n=81), Improving, 27, Not Changing, 44, Worsening, 10 Small Metro (n=83), Improving, 26, Not Changing, 48, Worsening,97 Micropolitan (n=82), Improving, 23, Not Changing, 52, Worsening, 7 Noncore (n=82), Improving, 23, Not Changing, 53, Worsening, 6

- For people in large central metro areas, 45% of quality measures were improving and 10% of quality measures were getting worse from 2000 through 2020 (Figure 39).
- For people in large fringe metro areas, 41% of quality measures were improving and 11% of quality measures were getting worse from 2000 through 2020.
- For people in medium metro areas, 33% of quality measures were improving and 12% of quality measures were getting worse from 2000 through 2020.
- For people in small metro areas, 31% of quality measures were improving and 11% of quality measures were getting worse from 2000 through 2020.
- For people in micropolitan areas, 28% of quality measures were improving and 9% of quality measures were getting worse from 2000 through 2020.
- For people in noncore areas, 28% of quality measures were improving and 7% of quality measures were getting worse from 2000 through 2020.

#### Changes in Disparities by Residence Location

Figure 40 Number and percentage of quality measures with disparity at baseline for which disparities related to residence location were improving or not changing, 2002 to 2020

Key: n = number of measures.

Note: Different data sources have different data years.

Stacked bar chart showing number of quality measures Total (n=114), Improving, 5, Not Changing, 105, Worsening, 4 Large Central Metro vs. Large Fringe Metro (n=24), Improving, 3, Not Changing, 21 Medium Metro vs. Large Fringe Metro (n=14), Not Changing,13, Worsening, 1 Small Metro vs. Large Fringe Metro (n=15), Not Changing, 14, Worsening, 1 Micropolitan vs. Large Fringe Metro (n=27), Not Changing, 26, Worsening, 1 Noncore vs. Large Fringe Metro (n=34), Improving, 2, Not Changing, 31, Worsening, 1

- From 2000 to 2020, disparities between people living in large central metro areas and people living in large fringe metro areas narrowed in 13% of quality measures (Figure 40).
- From 2000 to 2020, disparities between people living in medium metro areas and people living in large fringe metro areas expanded in 7% of quality measures.
- From 2000 to 2020, disparities between people living in small metro areas and people living in large fringe metro areas expanded in 7% of quality measures.
- From 2000 to 2020, disparities between people living in micropolitan areas and people living in large fringe metro areas expanded in 4% of quality measures.
- From 2000 to 2020, disparities between people living in noncore areas and people living in large fringe metro areas narrowed in 6% of quality measures and expanded in 3% of quality measures.

i Multiracial is defined as people indicating they were two or more of the following races: American Indian or Alaska Native, Asian, Black, Native Hawaiian/Pacific Islander, and White.