# APPENDIX B QUALITY TRENDS AND DISPARITIES TABLES

Appendix B contains data tables showing trends in quality for measures by topic (e.g., Access, Person-Centered Care), as well as single-year disparities information by demographic group (e.g., race, income). Data years vary by measure and data source and some data may not be available for some measures or groups.

## Data Source Changes Due to the COVID-19 Pandemic

In response to the 2019 novel coronavirus (COVID-19) public health emergency, the Centers for Medicare & Medicaid Services (CMS) granted exemptions to the current Medicare quality reporting requirements and value-based purchasing program requirements for 2020 quarters 1 and 2. Provider participation in Q1 and Q2 2020 was voluntary, and results were not publicly reported. Therefore, the NHQDR tables for hospital, hospice, and home health measures using 2020 CMS data are based on Q3 and Q4 2020 only. This approach is consistent with the publicly available data files on http://www.cms.gov in the Provider Data Catalog for 2020 for the Hospital Consumer Assessment of Healthcare Providers and Systems (HCAHPS), CAHPS Hospice, and Home Health CAHPS. Data from the Outcome and Assessment Information Set are from the last two quarters of 2020 and data from the Quality and Safety Review System were collected only for the last quarter of 2020.

The 2020 National Health Interview Survey (NHIS) data collection switched to a telephone-only mode beginning March 19, 2020. Personal visits resumed in all areas in September 2020, but cases were still attempted by telephone first. These changes resulted in lower response rates and differences in respondent characteristics for April–December 2020. Differences observed in estimate between April and December 2020 and earlier time periods may still be affected by these changes. NHIS data are based on household interviews of a sample of the civilian noninstitutionalized population.

The data collection for the 2020 National Survey on Drug Use and Health was also modified due to the pandemic.

## Abbreviations Used in Appendix B

AI/AN: American Indian or Alaska Native
NHPI: Native Hawaiian/Pacific Islander
NHQDR: National Healthcare Quality and Disparities Report
PG: poverty guideline

## Access to Care

Access to healthcare means having “the timely use of personal health services to achieve the best health outcomes.”^1^

1 Institute of Medicine, Committee on Monitoring Access to Personal Health Care Services. Access to Health Care in America. Millman M, ed. Washington, DC: National Academies Press; 1993. https://www.ncbi.nlm.nih.gov/books/NBK235882/. Accessed September 21, 2022 .

### Importance

Access to comprehensive, quality healthcare services is important for promoting and maintaining health, preventing and managing disease, reducing unnecessary disability and premature death, and achieving health equity for all Americans.^2^ Attaining good access to care means having:

- Health insurance that facilitates entry into the healthcare system.
- Timely access to needed care.
- A usual source of care with whom the patient can develop a relationship.
- The ability to receive care when there is a perceived need for care.

2 Office of Disease Prevention and Health Promotion. HealthyPeople.gov. Access to Health Services. https://www.healthypeople.gov/2020/topics-objectives/topic/Access-to-Health-Services. Accessed August 20, 2022 .

### Key Findings

Access to care measures that improved overall include:

- People under age 65 who were uninsured all year.
- Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed.
- People under age 65 with any period of uninsurance during the year.

Access to care measures that showed large disparities include:

- People under age 65 with any private health insurance.
- People in fair or poor health with a specific source of ongoing care.
- People under age 65 with health insurance.
- People with a specific source of ongoing care.

### Section: Getting Appointments for Care

### Section: Waiting Time

### Section: Health Insurance

### Section: Usual Source of Care

### Section: Patient Perception of Need

## Affordable Care

The goal of the Affordable Care Act was to establish quality, affordable healthcare for Americans. The law also created a platform to test new healthcare payment and delivery models through the Centers for Medicare & Medicaid Services. Tracking this quality domain helps healthcare professionals, researchers, and policymakers better understand the status of affordable care.

Reducing the cost of healthcare will support two related goals under this quality domain. The first includes ensuring affordable and accessible high-quality healthcare for people, families, caregivers, employers, and governments. The second is supporting and enabling communities to ensure accessible, high-quality care while reducing waste and fraud.

### Importance

Affordability of care remains a central barrier to access to care for many individuals and families and caregivers. Several financial and nonfinancial barriers contribute to the inaccessibility of care. Financial barriers include high premiums and copays, lack of insurance, and underinsurance. Nonfinancial barriers include transportation challenges, negative interactions with care teams, delayed access to a healthcare provider, and inability to access care due to competing demands (e.g., childcare, work schedules).^1^ Past research continues to show that lack of insurance and inaccessible care are linked to patient mortality.^2,3^

1 Kullgren JT, McLaughlin CG, Mitra N, Armstrong K. Nonfinancial barriers and access to care for U.S. adults. Health Serv Res. 2012;47(1 Pt 2):462–85. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3393009/. Accessed August 24, 2022 22092449 .

2 Wilper AP, Woolhandler S, Lasser KE, McCormick D, Bor DH, Himmelstein DU. Health insurance and mortality in U.S. adults. Am J Public Health. 2009;99(12):2289–95. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2775760/. Accessed August 24, 2022 19762659 .

3 Institute of Medicine; Committee on the Consequences of Uninsurance. Care Without Coverage: Too Little, Too Late. Washington, DC: National Academies Press; 2002. https://www.nap.edu/catalog/10367/carewithout-coverage-too-little-too-late. Accessed August 24, 2022 .

### Key Findings

Affordable care measures that show worsening disparities include:

- People under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income.
- People without a usual source of care who indicated a financial or insurance reason for not having a source of care.

### Section: Financial Burden of Healthcare

### Section: Usual Source of Care

## Effectiveness of Care

As better understanding of health has led to superior ways of preventing, diagnosing, and treating diseases, the health of most Americans has improved dramatically. Still, more than half of all Americans are managing one chronic disease and do not receive the full benefits of high-quality care.^1,2^

1 Centers for Disease Control and Prevention, National Center for Chronic Disease Prevention and Health Promotion. Chronic Diseases in America. Last reviewed January 2021. https://www.cdc.gov/chronicdisease/resources/infographic/chronic-diseases.htm. Accessed August 24, 2022 .

2 Raghupathi W, Raghupathi V. An empirical study of chronic diseases in the United States: a visual analytics approach. Int J Environ Res Public Health. 2018 Mar;15(3):431. 10.3390/ijerph15030431. Accessed August 24, 2022 29494555 .

### Importance

Effective treatment interventions have been shown to reduce mortality and morbidity among people with chronic diseases. The following are some of the leading causes of death in the United States, number of deaths from those causes in 2020, and estimated healthcare costs for the conditions. Condition-specific costs were obtained from separate sources and methodologies may differ^3^:

- Heart disease: 696,962 deaths in 2020 and $219 billion annual average for 2014-2015.^4^
  4 Benjamin EJ, Virani SS, Callaway CW, .; American Heart Association Council on Epidemiology and Prevention Statistics Committee and Stroke Statistics Subcommittee. Heart disease and stroke statistics—2018 update: a report from the American Heart Association. Circulation. 2018;137(12):e67–e492. https://www.ahajournals.org/doi/full/10.1161/CIR.0000000000000558. Accessed August 24, 2022 29386200 .
- Cancer: 602,350 deaths in 2020 and $183 billion in 2015.^5^
  5 Mariotto AB, Enewold L, Zhao J, Zeruto CA, Yabroff KR. Medical care costs associated with cancer survivorship in the United States. Cancer Epidemiol Biomarkers Prev. 2020 Jul;29(7):1304–1312. 10.1158/1055-9965.EPI-19-1534 32522832 .
- COVID-19: 350,831 deaths in 2020.^6^
  6 Validated healthcare costs for COVID-19 are not available at this time.
- Accidents (unintentional injuries): 200,955 deaths in 2020 and $327 billion in 2019.^7^
  7 Peterson C, Miller GF, Barnett SB, Florence C. Economic cost of injury — United States, 2019. MMWR Morb Mortal Wkly Rep 2021;70:1655–1659. 10.15585/mmwr.mm7048a1. Accessed August 24, 2022 34855726 .
- Stroke (cerebrovascular diseases): 160,264 deaths and $45.5 billion annual average for 2014-2015.^4^
- Chronic lower respiratory diseases: 152,657 deaths in 2020 and $49 billion for COPD in 2020^8^ and $50 billion for asthma in 2013.^9^
  8 Centers for Disease Control and Prevention. Chronic Obstructive Pulmonary Disease. COPD Costs. Last reviewed February 2018. https://www.cdc.gov/copd/infographics/copd-costs.html. Accessed August 24, 2022 .
  9 Nurmagambetov T, Kuwahara R, Garbe P. The economic burden of asthma in the United States, 2008-2013. Ann Am Thorac Soc. 2018 Mar;15(3):348–356. 10.1513/AnnalsATS.201703-259OC. Accessed August 24, 2022 29323930 .
- Alzheimer’s disease: 121,499 deaths in 2019 and $321 billion estimated in 2022.^10^
  10 2022 Alzheimer’s Disease Facts and Figures. Alzheimer’s Impact Movement and Alzheimer’s Association. March 2022. https://www.alz.org/media/Documents/alzheimers-facts-and-figures.pdf. Accessed September 8, 2022 .
- Diabetes: 102,188 deaths and $237 billion in 2017.^11^
  11 American Diabetes Association. Economic costs of diabetes in the U.S. in 2017. Diabetes Care. 2018;41(5):917–928. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5911784/. Accessed August 24, 2022 29567642 .
- Influenza and pneumonia: 53,544 deaths in 2020 and $3 billion in 2015 for influenza^12^ and $13 billion on average 2013-2014 for pneumonia.^13^
  12 Putri WCWS, Muscatello DJ, Stockwell MS, Newall AT. Economic burden of seasonal influenza in the United States. Vaccine. 2018 Jun 22;36(27):3960–3966. https://pubmed.ncbi.nlm.nih.gov/29801998/. Accessed August 24, 2022 29801998 .
  13 Tong S, Amand C, Kieffer A, Kyaw MH. Trends in healthcare utilization and costs associated with pneumonia in the United States during 2008–2014. BMC Health Serv Res 18, 715 (2018). https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6137867/. Accessed August 24, 2022 .
- Nephritis, nephrotic syndrome, and nephrosis: 52,547 deaths in 2020 and $82 billion in Medicare for chronic kidney disease without end-stage kidney disease and $49.2 billion in Medicare for end stage kidney disease in 2018.^14^
  14 United States Renal Data System. 2020 USRDS Annual Data Report: Epidemiology of Kidney Disease in the United States. Bethesda, MD: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases; 2020. https://adr.usrds.org/2020/. Accessed August 24, 2022 .

3 Murphy SL, Kochanek KD, Xu JQ, Arias E. Mortality in the United States, 2020. NCHS Data Brief no. 427. Hyattsville, MD: National Center for Health Statistics; 2021. https://www.cdc.gov/nchs/data/databriefs/db427.pdf. Accessed August 24, 2022 .

### Key Findings

Effective care measures that improved overall include:

- Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined.
- Deaths per 1,000 hospital admissions with pneumonia, age 18 and over.
- HIV infection deaths per 100,000 population.
- Deaths per 1,000 hospital admissions with heart failure, age 18 and over.
- Patients with tuberculosis who completed a curative course of treatment within 1 year of initiation of treatment.

Effective care measures that worsened overall include:

- Hospital inpatient stays involving opioid-related diagnoses per 100,000 population.
- Emergency department visits involving opioid-related diagnoses per 100,000 population.
- Hospital admissions for heart failure per 100,000 population, age 18 and over.
- Suicide deaths among people age 12 and over per 100,000 population.
- Adults age 40 and over with diagnosed diabetes who had their feet checked for sores or irritation in the calendar year.

Effective care measures that showed large disparities include:

- HIV infection deaths per 100,000 population.
- New HIV cases per 100,000 population age 13 and over.
- Adjusted incident rates of end stage renal disease due to diabetes per million population.

Effective care measures that showed worsening disparities include:

- Hospital admissions for heart failure per 100,000 population, age 18 and over.
- Emergency department visits involving opioid-related diagnoses per 100,000 population.
- Hospital inpatient stays involving opioid-related diagnoses per 100,000 population.

### Section: Cancer

### Section: Cardiovascular Disease

### Section: Chronic Kidney Disease

### Section: Diabetes

### Section: HIV/AIDS

### Section: Mental Health and Substance Use Disorder

### Section: Musculoskeletal Disease

### Section: Respiratory Diseases

## Patient Safety

The National Academy of Medicine, formerly Institute of Medicine (IOM), defines patient safety as “freedom from accidental injury due to medical care or medical errors.”^1^ In 1999, the IOM published their landmark report, To Err Is Human: Building a Safer Health System,^1^ which called for a national effort to reduce medical errors and improve patient safety.

1 Committee on Quality of Health Care in America, Institute of Medicine. To Err Is Human: Building a Safer Health System. Kohn LT, Corrigan JM, Donaldson MS, eds. Washington, DC: National Academies Press; 2000. http://www.nap.edu/catalog/9728.html. Accessed August 25, 2022 .

In 2015, the National Academy of Medicine built on its initial report on patient safety by publishing Improving Diagnosis in Health Care, which identifies eight major goals for effecting progress on diagnostic error and improving patient safety outcomes.^2^ Although To Err Is Human did not fully address improving diagnostic safety and quality, the patient safety field has now established consensus that more attention needs to be placed on reducing diagnostic error.

2 Committee on Diagnostic Error in Health Care; Board on Health Care Services; Institute of Medicine; National Academies of Sciences, Engineering, and Medicine. Improving Diagnosis in Health Care. Balogh EP, Miller BT, Ball JR, eds. Washington, DC: National Academies Press; December 2015. http://nap.edu/21794. Accessed August 25, 2022 .

In addition to providing reports and materials, AHRQ has identified three long-term goals related to improving patient safety:

- Reducing preventable hospital admissions and readmissions,
- Reducing the incidence of adverse healthcare-associated conditions (HACs), and
- Reducing harm from inappropriate or unnecessary care.

To meet these goals, AHRQ supports research and quality improvement programs to reduce healthcare-associated infections (HAIs) and HACs, adverse drug events, and other preventable adverse events.

A common cause of adverse events is gaps in communication either between providers or with patients, their family members, or caregivers. Communication gaps may occur unintentionally and may result from implicit biases among healthcare providers.^3^ Thus, researchers, providers, and policymakers are considering patient safety and person-centered care together to better understand breakdowns in care so that patients experience safer care and better health outcomes.

3 Hall WJ, Chapman MV, Lee KM, Merino YM, Thomas TW, Payne BK, Eng E, Day SH, Coyne-Beasley T. Implicit racial/ethnic bias among health care professionals and its influence on health care outcomes: a systematic review. Am J Public Health. 2015;105(12):e60–e76. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4638275/. Accessed August 25, 2022 .

### Importance

The number of deaths in U.S. hospitals due to medical error each year has been estimated at 44,000-98,000.^2^ The age-standardized mortality rate due to adverse effects of medical treatment has been estimated at 1.15 per 100,000 population.^4^ In addition, the number of hospital-acquired conditions in U.S. hospitals in 2017 was 2,550,000,^5^ and the all-payer 30-day readmission rate in 2016 was 13.9% of admissions.^6^ More recently, the increase in ventilator-associated events during the 2021 COVID-19 delta surge was 60%.^7^

4 Sunshine JE, Meo N, Kassebaum NJ, Collison ML, Mokdad AH, Naghavi M. Association of adverse effects of medical treatment with mortality in the United States: a secondary analysis of the Global Burden of Diseases, Injuries, and Risk Factors Study. JAMA Netw Open 2019;2(1):e187041. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6484545/. Accessed August 25, 2022 30657530 .

5 AHRQ National Scorecard on Hospital-Acquired Conditions: Final Results for 2014 Through 2017. https://www.ahrq.gov/sites/default/files/wysiwyg/professionals/quality-patient-safety/pfp/Updated-hacreportFInal2017data.pdf. Accessed August 25, 2022 .

6 Bailey MK, Weiss AJ, Barrett ML, Jiang HJ. Characteristics of 30-Day Readmissions, 2010-2016. HCUP Statistical Brief #248. Rockville, MD: Agency for Healthcare Research and Quality; February 2019. www.hcup-us.ahrq.gov/reports/statbriefs/sb248-Hospital-Readmissions-2010-2016.pdf (https://datatools.ahrq.gov/nhqdr). Accessed August 25, 2022 .

7 Lastinger L, Alvarez C, Kofman A, Konnor R, Kuhar D, Nkwata A, Patel P, Pattabiraman V, Xu S, Dudeck M. Continued increases in the incidence of healthcare-associated infection (HAI) during the second year of the coronavirus disease 2019 (COVID-19) pandemic. Infect Control Hosp Epidemiol. 2022 May 20:1–5. doi: 10.1017/ice.2022.116. Accessed August 25, 2022 .

Additional hospital inpatient costs due to hospital-acquired conditions (2014)^6^ include:

- Central line-associated bloodstream infection, $48,108.
- Ventilator-associated pneumonia, $47,238.
- Surgical site infection, $28,219.
- Venous thromboembolism, $17,367.

### Key Findings

Patient safety measures that improved overall include:

- Postoperative respiratory failure, prolonged mechanical ventilation, or reintubation per 1,000 elective-surgery admissions, age 18 and over.
- Long-stay nursing home residents with a urinary tract infection.
- Short-stay nursing home patients with pressure ulcers that are new or worsened.
- Hospital admissions with iatrogenic pneumothorax per 1,000 medical and surgical admissions, age 18 and over.
- Home health care patients whose management of oral medications improved.

Patient safety measures that worsened overall include:

- Adults who reported a home health care provider asking to see all the prescription and over-the-counter medicines they were taking, when they first started getting home health care.

Patient safety measures that experienced significant disparities include:

- Deaths per 1,000 elective-surgery admissions who developed serious treatable complications of care during hospitalization, ages 18-89 or obstetric admissions.
- Adults age 65 and over who received in the calendar year at least 1 of 33 potentially inappropriate prescription medications for older adults.
- Home health care patients whose management of oral medications improved.

### Section: Healthcare-Associated Infections

### Section: Surgical Care

### Section: Other Complications of Hospital Care

### Section: Complications of Medication

### Section: Birth-Related Complications

### Section: Inappropriate Treatment

### Section: Supportive and Palliative Care

### Section: Home Health Communication

## Person-Centered Care

The National Academy of Medicine, formerly Institute of Medicine (IOM), identifies patient centeredness as a core component of quality healthcare.^1^ Patient centeredness is defined as:

[H]ealth care that establishes a partnership among practitioners, patients, and their families (when appropriate) to ensure that decisions respect patients’ wants, needs, and preferences and that patients have the education and support they need to make decisions and participate in their own care.^2^

2 Institute of Medicine Committee on the National Quality Report on Health Care Delivery. Envisioning the National Health Care Quality Report. Hurtado MP, Swift EK, Corrigan JM, eds. Washington, DC: National Academies Press; 2001. http://nap.edu/10073. Accessed August 25, 2022 .

1 Institute of Medicine Committee on Quality of Health Care in America. Crossing the Quality Chasm: A New Health System for the 21st Century. Washington, DC: National Academies Press; 2001. https://nap.nationalacademies.org/catalog/10027/crossing-the-quality-chasm-a-new-health-system-for-the. Accessed August 25, 2022 .

### Importance

Person-centered decision making (when physicians consider the needs and circumstances of an individual) for planning an individual’s care has been shown to improve healthcare outcomes.^3^ In addition, person-centered approaches to care have been shown to improve individuals’ health status. These approaches rely on building a relationship between the individual and the provider, improving communication, fostering a positive atmosphere, and encouraging individuals to actively participate in interactions with their provider.^4^ Finally, person-centered care can reduce the chance of misdiagnosis due to poor communication.^5^

3 Holmes-Rovner M, Montgomery JS, Rovner DR, Scherer LD, Whitfield J, Kahn VC, Merkle EC, Ubel PA, Fagerlin A. Informed decision making: assessment of the quality of physician communication about prostate cancer diagnosis and treatment. Med Decis Mak. 2015;35(8):999–1009. doi: 10.1177/0272989X15597226. Accessed August 25, 2022 .

4 Weiner SJ, Schwartz A, Sharma G, Binns-Calvey A, Ashley N, Kelly B, Dayal A, Patel S, Weaver FM, Harris I. Patient-centered decision making and health care outcomes: an observational study. Ann Intern Med. 2013;158(8):573–9. https://www.acpjournals.org/doi/10.7326/0003-4819-158-8-201304160-00001. Accessed August 25, 2022 23588745 .

5 Okunrintemi V, Spatz ES, Di Capua P, Salami JA, Valero-Elizondo J, Warraich H, Vira ni SS, Bla ha MJ, Blankstein R, Butt AA, Borden WB, Dharmarajan K, Ting H, Krumholz HM, Nasir K. Patient-provider communication and health outcomes among individuals with atherosclerotic cardiovascular disease in the United States: Medical Expenditure Panel Survey 2010 to 2013. Circ Cardiovasc Qual Outcomes. 2017;10(4):1–8. https://www.ahajournals.org/doi/full/10.1161/CIRCOUTCOMES.117.003635. Accessed August 25, 2022 .

Person-centered care and successful communication help lead to increased individual and provider satisfaction, trust in the provider, and functional and psychological well-being. Effective communication also leads to improved outcomes, including:

- A small but significant absolute risk reduction of mortality from coronary artery disease,
- Improved control of diabetes and hyperlipidemia,
- Better adherence to antihypertensive medication,
- Bereavement adjustment in caregivers of cancer patients, and
- Higher self-efficacy of adherence to HIV medications.^6^
  6 Chou C. Time to start using evidence-based approaches to patient engagement. NEJM Catalyst. 2018;4(2) .

In addition to improved outcomes, research indicates that effective person-centered care may result in decreased healthcare costs:

- Poor communication, lack of collaboration, and lack of support for self-care are associated with suffering and waste in healthcare.^6^
- Person-centeredness has been shown to reduce overuse of medical care.^7^
  7 Øvretveit J. Do Changes to Patient-Provider Relationships Improve Quality and Save Money? A Review of the Evidence About Value Improvements Made by Changing Communication, Collaboration, and Support for Self-Care. London, UK: The Health Foundation; June 2012. http://www.health.org.uk/publications/do-changes-to-patient-provider-relationships-improve-quality-and-save-money. Accessed August 25, 2022 .
- Improved communication methods can lower barriers to discussion about medication costs with individuals.^8^
  8 Bertakis KD, Azari R. Patient-centered care is associated with decreased health care utilization. J Am Board Fam Med. 2011;24(3):229–39. https://www.jabfm.org/content/24/3/229.long. Accessed August 25, 2022 21551394 .
- Improved communication between individuals and providers during medical decision making can reduce costs.^9^
  9 Slota C, Davis SA, Blalock SJ, Carpenter DM, Muir KW, Robin AL, Sleath B. Patient-physician communication on medication cost during glaucoma visits. Optom Vis Sci. 2017;94(12):1095–1101. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5726412/. Accessed August 25, 2022 29194229 .

### Key Findings

Person-centered care measures that improved overall include:

- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always gave them easy-to-understand instructions about what to do for a specific illness or health condition.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never spent enough time with them.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say.

Person-centered care measures that had disparities include:

- Adults with limited English proficiency and usual source of care (USC) whose USC had language assistance.
- Adults who reported that home health care providers always treated them with courtesy and respect in the last 2 months of care.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand.

### Section: Patient Experience of Care

### Section: Hospital Communication

### Section: Home Health Communication

### Section: Hospice Care

## Care Coordination

Care coordination is a conscious effort to ensure that all key information needed to make care decisions is available to patients and providers. It is defined as the deliberate organization of patient care activities between two or more participants involved in a patient’s care to facilitate appropriate delivery of healthcare services.^1^ Care coordination is multidimensional and essential to preventing adverse events, ensuring efficiency, and making care person centered.^2^

1 Peterson K, Anderson J, Bourne D, Boundy E. Scoping Brief: Care Coordination Theoretical Models and Frameworks. 2018 Jun. In: VA Evidence Synthesis Program Evidence Briefs. Washington, DC: Department of Veterans Affairs; 2011. https://www.ncbi.nlm.nih.gov/books/NBK525002/. Accessed September 21, 2022 .

2 Noël PH, Barnard JM, Leng M, Penney LS, Bharath PS, Olmos-Ochoa TT, Chawla N, Rose DE, Stockdale SE, Simon A, Lee ML, Finley EP, Rubenstein LV, Ganz DA. The Coordination Toolkit and Coaching Project: cluster-randomized quality improvement initiative to improve patient experience of care coordination. J Gen Intern Med. 2022;37(1):95–103. 10.1007/s11606-021-06926-y. Accessed September 21, 2022 34109545 .

Patients in greatest need of care coordination include those with:

- Multiple chronic medical conditions,
- Concurrent care from several health professionals across care settings,
- Many medications,
- Extensive diagnostic workups, and
- Transitions from one care setting to another.

Effective care coordination requires well-defined multidisciplinary teamwork based on the principle that all who interact with a person must work together to ensure the delivery of safe, high-quality care in every setting.

### Importance

Care coordination interventions have been shown to:

- Reduce mortality among patients with heart failure,
- Reduce mortality and dependency among patients with stroke,
- Reduce symptoms among patients with depression and at the end of life, and
- Improve glycemic control among patients with diabetes.^1^
  1 One case was reported in New York in 2022, in an unvaccinated individual.

Care coordination interventions have also been shown to:

- Reduce hospitalizations among patients with heart failure,
- Reduce readmissions among patients with mental health conditions, and
- Be cost-effective when applied to treatment of depression.^1^

### Key Findings

Care coordination measures that improved overall include:

- Hospital admissions for urinary tract infection per 100,000 population.
- Hospital admissions for asthma per 100,000 population, ages 2-17.
- Home health care patients who had to be admitted to the hospital.

Care coordination measures that worsened overall include:

- Hospital admissions with diabetes with short-term complications per 100,000 population, age 18 and over.
- Hospital admissions with diabetes with long-term complications per 100,000 population, age 18 and over.
- Lower extremity amputations among admissions for diabetes per 100,000 population, age 18 and over.
- Adult hospital patients who strongly disagree or disagree that staff took their preferences and those of their family and caregiver into account when deciding what the patients discharge healthcare would be.
- Home health care patients who had an emergency department visit without a hospitalization.

Care coordination measures that showed worsening disparities include:

- Emergency department visits for asthma per 10,000 population, age 2-19.
- Hospital admissions with hypertension per 100,000 population, age 18 and over.
- Hospital admissions for urinary tract infection per 100,000 population, ages 3 months to 17 years.
- Hospital admissions for asthma per 100,000 population, ages 2-17.
- Hospital admissions for uncontrolled diabetes without complications per 100,000 population, age 18 and over.

### Section: Transitions of Care

### Section: Medication Information

### Section: Preventable Emergency Department Visits

### Section: Preventable Hospitalizations

### Section: Preventable Hospitalizations Among Home Health and Nursing Home Patients

### Section: Supportive and Palliative Care

### Section: Potentially Avoidable Admissions

## Healthy Living

Many illnesses associated with chronic conditions are related to unhealthy behaviors, environmental hazards, and poor social supports. These illnesses can be prevented by increasing access to effective clinical preventive services and promoting community interventions that advance public and population health. Working with communities is critical to ensure that immunizations and early detection and prevention services reach everyone who needs them and to build healthy neighborhoods and support networks.

### Importance

Promoting healthy lifestyles that prevent disease and disability is better for people and more efficient than treating conditions after organ damage has occurred. Healthy living is supported through preventive care strategies that cross all age groups and the care continuum. Among the most impactful preventive strategies are vaccinations for children and prenatal care.

Advances in medical science protect children against more diseases than ever before. Some diseases that once injured or killed thousands of children have been eradicated completely and others are close to eradication, primarily due to safe and effective vaccines. Polio is one example of the great impact vaccines have had in the United States. Polio was once America’s most feared disease, causing death and paralysis across the country, but today, thanks to vaccination, there are no reports of polio in the United States.^1^

A strong body of research shows the cost-effectiveness of immunization; however, opportunities still exist for providers, patients, and systems to optimize immunization participation. It is less expensive to prevent a disease using immunization than to treat it. In a 2005 study on the economic impact of routine childhood immunization in the United States, researchers estimated that for every dollar spent, the vaccination program saved more than $5 in direct costs and approximately $11 in additional costs to society.^2,3^

2 Zhou F, Santoli J, Messonnier ML, Yusuf HR, Shefer A, Chu SY, Rodewald L, Harpaz R. Economic evaluation of the 7-vaccine routine childhood immunization schedule in the United States, 2001. Arch Pediatr Adolesc Med. 2005 Dec;159(12):1136–44. https://www.ncbi.nlm.nih.gov/pubmed/16330737. Accessed September 21, 2022 16330737 .

3 Leidner AJ, Murthy N, Chesson HW, Biggerstaff M, Stoecker C, Harris AM, Acosta A, Dooling K, Bridges CB. Cost-effectiveness of adult vaccinations: a systematic review. Vaccine 2019;37(2):226–34. 10.1016/j.vaccine.2018.11.056. Accessed September 21, 2022 30527660 .

### Key Findings

Healthy living measures that improved overall include:

- Adolescents ages 16-17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis since the age of 10 years.
- Adolescents ages 16-17 who received 1 or more doses of meningococcal conjugate vaccine.
- Home health care patients who had influenza vaccination during flu season.
- Long-stay nursing home residents with physical restraints.
- Home health care patients whose ability to get in and out of bed improved.

Healthy living measures that worsened overall include:

- Long-stay nursing home residents who were assessed for pneumococcal vaccination.
- Children ages 2-19 with obesity.

Healthy living measures that showed disparities include:

- Children ages 5-17 with untreated dental caries.
- Adults without hypertension who had their blood pressure measured in the past 2 years.
- Children ages 19-35 months who received 1 or more doses of measles-mumps-rubella vaccine.
- Children ages 19-35 months who received 1 or more doses of varicella vaccine.
- Children ages 0-17 with a wellness checkup in the past 12 months.

### Section: Maternal and Child Health

### Section: Lifestyle Modification

### Section: Functional Status Preservation and Rehabilitation

### Section: Supportive and Palliative Care

### Section: Clinical Preventive Services

## Supplemental Measures

### Subcategory: Access

### Subcategory: Person-Centered Care

### Subcategory: Care Coordination

### Subcategory: Effectiveness of Care

### Subcategory: Affordable Care