# APPENDIX A METHODS OF THE NATIONAL HEALTHCARE QUALITY AND DISPARITIES REPORT AND RELATED CHARTBOOKS

This appendix describes the methods used to select and analyze measures related to access to healthcare and quality of healthcare. The appendix also describes methods for analyzing trends, benchmarks, and disparities. In addition, the appendix includes data sources used to prepare the report, data limitations, and reporting conventions.

## Measures

### Access to Healthcare

Purpose. Assess access to care for the overall U.S. population and priority populations; identify racial, ethnic, and socioeconomic disparities; track changes in access to care over time; and identify aspects of access to care that are improving and aspects that are not improving.

Approach. Factors that facilitate accessing healthcare, including having health insurance and a usual source of care, have been tracked since the first reports. Measures of timeliness of care and infrastructure to provide healthcare to minority and low-income populations were added to the access measure set.

Summaries of Access. At times, the report will present summary information across a panel of access measures, including measures widely considered important for accessing healthcare, such as getting care in a timely manner.

The access measure panel excludes measures with less clear interpretation. For example, increases in the percentage of people under age 65 with any period of public insurance during the year may indicate people lost their private insurance, which is undesirable. On the other hand, they obtained public insurance coverage, which indicates access to some form of health insurance is improving.

Similarly, use of emergency departments as a usual source of care is not included in the access measure panel, because rising rates have multiple interpretations. They could reflect meeting a previously unmet community need, which would be desirable, or problems getting care in provider offices, which would be undesirable. Researchers, policymakers, and other users should explore these data further to understand the underlying causes.

### Quality of Healthcare

Purpose. Assess quality of care for the overall U.S. population and priority populations; identify disparities among racial, ethnic, and socioeconomic groups; track changes in quality of care over time; and identify aspects of quality of care that are improving and aspects that are not improving.

Initial Approach. The selection of quality measures to include in the first reports involved several steps:

- The Institute of Medicine (IOM) provided criteria for the selection of quality measures in 2001: overall importance of the aspects of quality being measured, scientific soundness of the measures, and feasibility of the measures. It also provided criteria for the measure set as a whole: balance, comprehensiveness, and robustness.
- IOM and AHRQ issued calls for measures that yielded hundreds of measures submitted by private and governmental organizations.
- A Federal Measures Workgroup was convened to apply the IOM criteria to the measures submitted for consideration.
- A preliminary measure set was published in the Federal Register for public comment; additional comments were obtained through a hearing organized by the National Committee on Vital and Health Statistics.
- In 2003, this process yielded an initial measure set that included 147 measures from two dozen data sources.

Types of Quality Measures. Most measures tracked in the report reflect processes of care, outcomes of care, and patient perceptions of care:

- Processes of Care. These measures generally represent percentages of people receiving care they need or percentages of people receiving care they should not receive. Measures are specified so that everyone in the denominator needs the service and optimal care equals 100%. These measures are generally not adjusted for age and sex since need is captured in the specification of the denominator.
- Outcomes of Care. These measures generally represent rates of adverse events or deaths. Because death rates often reflect factors other than healthcare, only death rates with moderate ties to processes of care are tracked. For example, colorectal cancer death rates are tracked because they are related to rates of colorectal cancer screening.
- Patient Perceptions of Care. These measures generally represent percentages of people who perceived problems with aspects of their care.

Refinement of the Measure Set. Since the first reports in 2003, the measure set has been reviewed each year and changes made as needed. All changes are approved by the U.S. Department of Health and Human Services Interagency Work Group that supports the NHQDR.

Additions have been made to the measure set as new domains of quality, data, and measures have become available. For example, Care Coordination and Affordable Care were not recognized quality domains when the reports started, and measures of these domains were identified and added after they were recognized.

Deletions have been made when data collection for measures ceased or when new scientific information indicated that a measure did not represent high-quality care. In addition, process measures that achieve overall performance levels exceeding 95% are not tracked in the report. The success of these measures limits their utility for tracking improvement over time. Because these measures cannot improve to a significant degree, including them in the measure set creates a ceiling effect that may dampen quantification of rates of change over time. Data on retired measures continue to be collected and these measures will be added back to the report if their performance falls below 95%.

Modifications have been made when clinical recommendations change. For example, clinical recommendations often set new target levels or recommended frequencies for specific services.

Summaries of Quality. At times, the report will present summary information across a panel of quality measures. This panel includes measures that are widely considered important for healthcare quality, such as measures of processes, outcomes, and patient perceptions, as noted above. The panel excludes measures with less clear interpretation, typically measures of infrastructure and costs.

## Data Sources

### Overview of Data

The data included in the report were determined by the measures the IWG and the NHQDR team chose to track. The report is based on dozens of data sources to provide a comprehensive assessment of access to healthcare, quality of care, and disparities in the United States. Most are nationally representative or cover the entire U.S. population.

Different types of data are used to provide complementary perspectives on healthcare and include patient and population surveys, provider surveys, administrative data from facilities, medical records, registries, surveillance systems, and vital statistics. Settings of care covered include ambulatory care, health centers, emergency departments, hospitals, nursing homes, hospices, and home health.

Data experts from contributing agencies or organizations generate descriptive summary statistics from the micro data for the NHQDR measures and population groups of interest. For certain measures, the NHQDR team downloads summary statistics directly from trusted websites.

All survey design features are taken into account. The percentages or rates are weighted to represent the targeted population. At a minimum, statistics with a sample size of fewer than 30 individuals or relative standard errors larger than 30% are suppressed for statistical reliability, data quality, and confidentiality. Some agencies contributing data applied more strict suppression criteria.

The NHQDR team has maintained and accumulated the data since 2003, the first year of the reports. Some survey designs, questionnaires, data collection methods, definitions, and data calculation methods have changed over the years. The team and the agencies contributing data worked together to address the changes and to ensure that only comparable data are trended over time. Some contributing agencies informed the team about the changes, provided recommendations, and adjusted the measures or removed the noncomparable data from the database. Data are retained if the changes are considered minor and do not significantly affect the estimates.

Only data sources that are regularly included in the report are listed below. The list does not include sources that do not collect data on a regular basis; such data are presented intermittently in the report when they address topics or populations not well covered by regular data collection.

### Federal Sources of Data

#### Agency for Healthcare Research and Quality

- Healthcare Cost and Utilization Project (HCUP)
- National Consumer Assessment of Healthcare Providers and Systems (CAHPS^®^) Database – CAHPS^®^ Health Plan Survey Database

#### Centers for Disease Control and Prevention

- Behavioral Risk Factor Surveillance System (BRFSS)
- National Ambulatory Medical Care Survey (NAMCS)
- National Electronic Health Records Survey (NEHRS)
- National Health and Nutrition Examination Survey (NHANES)
- National Health Interview Survey (NHIS)
- National HIV Surveillance System (NHSS)
- National Hospital Ambulatory Medical Care Survey (NHAMCS)
- National Immunization Survey (NIS)
- National Program of Cancer Registries (NPCR)
- National Tuberculosis Surveillance System (NTSS)
- National Vital Statistics System—Linked Birth and Infant Death Data (NVSS-L)
- National Vital Statistics System—Mortality (NVSS-M)
- National Vital Statistics System—Natality (NVSS-N)

#### Centers for Medicare & Medicaid Services

- Home Health Care CAHPS (HHCAHPS) Survey
- Home Health Outcome and Assessment Information Set (OASIS)
- Hospital CAHPS (HCAHPS) Survey
- Hospice CAHPS Survey
- Hospital Inpatient Quality Reporting (Hospital IQR) Program
- Hospital Outpatient Quality Reporting (Hospital OQR) Program
- Minimum Data Set (MDS)

#### Health Resources and Services Administration

- HIV/AIDS Bureau - Ryan White HIV/AIDS Program
- Uniform Data System (UDS)

#### Indian Health Service

- Indian Health Service (IHS) National Data Warehouse (NDW) Workload and Population Data Mart (WPDM)

#### National Institutes of Health

- United States Renal Data System (USRDS)

#### Substance Abuse and Mental Health Services Administration

- National Survey on Drug Use and Health (NSDUH)
- Substance Use Disorder Treatment Episode Data Set (TEDS)

#### United States Census Bureau

- American Community Survey (ACS)

#### Multiagency Data Sources

- Medical Expenditure Panel Survey (MEPS)
- Quality and Safety Review System (QSRS)

### Academic Institutions

#### University of Michigan

- University of Michigan Kidney Epidemiology and Cost Center (UMKECC)

### Professional Organizations and Associations

#### American Hospital Association

- American Hospital Association (AHA) Annual Survey Information Technology Supplement

#### Commission on Cancer and American Cancer Society

- National Cancer Data Base (NCDB)

## Populations

### Overall U.S. Population

Purpose. A key function of the NHQDR and related chartbooks is to assess access to healthcare and quality of healthcare for the overall U.S. population.

Approach. National data are used as collected without additional exclusions. Common population limitations for data collection include the following:

- Most federal health surveys are limited to the civilian noninstitutionalized population and do not include people on active duty in the military or who reside in nursing homes or penal or mental institutions.
- Many facility data collections do not include federal facilities run by the Departments of Defense or Veterans Affairs or IHS.

### Priority Populations

Purpose. Another key function of the NHQDR and related chartbooks is to assess access to healthcare and quality of healthcare for select populations defined by age, sex, race, ethnicity, income, education, health insurance, and geographic location.

Approach. To the extent supported by data collection, definitions of priority populations are standardized across different data sources. The NHQDR also includes categories beyond those specified by the statute identifying priority populations. While the statute includes low-income groups, it does not mention other social determinants of health, such as insurance status and education. The NHQDR includes these categories, as analyses of disparities in these areas demonstrate the impact of socioeconomic factors on quality of and access to healthcare.

Commonly used population categories in the NHQDR across multiple databases include:

- Age: 0-17, 18-44, 45-64, and 65 and over.
- Sex: Male and female.
- Race: White, Black, Asian, Native Hawaiian or Pacific Islander, American Indian or Alaska Native, and more than one race.^i^
- Ethnicity and race: Hispanic, non-Hispanic Asian, non-Hispanic Black, and non-Hispanic White.^ii^
- Income: Less than 100% of poverty guideline (PG), 100-199% of PG, 200-399% of PG, and 400% of PG or more.^iii^
- Education: Less than a high school education,^iv^ high school graduates, and people with any college education.
- Health insurance, ages 0-64: Any private insurance, public insurance^v^ only, and no insurance.
- Health insurance, age 65 and over: Medicare and any private insurance, Medicare and other public insurance, and Medicare only.
- Disabilities: Disability status is defined by following the methodology of the American Community Survey, which is different from the activity limitation definition used in the 2007-2018 NHQDR. Adults age 18 and over are defined as with disability if reporting at least one of the following: serious difficulty hearing, serious difficulty seeing, serious cognitive difficulty, serious difficulty walking or climbing stairs, difficulty dressing or bathing, and difficulty doing errands.
- Children with special health care needs (CSHCN): Children ages 0-17 with activity limitations or need or use of more healthcare or other services than is usual for most children of the same age. Question sequences^vi^ are asked about the following five health consequences: the need or use of medicines prescribed by a doctor; the need or use of more medical care, mental health care, or education services than is usual for most children; limitations or inability to do things most children can do; the need or use of special therapy, such as physical, occupational, or speech therapy; and the need or use of treatment or counseling for emotional, developmental, or behavioral problems. Children reporting at least one of the five health consequences were identified as having a special health care need.
- Geographic location: Large central metropolitan, large fringe metropolitan, medium metropolitan, small metropolitan, micropolitan, and noncore areas are typically based on the 2013 National Center for Health Statistics Urban-Rural Classification Scheme (https://www.cdc.gov/nchs/data_access/urban_rural.htm).^vii^ The 2013 scheme includes six urbanization categories, including:
  ■ Four metropolitan county designations or counties meeting the metropolitan statistical area (MSA) criteria defined by the Office of Management and Budget (OMB):
    ♦ Large Central Metropolitan: Large central metropolitan counties in an MSA of 1 million or more population:
      1. That contain the entire population of the largest principal city of the MSA, or
      2. Whose entire population is contained within the largest principal city of the MSA, or
      3. That contain at least 250,000 residents of any principal city in the MSA.
    ♦ Large Fringe Metropolitan: Counties in MSAs of 1 million or more population that do not qualify as large central. Large fringe metropolitan areas are also described as suburban areas. This category is the reference group that all other residence locations are compared with in this report.
    ♦ Medium Metropolitan: Counties in MSAs of 250,000 to 999,999 population.
    ♦ Small Metropolitan: Counties in MSAs of less than 250,000 population.
  ■ Two nonmetropolitan county designations for counties not meeting the MSA criteria defined by OMB:
    ♦ Micropolitan: Counties in a micropolitan statistical area.
    ♦ Noncore: Nonmetropolitan counties that are not in a micropolitan statistical area.

Special Analyses. Other important groups have been more difficult to identify in healthcare data:

- Beginning with the 2012 reports, contrasts by granular racial/ethnic subgroups have been included when available. The NHQDR team has not yet found a healthcare data source that includes all the subgroups of interest, because sample sizes have been too small to yield statistically reliable data. Thus, limited data have been presented for Hispanic subgroups (Mexican, Puerto Rican, Cuban, other Hispanic/Latino/Spanish origin), Asian subgroups (Asian Indian, Chinese, Filipino, Japanese, Korean, Vietnamese, other Asian), and Native Hawaiian and Other Pacific Islander subgroups (Native Hawaiian, Guamanian or Chamorro, Samoan, other Pacific Islanders).
- Beginning with the 2013 reports, analyses of a few multiple chronic conditions have been included, but data sources differ in the chronic conditions that can be identified. Improving measurement and data for these groups is critical to understanding the reasons people with multiple chronic conditions cannot access high-quality healthcare and to develop effective interventions to help them overcome these barriers. Due to the change from International Classification of Diseases, Ninth Revision (ICD-9-CM) codes to ICD-10-CM codes, the chronic condition data are not available in the 2022 NHQDR.

## Analyses

NHQDR analyses typically assess size of disparities, trend over time, trend in disparities, and comparison with benchmark for each measure. The results of the analyses are summarized in charts, tables, and maps and posted on the NHQDR website. The source data for all these analyses are the summary statistics, either percentages or rates, at the national, subgroup, or state level, instead of micro data. Some figures used two-dimensional data, such as ethnicity by income.

### Data Preparation

For all analyses, estimates are aligned to the negative direction. For measures where higher estimates are desirable, the estimates are usually reported as percentages instead of rates. The percentages are flipped (negatively aligned) by deducting the percentage from 100%. An example of negative alignment would be changing “Adults who had an influenza vaccine” to “Adults who did not have an influenza vaccine.”

The flipped or negatively aligned estimate will be referred to as the aligned rate in the text below. For measures where lower estimates are desirable, the estimates are not flipped. The result is interpreted based on the direction of the measures, although the rates are aligned to the negative direction for positive measures.

The NHQDR applies these methods to measure changes in trends and to assess disparities. This approach is used uniformly across all measures from different data sources in order to determine whether the differences between comparison groups and reference groups are statistically significant (not due to chance) and are more likely to be true differences. These methods improve uniformity for comparability and ease of understanding of the findings and increase the sensitivity (i.e., the likelihood of a difference being considered statistically significant) but have some limitations. (Refer to “Analysis Limitations” later in this document.)

For analyses of disparities in the current year and change in disparities over time, comparisons are typically made between a priority population or comparison group and a reference group. The largest subgroup or the subgroup that often received the best healthcare is used as the reference group. Table 1 provides examples of specific reference groups.

Table 1 Reference groups

Variable Category | Reference Group
Gender | Male
Age | 18-44 years
Ethnicity/race | Non-Hispanic White
Race | White
Income | 400% of PG or more
Education | Any college education
Disability status | Adults without any disability
Metropolitan status | Large fringe metropolitan (suburb) or metropolitan (urban)
Health insurance | Any private insurance

For comparisons among racial groups, if a measure had data for separate racial categories, racial data were used. If a measure only had a combined race and ethnicity category, those categories (e.g., non-Hispanic White, non-Hispanic Black, Hispanic) were used. Occasionally, comparisons of ethnicity without race information were used (Hispanic, all races and non-Hispanic, all races).

### Trends in Quality

Purpose. To assess change over time considering both magnitude of change and statistical significance. Magnitude of change was considered important because large databases could have trends that were statistically significant but not large enough to be clinically meaningful.

Data Requirement. Estimates for at least four time points between 2000 and the most recent year; fewer than four time points were deemed insufficient to calculate slopes of regression lines.

Approach. Data preparation is applied as discussed above. Average annual percentage change (AAPC) was estimated using unweighted log-linear regression. In previous years, weighted regression was used with weight = (M^2^/v), where M^2^ is the square of the measure value and v is the variance. We recently changed to unweighted regression to be more consistent with methods used in the CMS National Impact Assessments and because analyses demonstrated few differences between weighted and unweighted regressions.

Model. ln(M) = β_0_ + β_1_Y, where ln(M) is the natural logarithm of the aligned rate, β_0_ is the intercept or constant, and β_1_ is the coefficient corresponding to year Y (e.g., the average annual percentage change = 100 × (exp(β)−1)).

Interpretation:

- Improving = Average annual percentage change >1% per year in a favorable direction and p<0.10.^viii^
- Not Changing = Average annual percentage change ≤1% per year or p ≥0.10.
- Worsening = Average annual percentage change >1% per year in an unfavorable direction and p<0.10.

Since the rates were aligned to the negative direction, if the p value is less than 0.10, AAPC less than −1% indicates improving and more than 1% indicates worsening.

The rates are assumed to change at a constant percentage of the rate of the previous year. For example, if the rate is 50/1,000 in 2000 and the average annual percentage change is 10%, then the expected rate is 50/1,000 + (50 × 10%) = 50.5/1,000 in 2001, instead of 50/1,000 +10 = 60/1,000.

Measures changing the most quickly are also identified.

- Improving Quickly = Average annual percentage change >10% per year in a favorable direction and p<0.10.

### Achievable Benchmarks

Purpose. To define a high level of performance that has been attained to help readers understand national and state performance and to serve as an achievable quality improvement goal.

Approach. Data preparation is applied as discussed above. Average of the top 10% best performing states is calculated.

Data Requirement. Estimates for 2015, 2016, or 2017 are required for at least 30 states. About 240 NHQDR measures meet this requirement.

Calculation. Average of estimates from the top 10% of states (e.g., average of top five states if estimates are available on all 50 states and DC). Territories are included in the calculation of the number of states in the top 10% (e.g., top 5 of 50) but are excluded from the top 10% of states for the benchmark calculation because the estimates usually are associated with larger variance.

Updates. Data from 2015 are preferred over more recent data for the benchmark calculation. If a measure does not have 2015 data, 2016 data or 2017 data are used. A benchmark is not calculated if a measure’s latest data year is 2013 or earlier. The overall state-level benchmark is used for all comparisons. A benchmark for each priority population group is not calculated.

Interpretation:

- Figures. When available, benchmarks are shown as dashed red lines on figures.
- Time to Benchmark. When a subpopulation group has at least 4 years of data, time to reach the benchmark is estimated based on the distance between the benchmark and current year’s rate and the average annual change. The average annual change is calculated using unweighted linear regression.
- Model. M = β_0_ + β_1_Y, where M is the aligned rate of a subgroup, β_0_ is the intercept or constant, and β_1_ is the coefficient corresponding to year Y. The average annual change is used to extrapolate forward to the time when the benchmark will be achieved. Year to reach benchmark is calculated using the formula below:
  - Year to reach benchmark = (Benchmark − Current year’s rate)/average annual change
  - The result is classified into five exclusive categories describing the direction of the measure compared with the benchmark:
    1. Better than benchmark: rate in the most recent year is better than the benchmark and is changing in the desirable direction.
    2. Approaching benchmark: a rate calculated for cases where the trend shows improvement toward the benchmark. The estimated number of years to reach the benchmark is calculated using the method mentioned above.
    3. Insignificant change: the average annual change is not statistically significant (p≥0.05) or the average annual change is zero.
    4. No progress toward benchmark: rate in the most recent year is worse than the benchmark and is changing in the undesirable direction.
    5. Better than benchmark and going away from benchmark: rate in the most recent year is better than the benchmark, but the trend showed worsening.

### Disparities Between Two Subpopulations

Purpose. To assess whether access or quality differs between two subpopulations for the most recent data year. Comparisons are typically made between a priority population group and a reference group within a population characteristic (e.g., Black individuals vs. White individuals within the race characteristic). The best performing subgroup is typically used as the reference group.

Measures are excluded from the analysis if the most recent available data are too old. Before the 2016 report, the latest available data were used for the current year disparities analysis. Beginning with the 2016 report, we exclude measures from the disparities analysis if the most recent data were 3 years older than the report year. For the 2022 report, 2018 is the earliest data year included as current data.^ix^ An exception is applied to the measure Patients with treated chronic kidney failure who received a transplant within 3 years of date of renal failure. An additional 2 years of data were used for this measure because the measure includes a 3-year waiting period.

Approach. Data preparation is applied as discussed above. Two criteria are applied to determine whether the difference between two groups is meaningful:

- The absolute difference between the priority population group and the reference group must be statistically significant with p<0.05 on a two-tailed test.
- The relative difference between the priority population group and the reference group must be at least 10% when framed positively or negatively ([p1 − p2]/p2≥0.1), where p1 is priority group’s aligned rate and p2 is reference group’s aligned rate.

Interpretation:

- Better = Priority population estimate more favorable than reference group estimate by at least 10% and with p<0.05.
- Same = Priority population and reference group estimates differ by less than 10% or p≥0.05.
- Worse = Priority population estimate less favorable than reference group estimate by at least 10% and with p<0.05.

Summaries of Disparities. Disparities across panels of measures are usually summarized as stacked bar charts showing the percentage of measures that are Better, Same, or Worse for priority populations compared with a reference group.

### Trends in Disparities Between Two Subpopulations

Purpose. To observe whether the difference in access or quality between two subpopulations has changed over time. Comparisons are typically made between a priority population group and a reference group within a population characteristic (e.g., Black individuals vs. White individuals within the race characteristic).

Approach. Data preparation is applied as discussed above, and analyses use unweighted linear regression.

Data Requirement. Estimates for at least four time points between 2000 and the most recent data year for both the priority population and reference group; fewer than four time points were deemed insufficient to calculate slopes of regression lines.

Model. M = β_0_ + β_1_Y, where M is the aligned rate of a subgroup, β_0_ is the intercept or constant, and β_1_ is the coefficient corresponding to year Y.

The coefficient is the average annual change (AAC). For example, if the AAC is −1, and the mean rate is 50 per 1,000 in 2000, then the expected mean rate is 50 + (−1) = 49 in 2001 and 49 + (−1) = 48 in 2002. It means the mean rate decreased by 1 unit per year.

The difference in the AAC between the priority population group and the reference group and the standard error are calculated as follows:

Difference in AAC = AAC (priority population group) – AAC (reference group)

Standard error = square root of [STDErr(PPG)^2 + STDErr (Ref Group)^2]

Standard errors from the regression coefficients are used to calculate the standard error of the absolute difference.

Interpretation:

- Improving = The difference in the AAC of the priority population and reference group is <−1 (in a favorable direction) and p<0.10 for testing that regression coefficients are the same.
- Not Changing = Absolute value of the difference in the AAC of the priority population and reference group is <1 or the absolute value of the difference in the AAC of the priority population and reference group is >1 and p≥0.10 for testing that regression coefficients are the same.
- Worsening = The difference in the AAC of the priority population and reference group is >1 (in an unfavorable direction) and p<0.10 for testing that regression coefficients are the same.

Example: Because the rates are aligned to the negative direction, a negative AAC value indicates a measure/subgroup’s mean has been decreasing (improving) over the years, and a positive value indicates the subgroup’s mean has been increasing (worsening) over the years. Taking the “hospital admissions for uncontrolled diabetes without complications per 100,000 population” measure as an example, if the AAC of the Black group is −2.9 and the AAC of the White group is −0.4, the difference is (−2.9) − (−0.4) = −2.5. This difference indicates that the Black mean rate has been improving (decreasing) faster than the White mean rate or the disparity between Black people and White people is improving (i.e., narrowing).

Measures with disparities that are changing the most quickly for each priority population are identified.

Disparities Eliminated = Disparity improving and priority population estimates reached or surpassed reference group estimate.

### State Maps

Purpose. To show differences in quality and disparities between states.

Approach. Same as for other analyses, rates were aligned to the negative direction for the calculation of the performance score.

The quality map featured in the Overview section of the 2022 NHQDR (Figure 29, Portrait of American Healthcare) shows each state’s performance in quartiles based on the state’s performance score. The performance score for individual measures is assigned as follows:

- -1 point for each measure that was better than the national average.
- 0 points for each measure that was the same as the national average.
- 1 point for each measure that was worse than the national average.

The state’s performance score is calculated by summing the individual scores over all measures and then dividing by the total number of measures.

Performance score = (−1 * Number of Better measures + Number of Worse measures)/Total number of measures

Then the state’s performance scores are ranked into four groups as quartiles for the map.

Interpretation: The first quartile (best quality) of the map indicates that the states performed better on more measures and performed worse on fewer measures than the national average. The fourth quartile (worst quality) indicates that the states performed better on fewer measures and performed worse on more measures than the national average.

The disparities map featured in the Portrait of American Healthcare section of the 2022 NHQDR (Figure 30) shows the average differences in quality of care for American Indian and Alaska Native (AI/AN), Asian, Black, Hispanic, Native Hawaiian/Pacific Islander (NHPI), and multiracial people compared with the reference group, non-Hispanic White or White people.

All core measures in this report that had state-level data to assess racial/ethnic disparities were used. For measures with ethnicity data, Hispanic, non-Hispanic Black, and non-Hispanic Asian people were compared with non-Hispanic White people. For measures without ethnicity data, Black, Asian, NHPI, AI/AN, and multiracial people were compared with White people. The comparison method is the same as the current year disparities analysis.

The performance score for individual measures is assigned as follows:

- -1 point for a subgroup that was better than the reference group.
- 0 points for a subgroup that was the same as the reference group.
- 1 point for a subgroup that was worse than the reference group.

The state’s disparities score is calculated by summing the individual scores over all measures and over all subgroups and then dividing by the sum of the number of measures and multiplying by the number of subgroups.

Disparities score = (−1 * Number of Better measures * number of subgroups + Number of Worse measures * number of subgroups)/(Total number of measures * number of subgroups)

Then the state’s disparities scores are ranked into quartiles for the map. States with fewer than 50 measures by subgroup combination are excluded from the quartile analysis. States with lower disparities scores indicate fewer disparities, regardless of overall quality among states.

## Analysis Limitations

As noted earlier, the methods used in the NHQDR improve uniformity for comparability and ease of understanding of the findings and increase the sensitivity (i.e., the likelihood of a difference being considered statistically significant) but have some limitations.

To analyze all measures across the measure set in the same way for assessing disparities, some measures are flipped so that all measures are aligned in the negative direction (e.g., “Adults who had an influenza vaccine” is changed to “Adults who did not have an influenza vaccine”). The alignment of all the measures in the same direction provides a standard way to analyze the data. However, this effect is most reliable when the original rates are well above 50%. The effect is greatly diminished if the rates are near 50% and can have the opposite effect if the original rates are well below 50%.

The z-score of absolute difference is an additional criterion for statistical reliability. It takes into account the standard errors of the point estimates. That is, if the standard errors are comparatively large, then z-scores provide an additional check on the meaningfulness of the difference and reduce the possibility of labeling the differences as worse or better when those differences are not statistically valid. Therefore, the findings in the NHQDR may be different from other studies that look at the same measures and data due to the increased sensitivity of our methodology.

In some cases, changes in the measures or how to interpret the measures may have an impact on the effectiveness of the methodology used for this report. AHRQ is continually reviewing all aspects of its methodology for determining and reporting disparities and maintaining consistency.

### Limitations Due to the COVID-19 Pandemic

In response to the 2019 novel coronavirus (COVID-19) public health emergency, the Centers for Medicare & Medicaid Services (CMS) granted exemptions to the current Medicare quality reporting requirements and value-based purchasing program requirements for 2020 quarters 1 and 2. Provider participation in Q1 and Q2 2020 was voluntary and results were not publicly reported. Therefore, the NHQDR tables for hospital, hospice, and home health measures using 2020 CMS data are based on Q3 and Q4 2020 only.

This approach is consistent with the publicly available data files on http://www.cms.gov in the Provider Data Catalog for 2020 for the Hospital Consumer Assessment of Healthcare Providers and Systems (HCAHPS), Hospice CAHPS, and Home Health CAHPS.

The 2020 National Health Interview Survey (NHIS) data collection switched to a telephone-only mode beginning March 19, 2020. Personal visits resumed in all areas in September 2020, but cases were still attempted by telephone first. These changes resulted in lower response rates and differences in respondent characteristics for April-December 2020. Differences observed in estimates between April and December 2020 and earlier time periods may still be affected by these changes. NHIS data are based on household interviews of a sample of the civilian noninstitutionalized population. The data collection for the 2020 National Survey on Drug Use and Health was also modified due to the pandemic.

In addition, the Quality and Safety Review System data were only collected for the last quarter of 2020. For Outcome and Assessment Information Set data, CMS granted a temporary exemption for reporting home health care data to CMS through June 30, 2020. The data collection for the 2020 the National Survey on Drug Use and Health was also modified due to the pandemic.

### Limitations With HCUP Data

In the 2017 NHQDR, all available HCUP measures included in the report and NHQDR database had trend data. However, due to the conversion from ICD-9-CM to ICD-10-CM codes, trend data are not included in the 2018-2021 NHQDRs. Since 4 years of data (2016-2019) are available for the 2022 NHQDR, HCUP measures include trend data for this year’s report.

Historically, the NHQDR and derivative products such as the State Snapshots have included state-specific estimates for selected AHRQ Quality Indicators (QIs) based on HCUP data. The 2017-2019 NHQDRs do not include state-specific QI estimates, in part because the ICD-10 version of the QI software used in the 2017-2019 reports did not include risk adjustment.

The risk-adjusted state estimates became available for the 2021 NHQDR and are included in all analyses in the 2022 NHQDR and on the website.

### General Limitations

Some common limitations affect analyses of multiple data sources. For example, data may be unavailable or statistically unreliable, or they may not meet confidentiality criteria for relatively small subpopulations, such as the NHPI population, some rural communities, and some states. The 2021 state data analysis, for example, included 182 measures. California had data for 179 measures, while Wyoming only had data for 113 measures. Estimates are suppressed if the sample size is small or the relative standard error is larger than 30%.

For some outcome measures, small sample size may indicate the subgroup or state is doing better than others because they have fewer people in the denominator. These include measures such as HIV/AIDS care (people age 13 and over living with diagnosed HIV whose most recent viral load in the last 12 months was under 200 copies/mL) and emergency department visit or hospital admission involving opioid-related diagnoses per 100,000 population.

In addition, while most national surveys conduct data collections annually, not all modules are completed each year. Thus, data are missing for some measures included in the report.

Timeliness of national data for national surveys and data systems are also a factor since it takes time to process and ensure data quality for reporting, resulting in about a 2-year lag between the year the data are collected and the year they can be included.

Finally, for various reasons (e.g., data collection was discontinued), data for all years for all measures are not available. We exclude measures for which data will not be available in the future. Lack of data for some measures affects the measure numbers in the summary figures, such as trends in quality.

## Reporting Conventions

For ease of reporting, some shorthand is used in presenting results. Unless otherwise specified:

- State maps are usually grouped in quartiles. Data are excluded from territories with a large variation or that looked like outliers.
- Results presented in text or bullets meet our criteria for magnitude and statistical significance.
- Children are ages 0-17, adults are age 18 and over, and older adults are age 65 and over.
- “Black” individuals are those who identify their race as Black or African American.
- “Hispanic” individuals are those who identify their ethnicity as Hispanic, Latino/a, or Spanish origin and includes all races. The race categories for Hispanic individuals are not always specified in the report.
- “Measure improved” indicates performance on the measure improved; “measure got worse” indicates performance on the measure showed worsening.
- “Disparities improved” indicates the disparity narrowed. “Disparities worsened” indicates the disparity widened.

i Asian includes the former category of Asian or Pacific Islander prior to 1997 Office of Management and Budget guidelines, when information was not collected separately by group. Go to https://www.gpo.gov/fdsys/granule/FR-1997-10-30/97-28653 for more information.

ii Not all data sources collect information by race and ethnicity separately. In such cases, comparisons are made by combining racial/ethnic group categories (e.g., comparing non-Hispanic Black people and Hispanic people with non-Hispanic White people).

iii These are based on U.S. census poverty guidlines for each data year, which are used for statistical purposes.

iv Less than a high school education refers to people who did not complete high school.

v Public insurance includes Medicaid, Children’s Health Insurance Program, state-sponsored or other government-sponsored health plans, Medicare, and military plans.

vi A CSHCN Screener instrument was developed through a national collaborative process as part of the Child and Adolescent Health Measurement Initiative coordinated by the Foundation for Accountability. For more information, refer to Bethell CD, Read D, Stein REK, Blumberg SJ, Wells N, Newacheck PW. Identifying children with special health care needs: development and evaluation of a short screening instrument. Ambul Pediatr 2002 Feb;2(1):38–48. https://www.ncbi.nlm.nih.gov/pubmed/11888437. Accessed October 25, 2022 11888437 .

vii Readers examining long-term trends should note that the 2013 NCHS Urban-Rural Classification scheme is similar to the 2006 version that preceded it. Although minor differences between the two classification schemes may result in counties being classified in different categories, a 2014 analysis comparing the two classification schemes found that only 286 of 3,143 counties (9.1%) had different category assignments. See Ingram DD, Franco SJ. 2013 NCHS Urban-Rural Classification Scheme for Counties. Vital Health Stat 2. 2014 Apr;(166):1–73. https://www.cdc.gov/nchs/data/series/sr_02/sr02_166.pdf. Accessed October 25, 2022 .

viii A probability of 0.10 was selected as the significance level because the magnitude of the standard errors varied considerably by type of data. Favorable direction is defined as negative average annual percentage change for positive measures and positive average annual percentage change for negative measures.

ix In an effort to align the report year with the publication year, the NHQDR skipped 2020 in the numbering sequence. The 2020 report was published in 2021 and thus had a date of 2021. For data purposes, the 3-year timeframe started in 2020 and extended back 3 years to 2017.